# References

1 DiClemente, C. C., Norwood, A. E., Gregory, W. H., Travaglini, L., Graydon, M. M., & Corno, C. M. (2016). Consumer-centered, collaborative, and comprehensive care: The core essentials of recovery-oriented system of care. Journal of Addictions Nursing, 27(2), 94–100.27272993
2 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
3 Reif, S., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., … Delphin-Rittmon, M. E. (2014). Peer recovery support for individuals with substance use disorders: Assessing the evidence. Psychiatric Services, 65(7), 853–861.24838535
4 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
5 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2022). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings; A narrative review. Journal of Addiction Medicine, 16(1), 93–100.33560695
6 Ray, B., Watson, D. P., Xu, H., Salyers, M. P., Victor, G., Sightes, E., … Bo, N. (2021). Peer recovery services for persons returning from prison: Pilot randomized clinical trial investigation of SUPPORT. Journal of Substance Abuse Treatment, 126, 108339.34116824
7 Andreas, D., Ja, D. Y., & Wilson, S. (2010). Peers reach out supporting peers to embrace recovery (PROSPER): A center for substance abuse treatment recovery community services program. Alcoholism Treatment Quarterly, 28(3), 326–338.
8 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services. https://addiction.surgeongeneral.gov/sites/default/files/surgeon-generals-report.pdf.
9 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services. https://addiction.surgeongeneral.gov/sites/default/files/surgeon-generals-report.pdf.
10 Substance Abuse and Mental Health Services Administration. (2017). Peer support. https://samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peer-support-2017.pdf.
11 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. https://store.samhsa.gov/sites/default/files/d7/priv/pep12-recdef.pdf.
12 Substance Abuse and Mental Health Services Administration. (2022). Recovery and recovery support. https://www.samhsa.gov/find-help/recovery#recovery-support.
13 American Psychiatric Association. (2022). Diagnostic and statistical manual of mental disorders (5th ed., text revision). American Psychiatric Publishing.
14 Texas Health and Human Services. (n.d.). About peer support services. https://www.hhs.texas.gov/providers/behavioral-health-services-providers/peer-support-services/about-peer-support-services.
15 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
16 Kelly, J. F., Fallah-Sohy, N., Vilsaint, C., Hoffman, L. A., Jason, L. A., Stout, R. L., … Hoeppner, B. B. (2020). New kid on the block: An investigation of the physical, operational, personnel, and service characteristics of recovery community centers in the United States. Journal of Substance Abuse Treatment, 111, 1–10.32087832
17 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
18 Substance Abuse and Mental Health Services Administration. (2022). Peer support services in crisis care. Advisory. SAMHSA Publication No. PEP22-06-04-001. Substance Abuse and Mental Health Services Administration.
19 Substance Abuse and Mental Health Services Administration. (2022). Peer support services in crisis care. Advisory. SAMHSA Publication No. PEP22-06-04-001. Substance Abuse and Mental Health Services Administration.
20 University of Michigan Behavioral Health Workforce Research Center. (2019). National analysis of peer support providers: Practice settings, requirements, roles, and reimbursement. University of Michigan School of Public Health.
21 Center for Substance Abuse Treatment. (2006). Detoxification and substance abuse treatment. Treatment Improvement Protocol (TIP) Series 45. HHS Publication No. (SMA) 15-4131. Substance Abuse and Mental Health Services Administration.
22 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
23 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
24 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
25 Reif, S., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., … Delphin-Rittmon, M. E. (2014). Peer recovery support for individuals with substance use disorders: Assessing the evidence. Psychiatric Services, 65(7), 853–861.24838535
26 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
27 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
28 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
29 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
30 Miller, N. (2020, September 18). Getting paid: Peer support services [PowerPoint presentation]. https://uclaisap.org/MATPrescriberSupport/ppts/SustainableReimbursementofMAT5_SupportServices_091720_508slides.pdf.
31 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. (n.d.). Social determinants of health. https://health.gov/healthypeople/priority-areas/social-determinants-health.
32 Wagner, K. D., Mittal, M. L., Harding, R. W., Smith, K. P., Dawkins, A. D., Wei, X., … Oman, R. F. (2020). “It's Gonna be a Lifeline”: Findings from focus group research to investigate what people who use opioids want from peer-based post-overdose interventions in the emergency department. Annals of Emergency Medicine, 76(6), 717–727.32747080
33 White, W. (2009). Peer-based addiction recovery support: History, theory, practice, and scientific evaluation. Great Lakes Addiction Technology Transfer Center and Philadelphia Department of Behavioral Health and Mental Retardation Services.
34 Center for Substance Abuse Treatment. (2009). What are peer recovery support services? HHS Publication No. (SMA) 09-4454. Substance Abuse and Mental Health Services Administration.
35 Borkman, T. (1976). Experiential knowledge: A new concept for the analysis of self-help groups. Social Service Review, 50(3), 445–456.
36 Borkman, T. (1999). Understanding self-help/mutual aid: Experiential learning in the commons. Rutgers University Press.
37 Center for Substance Abuse Treatment. (2008). An introduction to mutual support groups for alcohol and drug abuse. Substance Abuse In Brief Fact Sheet, Vol. 5, Issue 1. Substance Abuse and Mental Health Services Administration.
38 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
39 White, W. (2006). Sponsor, recovery coach, addiction counselor: The importance of role clarity and role integrity. Philadelphia Department of Behavioral Health and Mental Retardation Services.
40 White, W. L. (2010). Nonclinical addiction recovery support services: History, rationale, models, potentials, and pitfalls. Alcoholism Treatment Quarterly, 28(3), 256–272.
41 Fairfax-Falls Church Community Services Board. (n.d.). Medication assisted peer support (MAPS). https://www.fairfaxcounty.gov/community-services-board/recovery/medication-assisted-peer-support.
42 Substance Abuse and Mental Health Services Administration. (2017). Family, parent and caregiver peer support in behavioral health. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf.
43 White, W. L., Kelly, J. F., & Roth, J. D. (2012). New addiction-recovery support institutions: Mobilizing support beyond professional addiction treatment and recovery mutual aid. Journal of Groups in Addiction and Recovery, 7(2-4), 297–317.
44 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
45 White, W. L., Kelly, J. F., & Roth, J. D. (2012). New addiction-recovery support institutions: Mobilizing support beyond professional addiction treatment and recovery mutual aid. Journal of Groups in Addiction and Recovery, 7(2-4), 297–317.
46 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
47 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2022). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings; A narrative review. Journal of Addiction Medicine, 16(1), 93–100.33560695
48 Bureau of Justice Assistance. (2022). Peer recovery support services in correctional settings. U.S. Department of Justice, Office of Justice Programs.
49 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
50 NORC at the University of Chicago & Center for Health & Justice at TASC. (2021). Report of the nation survey to assess first responder deflection programs in response to the opioid crisis: Final report. U.S. Department of Justice, Office of Justice Programs, Bureau of Justice Assistance.
51 White, W. (2009). Peer-based addiction recovery support: History, theory, practice, and scientific evaluation. Great Lakes Addiction Technology Transfer Center and Philadelphia Department of Behavioral Health and Mental Retardation Services.
52 Center for Substance Abuse Treatment. (2009). What are peer recovery support services? HHS Publication No. (SMA) 09-4454. Substance Abuse and Mental Health Services Administration.
53 White, W. L. (2010). Nonclinical addiction recovery support services: History, rationale, models, potentials, and pitfalls. Alcoholism Treatment Quarterly, 28(3), 256–272.
54 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
55 White, W. L. (2002). Addiction treatment in the United States: Early pioneers and institutions. Addiction, 97(9), 1087–1092.12199821
56 White, W. (2004). Addiction recovery mutual aid groups: An enduring international phenomenon. Addiction, 99, 532–538.15078227
57 Schwartz, M. A., & Tatalovich, R. (2018). The rise and fall of moral conflicts in the United States and Canada. University of Toronto Press.
58 Zemore, S. E., Kaskutas, L. A., Mericle, A., & Hemberg, J. (2017). Comparison of 12-Step groups to mutual help alternatives for AUD in a large, national study: Differences in membership characteristics and group participation, cohesion, and satisfaction. Journal of Substance Abuse Treatment, 73, 16–26.28017180
59 Zemore, S. E., Lui, C., Mericle, A., Hemberg, J., & Kaskutas, L. A. (2018). A longitudinal study of the comparative efficacy of Women for Sobriety, LifeRing, SMART Recovery, and 12-step groups for those with AUD. Journal of Substance Abuse Treatment, 88, 18–26.29606223
60 LifeRing Secular Recovery^®^. About LifeRing. https://lifering.org/.
61 Connors, G. J., & Dermen, K. H. (1996). Characteristics of participants in Secular Organizations for Sobriety (SOS). American Journal of Drug and Alcohol Abuse, 22(2), 281–295.8727060
62 Beck, A. K., Forbes, E., Baker, A. L., Kelly, P. J., Deane, F. P., Shakeshaft, A., … Kelly, J. F. (2017). Systematic review of SMART Recovery: Outcomes, process variables, and implications for research. Psychology of Addictive Behaviors, 31(1), 1–20.28165272
63 Substance Abuse and Mental Health Services Administration. (2014). Celebrating recovery in American Indian/Alaska Native communities. Prevention and Recovery, 2(8), pp. 1–4.
64 Zemore, S. E., Lui, C., Mericle, A., Hemberg, J., & Kaskutas, L. A. (2018). A longitudinal study of the comparative efficacy of Women for Sobriety, LifeRing, SMART Recovery, and 12-Step groups for those with AUD. Journal of Substance Abuse Treatment, 88, 18–26.29606223
65 Hendry, P., Hill, T., & Rosenthal, H. (2014). Peer services toolkit: A guide to advancing and implementing peer-run behavioral health services. ACMHA: The College for Behavioral Health Leadership and Optum.
66 Government Accountability Office. (2020). Substance use disorder: Medicaid coverage of peer support services for adults. (GAO-20-616).
67 Laudet, A. B., & Humphreys, K. (2013). Promoting recovery in an evolving policy context: What do we know and what do we need to know about recovery support services? Journal of Substance Abuse Treatment, 45(1), 126–133.23506781
68 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267–S274.29779551
69 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions (p. S263). American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
70 Grigson, P. S. (2018). Addiction: A multi-determined chronic disease. Brain Research Bulletin, 138, 1–4.29203266
71 White, W. (2005). Recovery: Its history and renaissance as an organizing construct. Alcoholism Treatment Quarterly, 23(1), 3–15.
72 Alcoholics Anonymous. (1939). Alcoholics Anonymous: The story of how many thousands of men and women have recovered from alcoholism (1st ed.). The Works Publishing Company.
73 Kaskutas, L. A., Borkman, T. J., Laudet, A., Ritter, L. A., Witbrodt, J., Subbaraman, M. S., … Bond, J. (2014). Elements that define recovery: The experiential perspective. Journal of Studies on Alcohol and Drugs, 75(6), 999–1010.25343658
74 Kelly, J. F., & Hoeppner, B. (2015). A biaxial formulation of the recovery construct. Addiction Research and Theory, 23(1), 5–9.
75 Betty Ford Institute Consensus Panel. (2007). What is recovery? A working definition from the Betty Ford Institute. Journal of Substance Abuse Treatment, 33(3), 221–228.17889294
76 Hawk, M., Coulter, R. W., Egan, J. E., Fisk, S., Reuel Friedman, M., Tula, M., & Kinsky, S. (2017). Harm reduction principles for healthcare settings. Harm Reduction Journal, 14(1), 1–9.28056990
77 White, W. L. (2007). Addiction recovery: Its definition and conceptual boundaries. Journal of Substance Abuse Treatment, 33, 229–241.17889295
78 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
79 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery (p. 3). Substance Abuse and Mental Health Services Administration.
80 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. Substance Abuse and Mental Health Services Administration.
81 Substance Abuse and Mental Health Services Administration. (2017). Peers supporting recovery from substance use disorders. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peers-supporting-recovery-substance-use-disorders-2017.pdf.
82 White, W. & Cloud, W. (2008). Recovery capital: A primer for addictions professionals. Counselor, 9(5), 22–27.
83 Substance Abuse and Mental Health Services Administration. (2017). Value of peers, 2017. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/value-of-peers-2017.pdf.
84 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
85 DiClemente, C. C., Norwood, A. E., Gregory, W. H., Travaglini, L., Graydon, M. M., & Corno, C. M. (2016). Consumer-centered, collaborative, and comprehensive care: The core essentials of recovery-oriented system of care. Journal of Addictions Nursing, 27(2), 94–100.27272993
86 Dunn, L. (2020, November 6). What is diversity, equity & inclusion (DEI)? InclusionHub. Retrieved December 20, 2022, from https://www.inclusionhub.com/articles/what-is-dei.
87 Centers for Medicare & Medicaid Services. (2022). Diversity, equity, and inclusion. https://www.cms.gov/about-cms/careers-cms/diversity-equity-and-inclusion.
88 Centers for Medicare & Medicaid Services. (2022). Diversity, equity, and inclusion. https://www.cms.gov/about-cms/careers-cms/diversity-equity-and-inclusion.
89 Centers for Medicare & Medicaid Services. (2022). Diversity, equity, and inclusion. https://www.cms.gov/about-cms/careers-cms/diversity-equity-and-inclusion.
90 Centers for Medicare & Medicaid Services. (2022). Diversity, equity, and inclusion. https://www.cms.gov/about-cms/careers-cms/diversity-equity-and-inclusion.
91 White House. (2021). Executive order on diversity, equity, inclusion, and accessibility in the federal workforce. https://www.whitehouse.gov/briefing-room/presidential-actions/2021/06/25/executive-order-on-diversity-equity-inclusion-and-accessibility-in-the-federal-workforce/.
92 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. Substance Abuse and Mental Health Services Administration. https://store.samhsa.gov/sites/default/files/d7/priv/pep12-recdef.pdf.
93 White, W. (2009). Peer-based addiction recovery support: History, theory, practice, and scientific evaluation. Great Lakes Addiction Technology Transfer Center and Philadelphia Department of Behavioral Health and Mental Retardation Services.
94 Center for Substance Abuse Treatment. (2009). What are peer recovery support services? HHS Publication No. (SMA) 09-4454. Substance Abuse and Mental Health Services Administration.
95 Mutha, S., Allen, C., & Welch, M. (2002). Toward culturally competent care: A toolbox for teaching communication strategies. Center for Health Professions, University of California, San Francisco.
96 Spagnolo, A. B., Pratt, C. W., Jia, Y., DeMasi, M., Cronise, R., & Gill, K. (2022). The competencies of telehealth peer support: Perceptions of peer support specialists and supervisors during the COVID-19 pandemic. Community Mental Health Journal, 1–7. Advance online publication. doi:10.1007/s10597-022-00950-w.
97 Moskal, D., Whitaker, H., Bernstein, J. F., Maisto, S. A., & Connors, G. J. (2021). Evaluation of a web-based psychosocial education and peer support program for alcohol use concerns. Alcoholism Treatment Quarterly, 39(3), 366–382.34326569
98 Moskal, D., Whitaker, H., Bernstein, J. F., Maisto, S. A., & Connors, G. J. (2021). Evaluation of a web-based psychosocial education and peer support program for alcohol use concerns. Alcoholism Treatment Quarterly, 39(3), 366–382.34326569
99 Blonigen, D. M., Harris-Olenak, B., Kuhn, E., Timko, C., Humphreys, K., Smith, J. S., & Dulin, P. (2021). Using peers to increase veterans’ engagement in a smartphone application for unhealthy alcohol use: A pilot study of acceptability and utility. Psychology of Addictive Behaviors, 35(7), 829–839.32597665
100 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
101 North Carolina Department of Health and Human Services, Injury and Violence Prevention Branch. (2020). Post-overdose response team (PORT) toolkit. North Carolina Department of Health and Human Services, Division of Public Health.
102 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
103 Chapman, S. A., Blash, L., & Spetz, J. (2018). California peer providers in transitions of care. Healthforce Center, University of California-San Francisco. https://healthforce.ucsf.edu/sites/healthforce.ucsf.edu/files/publication-pdf/California_Peer_Providers_in_Transition_of_Care_0.pdf.
104 Tofighi, B., Chemi, C., Ruiz-Valcarcel, J., Hein, P., & Hu, L. (2019). Smartphone apps targeting alcohol and illicit substance use: Systematic search in commercial app stores and critical content analysis. JMIR mHealth and uHealth, 7(4), e11831.31008713
105 Campbell, A. N., Nunes, E. V., Matthews, A. G., Stitzer, M., Miele, G. M., Polsky, D., … Ghitza, U. E. (2014). Internet-delivered treatment for substance abuse: A multisite randomized controlled trial. American Journal of Psychiatry, 171(6), 683–690.24700332
106 Gustafson, D. H., McTavish, F. M., Chih, M. Y., Atwood, A. K., Johnson, R. A., Boyle, M. G., … Shah, D. (2014). A smartphone application to support recovery from alcoholism: A randomized clinical trial. JAMA Psychiatry, 71(5), 566–572.24671165
107 White, W. L. (2014). Slaying the dragon: The history of addiction treatment and recovery in America (2nd ed.). Chestnut Health Publications.
108 Laudet, A. B., & Humphreys, K. (2013). Promoting recovery in an evolving context: What do we know and what do we need to know about recovery support services? Journal of Substance Abuse Treatment, 45(1), 126–133.23506781
109 White, W. L., Kelly, J. F., & Roth, J. D. (2012). New addiction-recovery support institutions: Mobilizing support beyond professional addiction treatment and recovery mutual aid. Journal of Groups in Addiction & Recovery, 7(2-4), 297–317.
110 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
111 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
112 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. M. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
113 Scannell, C. (2021). Voices of hope: Substance use peer support in a system of care. Substance Abuse: Research and Treatment, 15, 11782218211050360.34675524
114 Rogers, E. S., & Swarbrick, M. (2016). Peer-delivered services: Current trends and innovations [Editorial]. Psychiatric Rehabilitation Journal, 39(3), 193–196.27618456
115 Substance Abuse and Mental Health Services Administration. Peer support workers for those in recovery. https://www.samhsa.gov/brss-tacs/recovery-support-tools/peers.
116 Watson, E. (2017). The mechanisms underpinning peer support: A literature review. Journal of Mental Health, 28(6), 677–688.29260930
117 OMNI Institute. (2020). Measuring outcomes of peer recovery support services. Virginia Department of Behavioral Health and Developmental Services.
118 White, W. (2009). Peer-based addiction recovery support: History, theory, practice, and scientific evaluation. Great Lakes Addiction Technology Transfer Center and Philadelphia Department of Behavioral Health and Mental Retardation Services.
119 Shalaby, R. A. H., & Agyapong, V. I. (2020). Peer support in mental health: Literature review. JMIR Mental Health, 7(6), e15572.32357127
120 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2021). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings—A narrative review. Journal of Addiction Medicine. Advance online publication. doi:10.1097/ADM.0000000000000810.
121 Tracy, K., Wachtel, L., & Goldmann, E. (2018). Beyond substance use reduction: The positive impact of mentorship for addiction problems (MAP). Journal of Alcoholism, Drug Abuse & Substance Dependance, 4, 009.
122 Best, D., & de Alwis, S. (2017). Community recovery as a public health intervention: The contagion of hope. Alcoholism Treatment Quarterly, 35(3), 187–199.
123 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
124 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
125 Riessman, F. (1965). The “Helper” therapy principle. Social Work, 10(2), 27–32.
126 Riessman, F. (1990). Restructuring help: A human services paradigm for the 1990s. American Journal of Community Psychology, 18(2), 221–230.
127 OMNI Institute. (2020). Measuring outcomes of peer recovery support services. Virginia Department of Behavioral Health and Developmental Services.
128 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
129 Watson, E. (2017). The mechanisms underpinning peer support: A literature review. Journal of Mental Health, 28(6), 677–688.29260930
130 Lennox, R., Lamarche, L., & O'Shea, T. (2021). Peer support workers as a bridge: A qualitative study exploring the role of peer support workers in the care of people who use drugs during and after hospitalization. Harm Reduction Journal, 18(1), 19.33593364
131 Williams, C. (2021). To help others, we must care for ourselves: The importance of self-care for peer support workers in substance use recovery. Journal of Addiction & Addictive Disorders, 8(2), 071.
132 Frings, D., & Albery, I. (2015). The social identity model of cessation maintenance: Formulation and initial evidence. Addictive Behaviors, 44, 35–42.25468675
133 Best, D., Beckwith, M., Haslam, C., Haslam, S. A., Jetten, J., Mawson, E., & Lubman, D. I. (2016). Overcoming alcohol and other drug addiction as a process of social identity transition: The social identity model of recovery (SIMOR). Addiction Research & Theory, 24(2), 111–123.
134 Paterno, M. T., Fiddian-Green, A., & Gubrium, A. (2018). Moms supporting moms: Digital storytelling with peer mentors in recovery from substance use. Health Promotion Practice, 19(6), 823–832.29298520
135 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
136 Dugdale, S., Elison, S., Davies, G., Ward, J., & Dalton, M. (2016). Using the transtheoretical model to explore the impact of peer mentoring on peer mentors. Journal of Groups in Addiction and Recovery, 11(3), 166–181.
137 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
138 New York State Office of Addiction Services and Supports. (2018). Peer integration and the stages of change toolkit. https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf.
139 OMNI Institute. (2020). Measuring outcomes of peer recovery support services. Virginia Department of Behavioral Health and Developmental Services.
140 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
141 Englander, H., Gregg, J., Gullickson, J., Cochran-Dumas, O., Colasurdo, C., Alla, J., … Nicolaidis, C. (2020). Recommendations for integrating peer mentors in hospital-based addiction care. Substance Abuse, 41(4), 419–424.31490736
142 Crane, D., Lepicki, T., & Knudsen, K. (2016). Unique and common elements of the role of peer support in the context of traditional mental health services. Psychiatric Rehabilitation Journal, 39(3), 282–288.27159112
143 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2021). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings—A narrative review. Journal of Addiction Medicine. Advance online publication. doi:10.1097/ADM.0000000000000810.
144 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
145 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2021). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings—A narrative review. Journal of Addiction Medicine. Advance online publication. doi:10.1097/ADM.0000000000000810.
146 Abraham, S., & Perez, P. (2018). Bridging the gap with peer support: Patricia's recovery story. Journal of Psychosocial Nursing and Mental Health Services, 56(3), 7–11.
147 Substance Abuse and Mental Health Services Administration. (2017). Peers supporting recovery from substance use disorders. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peers-supporting-recovery-substance-use-disorders-2017.pdf.
148 Crane, D., Lepicki, T., & Knudsen, K. (2016). Unique and common elements of the role of peer support in the context of traditional mental health services. Psychiatric Rehabilitation Journal, 39(3), 282–288.27159112
149 Gidugu, V., Rogers, E. S., Harrington, S., Maru, M., Johnson, G., Cohee, J., & Hinkel, J. (2015). Individual peer support: A qualitative study of mechanisms of its effectiveness. Community Mental Health Journal, 51(4), 445–452.25535049
150 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
151 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
152 Substance Abuse and Mental Health Services Administration. (2017). Peers supporting recovery from substance use disorders. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peers-supporting-recovery-substance-use-disorders-2017.pdf.
153 Substance Abuse and Mental Health Services Administration. (2017). Peers supporting recovery from substance use disorders. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peers-supporting-recovery-substance-use-disorders-2017.pdf.
154 White, W. L. (2010). Nonclinical addiction recovery support services: History, rationale, models, potentials, and pitfalls. Alcoholism Treatment Quarterly, 28(3), 256–272.
155 Substance Abuse and Mental Health Services Administration. (2017). Peers supporting recovery from substance use disorders. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peers-supporting-recovery-substance-use-disorders-2017.pdf.
156 National Council for Behavioral Health. (2017, May). Recovery housing issue brief: Information for state policymakers. https://www.fletchergroup.org/wp-content/uploads/2020/01/Recovery-Housing-Issue-Brief-Information-for-State-Policymakers.pdf.
157 Hill, T. (2020). The origins of recovery community centers: Context and history [PowerPoint slides]. http://www.recoveryanswers.org/assets/The-Origins-of-Recovery-Community-Centers.pdf.
158 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
159 Rebeiro Gruhl, K. L., LaCarte, S., & Calixte, S. (2016). Authentic peer support work: Challenges and opportunities for an evolving occupation. Journal of Mental Health, 25(1), 78–86.26397981
160 Watson, E. (2017). The mechanisms underpinning peer support: A literature review. Journal of Mental Health, 28(6), 677–688.29260930
161 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
162 Klee, A., Chinman, M., & Kearney, L. (2019). Peer worker services: New frontiers and new roles. Psychological Services, 16(3), 353.31393159
163 White, W. L. (2010). Nonclinical addiction recovery support services: History, rationale, models, potentials, and pitfalls. Alcoholism Treatment Quarterly, 28(3), 256–272.
164 White, W. L. (2009). Peer-based addiction recovery support: History, theory, practice, and scientific evaluation. Great Lakes Addiction Technology Transfer Center and Philadelphia Department of Behavioral Health and Mental Retardation Services.
165 Klee, A., Chinman, M., & Kearney, L. (2019). Peer worker services: New frontiers and new roles. Psychological Services, 16(3), 353.31393159
166 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
167 White, W. L. (2007). The new recovery advocacy movement in America. Addiction (Abingdon, England), 102(5), 696–703.17493104
168 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
169 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
170 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
171 Waye, K. M., Goyer, J., Dettor, D., Mahoney, L., Samuels, E. A., Yedinak, J. L., & Marshall, B. (2019). Implementing peer recovery services for overdose prevention in Rhode Island: An examination of two outreach-based approaches. Addictive Behaviors, 89, 85–91.30278306
172 OMNI Institute. (2020). Measuring outcomes of peer recovery support services. Virginia Department of Behavioral Health and Developmental Services.
173 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
174 Substance Abuse and Mental Health Services Administration. (2021). Comprehensive case management for substance use disorder treatment. Advisory.
175 Substance Abuse and Mental Health Services Administration. (2021). Comprehensive case management for substance use disorder treatment. Advisory.
176 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
177 Pace, C. A., Gergen-Barnett, K., Veidis, A., D'Afflitti, J., Worcester, J., Fernandez, P., & Lasser, K. E. (2018). Warm handoffs and attendance at initial integrated behavioral health appointments. Annals of Family Medicine, 16(4), 346–348.29987084
178 Richter, K. P., Faseru, B., Shireman, T. I., Mussulman, L. M., Nazir, N., Bush, T., … Martell, M. J. (2016). Warm handoff versus fax referral for linking hospitalized smokers to quitlines. American Journal of Preventive Medicine, 51(4), 587–596.27647059
179 Ashford, R. D., Curtis, B., & Brown, A. M. (2018). Peer-delivered harm reduction and recovery support services: Initial evaluation from a hybrid recovery community drop-in center and syringe exchange program. Harm Reduction Journal, 15(1), 1–9.29304871
180 Ashford, R. D., Brown, A. M., Dorney, G., McConnell, N., Kunzelman, J., McDaniel, J., & Curtis, B. (2019). Reducing harm and promoting recovery through community-based mutual aid: Characterizing those who engage in a hybrid peer recovery community organization. Addictive Behaviors, 98, 106037.31330467
181 Samuels, E. A., Bernstein, S. L., Marshall, B. D., Krieger, M., Baird, J., & Mello, M. J. (2018). Peer navigation and take-home naloxone for opioid overdose emergency department patients: Preliminary patient outcomes. Journal of Substance Abuse Treatment, 94, 29–34.30243414
182 White, W. L. (2010). Nonclinical addiction recovery support services: History, rationale, models, potentials, and pitfalls. Alcoholism Treatment Quarterly, 28(3), 256–272.
183 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
184 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
185 Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341.28787300
186 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
187 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
188 Rebeiro Gruhl, K. L., LaCarte, S., & Calixte, S. (2016). Authentic peer support work: Challenges and opportunities for an evolving occupation. Journal of Mental Health, 25(1), 78–86.26397981
189 Cronise, R., Teixeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39, 211–221.27618458
190 Crane, D., Lepicki, T., & Knudsen, K. (2016). Unique and common elements of the role of peer support in the context of traditional mental health services. Psychiatric Rehabilitation Journal, 39(3), 282–288.27159112
191 Cronise, R., Teixeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39, 211–221.27618458
192 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
193 Chang, B. H., Mueller, L., Resnick, S. G., Osatuke, K., & Eisen, S. V. (2016). Job satisfaction of Department of Veterans Affairs peer mental health providers. Psychiatric Rehabilitation Journal, 39, 47–54.26414749
194 Shalaby, R. A. H., & Agyapong, V. I. (2020). Peer support in mental health: Literature review. JMIR Mental Health, 7(6), e15572.32357127
195 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
196 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
197 Schober, M., & Baxter, K. (2020). Medicaid funding for family and youth peer support programs in the United States. National Technical Assistance Network for Children's Behavioral Health.
198 OMNI Institute. (2020). Measuring outcomes of peer recovery support services. Virginia Department of Behavioral Health and Developmental Services.
199 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
200 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
201 Rebeiro Gruhl, K. L., LaCarte, S., & Calixte, S. (2016). Authentic peer support work: Challenges and opportunities for an evolving occupation. Journal of Mental Health, 25(1), 78–86.26397981
202 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
203 Englander, H., Gregg, J., Gullickson, J., Cochran-Dumas, O., Colasurdo, C., Alla, J., … Nicolaidis, C. (2020). Recommendations for integrating peer mentors in hospital-based addiction care. Substance Abuse, 41(4), 419–424.31490736
204 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
205 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
206 Crane, D., Lepicki, T., & Knudsen, K. (2016). Unique and common elements of the role of peer support in the context of traditional mental health services. Psychiatric Rehabilitation Journal, 39(3), 282–288.27159112
207 Foglesong, D., Spagnolo, A. B., Cronise, R., Forbes, J., Swarbrick, P., Edwards, J. P., & Pratt, C. (2021). Perceptions of supervisors of peer support workers (PSW) in behavioral health: Results from a national survey. Community Mental Health Journal. Advance online publication. doi:10.1007/s10597-021-00837-2.
208 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
209 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
210 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
211 White, W. L. (2010). Nonclinical addiction recovery support services: History, rationale, models, potentials, and pitfalls. Alcoholism Treatment Quarterly, 28(3), 256–272.
212 White, W. (2006). Sponsor, recovery coach, addiction counselor: The importance of role clarity and role integrity. Philadelphia Department of Behavioral Health and Mental Retardation Services.
213 Myrick, K., & del Vecchio, P. (2016). Peer support services in the behavioral healthcare workforce: State of the field. Psychiatric Rehabilitation Journal, 39(3), 197–203.27183186
214 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
215 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
216 Herlihy, B. (2017). Boundaries across borders. https://www.counseling.org/docs/default-source/ethics/ethics-columns/ethics_november-2017_boundaries-across-borders.pdf?sfvrsn=1e25522c_6.
217 White, W., PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
218 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
219 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
220 Daniels, A. S., Ashenden, P., Goodale, L., & Stevens, T. (2016). National survey of compensation among peer support specialists. The College for Behavioral Health Leadership. https://papeersupportcoalition.org/wp-content/uploads/2016/01/CPS_Compensation_Report.pdf.
221 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. M. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
222 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
223 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
224 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
225 Rebeiro Gruhl, K. L., LaCarte, S., & Calixte, S. (2016). Authentic peer support work: Challenges and opportunities for an evolving occupation. Journal of Mental Health, 25(1), 78–86.26397981
226 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
227 Swarbrick, M., Tunner, T. P., Miller, D. W., Werner, P., & Tiegreen, W. W. (2016). Promoting health and wellness through peer-delivered services: Three innovative state examples. Psychiatric Rehabilitation Journal, 39(3), 204–210.27618457
228 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
229 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
230 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
231 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). American Psychiatric Publishing.
232 Koob, G. F., & Volkow, N. D. (2016). Neurobiology of addiction: A neurocircuitry analysis. Lancet Psychiatry, 3(8), 760–773.27475769
233 Volkow, N. D., Koob, G. F., & McLellan, A. T. (2016). Neurobiologic advances from the brain disease model of addiction. New England Journal of Medicine, 374(4), 363–371.26816013
234 National Institute on Drug Abuse. (2018, June). Understanding drug use and addiction. DrugFacts. https://www.drugabuse.gov/publications/drugfacts/understanding-drug-use-addiction.
235 Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. https://www.samhsa.gov/sites/default/files/20190718-samhsa-risk-protective-factors.pdf.
236 Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. https://www.samhsa.gov/sites/default/files/20190718-samhsa-risk-protective-factors.pdf.
237 Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. https://www.samhsa.gov/sites/default/files/20190718-samhsa-risk-protective-factors.pdf.
238 Cicchetti, D., & Handley, E. D. (2019). Child maltreatment and the development of substance use and disorder. Neurobiology of Stress, 10, 100144.30937350
239 Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. https://www.samhsa.gov/sites/default/files/20190718-samhsa-risk-protective-factors.pdf.
240 Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. https://www.samhsa.gov/sites/default/files/20190718-samhsa-risk-protective-factors.pdf.
241 Newcomb, M. E., Hill, R., Buehler, K., Ryan, D. T., Whitton, S. W., & Mustanski, B. (2020). High burden of mental health problems, substance use, violence, and related psychosocial factors in transgender, non-binary, and gender diverse youth and young adults. Archives of Sexual Behavior, 49(2), 645–659.31485801
242 Agosto, S., Reitz, K., Ducheny, K., & Moaton, T. (2019). Substance use and recovery in the transgender and gender nonconforming (TGNC) older adult community. In Transgender and gender nonconforming health and aging (pp. 97–112). Springer.
243 Evans-Polce, R. J., Veliz, P. T., Boyd, C. J., Hughes, T. L., & McCabe, S. E. (2020). Associations between sexual orientation discrimination and substance use disorders: Differences by age in US adults. Social Psychiatry and Psychiatric Epidemiology, 55(1), 101–110.30903234
244 Schuler, M. S., Prince, D. M., Breslau, J., & Collins, R. L. (2020). Substance use disparities at the intersection of sexual identity and race/ethnicity: Results from the 2015-2018 National Survey on Drug Use and Health. LGBT Health, 7(6), 283–291.32543315
245 Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. https://www.samhsa.gov/sites/default/files/20190718-samhsa-risk-protective-factors.pdf.
246 Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. https://www.samhsa.gov/sites/default/files/20190718-samhsa-risk-protective-factors.pdf.
247 National Institute on Drug Abuse. (2019, January). Treatment approaches for drug addiction. DrugFacts. https://nida.nih.gov/sites/default/files/drugfacts-treatmentapproaches.pdf.
248 Cloud, W., & Granfield, R. (2008). Conceptualizing recovery capital: Expansion of a theoretical construct. Substance Use & Misuse, 43(12-13), 1971–1986.19016174
249 Granfield, R., & Cloud, W. (1999). Coming clean: Overcoming addiction without treatment. New York University Press.
250 Granfield, R., & Cloud, W. (2001). Social context and “natural recovery”: The role of social capital in the resolution of drug-associated problems. Substance Use & Misuse, 36(11), 1543–1570.11693955
251 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
252 Substance Abuse and Mental Health Services Administration. (2014). SAMHSA's concept of trauma and guidance for a trauma-informed approach. HHS Publication No. (SMA) 14-4884. Substance Abuse and Mental Health Services Administration.
253 Foglesong, D., Knowles, K., Cronise, R., Wolf, J., & Edwards, J. P. (2021). National practice guidelines for peer support specialists and supervisors. Psychiatric Services. Advance online publication. doi:10.1176/appi.ps.202000901.
254 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. Substance Abuse and Mental Health Services Administration.
255 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Substance Abuse and Mental Health Services Administration.
256 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4801. Substance Abuse and Mental Health Services Administration.
257 Mendoza, N. S., Resko, S., Wohlert, B., & Baldwin, A. (2016). “We have to help each other heal”: The path to recovery and becoming a professional peer support. Journal of Human Behavior in the Social Environment, 26(2), 137–148.
258 White, W. (2006). Sponsor, recovery coach, addiction counselor: The importance of role clarity and role integrity. Philadelphia Department of Behavioral Health and Mental Retardation Services.
259 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
260 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions (p. S263). American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
261 Drebing, C. E., Reilly, E., Henze, K. T., Kelly, M., Russo, A., Smolinsky, J., … Penk, W. E. (2018). Using peer support groups to enhance community integration of veterans in transition. Psychological Services, 15(2), 135–145.29723015
262 Drebing, C. (2016). Leading peer support and self-help groups: A pocket resource for peer workers and support group facilitators. Alderon Press.
263 Substance Abuse and Mental Health Services Administration. (2017). Value of peers, 2017 [PowerPoint slides]. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/value-of-peers-2017.pdf.
264 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
265 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
266 Kelly, J. (2018). SAMHSA recovery research and evaluation technical expert panel summary report. Substance Abuse and Mental Health Services Administration.
267 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit (p. 57). https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
268 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 1–8.
269 Substance Abuse and Mental Health Services Administration. (2015). Core competencies for peer workers in behavioral health services. www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/core-competencies_508_12_13_18.pdf.
270 Inanlou, M., Bahmani, B., Farhoudian, A., & Rafiee, F. (2020). Addiction recovery: A systematized review. Iranian Journal of Psychiatry, 15(2), 172.32426014
271 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
272 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Substance Abuse and Mental Health Services Administration.
273 Wilson, D., Heaslip, V., & Jackson, D. (2018). Improving equity and cultural responsiveness with marginalised communities: Understanding competing worldviews. Journal of Clinical Nursing, 27(19-20), 3810–3819.29869819
274 Bascug, E., & Onken, S. (2015, August). Culturally competent care in recovery-oriented settings. [Webinar]. www.youtube.com/watch?v=L7E9Bk7S8k.
275 Clary, E., Ribar, C., & Weigensberg, E. (2020). Challenges in providing substance use disorder treatment to child welfare clients in rural communities. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
276 Grim, B. J., & Grim, M. E. (2019). Belief, behavior, and belonging: How faith is indispensable in preventing and recovering from substance abuse. Journal of Religion and Health, 58(5), 1713–1750.31359242
277 Substance Abuse and Mental Health Services Administration. (2016). Rural behavioral health: Telehealth challenges and opportunities. In Brief, Volume 9, Issue 2. https://store.samhsa.gov/sites/default/files/d7/priv/sma16-4989.pdf.
278 Clary, E., Ribar, C., Weigensberg, E., Radel, L., & Madden, E. (2020). Challenges in providing substance use disorder treatment to child welfare clients in rural communities. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
279 Lister, J. J., Weaver, A., Ellis, J. D., Himle, J. A., & Ledgerwood, D. M. (2020). A systematic review of rural-specific barriers to medication treatment for opioid use disorder in the United States. American Journal of Drug and Alcohol Abuse, 46(3), 273–288.31809217
280 Ashford, R. D., Meeks, M., Curtis, B., & Brown, A. M. (2019). Utilization of peer-based substance use disorder and recovery interventions in rural emergency departments: Patient characteristics and exploratory analysis. Journal of Rural Mental Health, 43(1).
281 Davis, S. M., Stover, A., Linn, H., Dower, J., McCawley, D., Winstanley, E., & Feinberg, J. (2021). Establishing peer recovery support services to address the Central Appalachian opioid epidemic: The West Virginia Peers Enhancing Education, Recovery, and Survival (WV PEERS) Pilot Program. Journal of Appalachian Health, 3(3), 36–50.35770037
282 Ashford, R. D., Meeks, M., Curtis, B., & Brown, A. M. (2019). Utilization of peer-based substance use disorder and recovery interventions in rural emergency departments: Patient characteristics and exploratory analysis. Journal of Rural Mental Health, 43(1).
283 Davis, S. M., Stover, A., Linn, H., Dower, J., McCawley, D., Winstanley, E., & Feinberg, J. (2021). Establishing peer recovery support services to address the Central Appalachian opioid epidemic: The West Virginia Peers Enhancing Education, Recovery, and Survival (WV PEERS) Pilot Program. Journal of Appalachian Health, 3(3), 36–50.35770037
284 Gruß, I., Firemark, A., & Davidson, A. (2021). Motherhood, substance use and peer support: Benefits of an integrated group program for pregnant and postpartum women. Journal of Substance Abuse Treatment, 131, 108450.34098285
285 Miler, J. A., Carver, H., Foster, R., & Parkes, T. (2020). Provision of peer support at the intersection of homelessness and problem substance use services: A systematic ‘state of the art’ review. BMC Public Health, 20(1), 1–18.31898494
286 Ray, B., Watson, D. P., Xu, H., Salyers, M. P., Victor, G., Sightes, E., … Bo, N. (2021). Peer recovery services for persons returning from prison: Pilot randomized clinical trial investigation of SUPPORT. Journal of Substance Abuse Treatment, 126, 108339.34116824
287 Kelley, A., Steinberg, R., McCoy, T. P., Pack, R., & Pepion, L. (2021). Exploring recovery: Findings from a six-year evaluation of an American Indian peer recovery support program. Drug and Alcohol Dependence, 221, 108559.33548899
288 Ashford, R. D., Meeks, M., Curtis, B., & Brown, A. M. (2019). Utilization of peer-based substance use disorder and recovery interventions in rural emergency departments: Patient characteristics and exploratory analysis. Journal of Rural Mental Health, 43(1), 17.
289 Hansen, M. A., Modak, S., McMaster, S., Zoorob, R., & Gonzalez, S. (2020). Implementing peer recovery coaching and improving outcomes for substance use disorders in underserved communities. Journal of Ethnicity in Substance Abuse, 1–14.
290 Hansen, M. A., Modak, S., McMaster, S., Zoorob, R., & Gonzalez, S. (2020). Implementing peer recovery coaching and improving outcomes for substance use disorders in underserved communities. Journal of Ethnicity in Substance Abuse, 1–14.
291 Families USA. (2019, November). Advancing health equity through community health workers and peer providers: Mounting evidence and policy recommendations. https://familiesusa.org/wp-content/uploads/2019/11/HEV_PCORI-CHW-Report_11-04-19.pdf.
292 Families USA. (2019, November). Advancing health equity through community health workers and peer providers: Mounting evidence and policy recommendations. https://familiesusa.org/wp-content/uploads/2019/11/HEV_PCORI-CHW-Report_11-04-19.pdf.
293 Families USA. (2019, November). Advancing health equity through community health workers and peer providers: Mounting evidence and policy recommendations. https://familiesusa.org/wp-content/uploads/2019/11/HEV_PCORI-CHW-Report_11-04-19.pdf.
294 Families USA. (2019, November). Advancing health equity through community health workers and peer providers: Mounting evidence and policy recommendations. https://familiesusa.org/wp-content/uploads/2019/11/HEV_PCORI-CHW-Report_11-04-19.pdf.
295 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
296 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
297 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
298 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
299 White, W., & Kurtz, E. (2006). The varieties of recovery experience. International Journal of Self Help and Self Care, 3(1-2), 21–61.
300 Kaplan, L. (2008). The role of recovery support services in recovery-oriented systems of care. HHS Publication No. (SMA) 08-4315. Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment.
301 Prochaska, J., & DiClemente, C. (1983). Stages and processes of self-change in smoking: Toward an integrative model of change. Journal of Consulting and Clinical Psychology, 5, 390–395.
302 Raihan, N., & Cogburn, M. (2021, March 3). Stages of change theory. StatPearls. https://www.ncbi.nlm.nih.gov/books/NBK556005/.
303 Norcross, J. C., Krebs, P. M., & Prochaska, J. O. (2011). Stages of change. Journal of Clinical Psychology, 67(2), 143–154.21157930
304 White, W., & Kurtz, E. (2006). The varieties of recovery experience. International Journal of Self Help and Self Care, 3(1-2), 21–61.
305 Kelly, J. F., Greene, M. C., & Bergman, B. G. (2018). Beyond abstinence: Changes in indices of quality of life with time in recovery in a nationally representative sample of U.S. adults. Alcoholism, Clinical and Experimental Research, 42(4), 770–780.29473966
306 Kelly, J. F., Greene, M. C., & Bergman, B. G. (2018). Beyond abstinence: Changes in indices of quality of life with time in recovery in a nationally representative sample of U.S. adults. Alcoholism, Clinical and Experimental Research, 42(4), 770–780.29473966
307 Kelly, J. F., Greene, M. C., & Bergman, B. G. (2018). Beyond abstinence: Changes in indices of quality of life with time in recovery in a nationally representative sample of U.S. adults. Alcoholism, Clinical and Experimental Research, 42(4), 770–780.29473966
308 Kelly, J. F., Abry, A. W., Milligan, C. M., Bergman, B. G., & Hoeppner, B. B. (2018). On being “in recovery”: A national study of prevalence and correlates of adopting or not adopting a recovery identity among individuals resolving drug and alcohol problems. Psychology of Addictive Behaviors, 32(6), 595–604.30070538
309 Granfield, R., & Cloud, W. (1999). Coming clean: Overcoming addiction without treatment. New York University Press.
310 Cloud, W., & Granfield, R. (2008). Conceptualizing recovery capital: Expansion of a theoretical construct. Substance Use & Misuse, 43(12-13), 1971–1986.19016174
311 White, W., & Cloud, W. (2008). Recovery capital: A primer for addictions professionals. Counselor, 9(5), 22–27.
312 White, W., & Cloud, W. (2008). Recovery capital: A primer for addictions professionals. Counselor, 9(5), 22–27.
313 Radcliffe, P., Tompkins, C., Timpson, H., Eckley, L., Sumnall, H., Pendlebury, M., & Hay, G. (2016). “Once you've been there, you're always recovering”: Exploring experiences, outcomes, and benefits of substance misuse recovery. Drugs and Alcohol Today, 16(1), 29–38.
314 Cloud, W., & Granfield, R. (2008). Conceptualizing recovery capital: Expansion of a theoretical construct. Substance Use & Misuse, 43(12-13), 1971–1986.19016174
315 Cloud, W., & Granfield, R. (2008). Conceptualizing recovery capital: Expansion of a theoretical construct. Substance Use & Misuse, 43(12-13), 1971–1986.19016174
316 Cloud, W., & Granfield, R. (2008). Conceptualizing recovery capital: Expansion of a theoretical construct. Substance Use & Misuse, 43(12-13), 1971–1986.19016174
317 Ashford, R. D., Brown, A., Canode, B., Sledd, A., Potter, J. S., & Bergman, B. G. (2021). Peer-based recovery support services delivered at recovery community organizations: Predictors of improvements in individual recovery capital. Addictive Behaviors, 119, 106945.33872848
318 Sánchez, J., Sahker, E., & Arndt, S. (2020). The assessment of recovery capital (ARC) predicts substance abuse treatment completion. Addictive Behaviors, 102, 106189.31778848
319 Ashford, R. D., Brown, A., Canode, B., Sledd, A., Potter, J. S., & Bergman, B. G. (2021). Peer-based recovery support services delivered at recovery community organizations: Predictors of improvements in individual recovery capital. Addictive Behaviors, 119, 106945.33872848
320 Hennessy, E. A. (2017). Recovery capital: A systematic review of the literature. Addiction Research and Theory, 25(5), 349–360.
321 Foglesong, D., Knowles, K., Cronise, R., Wolf, J., & Edwards, J. P. (2021). National practice guidelines for peer support workers and supervisors. Psychiatric Services, 73, 215–218.34253034
322 White, W., the PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
323 CAPRSS. (2017). Accreditation. www.manula.com/manuals/caprss/accreditation/main/en/topic/c-2017-caprss-council-on-accreditation-of-peer-recovery-support-services.
324 White, W., the PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
325 Shalaby, R. A. H., & Agyapong, V. I. O. (2020). Peer support in mental health: Literature review. JMIR Mental Health, 7(6), e15572.32357127
326 Winhusen, T., Wilder, C., Kropp, F., Theobald, J., Lyons, M. S., & Lewis, D. (2020). A brief telephone-delivered peer intervention to encourage enrollment in medication for opioid use disorder in individuals surviving an opioid overdose: Results from a randomized pilot trial. Drug and Alcohol Dependence, 216, 108270.32911132
327 Moskal, D., Whitaker, H., Bernstein, J. F., Maisto, S. A., & Connors, G. J. (2021). Evaluation of a web-based psychosocial education and peer support program for alcohol use concerns. Alcoholism Treatment Quarterly, 39(3), 366–382.34326569
328 Shachar, C., Engel, J., & Elwyn, G. (2020). Implications for telehealth in a postpandemic future: Regulatory and privacy issues. JAMA, 323(23), 2375–2376.32421170
329 Office for Civil Rights. (2020, March 30). Notification of enforcement discretion for telehealth remote communications during the COVID-19 nationwide public health emergency. U.S. Department of Health and Human Services. www.hhs.gov/hipaa/for-professionals/special-topics/emergency-preparedness/notification-enforcement-discretion-telehealth/index.html.
330 Shachar, C., Engel, J., & Elwyn, G. (2020). Implications for telehealth in a postpandemic future: Regulatory and privacy issues. JAMA, 323(23), 2375–2376.32421170
331 Shachar, C., Engel, J., & Elwyn, G. (2020). Implications for telehealth in a postpandemic future: Regulatory and privacy issues. JAMA, 323(23), 2375–2376.32421170
332 White, W., the PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
333 White, W., the PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
334 New York State Office of Addiction Services and Supports. (2018). Peer integration and the stages of change toolkit. https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf.
335 White, W., the PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
336 White, W., the PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
337 White, W., the PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, B. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
338 Valentine, P. (2014, May). Understanding the role of peer recovery coaches in the addiction profession. [Webinar PowerPoint]. https://www.naadac.org/assets/2416/2014-05-01_understanding_role_peer_recovery_coaches_webinarslides.pdf.
339 Russo, A., & Sweeney, P. (n.d.). Peer support provider: Walking the tightrope between helping others and maintaining your own wellness (p. 2). New England Mental Illness Research, Education and Clinical Centers, Peer Education Center. Continuing Education Series. https://www.mirecc.va.gov/visn1/docs/products/Peer_Support_Provider_Self-Care_Presentation.pdf.
340 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2022). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings—A narrative review. Journal of Addiction Medicine, 16(1), 93–100.33560695
341 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
342 Russo, A., & Sweeney, P. (n.d.). Peer support provider: Walking the tightrope between helping others and maintaining your own wellness. New England Mental Illness Research, Education and Clinical Centers, Peer Education Center. Continuing Education Series. www.mirecc.va.gov/visn1/docs/products/Peer_Support_Provider_Self-Care_Presentation.pdf.
343 Saakvitne, K. W., & Pearlman, L. A. (1996). Transforming the pain: A workbook on vicarious traumatization. W. W. Norton and Company.
344 Shinholser, J., & Payne, J. D. (2017). Recovery coach manual. The McShin Foundation. https://mcshin.org/wp-content/uploads/2019/07/McShin-RCM_for-web.pdf.
345 Ameli, R. (2020, December). Mindfulness basics. A mindfulness audio program. National Institutes of Health Clinical Center. www.cc.nih.gov/sites/nihinternet/files/internet-files/palliativecare/pdf/MindfulnessManual.pdf.
346 Ameli, R. (2020, December). Mindfulness basics. A mindfulness audio program. National Institutes of Health Clinical Center. www.cc.nih.gov/sites/nihinternet/files/internet-files/palliativecare/pdf/MindfulnessManual.pdf.
347 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
348 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
349 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
350 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
351 Gordon, T. (2018, September). What are the roadblocks to helping your child? Gordon Training International. http://www.gordontraining.com/parenting/roadblocks-helping-child/.
352 Pantridge, C. E., Charles, V. A., Dehart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support workers in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
353 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
354 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
355 White, W. (2019, June 13). Self-disclosure and recovery support services. [Blog Post]. https://www.chestnut.org/Blog/Posts/305/William-White/2019/6/SelfDisclosure-and-Recovery-Support-Services/blog-post/blog-and-news-postings-details.
356 White, W. (2019, June 13). Self-disclosure and recovery support services. [Blog Post]. https://www.chestnut.org/Blog/Posts/305/William-White/2019/6/SelfDisclosure-and-Recovery-Support-Services/blog-post/blog-and-news-postings-details.
357 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
358 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit (p. 203). https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
359 White, W. L. (2009). Peer-based addiction recovery support: History, theory, practice, and scientific evaluation. Philadelphia Department of Behavioral Health and Mental Retardation Services.
360 White, W. L. (2009). Peer-based addiction recovery support: History, theory, practice, and scientific evaluation. Philadelphia Department of Behavioral Health and Mental Retardation Services.
361 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit (p. 203). https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
362 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit (p. 84). https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
363 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
364 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
365 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
366 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
367 Substance Abuse and Mental Health Services Administration. (2016, April). Learn the eight dimensions of wellness. (Poster). https://store.samhsa.gov/product/Learn-the-Eight-Dimensions-of-Wellness-Poster-/SMA16-4953.
368 Karosses, D. N., & Alexopoulos, G. S. (2014). Problemsolving therapy in the elderly. Current Treatment Options in Psychiatry, 1(1), 15–26.24729951
369 Bennett, M., & Bellack, A. (2015). Recovery coach manual. OnTrackNY. www.ontrackny.org/portals/1/Files/Resources/RecoveryCoach_2015.01.21.pdf.
370 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit (p. 161). https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
371 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
372 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
373 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
374 White, W. L. (2009). The mobilization of community resources to support long-term addiction recovery. Journal of Substance Abuse Treatment, 36(2), 146–158.19161895
375 White, W. L. (2009). The mobilization of community resources to support long-term addiction recovery. Journal of Substance Abuse Treatment, 36(2), 146–158.19161895
376 Ashford, R. D., Brown, A. M., Ryding, R., & Curtis, B. (2020). Building recovery ready communities: The recovery ready ecosystem model and community framework. Addiction Research and Theory, 28(1), 1–11.
377 Substance Abuse and Mental Health Services Administration. (2022). Medication-assisted treatment (MAT). https://www.samhsa.gov/medication-assisted-treatment.
378 Substance Abuse and Mental Health Services Administration. (2018). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. HHS Publication No. (SMA) 19-5063. Substance Abuse and Mental Health Services Administration.
379 White, W. L., Kelly, J. F., & Roth, J. D. (2012). New addiction-recovery support institutions: Mobilizing support beyond professional addiction treatment and recovery mutual aid. Journal of Groups in Addiction and Recovery, 7(2-4), 297–317.
380 White, W. L., Kelly, J. F., & Roth, J. D. (2012). New addiction-recovery support institutions: Mobilizing support beyond professional addiction treatment and recovery mutual aid. Journal of Groups in Addiction and Recovery, 7(2-4), 297–317.
381 Watson, E. (2017). The mechanisms underpinning peer support: A literature review. Journal of Mental Health, 28(6), 677–688.29260930
382 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
383 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
384 Advancement Project—Healthy City Community Research Lab. (2012). Participatory asset mapping—A community research lab toolkit. www.communityscience.com/knowledge4equity/AssetMappingToolkit.pdf.
385 Best, D., Irving, J., Collinson, B., Andersson, C., & Edwards, M. (2016). Recovery networks and community connections: Identifying connection needs and community linkage opportunities in early recovery populations. Alcoholism Treatment Quarterly, 35(1), 2–15.
386 Walsh, M., Kittler, M. G., Throp, M., & Shaw, F. (2019). Designing a recovery-orientated system of care: A community operational research perspective. European Journal of Operational Research, 272(2), 595–607.
387 Advancement Project—Healthy City Community Research Lab. (2012). Participatory asset mapping—A community research lab toolkit. www.communityscience.com/knowledge4equity/AssetMappingToolkit.pdf.
388 White, W. (2006). The rhetoric of recovery advocacy: An essay on the power of language. In White, W. Let's go make some history: Chronicles of the new addiction recovery advocacy movement (p. 26, pp. 37–76). Johnson Institute and Faces & Voices of Recovery.
389 White, W. L., Kelly, J. F., & Roth, J. D. (2012). New addiction-recovery support institutions: Mobilizing support beyond professional addiction treatment and recovery mutual aid. Journal of Groups in Addiction and Recovery, 7(2-4), 297–317.
390 Utah Support Advocates for Recovery Awareness. (2018). Speak out. www.myusara.com/advocacy/speak.
391 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
392 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
393 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
394 National Alliance for Recovery Residences (NARR). (n.d.). National standard 3.0 compendium. https://narronline.org/wp-content/uploads/2019/02/NARR-Standard-Compendium-v3.pdf.
395 New York State Office of Addiction Services and Supports. (2018). Peer integration and stages of change toolkit. https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf.
396 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2021). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings; A narrative review. Journal of Addiction Medicine. Advance online publication. doi:10.1097/adm.0000000000000810.
397 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2021). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings; A narrative review. Journal of Addiction Medicine. Advance online publication. doi:10.1097/adm.0000000000000810.
398 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
399 Cos, T. A., LaPollo, A. B., Aussendorf, M., Williams, J. M., Malayter, K., & Festinger, D. S. (2020). Do peer recovery specialists improve outcomes for individuals with substance use disorder in an integrative primary care setting? A program evaluation. Journal of Clinical Psychology in Medical Settings, 27(4), 704–715.31520183
400 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
401 Mette, E., Townley, C., & Purington, K. (2019). 50-state scan: How Medicaid agencies leverage their non-licensed substance use disorder workforce. National Academy for State Health Policy.
402 Byrne, L., Roennfeldt, H., Wolf, J., Linfoot, A., Foglesong, D., Davidson, L., & Bellamy, C. (2021). Effective peer employment within multidisciplinary organizations: Model for best practice. Administration and Policy in Mental Health. Advance online publication. doi:10.1007/s10488-021-01162-2.
403 National Council for Mental Wellbeing. (2022). Establishing peer support services for overdose response: A toolkit for health departments. https://www.usf.edu/cbcs/mhlp/tac/documents/behavioral-healthcare/cooccurring/establishing_peer_support_services_for_overdose_response_toolkit_march_2022.pdf.
404 Great Lakes ATTC & NAADAC. (2020). Peer Recovery Support Series, Section I: Building a successful culture in your organization [PowerPoint slides]. https://www.naadac.org/building-organization-peer-recovery-webinar.
405 Kelly, J. F., Stout, R. L., Jason, L. A., Fallah-Sohy, N., Hoffman, L. A., & Hoeppner, B. B. (2020). One-stop shopping for recovery: An investigation of participant characteristics and benefits derived from U.S. recovery community centers. Alcoholism: Clinical and Experimental Research, 44(3), 711–721.32012306
406 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
407 Kaplan, L., Nugent, C., Baker, M., Clark, H. W., & Veysey, B. M. (2010). Introduction: The recovery community services program. Alcoholism Treatment Quarterly, 28(3), 244–255.
408 Gaumond, P., & Whitter, M. (2009). Access to Recovery (ATR) approaches to recovery-oriented systems of care: Three case studies. HHS Publication No. (SMA) 09-4440. Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment.
409 Myrick, K., & Del Vecchio, P. (2016). Peer support services in the behavioral healthcare workforce: State of the field. Psychiatric Rehabilitation Journal, 39(3), 197–203.27183186
410 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267–S274.29779551
411 Mette, E., Townley, C., & Purington, K. (2019). 50-state scan: How Medicaid agencies leverage their non-licensed substance use disorder workforce. National Academy for State Health Policy.
412 Substance Abuse and Mental Health Services Administration. (2021). National Survey of Substance Abuse Treatment Services (N-SSATS): 2020; Data on substance abuse treatment facilities. Substance Abuse and Mental Health Services Administration.
413 University of Michigan Behavioral Health Workforce Research Center. (2019). National analysis of peer support providers: Practice settings, requirements, roles, and reimbursement. University of Michigan School of Public Health.
414 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
415 Council on Accreditation of Peer Recovery Support Services. (2017). Accreditation. www.manula.com/manuals/caprss/accreditation/main/en/topic/c-2017-caprss-council-on-accreditation-of-peer-recovery-support-services.
416 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
417 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
418 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review. https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
419 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2021). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings; A narrative review. Journal of Addiction Medicine. Advance online publication. doi:10.1097/adm.0000000000000810.
420 Pantridge, C. E., Charles, V. A., Dehart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
421 Englander, H., Mahoney, S., Brandt, K., Brown, J., Dorfman, C., Nydahl, A., … Gregg, J. (2019). Tools to support hospital-based addiction care: Core components, values, and activities of the improving addiction care team. Journal of Addiction Medicine, 13(2), 85–89.30608265
422 Pantridge, C. E., Charles, V. A., Dehart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
423 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
424 Fortuna, K. L., Myers, A. L., Walsh, D., Walker, R., Mois, G., & Brooks, J. M. (2020). Strategies to increase peer support specialists’ capacity to use digital technology in the era of COVID-19: Pre-post study. JMIR Mental Health, 7(7), e20429.32629424
425 Burden, E. (2020, May 7). 5 key practices for providing tech-assisted peer support. Addiction Professional. https://www.hmpgloballearningnetwork.com/site/addiction/article/5-key-practices-providing-tech-assisted-peer-support.
426 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
427 Magidson, J. M., Regan, S. R., Jack, H., & Wakeman, S. (2018). Reduced hospitalizations and increased abstinence six months after recovery coach contact. ASAM conference presentation. https://www.eventscribe.com/2018/ASAM/ajaxcalls/PosterInfo.asp?efp=Tk5JV0RMTEEzNDgz&PosterID=125204&rnd=0.9485711.
428 Winhusen, T., Wilder, C., Kropp, F., Theobald, J., Lyons, M. S., & Lewis, D. (2020). A brief telephone-delivered peer intervention to encourage enrollment in medication for opioid use disorder in individuals surviving an opioid overdose: Results from a randomized pilot trial. Drug and Alcohol Dependence, 216, 108270.32911132
429 O'Connell, M. J., Flanagan, E. H., Delphin-Rittmon, M. E., & Davidson, L. (2017). Enhancing outcomes for persons with co-occurring disorders through skills training and peer recovery support. Journal of Mental Health, 10, 1–6.
430 Kelley, A., Bingham, D., Brown, E., & Pepion, L. (2017). Assessing the impact of American Indian peer recovery support on substance use and health. Journal of Groups in Addiction and Recovery, 12, 296–308.
431 Hansen, M. A., Modak, S., McMaster, S., Zoorob, R., & Gonzalez, S. (2020). Implementing peer recovery coaching and improving outcomes for substance use disorders in underserved communities. Journal of Ethnicity in Substance Abuse, 1–14.
432 Laudet, A. B., Harris, K., Kimball, T., Winters, K. C., & Moberg, D. P. (2016). In college and in recovery: Reasons for joining a collegiate recovery program. Journal of American College Health, 64, 238–246.26731130
433 Ashford, R. D., Brown, A., Canode, B., Sledd, A., Potter, J. S., & Bergman, B. G. (2021). Peer-based recovery support services delivered at recovery community organizations: Predictors of improvements in individual recovery capital. Addictive Behaviors, 119, 106945.33872848
434 Ray, B., Watson, D. P., Xu, H., Salyers, M. P., Victor, G., Sightes, E., … Bo, N. (2021). Peer recovery services for persons returning from prison: Pilot randomized clinical trial investigation of SUPPORT. Journal of Substance Abuse Treatment, 126, 108339.34116824
435 Possemato, K., Johnson, E. M., Emery, J. B., Wade, M., Acosta, M. C., Marsch, L. A., … Maisto, S. A. (2019). A pilot study comparing peer supported web-based CBT to self-managed web CBT for primary care veterans with PTSD and hazardous alcohol use. Psychiatric Rehabilitation Journal, 42(3), 305.30489140
436 Tracy, K., Wachtel, L., & Goldmann, E. (2018). Beyond substance use reduction: The positive impact of Mentorship for Addiction Problems (MAP). Journal of Alcohol, Drug Dependence and Substance Abuse, 4, 009.
437 Winhusen, T., Wilder, C., Kropp, F., Theobald, J., Lyons, M. S., & Lewis, D. (2020). A brief telephone-delivered peer intervention to encourage enrollment in medication for opioid use disorder in individuals surviving an opioid overdose: Results from a randomized pilot trial. Drug and Alcohol Dependence, 216, 108270.32911132
438 Tate, M. C., Roy, A., Pinchinat, M., Lund, E., Fox, J. B., Cottrill, S., … Stein, L. (2021). Impact of being a peer recovery specialist on work and personal life: Implications for training and supervision. Community Mental Health Journal. Advance online publication. doi:10.1007/s10597-021-00811-y.
439 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
440 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
441 Byrne, L., Roennfeldt, H., Wolf, J., Linfoot, A., Foglesong, D., Davidson, L., & Bellamy, C. (2021). Effective peer employment within multidisciplinary organizations: Model for best practice. Administration and Policy in Mental Health. Advance online publication. doi:10.1007/s10488-021-01162-2.
442 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
443 Byrne, L., Roennfeldt, H., Wolf, J., Linfoot, A., Foglesong, D., Davidson, L., & Bellamy, C. (2021). Effective peer employment within multidisciplinary organizations: Model for best practice. Administration and Policy in Mental Health. Advance online publication. doi:10.1007/s10488-021-01162-2.
444 Foglesong, D., Spagnolo, A. B., Cronise, R., Forbes, J., Swarbrick, P., Edwards, J. P., & Pratt, C. (2021). Perceptions of supervisors of peer support workers (PSW) in behavioral health: Results from a national survey. Community Mental Health Journal. Advance online publication. doi:10.1007/s10597-021-00837-2.
445 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
446 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
447 Mancini, M. A. (2018). An exploration of factors that effect the implementation of peer support services in community mental health settings. Community Mental Health Journal, 54(2), 127–137.28466237
448 Davis, J. K. (2013). Predictors of job satisfaction among peer providers on professional treatment teams in community-based agencies. Psychiatric Services (Washington, D.C.), 64(2), 181–184.23370625
449 Foglesong, D., Spagnolo, A. B., Cronise, R., Forbes, J., Swarbrick, P., Edwards, J. P., & Pratt, C. (2021). Perceptions of supervisors of peer support workers (PSW) in behavioral health: Results from a national survey. Community Mental Health Journal. Advance online publication. doi:10.1007/s10597-021-00837-2.
450 Byrne, L., Roennfeldt, H., Wolf, J., Linfoot, A., Foglesong, D., Davidson, L., & Bellamy, C. (2021). Effective peer employment within multidisciplinary organizations: Model for best practice. Administration and Policy in Mental Health. Advance online publication. doi:10.1007/s10488-021-01162-2.
451 New York City Department of Health and Mental Hygiene. (n.d.). Integrating peers into treatment programs in New York City: An in-depth guide for substance use disorder treatment providers. https://www1.nyc.gov/assets/doh/downloads/pdf/mh/peers-treatment-programs.pdf.
452 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions (p. S263). American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
453 New York City Department of Health and Mental Hygiene. (n.d.). Integrating peers into treatment programs in New York City: An in-depth guide for substance use disorder treatment providers. https://www1.nyc.gov/assets/doh/downloads/pdf/mh/peers-treatment-programs.pdf.
454 Smelson, D. A., Kline, A., Ziedonis, D., Hills, S., & Woods, C. (n.d.). Maintaining independence and sobriety through systems integration, outreach, and networking: The MISSION treatment manual. https://www.umassmed.edu/contentassets/58c9d438c9ef4f7f8a4a44e9452d471a/mission-manual-final.pdf.
455 Englander, H., Mahoney, S., Brandt, K., Brown, J., Dorfman, C., Nydahl, A., … Gregg, J. (2019). Tools to support hospital-based addiction care: Core components, values, and activities of the improving addiction care team. Journal of Addiction Medicine, 13(2), 85–89.30608265
456 TennCare. (2016). TennCare policy manual: Peer recovery services. https://www.tn.gov/content/dam/tn/tenncare/documents2/ben11002.pdf.
457 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
458 Mette, E., Townley, C., & Purington, K. (2019). 50-state scan: How Medicaid agencies leverage their non-licensed substance use disorder workforce. National Academy for State Health Policy.
459 Medicaid and CHIP Access Commission. (2019). Recovery support services for Medicaid beneficiaries with a substance use disorder [Issue brief].
460 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267–S274.29779551
461 Medicaid and CHIP Access Commission. (2019). Recovery support services for Medicaid beneficiaries with a substance use disorder [Issue brief].
462 Hendry, P. (2019). How are peer support services paid for? Is peer support Medicaid reimbursable? SMI Advisor. https://smiadviser.org/knowledge_post/how-are-peer-support-services-paid-for-is-peer-support-medicaid-reimbursable.
463 Cronise, R., Teizeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
464 National Council for Behavioral Health. (n.d.). Peer support workers in emergency departments: Engaging individuals surviving opioid overdoses; Qualitative assessment [Issue brief]. https://peerrecoverynow.org/ResourceMaterials/Peer%20Support%20Workers%20in%20EDs%20–%20Issue%20Brief%20-%20Kris%20Kelly.pdf.
465 Peer Recovery Center of Excellence. (2023). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
466 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems & authorities to promote peer specialist/peer recovery coaching services: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
467 Kaufman, L., Kuhn, W., & Stevens Manser, S. (2016). Peer specialist training and certification programs: A national overview. University of Texas at Austin, School of Social Work, Texas Institute for Excellence in Mental Health.
468 Daniels, A. S., Tunner, T. P., Powell, I., Fricks, L., & Ashenden, P. (2014). Pillars of peer support services summit six: Peer specialist supervision. https://mopeerspecialist.com/wp-content/uploads/2018/03/POPS2014.pdf.
469 Silver, J., & Nemec, P. B. (2016). The role of the peer specialists: Unanswered questions. Psychiatric Rehabilitation Journal, 39(3), 289–291.27618464
470 Alberque, F., & Dixon, H. (2016). Peer supervision: Training and credentialing peer supervisors. International Association of Peer Supporters [PowerPoint presentation]. https://www.peersupportworks.org/wp-content/uploads/2021/05/Peer-Supervision-Training-and-Credentialing-iNAPS-2016.pdf.
471 Smith, D. G. (2007, August 15). Letter to state Medicaid directors (SMDL #07-011) U.S. Department of Health and Human Services. https://downloads.cms.gov/cmsgov/archived-downloads/SMDL/downloads/SMD081507A.pdf.
472 Foglesong, D., Spagnolo, A. B., Cronise, R., Forbes, J., Swarbrick, P., Edwards, J. P., & Pratt, C. (2021). Perceptions of supervisors of peer support workers (PSW) in behavioral health: Results from a national survey. Community Mental Health Journal. Advance online publication. doi:10.1007/s10597-021-00837-2.
473 National Association of Peer Supporters. (2019). National practice guidelines for peer specialists and supervisors. N.A.P.S.
474 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems & authorities to promote peer specialist/peer recovery coaching services: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
475 Brady, L. A., Wozniak, M. L., Brimmer, M. J., Terranova, E., Moore, C., Kahn, L., … Thomas, M. (2022). Coping strategies and workplace supports for peers with substance use disorders. Substance Use & Misuse, 1-7. Advance online publication. doi:10.1080/10826084.2022.2112228.
476 U.S. Department of Health and Human Services, Office of Minority Health. (n.d.). National CLAS Standards. https://thinkculturalhealth.hhs.gov/clas.
477 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
478 Dunlap, B., Basye, A., & Skillman, S. M. (2021). Background checks and the health workforce: Practices, policies and equity. University of Washington, Center for Health Workforce Studies.
479 Tate, M. C., Roy, A., Pinchinat, M., Lund, E., Fox, J. B., Cottrill, S., … Stein, L. (2021). Impact of being a peer recovery specialist on work and personal life: Implications for training and supervision. Community Mental Health Journal. Advance online publication. https://link.springer.com/article/10.1007/s10597-021-00811-y.
480 Cronise, R., Teizeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
481 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
482 Cronise, R., Teizeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
483 Great Lakes ATTC & NAADAC. (2020). Peer Recovery Support Series, Section II: Hiring, onboarding, and integration [Webinar transcript]. https://www.naadac.org/hiring-onboarding-PRSS-webinar.
484 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting Inc. (2017). Peer support toolkit (p. 61). https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
485 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
486 Great Lakes ATTC & NAADAC. (2020). Peer Recovery Support Series, Section II: Hiring, onboarding, and integration [Webinar transcript]. https://www.naadac.org/hiring-onboarding-PRSS-webinar.
487 New York State Office of Addiction Services and Supports. (2018). Peer integration and the stages of change toolkit. https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf.
488 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
489 Peer Recovery Center of Excellence. (2023). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
490 Great Lakes ATTC & NAADAC. (2020). Peer Recovery Support Series, Section II: Hiring, onboarding, and integration [Webinar transcript]. https://www.naadac.org/hiring-onboarding-PRSS-webinar.
491 Fairfax County (VA). (2021, August 5). Peer support specialist. Retrieved July 20, 2022, from https://agency.governmentjobs.com/fairfaxcounty/default.cfm?action=specbulletin&ClassSpecID=969801.
492 Kansas Department for Aging and Disability Services, Behavioral Health Services Commission. (n.d.). Kansas Certified Peer Mentoring Certification (SUD). Retrieved July 20, 2022, from https://kdads.ks.gov/provider-home/providers/peer-support-services/kansas-certified-peer-mentor-certification-(sud).
493 New York City Department of Health and Mental Hygiene. (n.d.). Integrating peers into treatment programs in New York City: An in-depth guide for substance use disorder treatment providers. https://www1.nyc.gov/assets/doh/downloads/pdf/mh/peers-treatment-programs.pdf.
494 New York City Department of Health and Mental Hygiene. (n.d.). Integrating peers into treatment programs in New York City: An in-depth guide for substance use disorder treatment providers (p. 16). https://www1.nyc.gov/assets/doh/downloads/pdf/mh/peers-treatment-programs.pdf.
495 Great Lakes ATTC & NAADAC. (2020). Peer Recovery Support Series, Section II: Hiring, onboarding, and integration [Webinar transcript]. https://www.naadac.org/hiring-onboarding-PRSS-webinar.
496 Shalaby, R., & Agyapong, V. (2020). Peer support in mental health: Literature review. JMIR Mental Health, 7(6), e15572.32357127
497 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267–S274.29779551
498 Scannell, C. (2021). Voices of hope: Substance use peer support in a system of care. Substance Abuse: Research and Treatment, 15, 11782218211050360.34675524
499 Mancini, M. A. (2018). An exploration of factors that effect the implementation of peer support services in community mental health settings. Community Mental Health Journal, 54(2), 127–137.28466237
500 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267–S274.29779551
501 Scannell, C. (2021). Voices of hope: Substance use peer support in a system of care. Substance Abuse: Research and Treatment, 15, 11782218211050360.34675524
502 Cabral, L., Strothers, H., Muhr, K., Sefton, L., & Savageau, J. (2014). Clarifying the role of the mental health peer specialist in Massachusetts, USA: Insights from peer specialists, supervisors and clients. Health and Social Care in the Community, 22(1), 104–112.24313729
503 Alberta, A. J., Ploski, R. R., & Carlson, S. L. (2012). Addressing challenges to providing peer-based recovery support. Journal of Behavioral Health Services and Research, 39(4), 481–491.22828975
504 Cronise, R., Teizeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
505 Cronise, R., Teizeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
506 Jenkins, S., Chenneville, T., & Salnaitis, C. (2018). Are peer specialists happy on the job? Psychiatric Rehabilitation Journal, 41(1), 72–75.28447820
507 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
508 Silver, J., & Nemec, P. B. (2016). The role of the peer specialists: Unanswered questions. Psychiatric Rehabilitation Journal, 39(3), 289–291.27618464
509 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267–S274.29779551
510 Byrne, L., Roennfeldt, H., Wolf, J., Linfoot, A., Foglesong, D., Davidson, L., & Bellamy, C. (2021). Effective peer employment within multidisciplinary organizations: Model for best practice. Administration and Policy in Mental Health. Advance online publication. doi:10.1007/s10488-021-01162-2.
511 Lapidos, A., Jester, J., Ortquist, M., Werner, P., Ruffolo, M. C., & Smith, M. (2018). Survey of peer support specialists: Professional activities, self-rated skills, job satisfaction, and financial well-being. Psychiatric Services (Washington, D.C.), 69(12), 1264–1267.30301447
512 Ventura County (CA). (2022). Peer specialist I/II/III. Retrieved July 20, 2022, from https://www.governmentjobs.com/careers/ventura/jobs/3491140/peer-specialist-i-ii-iii.
513 U.S. Department of Veterans Affairs, Veterans Health Administration. (2019, August 13). Psychosocial rehabilitation and recovery services. (VHA Directive 1163).
514 U.S. Department of Veterans Affairs. (2013). Peer specialist toolkit: Implementing peer support services in VHA. https://www.mirecc.va.gov/visn4/docs/Peer_Specialist_toolkit_Final.pdf.
515 U.S. Department of Veterans Affairs, Veterans Health Administration. (2019, August 13). Psychosocial rehabilitation and recovery services. (VHA Directive 1163).
516 Georgia Mental Health Consumer Network. (n.d.). Georgia's military veterans find purpose for their experience. Retrieved July 12, 2022, from https://www.gmhcn.org/articles.
517 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings; A literature review (p. 23). https://peerrecoverynow.org/documents/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf.
518 Miles, J. (2019). Changes in residential substance use treatment service access resulting from recent Medicaid Section 1115 waivers. Psychiatric Services (Washington, D.C.), 70(5), 428–431.30755128
519 University of Michigan Behavioral Health Workforce Research Center. (2019). National analysis of peer support providers: Practice settings, requirements, roles, and reimbursement. University of Michigan School of Public Health.
520 Substance Abuse and Mental Health Services Administration. (2022, March 24). Certified community behavioral health clinics (CCBHCs). Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/certified-community-behavioral-health-clinics.
521 Matti, E., Baum, N., & Udow-Phillips, M. (2021). Certified community behavioral health clinics (CCBHCs): An overview. Center for Health and Research Transformation.
522 Becker, C. (2022, July 7). The value of certified community behavioral health clinics. State Legislatures News. https://www.ncsl.org/research/health/the-value-of-certified-community-behavioral-health-clinics-magazine2022.aspx.
523 Centers for Medicare & Medicaid Services, Health Home Information Resource Center. (2022, March). Conditions targeted by Medicaid health homes.
524 Centers for Medicare & Medicaid Services, Health Home Information Resource Center. (2022, March). State-by-state health home state plan amendment matrix.
525 Centers for Medicare & Medicaid Services. (2020, December). Best practices for designing and implementing substance use disorder (SUD)-focused health homes. https://www.medicaid.gov/state-resource-center/downloads/best-practices-health-homes-support-act-section-1006a.pdf.
526 U.S. Government Accountability Office. (2021). Medicaid behavioral health: CMS guidance needed to better align demonstration payment rates with costs and prevent duplication (GAO-21-104466).
527 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems & authorities to promote peer specialist/peer recovery coaching services: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
528 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
529 Mette, E., Townley, C., & Purington, K. (2019). 50-state scan: How Medicaid agencies leverage their non-licensed substance use disorder workforce. National Academy for State Health Policy. https://www.nashp.org/wp-content/uploads/2019/11/SUD-Scan-findgs-final-11.21.19.pdf.
530 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
531 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. M. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6), S258–S266.29779550
532 Riessman, F. (1965). The “Helper” therapy principle. Social Work, 10(2), 27–32.
533 Riessman, F. (1990). Restructuring help: A human services paradigm for the 1990s. American Journal of Community Psychology, 18(2), 221–230.
534 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems and authorities to promote peer specialist/peer recovery coaching services. Bringing Recovery Supports to Scale, Technical Assistance Center Strategy. Expert Panel Meeting Report, March 21-22, 2012. Substance Abuse and Mental Health Services Administration.
535 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
536 Daniels, A. S., Tunner, T. P., Powell, I., Fricks, L., & Ashenden, P. (2015). Pillars of Peer Support Services Summit Six: Peer specialist supervision. https://mopeerspecialist.com/wp-content/uploads/2018/03/POPS2014.pdf.
537 Foglesong, D., Spagnolo, A. B., Cronise, R., Forbes, J., Swarbrick, P., Edwards, J. P., & Pratt, C. (2021, June). Perceptions of supervisors of peer support workers (PSW) in behavioral health: Results from a national survey. Community Mental Health Journal, 1-7. Advance online publication. https://doi.org/10.1007/s10597-021-00837-2.
538 Daniels, A. S., Tunner, T. P., Powell, I., Fricks, L., & Ashenden, P. (2015). Pillars of Peer Support Services Summit Six: Peer specialist supervision. https://mopeerspecialist.com/wp-content/uploads/2018/03/POPS2014.pdf.
539 Tucker, S. J., Tiegreen, W., Toole, J., Banathy, J., Mulloy, D., & Swarbrick, M. (2013). Supervisor guide: Peer support whole health and wellness coach. Georgia Mental Health Consumer Network.
540 Phillips, K., Harrison, J., & Jabalee, C. (2019). Supervising peer workers: A toolkit for implementing and supporting successful peer staff roles in mainstream mental health and addiction organizations. Canadian Mental Health Association, Centre for Excellence in Peer Support.
541 Utah State University. (2020). Utah supervisor guide for peer support. Certified Peer Support Specialist Training Program. https://dsamh.utah.gov/wp-content/uploads/2020/09/Utah-Peer-Support-Supervisor-Guide-3-9-2020.pdf.
542 Kuhn, W., Bellinger, J., Stevens-Manser, S., & Kaufman, L. (2015). Integration of peer specialists working in mental health service settings. Community Mental Health Journal, 51, 453–458.25672842
543 Forbes, J., Pratt, C., & Cronise, R. (2022). Experiences of peer support specialists supervised by nonpeer supervisors. Psychiatric Rehabilitation Journal, 45(1), 54–60.33793288
544 Martin, E., Jordan, A., Razavi, M., Burnham, V., IV, Linfoot, A., Knudson, M., … Dumas, L. (2017). Substance use disorder peer supervision competencies. The Regional Facilitation Center. https://oasas.ny.gov/system/files/documents/2019/12/peer-supervision-competencies-2017.pdf.
545 Jenkins, S., Chenneville, T., & Salnaitis, C. (2018). Are peer specialists happy on the job? Psychiatric Rehabilitation Journal, 41(1), 72–75.28447820
546 Mette, E., Townley, C., & Purington, K. (2019). 50-state scan: How Medicaid agencies leverage their non-licensed substance use disorder workforce. National Academy for State Health Policy. https://www.nashp.org/wp-content/uploads/2019/11/SUD-Scan-findgs-final-11.21.19.pdf.
547 Davis, J. K. (2015). Supervision of peer specialists in community mental health centers: Practices that predict role clarity. Social Work in Mental Health, 13(2), 145–158.
548 Tracy, K., Burton, M., Miescher, A., Galanter, M., Babuscio, T., Frankforter, T., … Rounsaville, B. (2011). Mentorship for Alcohol Problems (MAP): A peer to peer modular intervention for outpatients. Alcohol and Alcoholism, 47(1), 42–47.22045903
549 Weikel, K., Tomer, A., Davis, L., & Sieke, R. (2017). Recovery and self-efficacy of a newly trained certified peer specialist following supplemental weekly group supervision: A case-based time-series analysis. American Journal of Psychiatric Rehabilitation, 20(1), 1–15.
550 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
551 Loveland, D., & Boyle, M. (2005). Manual for recovery coaching and personal recovery plan development. Behavioral Health Recovery Management. https://facesandvoicesofrecovery.org/resource/manual-for-recovery-coaching-and-personal-recovery-plan-development/.
552 Davis, J. K. (2015). Supervision of peer specialists in community mental health centers: Practices that predict role clarity. Social Work in Mental Health, 13(2), 145–158.
553 Resources for Integrated Care. (2019). Implementing effective supervision of peer support staff: Spotlight on the Council of Southeast Pennsylvania, Inc. Retrieved July 22, 2022, from https://www.resourcesforintegratedcare.com/wp-content/uploads/2019/04/BH_Implementing_Effective_Supervision_of_Peer_Support_Staff_Spotlight_on_the_Council_of_Southeast_Pennsylvania.pdf.
554 Martin, E., Jordan, A., Razavi, M., Burnham, V., IV, Linfoot, A., Knudson, M., … Dumas, L. (2017). Substance use disorder peer supervision competencies. The Regional Facilitation Center. https://oasas.ny.gov/system/files/documents/2019/12/peer-supervision-competencies-2017.pdf.
555 Indiana Family & Social Services Administration. (n.d.). Supervision competencies for effective and ethical peer recovery coach supervision.
556 White, W. (2017, May). New resource on supervision of peer recovery support services [Blog Post]. https://www.chestnut.org/Blog/Posts/205/William-White/2017/5/New-Resource-on-Supervision-of-Peer-Recovery-Support-Services/blog-post/blog-and-news-postings-details.
557 Martin, E., Jordan, A., Razavi, M., Burnham, V., IV, Linfoot, A., Knudson, M., … Dumas, L. (2017). Substance use disorder peer supervision competencies. The Regional Facilitation Center. https://oasas.ny.gov/system/files/documents/2019/12/peer-supervision-competencies-2017.pdf.
558 Jenkins, S., Chenneville, T., & Salnaitis, C. (2018). Are peer specialists happy on the job? Psychiatric Rehabilitation Journal, 41(1), 72–75.28447820
559 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
560 Daniels, A. S., Tunner, T. P., Powell, I., Fricks, L., & Ashenden, P. (2015). Pillars of Peer Support Services Summit Six: Peer specialist supervision. https://mopeerspecialist.com/wp-content/uploads/2018/03/POPS2014.pdf.
561 Daniels, A. S., Tunner, T. P., Powell, I., Fricks, L., & Ashenden, P. (2015). Pillars of Peer Support Services Summit Six: Peer specialist supervision. https://mopeerspecialist.com/wp-content/uploads/2018/03/POPS2014.pdf.
562 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
563 Clarke, P. B., & Giordano, A. L. (2013). The motivational supervisor: Motivational interviewing as a clinical supervision approach. Clinical Supervisor, 32(2), 244–259.
564 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
565 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
566 Beckman, M., Bohman, B., Forsberg, L., Rasmussen, F., & Ghaderi, A. (2017). Supervision in motivational interviewing: An exploratory study. Behavioural and Cognitive Psychotherapy, 45(4), 351–365.28318480
567 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
568 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
569 Forbes, J., Swarbrick, P., Edwards, J. P., & Pratt, C. (2021). Perceptions of supervisors of peer support workers (PSW) in behavioral health: Results from a national survey. Community Mental Health Journal, 1–7.
570 Vandewalle, J., Debyser, B., Beeckman, D., Vandecasteele, T., Van Hecke, A., & Verhaeghe, S. (2016). Peer workers’ perceptions and experiences of barriers to implementation of peer worker roles in mental health services: A literature review. International Journal of Nursing Studies, 60, 234–250.27297384
571 Mancini, M. A. (2018). An exploration of factors that affect the implementation of peer support services in community mental health settings. Community Mental Health Journal, 54(2), 127–137.28466237
572 Cabral, L., Strother, H., Muhr, K., Sefton, L., & Savageau, J. (2014). Clarifying the role of the mental health peer specialist in Massachusetts, USA: Insights from peer specialists, supervisors, and clients. Health and Social Care in the Community, 22(1), 104–112.24313729
573 Walker, G., & Bryant, W. (2013). Peer support in adult mental health services: A metasynthesis of qualitative findings. Psychiatric Rehabilitation Journal, 36(1), 28–34.23477647
574 Davis, J. K. (2015). Supervision of peer specialists in community mental health centers: Practices that predict role clarity. Social Work in Mental Health, 13(2), 145–158.
575 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
576 Cabral, L., Strother, H., Muhr, K., Sefton, L., & Savageau, J. (2014). Clarifying the role of the mental health peer specialist in Massachusetts, USA: Insights from peer specialists, supervisors, and clients. Health and Social Care in the Community, 22(1), 104–112.24313729
577 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches (p. 321). Substance Abuse, 39(3), 307–314.28991516
578 California Association of Social Rehabilitation Agencies. (2014). Meaningful roles for peer providers in integrated healthcare: A guide. https://www.mhanational.org/sites/default/files/Meaningful%20Roles%20for%20Peer%20_Providers.pdf.
579 Tracy, K., Wachtel, L., & Goldmann, E. (2018). Beyond substance use reduction: The positive impact of Mentorship for Addiction Problems (MAP). Journal of Alcohol, Drug Dependence and Substance Abuse, 4, 009.
580 Tracy, K., Wachtel, L., Goldmann, E., Nissenfeld, J., Burton, M., Galanter, M., & Ball, S. A. (2020). Mentorship for Addiction Problems (MAP): A new behavioral intervention to assist in the treatment of substance use disorders. Journal of Studies on Alcohol and Drugs, 81(5), 664–672.33028480
581 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
582 White, W. (2006). Sponsor, recovery coach, addiction counselor: The importance of role clarity and role integrity. Philadelphia Department of Behavioral Health and Mental Retardation Services.
583 California Association of Social Rehabilitation Agencies. (2014). Meaningful roles for peer providers in integrated healthcare: A guide. https://www.mhanational.org/sites/default/files/Meaningful%20Roles%20for%20Peer%20Providers.pdf.
584 Sun, L., Gao, Y., Yang, J., Zang, X. Y., & Wang, Y. G. (2016). The impact of professional identity on role stress in nursing students: A cross-sectional study (p. 2). International Journal of Nursing Studies, 63, 1–8.27565423
585 Phillips, K. (2018). Supervising peer staff roles: Literature review and focus group results. Canadian Mental Health Association, Centre for Excellence in Peer Support.
586 Phillips, K., Harrison, J., & Jabalee, C. (2019). Supervising peer workers: A toolkit for implementing and supporting successful peer staff roles in mainstream mental health and addiction organizations. Canadian Mental Health Association, Centre for Excellence in Peer Support.
587 Martin, E., Jordan, A., Razavi, M., Burnham, V., IV, Linfoot, A., Knudson, M., … Dumas, L. (2017). Substance use disorder peer supervision competencies. The Regional Facilitation Center. https://oasas.ny.gov/system/files/documents/2019/12/peer-supervision-competencies-2017.pdf.
588 White, W. L., & Evans, J. (2013). The recovery agenda: The shared role of peers and professionals. Public Health Reviews, 35(2).
589 Kuhn, W., Bellinger, J., Stevens-Manser, S., & Kaufman, L. (2015). Integration of peer specialists working in mental health service settings. Community Mental Health Journal, 51, 453–458.25672842
590 Myrick, K., & del Vecchio, P. (2016). Peer support in the behavioral healthcare workforce: State of the field. Psychiatric Rehabilitation Journal, 39(3), 197–203.27183186
591 Cronise, R., Teixeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
592 Jack, H. E., Oller, D., Kelly, J., Magidson, J. F., & Wakeman, S. E. (2017). Addressing substance use disorder in primary care: The role, integration, and impact of recovery coaches. Substance Abuse, 39(3), 307–314.28991516
593 Cabral, L., Strother, H., Muhr, K., Sefton, L., & Savageau, J. (2014). Clarifying the role of the mental health peer specialist in Massachusetts, USA: Insights from peer specialists, supervisors, and clients. Health and Social Care in the Community, 22(1), 104–112.24313729
594 Firmin, R. L., Mao, S., Bellamy, C. D., & Davidson, L. (2019). Peer support specialists’ experiences of microaggressions. Psychological Services, 16(3), 456–462.30382746
595 Cronise, R., Teixeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
596 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
597 Alberta, A. J., Ploski, R. R., & Carlson, S. L. (2012). Addressing challenges to providing peer-based recovery support. Journal of Behavioral Health Services and Research, 39(4), 481–491.22828975
598 Vandewalle, J., Debyser, B., Beeckman, D., Vandecasteele, T., Van Hecke, A., & Verhaeghe, S. (2016). Peer workers’ perceptions and experiences of barriers to implementation of peer worker roles in mental health services: A literature review. International Journal of Nursing Studies, 60, 234–250.27297384
599 Cabral, L., Strother, H., Muhr, K., Sefton, L., & Savageau, J. (2014). Clarifying the role of the mental health peer specialist in Massachusetts, USA: Insights from peer specialists, supervisors, and clients. Health and Social Care in the Community, 22(1), 104–112.24313729
600 Alberta, A. J., Ploski, R. R., & Carlson, S. L. (2012). Addressing challenges to providing peer-based recovery support. Journal of Behavioral Health Services and Research, 39(4), 481–491.22828975
601 Lapidos, A., Jester, J., Ortquist, M., Werner, P., Ruffolo, M. C., & Smith, M. (2018). Survey of peer support specialists: Professional activities, self-rated skills, job satisfaction, and financial well-being. Psychiatric Services (Washington, D.C.), 69(12), 1264–1267.30301447
602 Jones, N., Kosyluk, K., Gius, B., Wolf, J., & Rosen, C. (2020). Investigating the mobility of the peer specialist workforce in the United States: Findings from a national survey. Psychiatric Rehabilitation Journal, 43(3), 179–188.31789547
603 Walker, G., & Bryant, W. (2013). Peer support in adult mental health services: A metasynthesis of qualitative findings. Psychiatric Rehabilitation Journal, 36(1), 28–34.23477647
604 Du Plessis, C., Whitaker, L., & Hurley, J. (2020). Peer support workers in substance abuse treatment services: A systematic review of the literature. Journal of Substance Use, 25(3), 225–230.
605 Tate, M. C., Roy, A., Pinchinat, M., Lund, E., Fox, J. B., Cottrill, S., … Stein, L. (2021). Impact of being a peer recovery specialist on work and personal life: Implications for training and supervision. Community Mental Health Journal. Advance online publication. doi:10.1007/s10597-021-00811-y.
606 Englander, H., Gregg, J., Gullickson, J., Cochran-Dumas, O., Colasurdo, C., Alla, J., Nicolaidis, C. (2020). Recommendations for integrating peer mentors in hospital-based addiction care. Substance Abuse, 41(4), 419–424.31490736
607 Cronise, R., Teixeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
608 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54, S267–S274.29779551
609 Cronise, R., Teizeira, C., Rogers, E. S., & Harrington, S. (2016). The peer support workforce: Results of a national survey. Psychiatric Rehabilitation Journal, 39(3), 211–221.27618458
610 Jenkins, S., Chenneville, T., & Salnaitis, C. (2018). Are peer specialists happy on the job? Psychiatric Rehabilitation Journal, 41(1), 72–75.28447820
611 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
612 Byrne, L., Roennfeldt, H., Wolf, J., Linfoot, A., Foglesong, D., Davidson, L., & Bellamy, C. (2021). Effective peer employment within multidisciplinary organizations: Model for best practice. Administration and Policy in Mental Health. Advance online publication. doi:10.1007/s10488-021-01162-2.
613 Lapidos, A., Jester, J., Ortquist, M., Werner, P., Ruffolo, M. C., & Smith, M. (2018). Survey of peer support specialists: Professional activities, self-rated skills, job satisfaction, and financial well-being. Psychiatric Services (Washington, D.C.), 69(12), 1264–1267.30301447
614 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267–S274.29779551
615 Ohio Laws and Administrative Rules. (April 8, 2022). Rule 5122-29-15.1. Adult, family, and youth certified peer supporter. Legislative Service Commission. https://codes.ohio.gov/ohio-administrative-code/rule-5122-29-15.1.
616 Substance Abuse and Mental Health Services Administration. (2021). National Survey of Substance Abuse Treatment Services (N-SSATS): 2020; Data on substance abuse treatment facilities. Substance Abuse and Mental Health Services Administration.
617 University of Michigan Behavioral Health Workforce Research Center. (2019). National analysis of peer support providers: Practice setting, requirements, roles, and reimbursement. University of Michigan School of Public Health.
618 Myrick, K., & del Vecchio, P. (2016). Peer support in the behavioral healthcare workforce: State of the field. Psychiatric Rehabilitation Journal, 39(3), 197–203.27183186
619 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
620 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
621 Substance Abuse and Mental Health Services Administration. (2017). Peer support. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peer-support-2017.pdf.
622 White, W. (2011, January/February). An interview with William White on recovery coaching. Inside Addiction: The Magazine, pp. 25–26.
623 Schuyler, A., Brown, J., & White, W. (2016). The recovery coach: Role clarity matrix. https://www.chestnut.org/resources/60ae2e1e-c67b-4fca-9610-21daf5b2ef5b/2016-Recovery-Coach-Role-Role-Clarity-Matrix.pdf.
624 White, W. (2006). Sponsor, recovery coach, addiction counselor: The importance of role clarity and role integrity. Philadelphia Department of Behavioral Health and Mental Retardation Services.
625 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
626 Stanojlovió, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
627 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
628 Peer Recovery Center of Excellence. (2023). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
629 White, W. L., & Evans, A. C. (2013). The recovery agenda: The shared role of peers and professionals. Public Health Reviews, 35, 4.
630 White, W. (2006). Sponsor, recovery coach, addiction counselor: The importance of role clarity and role integrity. Philadelphia Department of Behavioral Health and Mental Retardation Services.
631 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
632 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
633 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
634 Scannell, C. (2021). Voices of hope: Substance use peer support in a system of care. Substance Abuse: Research and Treatment, 15, 11782218211050360.34675524
635 University of Michigan Behavioral Health Workforce Research Center. (2019). National analysis of peer support providers: Practice settings, requirements, roles, and reimbursement. University of Michigan School of Public Health.
636 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
637 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
638 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
639 Magidson, J. M., Regan, S. R., Jack, H., & Wakeman, S. (2018). Reduced hospitalizations and increased abstinence six months after recovery coach contact. ASAM conference presentation. www.eventscribe.com/2018/ASAM/ajaxcalls/PosterInfo.asp?efp=Tk5JV0RMTEEzNDgz&PosterID=125204&rnd=0.9485711.
640 Winhusen, T., Wilder, C., Kropp, F., Theobald, J., Lyons, M. S., & Lewis, D. (2020). A brief telephone-delivered peer intervention to encourage enrollment in medication for opioid use disorder in individuals surviving an opioid overdose: Results from a randomized pilot trial. Drug and Alcohol Dependence, 216, 108270.32911132
641 O'Connell, M. J., Flanagan, E. H., Delphin-Rittmon, M. E., & Davidson, L. (2017). Enhancing outcomes for persons with co-occurring disorders through skills training and peer recovery support. Journal of Mental Health, 10, 1–6.
642 Kelley, A., Bingham, D., Brown, E., & Pepion, L. (2017). Assessing the impact of American Indian peer recovery support on substance use and health. Journal of Groups in Addiction & Recovery, 12, 296–308.
643 Hansen, M. A., Modak, S., McMaster, S., Zoorob, R., & Gonzalez, S. (2020). Implementing peer recovery coaching and improving outcomes for substance use disorders in underserved communities. Journal of Ethnicity in Substance Abuse, 1–14.
644 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
645 Ashford, R. D., Brown, A., Canode, B., Sledd, A., Potter, J. S., & Bergman, B. G. (2021). Peer-based recovery support services delivered at recovery community organizations: Predictors of improvements in individual recovery capital. Addictive Behaviors, 119, 106945.33872848
646 Ray, B., Watson, D. P., Xu, H., Salyers, M. P., Victor, G., Sightes, E., … Bo, N. (2021). Peer recovery services for persons returning from prison: Pilot randomized clinical trial investigation of SUPPORT. Journal of Substance Abuse Treatment, 126, 108339.34116824
647 Possemato, K., Johnson, E. M., Emery, J. B., Wade, M., Acosta, M. C., Marsch, L. A., … Maisto, S. A. (2019). A pilot study comparing peer supported web-based CBT to self-managed web CBT for primary care veterans with PTSD and hazardous alcohol use. Psychiatric Rehabilitation Journal, 42(3), 305.30489140
648 Tracy, K., Wachtel, L., & Goldmann, E. (2018). Beyond substance use reduction: The positive impact of Mentorship for Addiction Problems (MAP). Journal of Alcohol, Drug Dependence and Substance Abuse, 4, 009.
649 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
650 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
651 Randolph, D. A. (2018, January 19). Igniting motivation: Using peers to spark your tobacco cessation services [Blog post]. National Behavioral Health Network for Tobacco & Cancer Control. https://www.bhthechange.org/resources/igniting-motivation-using-peers-spark-tobacco-cessation-services/.
652 Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6), S267–S274.29779551
653 Gaiser, M. G., Buche, J. L., Wayment, C. C., Schoebel, V., Smith, J. E., Chapman, S. A., & Beck, A. J. (2021). A systematic review of the roles and contributions of peer providers in the behavioral health workforce. American Journal of Preventive Medicine, 61(4), e203–e210.34175172
654 Pantridge, C. E., Charles, V. A., DeHart, D. D., Iachini, A. L., Seay, K. D., Clone, S., & Browne, T. (2016). A qualitative study of the role of peer support specialists in substance use disorder treatment: Examining the types of support provided. Alcoholism Treatment Quarterly, 34(3), 337–353.
655 White, W. L., & PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, E. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
656 Southern Plains Tribal Health Board. (n.d.). Peer support toolkit. https://sites.utexas.edu/ignitingthesparkofhope/files/2021/06/Peer-Support-Toolkit_Booklet.pdf.
657 White, W. L., & PRO-ACT Ethics Workgroup, with legal discussion by Popovits, R., & Donohue, E. (2007). Ethical guidelines for the delivery of peer-based recovery support services. Philadelphia Department of Behavioral Health and Mental Retardation Services.
658 Substance Abuse and Mental Health Services Administration. (2015). Core competencies for peer workers in behavioral health services. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/core-competencies_508_12_13_18.pdf.
659 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
660 University of Massachusetts Medical School. (2018). Recovery coaches in opioid use disorder care. https://rizema.org/wp-content/uploads/2019/01/UMass-Recovery-Coach-Report.pdf.
661 Tate, M. C., Roy, A., Pinchinat, M., Lund, E., Fox, J. B., Cottrill, S., … Stein, L. (2022). Impact of being a peer recovery specialist on work and personal life: Implications for training and supervision. Community Mental Health Journal, 58(1), 193–204.33677802
662 Scannell, C. (2021). By helping others we help ourselves: Insights from peer support workers in substance use recovery. Advances in Mental Health, 1–10.
663 Scannell, C. (2021). By helping others we help ourselves: Insights from peer support workers in substance use recovery. Advances in Mental Health, 1–10.
664 Scannell C. (2021). Voices of hope: Substance use peer support in a system of care. Substance Abuse: Research and Treatment, 15, 11782218211050360.34675524
665 Scannell, C. (2021). By helping others we help ourselves: Insights from peer support workers in substance use recovery. Advances in Mental Health, 1–10.
666 Scannell, C. (2021). Voices of hope: Substance use peer support in a system of care. Substance Abuse: Research and Treatment, 15, 11782218211050360.34675524
667 Philadelphia Department of Behavioral Health and Intellectual disAbility Services and Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
668 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
669 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
670 Lodge, A. C., Earley, J., & Stevens Manser, S. (2021). Peers in Texas: Workforce outcomes. University of Texas at Austin, Texas Institute for Excellence in Mental Health, Steve Hicks School of Social Work.
671 Council of State Governments Justice Center and the Integrated Justice Information Systems Institute. (2021). Advancing the work of peer support specialists in behavioral health-criminal justice programming. https://csgjusticecenter.org/publications/advancing-the-work-of-peer-support-specialists-in-behavioral-health-criminal-justice-programming/.
672 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258–S266.29779550
673 Peer Recovery Center of Excellence. (2023). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
674 Peer Recovery Center of Excellence. (2023). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
675 University of Michigan Behavioral Health Workforce Research Center. (2018). Scopes of practice and reimbursement patterns of addiction counselors, community health workers, and peer recovery specialists in the behavioral health workforce. University of Michigan School of Public Health.
676 Missouri Reorganization Act of 1974, Title XL, Additional Executive Departments. (2013). Disqualification for employment because of conviction — appeal process — criminal record review, procedure — registry maintained, when — appeals procedure. § 630.170. Retrieved July 20, 2022, from https://revisor.mo.gov/main/OneSection.aspx?section=630.170.
677 Florida House of Representatives. (2022, February 1). House of Representatives staff analysis: CS/HB 795 Peer Specialists. https://www.flsenate.gov/Session/Bill/2022/795/Analyses/h0795c.HHS.PDF.
678 Nevada State Legislature. (2011 & rev. 2021). Nevada Revised Statute, Nevada Stat. § 449.174: Additional grounds for denial, suspension or revocation of license to operate certain facility, hospital, agency, program or home. Retrieved July 20, 2022, from https://www.leg.state.nv.us/nrs/nrs-449.html#NRS449Sec174.
679 Substance Abuse and Mental Health Services Administration. (2020). State-by-state directory of peer recovery coaching training and certification programs. https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Directory-of-Peer-Recovery-Coaching-Training-and-Certification-Programs_8_26_2020.pdf.
680 The Ohio Legislature. (2022). Ohio Administrative Code: Requirements and procedures for behavioral health services, § 5122-29-15.1: Adult, family, and youth certified peer supporter. https://codes.ohio.gov/ohio-administrative-code/rule-5122-29-15.1.
681 Peer Recovery Center of Excellence. (2023). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
682 Huebner, R. A., Hall, M. T., Smead, E., Willauer, T., & Posze, L. (2018). Peer mentoring services, opportunities, and outcomes for child welfare families with substance use disorders. Children and Youth Services Review, 84, 239–246.
683 Substance Abuse and Mental Health Services Administration. (n.d.). Family, parent and caregiver peer support in behavioral health. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf.
684 McSilver Institute for Poverty Policy and Research. (n.d.). Family peer support and advocacy. https://fdocuments.us/reader/full/part-1-introduction-family-peer-support-and-advocacy-peer-what-is-family-peer.
685 Families Together in New York State. (2017). What is family peer support? https://www.ftnys.org/wp-content/uploads/2021/01/FTNYS_101433_FAMILY-PEER-SUPPORT-BROCHURE_01-1.pdf.
686 Substance Abuse and Mental Health Services Administration. (n.d.). Family, parent and caregiver peer support in behavioral health. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf.
687 National Federation of Families. (2021). Certification competencies. https://www.ffcmh.org/certification-competencies.
688 Horigian, V. E., Anderson, A. R., & Szapocznik, J. (2016). Taking brief strategic family therapy from bench to trench: Evidence generation across translational phases. Family Process, 55(3), 529–542.27412949
689 O'Farrell, T. J., Schumm, J. A., Murphy, M. M., & Muchowski, P. M. (2017). A randomized clinical trial of behavioral couples therapy versus individually-based treatment for drug-abusing women. Journal of Consulting and Clinical Psychology, 85(4), 309–322.28333533
690 Substance Abuse and Mental Health Services Administration. (n.d.). Family, parent and caregiver peer support in behavioral health. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf.
691 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
692 Substance Abuse and Mental Health Services Administration. (n.d.). Family, parent and caregiver peer support in behavioral health. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf.
693 Substance Abuse and Mental Health Services Administration. (2020). State-by-state directory of parent peer support training and certification programs. https://c4innovates.com/brsstacs/BRSS-TACSState-by-State-Parent-Peer-Support-Training-Directory_2020.pdf.
694 Peer Recovery Center of Excellence. (2023). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
695 Substance Abuse and Mental Health Services Administration. (2020). State-by-state directory of parent peer support training and certification programs. https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Parent-Peer-Support-Training-Directory_2020.pdf.
696 Peer Recovery Center of Excellence. (2022). Comparative analysis of state requirements for peer support specialist training and certification in the United States.
697 Substance Abuse and Mental Health Services Administration. (2020). State-by-state directory of parent peer support training and certification programs. https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Parent-Peer-Support-Training-Directory_2020.pdf.
698 Philadelphia Department of Behavioral Health and Intellectual disAbility Services & Achara Consulting, Inc. (2017). Peer support toolkit. https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf.
699 University of Massachusetts Medical School. (2018). Recovery coaches in opioid use disorder care. https://rizema.org/wp-content/uploads/2019/01/UMass-Recovery-Coach-Report.pdf.
700 Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341.28787300
701 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
702 Center for Behavioral Health Statistics and Quality. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. Substance Abuse and Mental Health Services Administration.
703 Slaunwhite, A. K., Ronis, S. T., Sun, Y., & Peters, P. A. (2017). The emotional health and well-being of Canadians who care for persons with mental health or addictions problems. Health and Social Care in the Community, 25(3), 840–847.27412924
704 Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341.28787300
705 Whalen, J. (2018, March 8). After addiction comes families’ second blow: The crushing cost of rehab. Wall Street Journal.
706 Daley, D. C., Smith, E., Balogh, D., & Toscaloni, J. (2018). Forgotten but not gone: The impact of the opioid epidemic and other substance use disorders on families and children. Commonwealth, 20(2-3).
707 Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341.28787300
708 Edwards, M., Best, D., Irving, J., & Andersson, C. (2018). Life in recovery: A families’ perspective. Alcoholism Treatment Quarterly, 36(4), 437–458.
709 Daley, D. C., Smith, E., Balogh, D., & Toscaloni, J. (2018). Forgotten but not gone: The impact of the opioid epidemic and other substance use disorders on families and children. Commonwealth, 20(2-3).
710 Whalen, J. (2018, March 8). After addiction comes families’ second blow: The crushing cost of rehab. Wall Street Journal.
711 Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341.28787300
712 Edwards, M., Best, D., Irving, J., & Andersson, C. (2018). Life in recovery: A families’ perspective. Alcoholism Treatment Quarterly, 36(4), 437–458.
713 Daley, D. C., Smith, E., Balogh, D., & Toscaloni, J. (2018). Forgotten but not gone: The impact of the opioid epidemic and other substance use disorders on families and children. Commonwealth, 20(2-3).
714 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
715 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
716 Whalen, J. (2018, March 8). After addiction comes families’ second blow: The crushing cost of rehab. Wall Street Journal. https://www.wsj.com/articles/after-addiction-comes-families-second-blow-crushing-cost-of-rehab-1520528850.
717 Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341.28787300
718 Sarno, M., De Candia, V., Rancati, F., Madeddu, F., Calati, R., & Di Pierro, R. (2021). Mental and physical health in family members of substance users: A scoping review. Drug and Alcohol Dependence, 219, 108439.33333362
719 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
720 Stringer, K. L., & Baker, E. H. (2018). Stigma as a barrier to substance abuse treatment among those with unmet need: An analysis of parenthood and marital status. Journal of Family Issues, 39(1), 3–27.29307947
721 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
722 Matthew, K. J., Regmi, B., & Lama, L. D. (2018). Role of family in addictive disorders. International Journal of Psychosocial Rehabilitation, 22(1) 65–75.
723 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
724 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
725 Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341.28787300
726 O'Farrell, T. J., Schumm, J. A., Murphy, M. M., & Muchowski, P. M. (2017). A randomized clinical trial of behavioral couples therapy versus individually-based treatment for drug-abusing women. Journal of Consulting and Clinical Psychology, 85(4), 309–322.28333533
727 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
728 Horigian, V. E., Anderson, A. R., & Szapocznik, J. (2016). Taking brief strategic family therapy from bench to trench: Evidence generation across translational phases. Family Process, 55(3), 529–542.27412949
729 Horigian, V. E., Anderson, A. R., & Szapocznik, J. (2016). Taking brief strategic family therapy from bench to trench: Evidence generation across translational phases. Family Process, 55(3), 529–542.27412949
730 Horigian, V. E., Anderson, A. R., & Szapocznik, J. (2016). Taking brief strategic family therapy from bench to trench: Evidence generation across translational phases. Family Process, 55(3), 529–542.27412949
731 Horigian, V. E., Anderson, A. R., & Szapocznik, J. (2016). Taking brief strategic family therapy from bench to trench: Evidence generation across translational phases. Family Process, 55(3), 529–542.27412949
732 Allen, M. L., Garcia-Huidobro, D., Porta, C., Curran, D., Patel, R., Miller, J., & Borowsky, I. (2016). Effective parenting interventions to reduce youth substance use: A systematic review. Pediatrics, 138(2), e20154425.27443357
733 Liddle, H. A., Dakof, G. A., Rowe, C. L., Henderson, C., Greenbaum, P., Wang, W., & Alberga, L. (2018). Multidimensional family therapy as a community-based alternative to residential treatment for adolescents with substance use and co-occurring mental health disorders. Journal of Substance Abuse Treatment, 90, 47–56.29866383
734 Kirby, K. C., Benishek, L. A., Kerwin, M. E., Dugosh, K. L., Carpenedo, C. M., Bresani, E., … Meyers, R. J. (2017). Analyzing components of community reinforcement and family training (CRAFT): Is treatment entry training sufficient? Psychology of Addictive Behaviors, 31(7), 818.28836796
735 Bischof, G., Iwen, J., Freyer-Adam, J., & Rumpf, H. J. (2016). Efficacy of the community reinforcement and family training for concerned significant others of treatment-refusing individuals with alcohol dependence: A randomized controlled trial. Drug and Alcohol Dependence, 163, 179–185.27141840
736 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
737 Ast, L. (2018). Developing alternative stories with partners of illicit substance users. Journal of Family Psychotherapy, 29(3), 201–222.
738 Daley, D. C., Smith, E., Balogh, D., & Toscaloni, J. (2018). Forgotten but not gone: The impact of the opioid epidemic and other substance use disorders on families and children. Commonwealth, 20(2-3).
739 Daley, D. C., Smith, E., Balogh, D., & Toscaloni, J. (2018). Forgotten but not gone: The impact of the opioid epidemic and other substance use disorders on families and children. Commonwealth, 20(2-3).
740 Daley, D. C., Smith, E., Balogh, D., & Toscaloni, J. (2018). Forgotten but not gone: The impact of the opioid epidemic and other substance use disorders on families and children. Commonwealth, 20(2-3).
741 National Center on Substance Abuse and Child Welfare. (2018). The use of peers and recovery specialists in child welfare settings. https://ncsacw.acf.hhs.gov/files/peer19_brief.pdf.
742 Substance Abuse and Mental Health Services Administration. (2017). Family, parent and caregiver peer support in behavioral health. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf.
743 Huebner, R. A., Hall, M. T., Smead, E., Willauer, T., & Posze, L. (2018). Peer mentoring services, opportunities, and outcomes for child welfare families with substance use disorders. Children and Youth Services Review, 84, 239–246.
744 Kelly, J. F., Fallah-Sohy, N., Cristello, J., & Bergman, B. (2017). Coping with the enduring unpredictability of opioid addiction: An investigation of a novel family-focused peer-support organization. Journal of Substance Abuse Treatment, 77, 193–200.28222927
745 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
746 Yap, M. B., Cheong, T. W., Zaravinos-Tsakos, F., Lubman, D. I., & Jorm, A. F. (2017). Modifiable parenting factors associated with adolescent alcohol misuse: A systematic review and meta-analysis of longitudinal studies. Addiction, 112(7), 1142–1162.28178373
747 Stringer, K. L., & Baker, E. H. (2018). Stigma as a barrier to substance abuse treatment among those with unmet need: An analysis of parenthood and marital status. Journal of Family Issues, 39(1), 3–27.29307947
748 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
749 Matthew, K. J., Regmi, B., & Lama, L. D. (2018). Role of family in addictive disorders. International Journal of Psychosocial Rehabilitation, 22(1) 65–75.
750 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
751 Matthew, K. J., Regmi, B., & Lama, L. D. (2018). Role of family in addictive disorders. International Journal of Psychosocial Rehabilitation, 22(1) 65–75.
752 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
753 Matthew, K. J., Regmi, B., & Lama, L. D. (2018). Role of family in addictive disorders. International Journal of Psychosocial Rehabilitation, 22(1) 65–75.
754 Yap, M. B., Cheong, T. W., Zaravinos-Tsakos, F., Lubman, D. I., & Jorm, A. F. (2017). Modifiable parenting factors associated with adolescent alcohol misuse: A systematic review and meta-analysis of longitudinal studies. Addiction, 112(7), 1142–1162.28178373
755 Reiter, M. D. (2019). Substance abuse and the family: Assessment and treatment. Routledge.
756 Brown, S., Tracy, E. M., Jun, M., Park, H., & Min, M. O. (2015). Personal network recovery enablers and relapse risks for women with substance dependence. Qualitative Health Research, 25(3), 371–385.25231945
757 Brown, S., Tracy, E. M., Jun, M., Park, H., & Min, M. O. (2015). Personal network recovery enablers and relapse risks for women with substance dependence. Qualitative Health Research, 25(3), 371–385.25231945
758 Brown, S., Tracy, E. M., Jun, M., Park, H., & Min, M. O. (2015). Personal network recovery enablers and relapse risks for women with substance dependence. Qualitative Health Research, 25(3), 371–385.25231945
759 Brown, S., Tracy, E. M., Jun, M., Park, H., & Min, M. O. (2015). Personal network recovery enablers and relapse risks for women with substance dependence. Qualitative Health Research, 25(3), 371–385.25231945
760 Brown, S., Victor, B. G., Dayton, C. J., & Tracy, E. M. (2019). Maternal and paternal warmth impact recovery support and social network composition for substance dependent African American and Non-African American women. Addiction Research and Theory, 27(4), 294–304.31474814
761 Bradshaw, S. D., Shumway, S. T., Wang, E. W., Harris, K. S., Smith, D. B., & Austin-Robillard, H. (2016). Family functioning and readiness in family recovery from addiction. Journal of Groups in Addiction and Recovery, 11(1), 21–41.
762 Bradshaw, S., Shumway, S. T., Wang, E. W., Harris, K. S., Smith, D. B., & Austin-Robillard, H. (2015). Hope, readiness, and coping in family recovery from addiction. Journal of Groups in Addiction and Recovery, 10(4), 313–336.
763 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
764 White, W. L., & McLellan, A. T. (2008). Addiction as a chronic disease: Key messages for clients, families and referral sources. Counselor, 9(3), 24–33.
765 Kelly, J. F., Saitz, R., & Wakeman, S. (2016). Language, substance use disorders, and policy: The need to reach consensus on an “addiction-ary.” Alcoholism Treatment Quarterly, 34(1), 116–123.
766 Edwards, M., Best, D., Irving, J., & Andersson, C. (2018). Life in recovery: A families’ perspective. Alcoholism Treatment Quarterly, 36(4), 437–458.
767 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
768 Groshkova, T., Best, D., & White, W. (2012). The assessment of recovery capital: Properties and psychometrics of a measure of addiction recovery strengths. Supplemental Material. Drug and Alcohol Review, 32(2), 187–194. doi:10.1111/j.1465-3362.2012.00489.22882622
769 White, W. (2018). Recovery capital scale. https://www.chestnut.org/resources/4c4bb112-3d59-4984-98cb-3b637378965a/Recovery-Capital-Scale.pdf.
770 New York State Office of Alcoholism and Substance Abuse Services. (2018). Peer integration and stages of change toolkit. https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf.
771 University of Massachusetts Medical School. (December 2018). Recovery coaches in opioid use disorder care. https://rizema.org/wp-content/uploads/2019/01/UMass-Recovery-Coach-Report.pdf.