# TIP Development Participants

Note: The information given for participants in the TIP's development indicates their affiliations at the time of their participation and may not reflect their current affiliations.

## Consensus Panel

Each Treatment Improvement Protocol's (TIP) consensus panel is a group of primarily nonfederal addiction-focused clinical, research, administrative, and recovery support experts with deep knowledge of the TIP's topic. With the Substance Abuse and Mental Health Services Administration's Knowledge Application Program team, members of the consensus panel develop each TIP via a consensus-driven, collaborative process that blends evidence-based, best, and promising practices with the panel members’ expertise and combined wealth of experience.

### Chair

Amy Mericle, Ph.D.
TIP Chair Scientist
Alcohol Research Group
Public Health Institute
Emeryville, CA

### Panelists

Rev. Jan Brown, M.S., PRSS
Member, Faces and Voices Board of Directors
Founding/Executive Director
SpiritWorks Foundation
Williamsburg, VA

Stephen Gumbley, M.A.
Principal, Stephen Gumbley Consulting and Training
Pawtucket, RI

Beverly Haberle
Executive Director
The Council of Southeast Pennsylvania, Inc.
Doylestown, PA

Jason Howell, M.B.A., B.S., PRS
Executive Director
RecoveryPeople Founding Member
National Alliance for Recovery Residences
Elgin, TX

Keith O. Murphy
Counselor, Carpenter's Workshop
Substance Abuse Specialist/Recovery Counselor
Rutgers University Counseling Department
New Brunswick, NJ

Joe Powell
President/Chief Executive Officer
Association of Persons Affected by Addiction
Dallas, TX

Phillip Valentine
Executive Director
Connecticut Community for Addiction Recovery
Hartford, CT

Sarah Zemore
Senior Scientist
Director of Training, and Center Associate Director
Alcohol Research Group
Public Health Institute
Emeryville, CA

## Stakeholder Meeting Participants

Stakeholders represent a cross-section of key audiences with a deep interest in a TIP's subject matter. They review and comment on the draft outline and supporting materials for the TIP to ensure that its focus is clear, its stated purpose meets an urgent need in the field, and it will not duplicate existing resources produced by the federal government or other entities.

Sharon Amatetti, M.P.H.
Quality Improvement and Workforce Development Branch Chief
Center for Substance Abuse Treatment (CSAT)
Substance Abuse and Mental Health Services Administration (SAMHSA)
Rockville, MD

Rev. Jan Brown, M.S., PRSS
Member, Faces and Voices Board of Directors
Founding/Executive Director, SpiritWorks Foundation
Williamsburg, VA

Candi Byrne
Knowledge Application Program (KAP) Project Coordinator, CSAT, SAMHSA
Rockville, MD

Matthew Clune
Public Health Advisor, CSAT, SAMHSA
Rockville, MD

Peter Gaumond, M.A.
Senior Policy Analyst/Recovery Branch Chief
Office of National Drug Control Policy
Washington, DC

Stephen Gumbley, M.A.
Principal, Stephen Gumbley Consulting and Training
Pawtucket, RI

Mary Jo Mather
Executive Director
International Certification and Reciprocity Consortium (IC&RC)
Harrisburg, PA

Amy Mericle, Ph.D.
TIP Chair Scientist
Alcohol Research Group
Public Health Institute
Emeryville, CA

Amy Smith, M.A.
Public Health Advisor, CSAT, SAMHSA
Rockville, MD

Audra Stock, M.A.C., LPC
Director
Division of Service Improvement, CSAT, SAMHSA
Rockville, MD

Phillip Valentine
Executive Director
Connecticut Community for Addiction Recovery
Hartford, CT

Suzanne Wise
KAP Contracting Officer's Representative (COR), CSAT, SAMHSA
Rockville, MD

## Field Reviewers

Field reviewers represent each TIP's intended audiences. They work in addiction, primary care, and adjacent fields. Their direct frontline experience related to the TIP's topic allows them to provide valuable input on a TIP's relevance, utility, accuracy, and accessibility. Additional advisors to this TIP include members of a resource panel.

Kristen Aja
Senior Project Coordinator
Faces and Voices of Recovery
Washington, DC

Rebecca Allen, M.A.
Director of Recovery Advocacy
Connecticut Community for Addiction Recovery
Hartford, CT

Randy Anderson, LADC, RCPF
Founder and Principal
Bold North Recovery and Consulting
Golden Valley, MN

Justin R. Beattey, CAPRC II, CADAC II, CHW/CRS-GA, ICPR, MATS
Vice President of Education and Credentialing
Director, Mental Health America of Indiana
Stanley W. DeKemper Training Institute
Director, Indiana Association of Peer Recovery Support Services
Executive Director, Indiana Credentialing Association on Alcohol & Drug Abuse
Indianapolis, IN

Kyle Brewer, PRPS
Peer Specialist Program Manager, NAADAC
the Association for Addiction Professionals
Little Rock, AR

Meghan Brunner, M.LIS.
Digital Librarian, Addictions
Drug & Alcohol Institute
University of Washington
Seattle, WA

Chris Budnick, M.S.W., LCSW, LCAS, CCS
Executive Director
Healing Transitions
Raleigh, NC

Neil Campbell, M.S.
Executive Director
Georgia Council on Substance Abuse
Atlanta, GA

Fatina Cannon, LPC, LAC
Chief Clinical Officer
NorthStar Transitions
Boulder, CO

Elizabeth Conte, Ph.D., M.A., LPC, LCADC, ACS
Workforce Development Manager
Office of Treatment and Recovery Support
Division of Mental Health and Addiction Services
Hamilton, NJ

Jocelyn Cooper, LPC, LCADC, CCS, CPS
Consultant, New Jersey Prevention Network
Cherry Hill, NJ

Nicole Criss, D.H.S., M.S., NCPRSS, CPSS
Executive Director
The Peer Connection (FAVOR Grand Strand)
Conway, SC

Johanna M. Dolan, RCP, RPS, RCPF
Founder and CEO
Dolan Research International
Frederick, MD

John Fabiseski, CRS
Engagement Specialist and Certified Recovery Specialist Trainer
Pyramid Healthcare
Factoryville, PA

Andrew J. Finch, Ph.D.
Associate Professor
Practice of Human and Organizational Development
Vanderbilt University
Nashville, TN

Jesse Heffernan, RCP, HCEP
Cofounder, Helios Recovery Services LLC
Appleton, WI

Joseph Hogan-Sanchez
Director of Programs, Faces & Voices of Recovery
Austin, TX

Tom Hill, M.S.W.
National Council for Behavioral Health
Washington, DC

Joi Honer, CAC, CCDP
Director of Alumni and Community Engagement
Retreat Behavioral Health
Wernersville, PA

Norma Jaeger, Ph.D., M.S.
Executive Director
Recovery Idaho, Inc.
Meridian, ID

Andre Johnson, M.A.
President/CEO
Detroit Recovery Project
Detroit, MI

Laurie Johnson-Wade, CRS, FPS, RSS, CBC
Co-Founding Director
Lost Dreams Awakening Recovery Community Organization
New Kensington, PA

Honesty Liller
Chief Executive Officer
McShin Foundation
Richmond, VA

Kristin Kelly
Project Manager
Peer Recovery Center of Excellence
Madison, WI

Javad Mashkuri, M.D.
Owner and Chief Consultant
Vermont Emergency Addiction Services, LLC
Staff Physician, Weeks Medical Center Emergency Department
Lancaster, NH

James A. Peck, Psy.D.
Psychologist/Sr. Clinical Trainer
UCLA Integrated Substance Abuse Programs
Los Angeles, CA

Douglas L. Polcin, Ed.D., M.S., MFT
Project Director
Public Health Institute
Oakland, CA

Jenna Reidy, NCPRSS
Peer Recovery Workforce Development Trainer
New Jersey Prevention Network (NJPN)
Tinton Falls, NJ

Jordan Scott
Recovery Support Services Supervisor
Lehigh Valley Intake Unit Recovery Link
Bethlehem, PA

Toni Shaffer, M.B.A., CRC, CPSS
Peer Recovery Specialist
Trivium Life Services (formerly Recovery 4 Life)
Idaho Department of Labor
Nampa, ID

Paul Staciewicz, Ph.D.
American Psychological Association
Washington, DC

Bill Stauffer, CADC, CCS, LSW
Executive Director
Pennsylvania Recovery Organization Alliance Harrisburg, PA

Christine Timko, Ph.D.
VA Palo Alto Health Care System
Palo Alto, CA

J. Scott Tonigan, Ph.D.
Research Professor
Department of Psychology, University of New Mexico
Albuquerque, NM

Kathlene Tracy, Ph.D.
New York University
New York, NY

## Expert Advisor

Bill White, M.A.
Emeritus Senior Research Consultant
Chestnut Health Systems