# Chapter 8—Resources

Chapter 8, which lists resources on peer support services for all audiences, is organized into 12 sections:

• General Resources
• Community-Related Resources
• Implementing and Integrating Peer Support Services
• Peer Support Services in Specific Settings
• Resources for Peer Specialist Workforce Development
• Resources for Peer Providers
• Tools for Peer Specialists
• Resources for Peer Specialist Supervisors and Administrators
• Tools for Supervisors and Administrators
• Resources for People In or Seeking Recovery
• Resources for Families of People In or Seeking Recovery
• Selected State Resources

## General Resources

### General Information

Substance Abuse and Mental Health Services Administration (SAMHSA):

• Directory of Single State Agencies (SSA) for Substance Abuse Services (https://www.samhsa.gov/sites/default/files/ssa-directory.pdf): Some states use dedicated funds or general revenues to help provide peer support services. More information can be provided by each state's behavioral health authority using this directory.
• Peer Support Workers for those in Recovery (https://www.samhsa.gov/brss-tacs/recovery-support-tools/peers): This webpage explains who peer workers are and provides links to additional materials that describe how peers support and advance the recovery process.
• Medications, Counseling, and Related Conditions (https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions#opioid-dependency-medications): This webpage discusses medication-assisted treatment, which is the use of medications, in combination with counseling and behavioral therapies, to provide a “whole-patient” approach to the treatment of substance use disorders.
• Mental Health and Substance Use Disorders (https://www.samhsa.gov/disorders): This website provides basic information about co-occurring mental and substance use disorders and links to related resources.
• Peer Recovery Center of Excellence (https://www.peerrecoverynow.org/): Led by peer recovery leaders across the nation, the Center provides training and technical assistance related to substance use disorder recovery. Areas of focus include integrating peer support workers into nontraditional settings, building the capacity of recovery community organizations, developing the peer workforce, and providing evidence-based and practice-based resources.
  – The Center also hosts monthly Communities of Practice calls for peer support specialists and those who supervise them. Participants on the calls engage in sharing, networking, and mutual learning on topics relevant to the peer workforce. The schedule can be accessed at https://peerrecoverynow.org/training/communities-practice.aspx.
• Recovery Support Tools and Resources (https://www.samhsa.gov/brss-tacs/recovery-support-tools-resources): This webpage explains what recovery is and contains links to tools and resources that behavioral health professionals, peers, parents, and families can use to help support people in recovery.
• SAMHSA's Working Definition of Recovery: 10 Guiding Principles of Recovery (https://store.samhsa.gov/sites/default/files/d7/priv/pep12-recdef.pdf): This brochure explains the 10 guiding principles of recovery.
• Value of Peers, 2017 (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/value-of-peers-2017.pdf): This PowerPoint presentation provides information about peer workers and how recovery programs can benefit from their support.
• Video Trainings (https://www.samhsa.gov/brss-tacs/video-trainings#peer-support): These video trainings cover a wide range of topics for peer workers, including core competencies, recovery coaching, and integrating peers into the behavioral health service arena.

American Society of Addiction Medicine (ASAM) (https://www.asam.org/): ASAM is a professional medical society representing over 6,000 physicians, clinicians, and associated professionals. It is dedicated to increasing access to and improving the quality of addiction treatment, educating physicians and the public, supporting research and prevention, and promoting the appropriate role of physicians in the care of patients with addiction.

NAADAC's Recovery to Practice (RTP) Initiative (https://www.naadac.org/recovery-to-practice-initiative): This initiative led to the development of educational products to help guide the practical application of recovery principles to the addictions workforce. These curriculums, along with a certification program and other recovery resources, can be found on this webpage.

National Institute of Mental Health (NIMH) (https://www.nimh.nih.gov/): NIMH is the lead federal agency for research on mental disorders. Its website provides facts and information about a wide range of mental health categories and conditions.

National Institute on Alcohol Abuse and Alcoholism—Alcohol's Effects on Health (https://www.niaaa.nih.gov/alcohols-effects-health): This webpage provides research-based information on alcohol and its impact on individuals and families.

National Institute on Drug Abuse (NIDA) (https://www.drugabuse.gov/): The NIDA website provides information about different drugs and related topics, like the health consequences of drug misuse research topics, viral hepatitis, and HIV and AIDS.

Peer Recovery Center of Excellence, Peer Recovery Support Resources (https://peerrecoverynow.org/about/coe-products.aspx): This website contains information and videos on topics that are foundational to the recovery community, including recovery community organizations, peer support, recovery capital, and recovery-oriented systems of care.

Recovery Research Institute (https://www.recoveryanswers.org/): The Recovery Research Institute is a leading nonprofit research institute of Massachusetts General Hospital, an affiliate of Harvard Medical School, dedicated to the advancement of addiction treatment and recovery.

Rural Health Information Hub's Peer Specialist Programs (https://www.ruralhealthinfo.org/toolkits/substance-abuse/2/recovery/peer-specialist): The Rural Health Information Hub's Peer Specialist page discusses how to implement a peer specialist program and meaningful roles for peer specialists in integrated health care, and includes examples of successful programs.

Safe Project: Addiction & Mental Health Resources for the Black Community (https://www.safeproject.us/resource/black-community/): This webpage provides substance use–related and mental health resources for the Black community.

### Publications

SAMHSA:

• Addictions and Mental Health Recovery Dialogue: Similarities and Differences in Our Communities (https://www.samhsa.gov/sites/default/files/similarities-differences-dialogue.pdf)
• Advisory: Prescribing Pharmacotherapies for Patients With Alcohol Use Disorder (https://store.samhsa.gov/product/prescribing-pharmacotherapies-patients-with-alcohol-use-disorder/pep20-02-02-015)
• Comparative Analysis of State Requirements for Peer Support Specialist Training and Certification in the United States (https://peerrecoverynow.org/about/coe-products.aspx)
• Know Your Rights. Rights for Individuals on Medication-Assisted Treatment (https://www.samhsa.gov/sites/default/files/programs_campaigns/medication_assisted/Know-Your-Rights-Brochure.pdf)
• Medication for the Treatment of Alcohol Use Disorder: A Brief Guide (https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907)
• Peer Support (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peer-support-2017.pdf)
• Peers Supporting Recovery From Substance Use Disorders (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peers-supporting-recovery-substance-use-disorders-2017.pdf)
• TIP 39, Substance Use Disorder Treatment and Family Therapy (https://store.samhsa.gov/product/treatment-improvement-protocol-tip-39-substance-use-disorder-treatment-and-family-therapy/PEP20-02-02-012)
• TIP 42, Substance Use Disorder Treatment for People With Co-Occurring Disorders (https://store.samhsa.gov/product/tip-42-substance-use-treatment-persons-co-occurring-disorders/PEP20-02-01-004)
• TIP 57, Trauma-Informed Care in Behavioral Health Services (https://store.samhsa.gov/system/files/sma14-4816.pdf)
• TIP 59, Improving Cultural Competence (https://store.samhsa.gov/system/files/sma14-4849.pdf)
• TIP 60, Using Technology-Based Therapeutic Tools in Behavioral Health Services (https://store.samhsa.gov/product/TIP-60-Using-Technology-Based-Therapeutic-Tools-in-Behavioral-Health-Services/SMA15-4924)
• TIP 63, Medications for Opioid Use Disorder (https://store.samhsa.gov/product/TIP-63-Medications-for-Opioid-Use-Disorder-Full-Document/PEP21-02-01-002)
• What Are Peer Recovery Support Services? (https://www.store.samhsa.gov/system/files/sma09-4454.pdf)

National Institute on Drug Abuse–Principles of Drug Addiction Treatment: A Research-Based Guide (Third Edition) (https://www.drugabuse.gov/publications/principles-drug-addiction-treatment-research-based-guide-third-edition/preface): This guide provides an overview of the addiction treatment landscape in the U.S. and an outline of evidence-based treatment approaches.

North Star Guide for Recovery Leaders (https://facesandvoicesofrecovery.org/wp-content/uploads/2021/06/Race-Equity-in-Recovery-North-Star-final-2.pdf): Faces & Voices of Recovery provides this overview of the key elements for committing to an antiracism stance in any treatment environment.

The Recovery Coach: ROLE CLARITY MATRIX (https://www.chestnut.org/resources/60ae2e1e-c67b-4fca-9610-21daf5b2ef5b/2016-Recovery-Coach-Role-Role-Clarity-Matrix.pdf): This article discusses the differing roles of peer recovery coach, addiction counselor, and professional recovery coach.

State of the New Recovery Advocacy Movement (https://www.chestnut.org/resources/5cd82f5d-f9cb-4e50-8391-7eadb9700e34/2013-State-of-the-New-Recovery-Advocacy-Movement.pdf): In this article, Bill White offers his perspective on the accomplishments of the recovery movement.

Working While Disabled: How We Can Help (https://www.ssa.gov/pubs/EN-05-10095.pdf): This brochure helps people with disabilities learn about obtaining employment without losing Social Security benefits.

### Mutual-Help Groups

AA Agnostica (https://aaagnostica.org/): AA Agnostica meetings are 12-Step meetings for agnostics, atheists, and freethinkers who feel uncomfortable with the religious focus of traditional Alcoholics Anonymous^®^ meetings.

Adult Children of Alcoholics^®^ & Dysfunctional Families (https://adultchildren.org/): This is a 12-Step program of men and women who experienced abuse, neglect, and/or trauma in the home while growing up.

Al-Anon Family Groups (https://www.al-anon.org/): Al-Anon offers group meetings where friends and family members of people with substance use issues share their experiences and learn how to apply the principles of the Al-Anon program to their individual situations.

Alcoholics Anonymous^®^ (AA) (https://www.aa.org/): AA offers group meetings for people who have problems with drinking and wish to stop. AA sponsors provide members with more personal support from experienced individuals.

Celebrate Recovery^®^ (https://www.celebratere (https://www.celebraterecovery.com/) https://www.celebratere (https://www.celebraterecovery.com/)): Celebrate Recovery^®^ is a Christianity-focused 12-Step recovery program for anyone experiencing hurt, pain, or addiction of any kind. Celebrate Recovery^®^ is a safe place to find community and freedom from the issues that are controlling a person's life.

Cocaine Anonymous^®^ (https://ca.org/): Cocaine Anonymous® is a mutual-help support program for people with cocaine use disorder. Cocaine Anonymous® follows the 12-Step tradition and offers meetings worldwide.

Crystal Meth Anonymous^®^ (https://crystalmeth.org/index.php): Crystal Meth Anonymous® describes itself as a fellowship of people who share their experience, strength, and hope with each other, so they may solve their common problem and help others to recover from addiction to crystal meth.

Drug Addicts Anonymous^®^ (https://daausa.org/): Drug Addicts Anonymous® is a fellowship of people who have recovered from addiction and are committed to helping those who have not yet recovered.

Dual Recovery Anonymous^™^ (http://www.draonline.org/): Dual Recovery Anonymous™ is a mutual-help support program that follows 12-Step principles in supporting recovery from drug and alcohol addiction and emotional or mental illness.

Families Anonymous (https://www.families (https://familiesanonymous.org/) https://www.families (https://familiesanonymous.org/)): Families Anonymous is a 12-Step fellowship for the family and friends of individuals with drug, alcohol, or related behavioral issues.

Grief Recovery After a Substance Passing (GRASP) (http://grasphelp.org/): GRASP was created to offer understanding, compassion, and support for those who have lost someone they love through addiction and overdose.

Heroin Anonymous (http://www.heroinanonymous.org): Heroin Anonymous is a nonprofit fellowship of individuals in recovery from heroin addiction committed to helping each other stay sober. This organization holds local support meetings, a directory of which can be found on its website.

Learn to Cope (https://www.learn2cope.org/): Learn to Cope is a secular mutual-help support group that offers education, resources, and peer support for the family of people with substance use disorders (although they are primarily focused on opioid use disorder).

Medication-Assisted Recovery Anonymous (MARA^®^) (https://www.mara-international.org/): MARA® supports the idea that medication is a therapeutic tool of recovery that may or may not be discontinued in time, dependent on the needs of the individual.

Millati Islami (http://www.millatiislami.org/): Millati Islami is an Islam-focused 12-Step recovery program where people share experiences, strengths, and hopes while recovering from active addiction to mind- and mood-altering substances.

Nar-Anon Family Groups (https://www.nar-anon.org/): This organization offers group meetings where friends and family of people with drug use problems can share their experiences and learn to apply the 12-Step Nar-Anon program to their lives. Nar-Anon groups also offer more individualized support from experienced individuals in the program who act as sponsors.

Narcotics Anonymous (NA^®^) (https://www.na.org/): NA® is a global, community-based organization with a multilingual, multicultural membership that supports recovery from addiction through a 12-Step program, including regular attendance at group meetings. NA® does not focus on any particular addictive substance.

Parents of Addicted Loved Ones (https://palgroup.org/): This is a secular support group for parents who have a child with a substance use disorder. They only have meetings in some states but also host telephone meetings.

Recovery Dharma (https://recoverydharma.org/): Recovery Dharma is a peer-led, grassroots, democratically structured organization whose mission is to support individuals on their path of recovery from addiction using Buddhist practices and principles. The site contains links to virtual meetings worldwide.

Refuge Recovery (https://refugerecovery.org/): Refuge Recovery is a peer-led movement using Buddhist-inspired practices and principles, combined with successful recovery community structures, to overcome addiction.

Sober Faction (https://thesatanictemple.com/pages/sober-faction): Sober Faction meetings assist those who are suffering from addiction in finding sobriety without having to experience the burden of religious dogma and superstition.

Secular Organizations for Sobriety (http://www.sossobriety.org/): This is a nonprofit, nonreligious network of autonomous, nonclinical local groups that support people in achieving and maintaining abstinence from alcohol and substance use disorder.

SMART Recovery^®^ (https://www.smartrecovery.org/): SMART Recovery® is an international self-empowering recovery group that supports multiple pathways to a life beyond addiction. The website provides links to online and in-person meeting information and access to 24/7 chats, discussion board forums, YouTube videos, and publications. Using science-based recovery tools, participants learn how to design their own plans for change from addictive behaviors.

Women for Sobriety (https://womenforsobriety.org/): This is an abstinence-based mutual-help support program that helps women find their individual paths to recovery by addressing their unique needs during recovery. It offers recovery tools to help women in recovery develop coping skills focused on emotional growth, spiritual growth, self-esteem, and a healthy lifestyle.

### Advocacy and Guild Organizations

Association of Alternative Peer Groups (https://www.aapg-recovery.com/): The mission of the Association of Alternative Peer Groups is to develop and sustain effective alternative peer groups that support recovery.

Bringing Recovery Supports to Scale Technical Assistance Center Strategy (BRSS TACS) (https://www.samhsa.gov/brss-tacs): In 2011, SAMHSA initiated BRSS TACS to promote the widespread adoption of recovery-oriented supports, services, and systems for people in recovery from substance use and mental disorders. BRSS TACS offers resources to a wide audience, including peer supervisors and peer support workers. This link (https://www.samhsa.gov/brss-tacs/recovery-support-tools/peers) provides access to no-cost webinars and other resources on peer support services.

Buddhist Recovery Network (https://www.buddhistrecovery.org/): The Buddhist Recovery Network is a nonprofit organization that promotes the use of Buddhist teachings and practices to help people recover from the effects of addictive behaviors. It is open to people of all backgrounds and respectful of all recovery paths.

Doors to Wellbeing, National Consumer Technical Assistance Center (TAC) (https://www.doorstowellbeing.org): Doors to Wellbeing, a SAMHSA-funded National Consumer TAC, has as part of its mission working to enhance and expand peer support, especially that provided by youth and young adults. The Doors to Wellbeing website contains a range of materials on peer support and a database of state-specific information on peer specialist certification requirements, training providers, and funding. The site also provides links to a peer respite directory, webinars and trainings, and recovery curricula and videos.

Dual Diagnosis Recovery Network (https://www.dualdiagnosis.org/resource/ddrn/): Part of Foundations Recovery Network, the Dual Diagnosis Recovery Network is an advocacy group for people with co-occurring disorders. They offer information on mutual-help support programs, outreach, and education.

Faces & Voices of Recovery (http://facesandvoicesofrecovery.org/): This national recovery advocacy organization promotes recovery from SUDs and advocates for social and policy changes to reduce stigma and discrimination against people in recovery. This website contains recovery stories, news and events information, publications, and webinars. In addition, its Mutual Aid Resources page (https://facesandvoicesofrecovery.org/resources/mutual-aid-resources) provides an extensive list of additional mutual-help groups.

Hazelden Betty Ford Foundation (https://www.hazeldenbettyford.org/recovery/families-friends): This website includes support and tools for people in recovery and their families and friends.

Latino Recovery Advocacy (http://lararecovery.org/): This website offers strategies for recovery community organizations to build culturally appropriate addiction recovery services and language accessibility for the Hispanic and Latino population.

Legal Action Center (https://www.lac.org/): This organization offers information about the rights of people with criminal records, HIV and AIDS, and substance use disorders.

Mental Health America's Center for Peer Support (https://www.mentalhealthamerica.net/center-peer-support): The Center for Peer Support provides background and resource links on topics ranging from the history of peer support to current research. The Center also publishes an online newsletter and a blog.

NAADAC, The Association for Addiction Professionals (https://www.naadac.org/): NAADAC offers the National Certified Peer Recovery Support Specialist credential and webinars on peer support–related topics.

National Alliance for Recovery Residences (NARR) (https://narronline.org/): NARR's mission is to support people in recovery from addiction by improving their access to quality recovery residences through standards, support services, placement, education, research, and advocacy.

National Empowerment Center (https://power2u.org/): The National Empowerment Center has an extensive resource listing, including a directory of consumer-run organizations, peer support, and webinars.

National Federation of Families (https://www.ffcmh.org/resources-familyorg): This nationwide advocacy organization focuses on bringing lived experience to family support and provides resources on family-run organizations.

National Harm Reduction Coalition (https://harmreduction.org/): This national advocacy and capacity-building organization advances harm reduction policies, practices, and programs that address the adverse effects of drug use including overdose, HIV, hepatitis C, addiction, and incarceration.

Oxford House^™^ (https://www.oxfordhouse.org): Oxford Houses are democratically run, self-supporting, and drug-free homes. This publicly supported nonprofit is the umbrella organization that provides the network connecting all Oxford Houses and allocates resources to duplicate the Oxford House™ concept where needs arise.

Recovered (https://recovered.org/): This nationwide network of nearly 100 affiliates (previously known as the National Council on Alcoholism and Drug Dependence, or NCADD), provides information and referrals to local services, including counseling and treatment for addiction and mental issues.

Texas Institute for Excellence in Mental Health (https://sites.utexas.edu/mental-health-institute/publications/reports/): The Reports page of this website includes publications relating to peer providers, including training and certification (https://sites.utexas.edu/mental-health-institute/files/2017/01/Peer-Specialist-Training-and-Certification-Programs-A-National-Overview-2016-Update-1.5.17.pdf); youth behavioral health; recovery initiatives; and financing.

Young People in Recovery (https://youngpeople (https://youngpeopleinrecovery.org/) https://youngpeople (https://youngpeopleinrecovery.org/)): Young People in Recovery was founded in 2010 by a group of young people (ages 18–30) in recovery who wanted to help others. Its programs are designed for young people but serve individuals of every age. Chapters are usually led by a young person in recovery.

### Online Boards and Chat Rooms

12-Step forums: A variety of online NA and AA meetings are available online, each with their own attitude toward medication.

• 12Step.org (https://12step.org/social/online-meetings/ (https://12step.org/social/online-meetings/)) contains links to meetings for all types of 12-Step fellowships and other recovery groups.
• The AA Online Intergroup Directory lists numerous online AA meetings, which occur at specific times (https://www.aa-intergroup.org/).
• Advocacy: Speak Out (www.myusara.com/advocacy/speak): This resource is offered by the Utah Support Advocates for Recovery Awareness.
• The Never Alone Club, formerly known as the NA chatroom, is an ongoing chat group that asks participants not to talk about medication, although they may join the discussion (https://neveraloneclub.org/).

Facebook Forums and Groups: A handful of co-occurring disorders and drug and alcohol addiction recovery organizations are on Facebook. They include:

• Clean and Sober Today (https://www.facebook.com/groups/1822841161286327/).
• Dual Diagnosis Co-occurring Mental Illness & Substance Disorders First Treatment Programs (https://www.facebook.com/FirstDualDiagnosisTreatmentandPrograms1984/).
• Living with Dual Diagnosis (https://www.facebook.com/groups/202446319860866/).
• Methadone Anonymous (https://www.facebook.com/MethadoneAnonymous/).
• Recovery Group for Dual Diagnoses (https://www.facebook.com/events/139669280229645/).
• Secular Organizations for Sobriety (https://www.facebook.com/groups/251215211975/).
• Social Media 4Recovery (https://www.facebook.com/groups/748016625286020/).

Faces & Voices of Recovery, Mutual Aid Resources (https://facesandvoicesofrecovery.org/resources/mutual-aid-resources): This website provides a comprehensive listing of online and in-person mutual-help support programs for people in recovery and their family members.

In The Rooms^®^ (https://www.intherooms.com/): This is an online social network for people in recovery, families, friends, and allies. Membership is free. Members have access to live online recovery support meetings.

LifeRing^®^ Secular Recovery, Dual Diagnosis Recovery Online Support Groups (https://www.lifering.org/post/lifering-offers-dual-diagnosis-recovery-support-group-online): This online group offers a safe place for people with mental and substance use disorders to discuss problems and concerns.

Selected Papers of William L. White (https://www.chestnut.org/william-white-papers/blog): This site contains technical papers on peer recovery support services, including “The Varieties of Recovery Experience: A Primer for Addiction Treatment Professionals and Recovery Advocates” (https://www.chestnut.org/resources/a13cfc89-7920-43bf-b043-af7078aab8c7/2006-The-Varieties-of-Recovery-Experience-1.pdf), interviews with peer recovery support leaders, and numerous resources for peer specialists.

SMART Recovery^®^ Online Forum (https://www.smartrecovery.org/community/forum.php): This online mutual-help resource allows people in recovery to share their own recovery stories in a virtual community environment. The site offers 24/7 access to a chat room and message board for individuals who cannot dedicate 1–1.5 hours to a meeting, but who still need access to recovery support resources and individuals.

Women for Sobriety's Online Community (https://womenforsobriety.org/community/): This forum for women includes a 24/7 message board where women can share and seek recovery support and participate in daily online chat meetings.

### Recovery Schools

Association of Recovery in Higher Education (https://collegiaterecovery.org): This is a national organization of collegiate recovery programs that lists colleges and universities with recovery programs.

Association of Recovery Schools (https://recoveryschools.org): This is a national association of secondary schools built around recovery principles and school-based recovery support. The website provides information about advocacy and a listing of recovery schools.

## Community-Related Resources

Advancing Health Equity Through Community Health Workers and Peer Providers: Mounting Evidence and Policy Recommendations (https://familiesusa.org/wp-content/uploads/2019/11/HEV_PCORI-CHW-Report_11-04-19.pdf): This report reviews results from nine studies that provide further support for including community health workers and peer providers as important components of healthcare delivery that are particularly effective in addressing health and healthcare inequities.

Central East Addiction Technology Transfer Center (ATTC) Network: Anti-Stigma Toolkit: A Guide to Reducing Addiction-Related Stigma (https://attcnetwork.org/sites/default/files/2019-04/Anti-Stigma%20Toolkit.pdf): This guide provides the addiction treatment and recovering community with practical information and tools to enhance their capacity to engage in effective stigma reduction efforts.

Faces & Voices of Recovery:

• Advocacy Toolkit (https://facesandvoicesofrecovery.org/wp-content/uploads/2020/02/ADVOCACY-TOOLKIT.pdf): This toolkit provides guidance and tips on how to build relationships with elected officials and their staff as part of local advocacy efforts.
• Advocacy With Anonymity (https://facesandvoicesofrecovery.org/wp-content/uploads/2019/06/Advocacy-with-Anonymity.pdf): This resource offers tips on how someone in a 12-Step program can advocate for recovery while still observing the 12-Step tradition of keeping membership in the program private.
• All Recovery Meeting Format (https://facesandvoicesofrecovery.org/publication/all-recovery-meeting-format/): This webpage provides access to a script for opening “All Recovery” meetings, as an alternative to 12-Step meetings, to welcome participants who support the recovery lifestyle.
• Community Listening Forum Toolkit: Taking Action to Support Recovery in Your Community (https://facesandvoicesofrecovery.org/wp-content/uploads/2020/02/Community-Listening-ForumToolkitHR-1.pdf): This toolkit provides practical steps and sample resources, such as flyers, agendas, evaluations, and training materials for speakers to help organize a forum in local communities.
• Directory of Recovery Community Organizations (ofrecovery.org/arco/arco-members-on-the-map/ (https://facesandvoicesofrecovery.org/arco-members-on-the-map/)): This directory includes recovery community organizations that are members of the Association of Recovery Community Organizations (ARCO). The interactive map contains locations to visit RCOs and Recovery Community Centers throughout the United States.
• The Recovery Bill of Rights (https://facesandvoicesofrecovery.org/wp-content/uploads/2019/07/Recovery-Bill-of-Rights-legal.pdf): This product is an advocacy tool and statement of the principle that all Americans have a right to recover from problematic substance use.
• Recovery Voices Count: A Guide to Non-partisan Civic Engagement (https://facesandvoicesofrecovery.org/wp-content/uploads/2019/06/Recovery-Voices-Count-Guide.pdf): This toolkit provides a complete guide on how to organize the recovery community through community activities like voter registration, education, and participation.

Great Lakes Addiction Technology Transfer Center (ATTC) Network (https://attcnetwork.org/centers/great-lakes-attc/home): The Great Lakes ATTC has useful resources on building a recovery-oriented system of care (https://attcnetwork.org/centers/great-lakes-attc/recovery-oriented-systems-care-rosc-2) and online peer training through the Extension for Community Healthcare Outcomes (https://attcnetwork.org/centers/great-lakes-attc/calling-all-peers-learn-and-build-your-skills-peer-support-echo).

National Association of Recovery Residences’ A Primer on Recovery Residences (https://narronline.org/wp-content/uploads/2014/06/Primer-on-Recovery-Residences-09-20-2012a.pdf): This guide provides an introduction to recovery residences and answers frequently asked questions.

National Council for Mental Wellbeing (formerly the National Council for Behavioral Health):

• Establishing Peer Support Services for Overdose Response: A Toolkit for Health Departments (https://www.thenationalcouncil.org/program/tools-for-overdose-prevention/): Although the toolkit focuses on harm reduction to prevent and respond to opioid overdose, it contains a number of checklists and resource lists useful when introducing peer support services in other contexts.
• What is a CCBHC? (https://www.thenationalcouncil.org/program/ccbhc-success-center/ccbhc-overview/): This website contains data showing that Certified Community Behavioral Health Clinics are having tremendous success in tackling the dual mental health and substance use crises in America.

Participatory Asset Mapping—A Community Research Lab Toolkit (www.communityscience.com/knowledge4equity/AssetMappingToolkit.pdf): This resource can be used for identifying community strengths and supporting change initiatives.

Recovery Research Institute: Recovery Residences (https://www.recoveryanswers.org/resource/recovery-residences/): Recovery residences provide safe housing and opportunities to build social and leadership skills. Most are self-supporting and operate via democratic principles of self-governance.

William White's Blog (https://www.chestnut.org/william-white-papers/): This blog provides articles and current news about peer support services and advocacy from a leader in the recovery advocacy movement.

## Implementing and Integrating Peer Support Services

### Toolkits and Manuals

Friends of Recovery New York's Recovery Community Organization (RCO) Toolkit (https://for-ny.org/wp-content/uploads/2017/08/RCO_Toolkit_HIGHRES.pdf): This resource includes a chapter on building recovery capital.

Illinois Department of Human Services, Division of Alcoholism and Substance Abuse's Manual for Recovery Coaching and Personal Recovery Plan Development (https://chess.wisc.edu/niatx/toolkits/provider/FayetteManual.pdf): This manual is for peer specialists in integrated behavioral health settings. It includes templates for recovery plans and contingency management plans.

Integrating Peers Into Treatment Programs in New York City: An In-depth Guide for Substance Use Disorder Treatment Providers (https://www1.nyc.gov/assets/doh/downloads/pdf/mh/peers-treatment-programs.pdf): Developed by the New York City Department of Health and Mental Hygiene, this guide includes several tools for assessing organizational readiness for integrating peer workers to support the recovery, rehabilitation, and health of people who use drugs and other substances.

Maintaining Independence and Sobriety through Systems Integration, Outreach, and Networking: The MISSION Treatment Manual (https://www.umassmed.edu/contentassets/58c9d438c9ef4f7f8a4a44e9452d471a/mission-manual-final.pdf): The MISSION Treatment Manual has been prepared to enable others who work with formerly homeless persons with co-occurring disorders to implement, learn from, and make adaptations of the MISSION services in their own settings and with their own resources.

McShin Foundation's Recovery Coach Manual (https://mcshin.org/wp-content/uploads/2019/07/McShin-RCM_for-web.pdf): The McShin Foundation provides this recovery coach manual for peer specialists in SUD treatment and recovery settings.

New York State Office of Alcoholism and Substance Abuse Services’ Peer Integration and the Stages of Change ToolKit (https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf): This toolkit addresses the different stages of organizational change when a peer support program is integrated into a behavioral health organization. Topics include billable services, readiness assessment, management of volunteers, and community- and home-based services.

OnTrackNY's Recovery Coach Manual (https://www.ontrackny.org/portals/1/Files/Resources/RecoveryCoach_2015.01.21.pdf): OnTrackNY provides a recovery coach manual for peer specialists in substance use disorder treatment and recovery settings. It includes material on skills training, implementation, and sample assessment tools.

Peer Services Toolkit: A Guide to Advancing and Implementing Peer-run Behavioral Health Services (https://www.leaders4health.org/resources/peer-services-toolkit-a-guide-to-advancing-and-implementing-peer-run-behavioral-health-services/): This detailed guide contains tools to support advocacy efforts and capacity building at the local level and provides payers with background information on the need for and efficacy of peer support services. The guidebook defines the roles and requirements of effective peer specialists and provides agencies with examples of peer-run programs for use in different settings.

Philadelphia Department of Behavioral Health and Intellectual disAbility Services’ Peer Support Toolkit (https://dbhids.org/peer-support-toolkit/): This toolkit is designed to guide behavioral health service agencies in including peer specialists in their service settings. The kit is organized into four sections that discuss preparing the organizational culture, recruiting peer specialists, delivering services, and supervising and keeping peer specialists.

Recovery Community Organization Toolkit (https://facesandvoicesofrecovery.org/wp-content/uploads/2019/06/RCO-Toolkit.pdf): This toolkit is a product of Faces & Voices of Recovery. It describes the core principles and strategies for creating successful recovery community organizations.

Southern Plains Tribal Health Board, Peer Support Toolkit (https://sites.utexas.edu/ignitingthesparkofhope/files/2021/06/Peer-Support-Toolkit_Booklet.pdf): This document provides an overview about the effectiveness of peer support programs, important core roles, and items to consider for implementing a successful peer program.

University of Colorado Anschutz Medical Campus School of Medicine's DIMENSIONS: Peer Support Program Toolkit (https://www.bhwellness.org/toolkits/Peer-Support-Program-Toolkit.pdf): This toolkit explains how to create and sustain a peer support program. Topics covered include planning the program, identifying funding and peer-support champions, and understanding Americans with Disabilities Act requirements.

University of Massachusetts Medical School:

• Effectively Employing Young Adult Peer Providers: A Toolkit (https://www.umassmed.edu/globalassets/transitionsrtc/publications/effectivleyemployingyoungadultpeerproviders_a_toolkit.pdf): This toolkit was designed to help peer specialists serving youth with serious mental conditions learn how to effectively develop, integrate, and supervise a young adult peer workforce.
• Recovery Coaches in Opioid Use Disorder Care (https://www.mass.gov/files/documents/2019/05/24/UMass-Recovery-Coach-Report.pdf): This handbook is a guide for opioid use disorder treatment programs in successfully using peer specialists.

Veterans’ Health Administration's (VHA) Peer Specialist Toolkit: Implementing Peer Support Services in VHA (https://www.mirecc.va.gov/visn4/docs/Peer_Specialist_toolkit_Final.pdf): Although designed for VHA programs, this toolkit provides valuable tips on how and why to use peer support services in other healthcare settings. It reviews peer support research outcomes, addresses common false beliefs about peer specialists, and offers suggestions on how to add peer specialists into clinical teams.

### Webinars

SAMHSA:

• Building and Sustaining Peer Support Services in Practice: Tips From the Field (https://www.youtube.com/watch?v=VrYC1VmgdeE&feature=youtu.be): This webinar covers key issues in building or strengthening peer support services for people with serious mental illness or substance use disorders. It also helps agencies by offering information about how to hire and add peer specialists into recovery-oriented programs.
• Culturally Competent Care in Recovery Oriented Settings (www.youtube.com/watch?v=L7E9B_k7S8k): The authors use a social work lens to discuss culturally appropriate care as a central theme in recovery-oriented practice.

NAADAC's Cultural Humility Series, Part II: Social Class Bias and the Negative Impact on Treatment Outcomes (https://www.naadac.org/cultural-humility-social-class-bias-webinar): This presentation examines the role a counselor's implicit socioeconomic status bias may play in treatment disparities and whether training can effectively reduce clinician biases.

NAADAC's Peer Recovery Support Webinars (https://www.naadac.org/peer-recovery-support-webinars): These six free webinars from 2020 were created in collaboration with the Great Lakes ATTC. Topics include peer supervision and management, the integration of peer workers in addiction recovery services, and how to foster a peer recovery culture in addiction organizations.

National Association of Addiction Treatment Providers^®^ (NAATP) Diversity, Equity, Inclusivity & Belonging (DEIB) Webinars and Events (https://www.naatp.org/resources/dei/webinars-events): NAATP offers webinars on DEI-related topics, including implementing DEI, understanding the importance of antiracism in treatment environments, and working with individuals from LGBTQ+ populations. Free webinar videos and related PowerPoint presentations are available on the page.

National Federation of Families (https://www.ffcmh.org/resources-webinars): This webpage features links to webinars focused on family peer support, including its benefits, strategies for involving families, and certification.

### Other Resources

Live Another Day (https://liveanotherday.org/bipoc/): This website offers substance use and mental health recovery resources to support the Black, Indigenous, and People of Color community.

National Association of State Mental Health Program Directors’ Engaging Women in Trauma-Informed Peer Support: A Guidebook (https://nasmhpd.org/content/engaging-women-trauma-informed-peer-support-guidebook): This is a resource for peer specialists who want to integrate trauma-informed principles into their work with women.

New York Office of Mental Health's Best Practices for Effectively Integrating Peer Staff in the Workplace (https://www.academyofpeerservices.org/pluginfile.php/37061/mod_resource/content/1/presentation_pdf_best-practices_integrating_peer_staff_ja_2017.pdf): This slide presentation discusses methods for recruiting, training, and supporting peer specialists in a treatment setting. It describes the benefits that peers can bring to service delivery, describes their ability to engage with people in recovery through a shared experience, and provides evidence on the usefulness of including peer specialists in recovery services.

Recovery Café Network (https://recoverycafenetwork.org/ https://recoverycafenetwork.org/): The Recovery Café Network provides spaces where people in recovery can socialize and support each other in a substance-free setting.

Recovery Friendly Workplaces (https://www.opioidlibrary.org/featured_collection/recovery-friendly-workplaces/): This website highlights initiatives on creating recovery-friendly workplaces where businesses create policies and procedures that offer support for employees working on substance use disorder treatment and recovery.

SAMHSA's Equipping Behavioral Health Systems & Authorities To Promote Peer Specialist/Peer Recovery Coaching Services (https://www.samhsa.gov/sites/default/files/expert-panel-03212012.pdf): This report is the result of an expert panel meeting sponsored by SAMHSA's BRSS TACS. The report addresses the challenges facing behavioral health systems when adding peer support services, and provides recommendations for overcoming these challenges.

University of California Los Angeles’ Mindful Awareness Research Center (https://www.uclahealth.org/marc/): This website offers online classes and no-cost guided mindfulness practices and podcasts. It also provides links to other mindfulness resources.

## Peer Support Services in Specific Settings

SAMHSA:

• Peer Support: A Critical Component in Supported Housing (https://www.nasmhpd.org/sites/default/files/NASMHPD%20Housing_Final%20Submission.pdf): This slide presentation focuses on the services that peer support workers can provide for people with mental or substance use disorders in supportive housing. The presentation shows how the peer support worker's role complements that of the case manager, and sets out some of the benefits of using peer providers in these settings.
• Peer Support Roles in Criminal Justice Settings (https://www.usf.edu/cbcs/mhlp/tac/documents/behavioral-healthcare/peer-roles-cj-settings.pdf): This brief report summarizes the roles and responsibilities of mental and substance use disorder peer specialists working with people in recovery who are involved in the criminal justice system.
• Telehealth for the Treatment of Serious Mental Illness and Substance Use Disorders (https://store.samhsa.gov/product/telehealth-for-treatment-serious-mental-illness-substance-use-disorders/PEP21-06-02-001): This evidence-based resource guide to telehealth for substance use disorder treatment reviews relevant literature and research findings, examines emerging and best practices, discusses gaps in knowledge, and identifies challenges and strategies for implementation.
• The Use of Peers and Recovery Specialists in Child Welfare Settings (https://ncsacw.samhsa.gov/files/peer19_brief.pdf): This brief highlights how child welfare agencies and family court programs have integrated peers into their service delivery to support families affected by substance use disorders. Funding, roles, communication protocols, and supervision are among the topics covered.

Building Recovery Capital Through Digital Health Technologies (https://www.nfartec.org/wp-content/uploads/2018/04/building-recovery-capital-introductory-webinar.mid-america.final_.pdf): This presentation slide deck features peer support services and digital recovery support tools to help people in recovery.

National Council for Mental Wellbeing (formerly the National Council for Behavioral Health):

• Building Recovery: State Policy Guide for Supporting Recovery Housing (https://www.thenationalcouncil.org/resources/building-recovery-state-policy-guide-for-supporting-recovery-housing/): This resource provides strategies, tools, and examples of policy language that addresses the role and contribution of recovery housing, standards of care for recovery housing, and protections for people in recovery served by such residences.
• Peer Support Workers in Emergency Departments: Engaging Individuals Surviving Opioid Overdoses–Qualitative Assessment (https://www.thenationalcouncil.org/wp-content/uploads/2022/02/22.01.12_NC_PCSS_Peer-Support-Workers-Issue-Brief.pdf): This issue brief describes the value of using peer workers in emergency departments (EDs) to help guide patients with opioid use disorder toward proper treatment and recovery interventions after they leave the hospital. The document also highlights current and promising practices used to integrate peer support workers into ED settings.

National Drug Court Institute's E-Learning Center (https://www.ndci.org/resource/training/e-learning/): This resource makes online training available on a variety of topics, including medication for SUD treatment and trauma awareness.

Project Muse^®^: Establishing Peer Recovery Support Services to Address the Central Appalachian Opioid Epidemic: The West Virginia Peers Enhancing Education, Recovery, and Survival (WV PEERS) Pilot Program (https://muse.jhu.edu/article/801145/pdf): The WV PEERS program is based on peer recovery support, to engage individuals using opioids and link them with a range of services.

University of Massachusetts’ Recovery Coaches in Opioid Use Disorder Care (https://rizema.org/wp-content/uploads/2019/01/UMass-Recovery-Coach-Report.pdf): This handbook guides opioid use disorder treatment and service delivery programs in successfully using peer workers.

## Resources for Peer Specialist Workforce Development

SAMHSA:

• Advisory: Peer Support Services in Crisis Care (https://store.samhsa.gov/product/advisory-peer-support-services-crisis-care): This Advisory discusses the role of peer support workers and models of peer support services that are available to assist individuals who are experiencing a crisis.
• Core Competencies for Peer Workers in Behavioral Health Services (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/core-competencies_508_12_13_18.pdf): This report is a summary of core knowledge, skills, and abilities needed to ensure best practices in peer support services.
• Using Core Competencies to Support Peer Workers and Improve Service Delivery (https://www.youtube.com/watch?v=LamgkgijxX8&feature=youtu.be): This webinar addresses questions about using core competencies in the delivery of peer support services and about continuing professional development for peer specialists.

Government Accountability Office's Leading Practices for State Programs to Certify Peer Support Specialists: Mental Health Report to Congressional Committees (https://www.gao.gov/assets/700/695435.pdf): This report describes best practices for certifying peer specialists as identified by program officials in selected states that receive funding from SAMHSA. Leading practices include standardizing the competencies of peer specialists through training and certification.

Great Lakes ATTC: Workforce Recruitment and Retention, Part 3: Strategies for Rural Areas and Recruiting and Retaining Peer Support Workers (https://attcnetwork.org/centers/great-lakes-attc/workforce-recruitment-and-retention-part-3-strategies-rural-areas-and-0): This is the third webinar in a three-part series on workforce recruitment and retention in behavioral health, with a specific focus on the drug and alcohol addiction field. Part of the webinar is dedicated to recruiting and retaining peer specialists (not just in rural areas).

ICAADA Credential: Code of Ethics (https://icaada.org/credentials/code-of-ethics/): ICAADA, a subsidiary of Mental Health America of Indiana, provides credentialing and certification for behavioral health professionals. It offers the ICAADA CAPRC (Certified Addiction Peer Recovery Coach) Code of Ethics from the list of ethics documents on its website.

Mental Health America: The Peer Workforce (https://www.mentalhealthamerica.net/peer-workforce#Overview): This webpage briefly discusses and links to resources on peer support certification and compensation and other peer support workforce issues.

RESPECT Model (https://thinkculturalhealth.hhs.gov/assets/pdfs/resource-library/respect-model.pdf): Originally developed in 2002, this tool helps peer workers and treatment providers remember the key factors to ensure that they engage with people seeking recovery in a culturally and linguistically responsive competent manner.

### Peer Specialist Certification

SAMHSA's National Model Standards for Peer Support Certification (https://www.samhsa.gov/about-us/who-we-are/offices-centers/or/model-standards): These standards, which were drafted in collaboration with federal, state, tribal, and local partners and are inclusive of mental health, substance use, and family/youth peer certifications, recommend specific criteria for becoming a certified peer specialist. The domains addressed include, but are not limited to, training, examinations, formal education, and work experience.

BRSS TACS’ State-by-State Directory of Peer Recovery Coaching Training and Certification Programs (https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Directory-of-Peer-Recovery-Coaching-Training-and-Certification-Programs_8_26_2020.pdf): This SAMHSA resource is an alphabetical directory that lists certification requirements for peers in all 50 states and Washington, DC.

CARES Academy (https://gasubstanceabuse.org/cares-academy/): The CARES Academy provides in-class training, typically in the metro Atlanta area, to become a Certified Addiction Recovery Empowerment Specialist. Upon successful completion of the CARES exam, individuals working in eligible facilities can bill Medicaid for Certified Peer Specialist–Addictive Disease services.

Connecticut Community for Addiction Recovery Trainings (https://addictionrecoverytraining.org/training-products/): This site provides information on peer specialist training opportunities and credentialing.

Council on Accreditation of Peer Recovery Support Services (https://caprss.org/): The Council is an accrediting body for recovery-oriented organizations and other programs offering addiction-oriented peer support services.

Doors to Wellbeing (https://copelandcenter.com/peer-specialists): This program of the Copeland Center for Wellness and Recovery offers an online state-by-state database of certification requirements for peer specialists.

International Certification & Reciprocity Consortium (IC&RC) (https://www.international (https://www.internationalcredentialing.org/) https://www.international (https://www.internationalcredentialing.org/)): IC&RC is a nonprofit international organization that establishes standards and facilitates reciprocity for the credentialing of substance use disorder treatment providers. Many different certification and licensing boards in the United States and elsewhere oversee IC&RC credentials and examinations.

• More information on IC&RC's Peer Recovery credential can be found at https://www.internationalcredentialing.org/creds/pr.
• Member U.S. states that offer the Peer Recovery credential can be found at https://www.internationalcredentialing.org/memberboards.
• A study guide and other materials for exam preparation can be found at https://internationalcredentialing.org/examprep.
• A description of the reciprocity process for peer specialists holding the IC&RC peer recovery credential can be found at https://internationalcredentialing.org/reciprocity.
• The Candidate Guide for the IC&RC Peer Recovery Examination can be found at this link: https://internationalcredentialing.org/resources/Candidate%20Guides/PR_Candidate_Guide.pdf.

Mental Health America of Indiana Training Institute (https://www.mhaitraininginstitute.org/training-calendar-new/): This webpage contains a calendar for courses that provide continuing education units for certified peer support professionals.

NAADAC (https://www.naadac.org/ncprss): This website includes information about the certification process for becoming a National Certified Peer Recovery Support Specialist.

National Association of State Alcohol and Drug Abuse Directors’ Member Directory (http://nasadad.org/ssa-web-sites): This website provides links to state and territory single state agencies for substance use disorder treatment and prevention, including information about state certification of peer specialists.

National Federation of Families’ National Family Peer Specialist Certification (https://www.ffcmh.org/certification): This website provides information about the certification process for becoming a family peer specialist.

RI International, Peer and Organizational Activation and Training (https://riinternational.com/consulting/training/): This website features links to Certified Peer Support Specialist training opportunities and materials, including online courses.

University of Texas's Peer Specialist Training & Certification Programs—National Overview 2016 (http://sites.utexas.edu/mental-health-institute/files/2017/01/Peer-Specialist-Training-and-Certification-Programs-A-National-Overview-2016-Update-1.5.17.pdf): This document provides a compilation of information about peer specialist training and certification programs in the United States. The emphasis is on mental health–focused peer specialists.

Virginia Department of Behavioral Health & Developmental Services, Office of Recovery Services (https://dbhds.virginia.gov/office-of-recovery-services/): This website contains examples of training opportunities for peer specialists.

White Bison's Warrior Down/Recovery Coach (https://whitebison.org/warrior-down/): Facilitators can be trained to implement the curriculum on this website, which provides a relapse prevention and recovery support program for Native Americans/Alaska Natives who are completing treatment, returning to the community from incarceration, or who have been working on their recovery journey.

## Resources for Peer Providers

SAMHSA:

• Core Competencies for Peer Workers in Behavioral Health Services (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/core-competencies_508_12_13_18.pdf): This report is a summary of core knowledge, skills, and abilities needed to ensure best practices in peer support services.
• Cultural Humility Primer (https://attcnetwork.org/sites/default/files/2020-11/Peer%20Primer%20FINAL.pdf): Developed by the Northwest ATTC, this publication provides guidance to peer support specialists and recovery coaches for serving and supporting diverse individuals in their recovery journeys.
• Engaging Women in Trauma-Informed Peer Support: A Guidebook (http://www.nasmhpd.org/sites/default/files/PeerEngagementGuide_Color_REVISED_10_2012.pdf): This guide is a resource for peer specialists who want to learn how to integrate trauma-informed principles into their work.
• Frequently Asked Questions for Core Competencies for Peer Workers (https://www.samhsa.gov/brss-tacs/recovery-support-tools/peers/core-competencies-peer-workers-behavioral-health-services/frequently-asked-questions): This resource defines core competencies for peer specialists. The document also discusses the benefits of these competencies and how they can be used effectively to increase healing and wellness in people with mental illness or substance misuse.

Academy for Addiction Professionals’ “A Day in the Life: Peer Support Specialist” Blog (https://www.addictionacademy.com/2017/08/a-day-in-the-life-peer-support-specialist/): This blog posting gives readers an inside look into peer specialist jobs.

Agency for Healthcare Research and Quality's Implementation Quick Start Guide: Warm Handoff (https://www.ahrq.gov/sites/default/files/wysiwyg/professionals/quality-patient-safety/patient-family-engagement/pfeprimarycare/warm-handoff-qsg-brochure.pdf): This guide aims to improve patient safety in primary care settings by engaging patients and families.

Connecticut Community for Addiction Recovery Trainings (https://addictionrecoverytraining.org/training-products/): This site provides information on peer specialist training opportunities and credentialing.

DEI Mission and Definitions (https://www.thrivebhri.org/about-us/diversity-equity-inclusion/dei-mission-and-definitions): This webpage, produced by Thrive Behavioral Health in Rhode Island, provides expanded definitions of the terms “diversity,” “equity,” and “inclusion” that may be useful to programs and individuals wanting to implement these concepts in their services.

Faces & Voices of Recovery (https://facesandvoicesofrecovery.org): This national recovery advocacy organization promotes recovery from substance use disorders and advocates for social and policy changes to reduce stigma and discrimination against people in recovery. Personal stories about recovery by people from all walks of life can be found at https://facesandvoicesofrecovery.org/resources/recovery-stories.

Faces & Voices of Recovery's LGBTQ+ Recovery Resources (https://facesandvoicesofrecovery.org/2019/08/16/lgbtq-recovery-resources/): This webpage includes tips for making recovery spaces more inclusive for individuals who identify as LGBTQ+ as well as access to online communities, social media connections, gatherings and events, sober spaces, publications, meetings, and podcasts.

Improving Cultural Competency for Behavioral Health Professionals (https://thinkculturalhealth.hhs.gov/education/behavioral-health): The goal of this e-learning program is to help behavioral health professionals increase their cultural and linguistic competency.

Medication-Assisted Recovery Services (MARS^™^) Project (http://marsproject.org/): This peer-initiated and peer-based recovery support website includes links to upcoming trainings about medications that support recovery from problematic substance use, and offers an online Peer Recovery Network.

Motivational Interviewing Values Card Sort (https://www.motivationalinterviewing.org/sites/default/files/valuescardsort_0.pdf): This website showcases example of values cards, with a brief description of each value. The cards can be downloaded, printed, and cut into separate cards. Also included is a link (https://motivationalinterviewing.org/sites/default/files/valuesinstructions.pdf) to specific instructions for using the card sort.

NAADAC's Peer Recovery Support Resources (https://www.naadac.org/peer-recovery-support-resources): Resources on this webpage include online trainings, such as the Peer Recovery Support webinar series, the NAADAC code of ethics for peers, networking information, and credentialing support.

National Center for Cultural Competence, Georgetown University Center for Child & Human Development: Self-Assessment Checklist for Personnel Providing Behavioral Health Services and Supports to Children, Youth and their Families (https://nccc.georgetown.edu/documents/ChecklistBehavioralHealth.pdf): This checklist is intended to heighten the awareness and sensitivity of personnel to the importance of cultural diversity and cultural responsiveness in human service settings. It provides concrete examples of the kinds of values and practices that foster such an environment.

Northwest ATTC's Supporting Recovery from Opioid Use: A Peer's Guide to Person-Centered Care (https://attcnetwork.org/centers/northwest-attc/supporting-recovery-opioid-use-peers-guide-person-centered-care-online): This free online course was developed by the SAMHSA-funded Northwest ATTC for peer specialists and outreach workers. Its goal is to help peer providers better understand how to use person-centered care to engage people with opioid use disorder in recovery.

One Sky Center, American Indian/Alaska Native National Resource Center for Health, Education and Research (http://www.oneskycenter.org/): The Center provides culturally appropriate prevention and treatment resources, services, and training for Native population clients with mental and substance use disorders.

Peer Recovery Center of Excellence, State Certification Database (https://peerrecoverynow.org/resources/state-certifications.aspx): This directory contains information regarding the training and certification processes for all 50 U.S. states, 5 U.S. territories, and the District of Columbia.

Peer Support Provider: Walking the Tightrope Between Helping Others & Maintaining Your Own Wellness (https://www.mirecc.va.gov/visn1/docs/products/Peer_Support_Provider_Self-Care_Presentation.pdf): This resource aims to make peer support providers more aware of stressors commonly associated with their work, and offers them steps to maintain their own wellness.

Stages of Recovery (https://www.recoveryanswers.org/resource/stages-of-recovery/): The Recovery Research Institute explains the different stages of change that necessitate different recovery strategies.

Understanding the Role of Peer Recovery Coaches in the Addiction Profession (https://www.naadac.org/understanding-the-role-of-peer-recovery-coaches-in-the-addiction-profession): This webinar explains the roles of the peer recovery coach and discusses how a peer recovery coach's work differs from and complements that of an addiction counselor. The webinar also looks at the professional and personal development of peer recovery coaches.

The University of Missouri's Alcohol and Drug Education for Prevention and Treatment's Presentation: Motivational Interviewing Philosophy and Principles (https://adept.missouri.edu/wp-content/uploads/2017/06/Module-One-Motivational-Interviewing-Philosophy-and-Principles.pdf): This slide deck discusses motivational interviewing (MI) and the differences between MI as a counseling technique and MI as a philosophy of care.

Careers at VA (https://www.vacareers.va.gov/): Eligibility for peer apprentice and specialist positions is limited to veterans with at least 1 year in recovery. This webpage offers an interactive database of available positions.

### Ethical Guidelines

Ethical Guidelines for the Delivery of Peer-based Recovery Support Services (https://www.naadac.org/assets/2416/whitew2007_the_pro-act_ethics_workgroup.pdf): This document provides an indepth look at ethical guidelines and decision making for peer specialists. The guidelines provide scenarios demonstrating ethical dilemmas commonly encountered by peer specialists.

NAADAC's National Certified Peer Recovery Support Specialist (NCPRSS) Code of Ethics (https://www.naadac.org/assets/2416/nccap-peer-recovery-support-specialist-code-of-ethics-final06-22-16.pdf): These guidelines summarize ethical standards for the National Certification Commission for Addiction Professionals’ Peer Specialists.

N.A.P.S.’ National Practice Guidelines for Peer Supporters (https://na4ps.files.wordpress.com/2012/09/nationalguidelines1.pdf): These guidelines provide ethical and practice guidelines for peer specialists in behavioral health services.

Northeast & Caribbean ATTC's Professional Boundaries for Peer Advocates (https://attcnetwork.org/centers/northeast-caribbean-attc/webinar-professional-boundaries-peer-advocates-0): This training resource provides guidance on building a safe working environment, using boundaries between people in recovery and peer specialists.

The Vermont Certified Recovery Coach Academy Curriculum Overview (https://recoveryvermont.org/wp-content/uploads/2020/12/VRCA-Curriculum-Overview-2021.pdf): This resource can be downloaded for free and provides information on ethics, conduct, and standards. Page 9 describes a module on recovery coaching ethics and boundaries.

## Tools for Peer Specialists

### Mobile Applications Supporting Recovery

Addiction-Comprehensive Health Enhancement Support System (A-CHESS) (https://www.c4tbh.org/program-review/addiction-comprehensive-health-enhancement-support-system-a-chess/): A-CHESS is a smartphone application designed to provide continuing care to patients with alcohol use disorder. It offers support through static content and interactive features (e.g., alerts when the person using the app is nearing a high-risk location, such as a bar).

Pear reSET^®^ & reSET-O^®^ (https://peartherapeutics.com/products/reset-reset-o/): Both apps provide cognitive–behavioral therapy to support other clinical treatment approaches for SUDs, such as contingency management and the use of medication to support recovery.

### Recovery Capital Assessments

The Assessment of Recovery Capital and the Recovery Capital Scale are assessment tools to measure a person's recovery capital. They can also be used to guide conversations about recovery capital and recovery planning.

Building Recovery Capital Through Digital Health Technologies (www.nfartec.org/wp-content/uploads/2018/04/building-recovery-capital-introductory-webinar.mid-america.final_.pdf): This presentation describes peer support services and digital recovery support tools to help people in recovery.

The Comprehensive Opioid, Stimulant, and Substance Abuse Program's Peer Support Core Concept: Recovery Capital (https://www.cossapresources.org/Content/Documents/Articles/Altarum_Peer_Support_Recovery_Capital_for%20BJA.pdf): This document contains resources on assessing recovery capital.

Development and Validation of a Brief Assessment of Recovery Capital (BARC-10) for Alcohol and Drug Use Disorder (http://shura.shu.ac.uk/15835/2/Best%20-Development%20and%20validation%20of%20a%20Brief%20Assessment%20of%20Recovery%20Capital%20%28BARC-10%29%20%28Scale%29.pdf): This tool is a shortened version of the Assessment of Recovery Capital (ARC) that may be helpful in establishing recovery priorities.

Friends of Recovery–New York's Recovery Community Organization (RCO) Toolkit (https://for-ny.org/wp-content/uploads/2017/08/RCO_Toolkit_HIGHRES.pdf): This toolkit includes guidance and tools to help develop local recovery community organizations.

Maryland Assessment of Recovery Scale—MARS-12 (https://www.providerexpress.com/content/dam/ope-provexpr/us/pdfs/clinResourcesMain/rrToolkit/rrMARS.pdf): The scale is a 25-item self-report instrument that measures recovery of people with serious mental illness.

National Association of Drug Court Professionals’ E-Learning Center (https://www.nadcp.org/e-learning-center/): This resource lists current courses available from the National Association of Drug Court Professionals, including trainings on medication for substance use disorder and trauma awareness.

National Federation of Families’ Peer Support Specialist Resources (https://www.ffcmh.org/resources-peersupport): This nationwide advocacy organization lists numerous resources on its webpage.

Policy Research Associates–Achieving Well-Being in Recovery: A Review of Existing Measures (https://www.prainc.com/resources/achieving-recovery-existing-measures/): This 18-page resource includes sample research articles regarding each identified instrument for measuring wellness and their psychometric properties.

The Recovery Capital Scale & Plan (http://www.brauchtworks.com/assets/docs/Recovery_Capital_Scale__Plan_130611.176185022.pdf): This assessment tool helps recoverees measure their available recovery capital.

Wisconsin Recovery Thermometer Tool (https://www.dhs.wisconsin.gov/library/p-01289.htm): This tool can be used by people seeking mental health or co-occurring mental health and substance use recovery, or by those already on their recovery journey.

### Assessment of Recovery Capital

### Recovery Capital Scale

## Sample Recovery and Wellness Plans

These recovery and wellness plans are examples that can be used with people in recovery in different settings. Recovery and wellness plans should be filled out and kept by the person in recovery.

Sample Recovery Plan

The following is a sample wellness plan. It has been filled out by a recoveree named Thomas, whose goal is to get a job and go back to work. First, Thomas lists the goals that are most important—the things that will motivate him to follow through with his recovery. Then he lists the strengths that will help him reach the goals and the barriers that might get in his way. The short-term objective (i.e., the small first step) for Thomas is for him to work at a job for 5 or more hours a week. This might seem small, but it is a good step for Thomas as he works toward his longer term goal of going back to work full time and getting off of disability. The last part of the wellness plan is completed by Thomas, his peer worker, and his clinician.

GOALS – Goals are what you want to work on in your life. Describe your goals in your own words.

• I want to go back to work. I really want a job.

BARRIERS – Barriers are things that stand in the way of you accomplishing your goal.

• I feel nervous and anxious while looking for job openings or filling out applications.
• I have difficulty getting up in the morning, due to intense sadness and crying.
• I need help filling out paperwork and creating a résumé.

STRENGTHS – Strengths are things that you're good at—your talents, abilities, skills, and past experiences.

• I have a strong work ethic.
• I have work experience as a cashier.
• I am a good communicator.
• I have a strong connection with my peer worker.

OBJECTIVE – An objective is the short-term step that moves you toward your bigger goal.

In the next 90 days, I will find a paying job and work at least 5 hours per week.

INTERVENTIONS – Interventions are the things that you, your provider, and your peer worker will do to help you accomplish your objective and move you toward your goal.

• Psychiatrist will meet with Thomas once monthly for 30 minutes for the next 3 months to decrease symptoms by adjusting medication when needed.
• Clinician will meet weekly with Thomas for 45 minutes for 3 months to work with him on cognitive–behavioral therapy techniques (e.g., thought stopping, visualization, deep breathing) to manage his symptoms, which increase when he is pursuing job-related activities.
• Peer worker will support Thomas by helping him finish his résumé in the next 4 weeks and work on job applications for the next 3 months.
• Thomas will participate in the Wellness Recovery Action Planning group (facilitated by his peer worker) every other week to come up with simple, safe, and effective strategies for staying well and increasing his sense of control over his life and symptoms.

Source: Adapted with permission from the Yale Program for Recovery and Community Health.

### Sample Wellness Plan

## Resources for Peer Specialist Supervisors and Administrators

SAMHSA:

• Addiction Technology Transfer Center (ATTC) Network (https://attcnetwork.org/centers/selection): Administrators can access their specific ATTC for technical support and training by logging onto this website.
• Advisory: Using Motivational Interviewing in Substance Use Disorder Treatment (https://store.samhsa.gov/product/advisory-using-motivational-interviewing-substance-use-disorder-treatment/pep20-02-02-014): Based on TIP 35, this Advisory addresses the spirit, application, and fundamentals of motivational interviewing.
• Certified Community Behavioral Health Clinics (CCBHCs) (https://www.samhsa.gov/certified-community-behavioral-health-clinics): SAMHSA provides information on CCBHCs’ goals, funding, and requirements at this webpage.
• Diversity, Equity, and Inclusion Resources (https://soarworks.samhsa.gov/article/dei-resources): This SAMHSA webpage provides multiple resources associated with the document Guidance for Improving Staff Engagement: Integrating Diversity, Equity, and Inclusion in SOAR Work.
• Hiring and Supervising Peer Providers to Support Integrated Care (https://www.thenationalcouncil.org/resources/hiring-and-supervising-peer-providers-to-support-integrated-care-3/): This slide presentation, developed by the SAMHSA–HRSA Center for Integrated Health Solutions, covers supervision and support of peer specialists, basic knowledge requirements, and challenges of peer supervision.
• SAMHSA Regional Offices (https://www.samhsa.gov/about-us/who-we-are/regional-offices): Administrators can contact the appropriate regional offices to learn which local programs are providing peer support services.
• State-by-State Directory of Parent Peer Support Training and Certification Programs (https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Parent-Peer-Support-Training-Directory_2020.pdf): This directory lists information on family peer worker certification programs for states that had them as of 2020.
• Substance Abuse Confidentiality Regulations (https://www.samhsa.gov/about-us/who-we-are/laws-regulations/confidentiality-regulations-faqs): SAMHSA provides fact sheets and answers to frequently asked question regarding the substance abuse confidentiality regulations at this site.
• Supervision of Peer Workers (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/brss-209_supervision_of_peer_workers_overview_cp6.pdf): This fact sheet describes and explains how to use a group of resources created by SAMHSA's BRSS TACS for people supervising peer specialists. Parts of this resource includes a:
  – Slide deck with trainer notes. (https://www.samhsa.gov/sites/default/files/guidelines_peer-supervision_ppt_withpresenternotes_cp2.pdf)
  – 1-page supervisor self-assessment. (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/guidelines-peer-supervision-2-self-assessment-cp9.pdf)
  – Supervisor resource list. (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/guidelines-peer-supervision-3-resources-cp4.pdf)
• TIP 35: Enhancing Motivation for Change in Substance Use Disorder Treatment (https://store.samhsa.gov/product/TIP-35-Enhancing-Motivation-for-Change-in-Substance-Use-Disorder-Treatment/PEP19-02-01-003): This TIP describes how substance use disorder treatment providers can use these approaches and strategies to increase participation and retention in substance use disorder treatment.

American Society of Addiction Medicine (ASAM) ASAM Criteria^®^ (https://www.asam.org/asam-criteria/about-the-asam-criteria): This resource includes criteria for placement, continued stay, transfer, or discharge of patients with addiction and co-occurring conditions.

Cal Voices’ Employer Toolkit: Implementing Essential Organizational Changes To Successfully Integrate Peers (https://15d85744-5333-41e2-91ff-18e506035f98.filesusr.com/ugd/44a48f_dfb043b9.pdf (https://15d85744-5333-41e2-91ff-18e506035f98.filesusr.com/ugd/44a48f_97fd3e1daf754ed3b3646388dfb043b9.pdf)): This toolkit will help guide agencies through the process of integrating peer workers into behavioral health programs.

COBRE Lecture Series: Compensating for Systems Failures: The Transformation of the Community Health Worker/Peer Recovery Specialist Roles During Covid-19 (https://www.youtube.com/watch?v=8WV5Qx2tYZo): The presenters discuss the transition of peer recovery specialists from systems navigators and resource brokers within settings that adopted recovery-oriented patient care to supporting the basic needs of clients who are confronting interlocking systems failures, especially in the fragmented and privatized housing and mental health markets.

Community Catalyst: Peers Speak Out: Priority Outcomes for Substance Use Treatment and Services (https://communitycatalyst.org/resource/peers-speak-out/): The report details the research findings and recommended actions for service providers, policymakers, and researchers.

Council on Accreditation of Peer Recovery Support Services:

• Accreditation Readiness Self-Assessment (https://caprss.org/accreditation-readiness-self-assessment/): This short self-assessment will help program administrators to determine whether their program is accreditation ready. It focuses on key criteria for each of the accreditation domains and standards.
• Accreditation Resource Book (www.manula.com/manuals/caprss/accreditation/main/en/topic/c-2017-caprss-council-on-accreditation-of-peer-recovery-support-services): This resource lists program-wide standards required for peer support specialist accreditation.

Diversity, Equity, Inclusivity & Belonging Resources (https://www.naatp.org/resources/dei): This National Association of Addiction Treatment Providers website provides a wealth of resources, including links to webinars, videos, manuals, a blog, research, and other publications to help organizations learn and implement DEIB best practices.

Diversity, Equity, and Inclusion (DEI) Organizational Assessment Tools: A Resource Guide (https://heller.brandeis.edu/iere/pdfs/dei_organizational_assessment_tools.pdf): The instruments included in the guide outline a set of dimensions through which DEI is assessed, with specific indicators to reflect the extent to which DEI is put into practice.

How to Organize a Town Hall Meeting: A Planning Guide (https://facesandvoicesofrecovery.org/wp-content/uploads/2020/04/2-How-To-Org-A-Town-Hall-Mtg.pdf): This advocacy guide offers step-by-step instructions for holding effective town hall meetings to support recovery efforts in the community.

Magellan Health Services, Inc.'s Effective Supervision of Peer Specialists (https://alphacarecms.magellanhealth.com/training2/peersupport/magellanmodule7/main.htm): Magellan Health Services partnered with the Depression and Bipolar Support Alliance to develop this online course on the practice, power, and potential of peer specialists.

Medicaid Health Homes (https://www.medicaid.gov/resources-for-states/medicaid-state-technical-assistance/health-home-information-resource-center/index.html): The Medicaid Health Home State Plan Option allows states to design health homes to provide comprehensive care coordination for Medicaid beneficiaries with chronic conditions. This website is the health home information resource center.

National Alliance for Recovery Residences’ (NARR) National Standard 3.0. Compendium (https://narronline.org/wp-content/uploads/2019/02/NARR-Standard-Compendium-v3.pdf): The NARR Standard provides guidance for certifying effective recovery residences and incorporates the collaborative values of acute care and social models of recovery.

National Association of Peer Supporters’ National Practice Guidelines for Peer Specialists and Supervisors (https://www.peersupportworks.org/resources/national-practice-guidelines/): This document outlines the core values of peer support and describes each value in practice.

National Association of Peer Supporters’ Supervision Resources (https://www.peersupportworks.org/resources/supervision-resources/): This webpage includes links to recent peer supervision resources from a variety of government and nongovernmental sources. Topics include training for peer supervisors, trauma-informed peer supervisory practice, and personnel policies.

National Association of State Mental Health Program Directors’ Supervisor Guide: Peer Support Whole Health and Wellness (https://www.peersupportworks.org/wp-content/uploads/2021/05/Supervisor-Guide-to-Peer-Support-Whole-Health-and-Wellness-c-2013.pdf): This manual contains information, resources, and strategies that supervisors and managers of community behavioral health agencies can use to successfully introduce the peer support whole health and wellness service and the wellness coach role into the Georgia service delivery system.

National Conference of State Legislatures: The Value of Certified Community Behavioral Health Clinics (https://www.ncsl.org/research/health/the-value-of-certified-community-behavioral-health-clinics-magazine2022.aspx): This website contains information on connections and coalitions of CCBHCs as well as funding mechanisms.

National Council for Behavioral Health's Certified Community Behavioral Health Clinics, Peer-Delivered Services and Peer-Operated Agencies: Opportunities for Collaboration and Expansion (https://www.thenationalcouncil.org/wp-content/uploads/2022/03/110920_CCBHC_Peer_Services_Mtg_Toolkit-2.pdf): This report discusses partnerships between certified community behavioral health clinics and peer organizations that provide valuable opportunities to ensure the delivery of fidelity-level peer services that are especially successful in engaging individuals who have not connected to or responded to more traditional treatment and rehabilitation approaches.

The Regional Facilitation Center's Substance Use Disorder Peer Supervision Competencies (https://oasas.ny.gov/system/files/documents/2019/12/peer-supervision-competencies-2017.pdf): This report from The Regional Facilitation Center in Portland, Oregon, contains a list of 20 core competencies for peer specialists supervisors, along with details for each core competency.

Resources for Integrated Care: Peer Supports (https://www.resourcesforintegratedcare.com/concepts/behavioral-health/peer_supports): This organization offers guidance to providers and agencies on how to add and coordinate care for individuals who are dually eligible for Medicare and Medicaid services. The website includes several resources to help reduce stigma, discrimination, and bias against peer specialists, including tip sheets and videos.

• Some states are expanding their Medicaid coverage of peer support services using guidance provided by a 2007 letter about reimbursement from the Centers for Medicare & Medicaid Services (CMS) (https://downloads.cms.gov/cmsgov/archived-downloads/SMDL/downloads/SMD081507A.pdf).

Strategies for Effective Peer Supervision (2018) (https://soundcloud.com/resourcesforintegratedcare/how-behavioral-health-organizations-can-advocate-for-peers-2018): This podcast is supported through the Medicare–Medicaid Coordination Office at CMS.

Utah Supervisor Guide for Peer Support (https://dsamh.utah.gov/wp-content/uploads/2020/09/Utah-Peer-Support-Supervisor-Guide-3-9-2020.pdf): This guide is intended for those who supervise peer support specialists, family resource facilitators, family peer supporters, and youth peer supporters.

William White's The Recovery Coach: ROLE CLARITY MATRIX (https://www.chestnut.org/resources/60ae2e1e-c67b-4fca-9610-21daf5b2ef5b/2016-Recovery-Coach-Role-Role-Clarity-Matrix.pdf): The Matrix was developed to track and depict the evolving roles and key differences among peer recovery coaches, professional recovery coaches, and addiction counselors.

### Training Manuals

Training manuals and toolkits can give the supervisor or administrator a sense of the roles, skills, and abilities of peer specialists. They also show peers what to expect if and when they undergo peer training. The following examples of peer training manuals and toolkits are included here only for information. They cannot be used in place of actual training.

• 2019 Peer Toolkit for Workplace Success, from Cal Voices’ Workforce Integration Support and Education (WISE) Program (https://bhdp.sccgov.org/sites/g/files/exjcpb716/files/calvoices-2019-peer-toolkit-for-workplace-success-handbook-2019.pdf)
• City of Philadelphia Department of Behavioral Health and Intellectual disAbility Services, Peer Support Toolkit (https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf)
• Connecticut Community for Addiction Recovery (CCAR) Training: Coachervision: A Model for Recovery Coach Supervision (https://addictionrecoverytraining.org/coachervision/)
• Department of Veterans Affairs, Peer Specialist Toolkit: Implementing Peer Support Services in VHA (https://www.mirecc.va.gov/visn4/docs/Peer_Specialist_toolkit_Final.pdf)
• Florida Department of Children and Families, Office of Substance Abuse & Mental Health, Florida Peer Services Handbook (https://nuance.myflfamilies.com/sites/default/files/2022-12/DCF-Peer-Guidance.pdf)
• McShin Foundation's Recovery Coach Manual for the Substance Use Disorder Recovery Program (https://mcshin.org/wp-content/uploads/2019/07/McShin-RCM_for-web.pdf)
• Mississippi Department of Mental Health Certified Peer Support Specialist Provider Toolkit (http://www.dmh.ms.gov/wp-content/uploads/2015/01/CPSS-Provider-Toolkit-Final2.pdf)
• OnTrackNY's Recovery Coach Manual (https://www.ontrackny.org/portals/1/Files/Resources/RecoveryCoach_2015.01.21.pdf)
• The Regional Facilitation Center's Substance Use Disorder Peer Supervision Competencies (https://oasas.ny.gov/system/files/documents/2019/12/peer-supervision-competencies-2017.pdf)
• Via Hope's Texas Certified Peer Specialist Program Policy and Procedure Manual (https://www.viahope.org/wp-content/uploads/2018/03/Via-Hope-CPS-Policy-and-Procedure-Manual-April-2018.pdf)

## Tools for Supervisors and Administrators

Sample Job Description for a Peer Specialist

Job Title: Outreach Peer Support Specialist

Summary: The Outreach Peer Support Specialist works with people in the community who need recovery support. Peer Support Specialists provide individual and group support in many settings and provide referrals for resources like withdrawal management, housing, outpatient treatment, clothing, food, and overdose prevention/Narcan training. This staff member also provides educational outreach to providers and community groups.

Job Responsibilities:

• Provides community outreach
• Provides individual recovery support
• Works with recovery support groups
• Provides information and referrals for community-based resources
• Serves as advocate for program participants and helps them in developing self-advocacy skills
• Completes all required documentation clearly and on time
• Communicates effectively and respectfully with all program participants, coworkers, and community partners
• Maintains positive relationships
• Completes all trainings as assigned
• Other duties and responsibilities as assigned

Qualifications: To perform this job successfully, an individual must:

• Show an understanding of, and belief in, the recovery process.
• Be a person with lived recovery experience, with a minimum 2 years of continuous recovery.
• Have positive communication skills.
• Be 21 years old or older.

Education or Experience:

• High School diploma or GED required
• Associates Degree or higher preferred
• State-certified recovery coach or plan to complete this within first year
• Understanding of community resources and the recovery-oriented systems of care model

Certificates, Licenses, and Registrations: Must have a valid driver's license, registration, and car insurance (Provide a copy of each to your manager.)

Other Skills and Abilities:

• Knowledge of basic crisis intervention, motivational interviewing, and some case management techniques
• Ability to act as an advocate for the needs of the person in recovery

Physical Demands:

• The physical demands described here are those an employee must meet to successfully perform the essential functions of this job. Individuals with disabilities may be given reasonable accommodations to perform the essential functions.
• While performing the duties of this job, the employee must stand, walk, use his or her hands, feel objects or controls, talk, hear, and smell.
• The employee frequently must reach with his or her hands and arms, climb or balance, stoop, kneel, crouch, and sit.
• The employee may need to lift up to 25 pounds.

Work Environment: The work environment described here is one an employee faces while performing the essential functions of this job. Individuals with disabilities may be given reasonable accommodations to perform the essential functions.

Source: Adapted from University of Massachusetts Medical School (2018).^771^

## Resources for People In or Seeking Recovery

SAMHSA:

• Learn the Eight Dimensions of Wellness (https://store.samhsa.gov/product/Learn-the-Eight-Dimensions-of-Wellness-Poster-/SMA16-4953): This poster encourages mental health consumers, professionals, and primary care providers to communicate about overall wellness.
• Know Your Rights. Rights for Individuals on Medication-Assisted Treatment (https://www.samhsa.gov/sites/default/files/programs_campaigns/medication_assisted/Know-Your-Rights-Brochure.pdf): This publication explains patient rights and federal laws that protect people receiving medication for opioid use disorder.
• SAMHSA's Pacific Southwest Mental Health Technology Transfer Center, COVID-19 and Mental Health Resources: Substance Use Recovery (https://cars-rp.org/_MHTTC/docs/COVID-19%20MH%20Resources-Recovery.pdf): This fact sheet lists resources for people in recovery, including mobile apps that can support recovery.

ADA National Network's Addiction, Recovery, and Employment Webpage (https://adata.org/factsheet/ada-addiction-recovery-and-employment): At this site, people in recovery who are interested in becoming a peer worker can get information on how the Americans with Disabilities Act (ADA) addresses a history of substance use disorder and recovery at different stages of the employment process.

Faces & Voices of Recovery's Personal Stories of Recovery (https://facesandvoicesofrecovery.org/resources/recovery-stories): This webpage offers personal stories about recovery by people from all walks of life. The site also offers a Mutual Aid Resources page (https://facesandvoicesofrecovery.org/resources/mutual-aid-resources/) that provides an extensive list of mutual-help recovery groups and resources for individuals in recovery.

National Disability Institute's Disability Benefits Counseling Services (https://www.nationaldisabilityinstitute.org/wp-content/uploads/2018/11/benefits-counseling-services.pdf): This fact sheet is a free resource for Social Security Administration disability beneficiaries returning to work.

Social Security Administration's Ticket To Work Webpage (https://choosework.ssa.gov/about/get-started-today/): This site provides employment support services for Social Security disability beneficiaries.

Wellbriety Recovery Circles (White Bison; https://whitebison.org/): This website offers culturally based recovery resources for Indigenous people.

### Peer Specialist Locator

SAMHSA:

• SAMHSA's National Helpline (1-800-662-HELP [4357]) (https://www.samhsa.gov/find-help/national-helpline): This is a free, confidential, 24/7, 365-days-a-year treatment referral and information service (in English and Spanish) for individuals and families facing substance use and mental disorders. This service provides referrals to local treatment facilities, support groups, and community-based organizations, including any program that provides peer support services.
• FindTreatment.gov (https://findtreatment.gov/): FindTreatment.gov is the most comprehensive resource for persons seeking treatment for mental and substance use disorders in the United States and its territories. FindTreatment.gov provides the ability to search for substance use and mental health facilities, healthcare centers, buprenorphine practitioners, and opioid treatment providers. Contact a treatment facility to ask about peer support services.

Faces & Voices of Recovery's Association of Recovery Community Organizations Member Listing (https://facesandvoicesofrecovery.org/arco/arco-members-on-the-map): This website lists recovery community organizations that offer peer support services and are members of the Association of Recovery Community Organizations.

ICAADA Credential Verification (https://icaada.org/credentials/credential-verification/): This locator can be used to identify every Certified Addiction Peer Recovery Coach in Indiana.

My Maps (www.google.com/maps/about/mymaps): My Maps is a no-cost tool to create local community-based asset maps by importing information from a spreadsheet or adding resources individually.

NAADAC's Organizational Members Directory (https://www.naadac.org/organizational-members-directory): The directory lists organizations and agencies that belong to this association for people who work in the substance use disorder treatment field. These organizations and agencies may provide peer support services themselves or know about peer support services in their area.

Ohio Department of Mental Health & Addiction Services’ Online Peer Supporter Supervision Training (https://www.eventbrite.com/e/ohiomhas-online-peer-supporter-supervision-training-tickets-159118113561): This free 4-hour training will help supervisors develop an understanding about the role of peer supporters, the responsibilities of a supervisor, and effective supervision strategies.

Veterans’ Health Administration (VHA) Substance Use Disorder Treatment Programs (https://va.gov/directory/guide/SUD.asp): This VHA webpage provides a map with links to state-by-state SUD treatment programs for veterans.

## Resources for Families of People In or Seeking Recovery

SAMHSA:

• Learn the Eight Dimensions of Wellness (https://store.samhsa.gov/product/Learn-the-Eight-Dimensions-of-Wellness-Poster-/SMA16-4953): This poster encourages mental health consumers, professionals, and primary care providers to communicate about overall wellness. More information can be accessed at https://www.youtube.com/watch?v=tDzQdRvLAfM and in the SAMHSA publication Creating a Healthier Life: A Step-by-Step Guide to Wellness at https://store.samhsa.gov/sites/default/files/d7/priv/sma16-4958.pdf.
• Family, Parent and Caregiver Peer Support in Behavioral Health (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf): This easy-to-read brochure explains the value of peer support in substance use disorder recovery.
• Family Therapy Can Help (https://store.samhsa.gov/system/files/sma13-4784.pdf): This booklet provides information about how family therapy can be useful for people in recovery from mental illness, substance use disorders, or both.
• Finding Quality Treatment for Substance Use Disorders (https://store.samhsa.gov/product/Finding-Quality-Treatment-for-Substance-Use-Disorders/PEP18-TREATMENT-LOC): This fact sheet serves as a guide for individuals seeking behavioral health treatment. It describes three necessary steps to complete before using a treatment center and the five signs of a quality treatment center.
• 988 Suicide & Crisis Lifeline (https://www.samhsa.gov/find-help/988): The Lifeline provides free and confidential support for people in distress, prevention and crisis resources for individuals, and best practices for professionals.
• Peer Support (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peer-support-2017.pdf): This easy-to-understand brochure provides general information on peer support.
• What Are Peer Recovery Support Services? (https://store.samhsa.gov/product/What-Are-Peer-Recovery-Support-Services-/SMA09-4454): This manual provides indepth information on peer support services.
• What Is Substance Abuse Treatment? A Booklet for Families (https://store.samhsa.gov/product/What-Is-Substance-Abuse-Treatment-A-Booklet-for-Families/SMA14-4126): This brochure helps family members of people with substance use disorders (SUDs) better understand different types of SUD treatment options and how to access family resources.

Administration for Children & Families (https://www.acf.hhs.gov/): This division of the Department of Health and Human Services promotes the economic and social well-being of families, children, individuals, and communities.

Adult Children of Alcoholics^®^ & Dysfunctional Families (https://adultchildren.org/): This 12-Step mutual-help program is for adult children of people with alcohol use disorder.

Al-Anon and Alateen (https://al-anon.org/): These 12-Step mutual-help programs are for family members, adolescent children, and friends of people with alcohol use disorder.

Center for Motivation & Change (https://motivationandchange.com/family-services/resources-for-families/): This website provides no-cost evidence-based resources to family members of people in or seeking recovery.

Children and Family Futures (https://www.cffutures.org/): This nonprofit organization provides consultation, training and technical assistance, strategic planning, and evaluation services focused on improving practice and policy at the intersections of child welfare, substance use and mental disorder treatment, and court systems.

Community Reinforcement and Family Training (CRAFT) (https://www.apa.org/pi/about/publications/caregivers/practice-settings/intervention/community-reinforcement): The CRAFT program is a nonconfrontational evidence-based intervention that helps family and friends develop effective strategies for helping their loved one who has substance use issues or challenges and for feeling better themselves.

Evidence Base for Avoiding Family Separation in Child Welfare Practice (https://www.aliainnovations.org/research-brief): This research brief discusses the impacts of separating children from parents during their recovery from substance use-related problems.

Faces & Voices of Recovery (https://facesandvoicesofrecovery.org/resources/mutual-aid-resources/): The site includes a webpage that provides an extensive list of mutual-help recovery groups and resources for families of individuals in recovery.

Families Anonymous (https://www.familiesanonymous.org/): This 12-Step mutual-help program is for families and friends of people who misuse substances or have a mental illness.

Friends of Recovery New York's Family to Family Recovery Resource Guide (https://preventioncouncilputnam.org/wp-content/uploads/2017/07/Family_to_Family_Resource_Guide.pdf): This resource guide is designed to help families of people who misuse substances learn about drug and alcohol addiction, recovery, and how to help others who are significant in the person in recovery's life. It includes basic education, links to online videos, and real-life stories from families of people in recovery.

Learn to Cope (https://www.learn2cope.org/): This peer-based education and support organization is for family members of people who misuse substances (with a focus on opioid addiction). It includes chapters in several states, an online forum, and face-to-face group meetings.

Nar-Anon Family Groups (https://www.nar-anon.org/): This 12-Step mutual-help program is for family members of people who are addicted to drugs.

National Alliance on Mental Illness’ Family-to-Family Program (https://www.nami.org/Find-Support/NAMI-Programs/NAMI-Family-to-Family): This peer-led family psychoeducation program is for families of people with mental disorders (including substance use disorders). The Family-to-Family class locator (https://www.nami.org/Find-Your-Local-NAMI/Affiliate/Programs?classkey=a1x36000003TN9YAAW) assists families with finding a free 8-week course for family caregivers of individuals living with mental illness.

National Association for Children of Addiction (https://nacoa.org/families/): This nonprofit organization offers resources for children, adolescents, and adult children of people who misuse alcohol and other substances and for families in recovery.

National Federation of Families (https://www.ffcmh.org/): This nationwide advocacy organization focuses on bringing lived experience to family support, including resources for peer specialists, family-run organizations (https://www.ffcmh.org/resources-familyorg), and webinars about family support.

National Institute on Drug Abuse, If You Have a Problem with Drugs: For Teens and Young Adults (https://archives.nida.nih.gov/publications/step-by-step-guides-to-finding-treatment-drug-use-disorders/if-you-have-problem-drugs-teens-young-adults): This website, for adolescents and young adults who misuse substances and their parents, answers common questions about drugs and drug problems.

Partnership to End Addiction (https://drugfree.org/get-support/): This website includes a parent blog, stories of hope from parents of children who misuse substances, and a parent helpline.

SMART Recovery^®^, Family & Friends (https://www.smartrecovery.org/family/): This program uses specific training techniques to explain how families and friends can help their loved ones move toward a more balanced and purposeful life. The website provides information about online meetings, a family message board, and links to a handbook and a facilitator manual (both can be purchased for a small fee).

### Family Peer Specialist Certification (Selected States)

The following resources provide Peer Specialist training and certification for families:

• Colorado's Peer & Family Specialist Certification (https://coprovidersassociation.org/certifications/peer-family-specialist-certification/)
• Florida's Certified Recovery Peer Specialist (https://flcertificationboard.org/certifications/certified-recovery-peers-specialist/)
• ICAADA Certified Addiction Recovery Coach (https://icaada.org/credentials/carc/)
• Idaho's Certified Family Support Specialists (https://healthandwelfare.idaho.gov/Medical/MentalHealth/PeerSpecialistsFamilySupportPartners/tabid/2935/Default.aspx)
• National Federation of Families’ National Family Peer Specialist Certification (https://www.ffcmh.org/certification)
• New York's Certified Recovery Peer Advocate–Family (http://www.asapnys.org/certified-recovery-peer-advocate-family/)
• New York's Family Peer Advocate (https://www.ftnys.org/training-credentialing/family-peer-advocate-credential/)
• Pennsylvania Certification Board (https://www.pacertboard.org/certifications)
• Utah's Family Peer Support Specialist (https://sumh.utah.gov/education/certification/peer-support)
• Wisconsin Certified Parent Peer Specialist (https://www.wicps.org/parent-peer-specialist/)

## Selected State Resources

The resources in this section include some helpful peer support–related material created by state agencies and by organizations with a state-specific focus. The websites of statewide peer specialist networks can also be a good source of information.

California Association of Social Rehabilitation Agencies’ Meaningful Roles for Peer Providers in Integrated Healthcare: A Guide (http://www.casra.org/docs/casra-meaningful-roles-for-peer-providers-in-integrated-healthcare-toolkit-11-13-14.pdf): This detailed 2014 guide covers topics that range from writing peer specialist job descriptions to creating job opportunities for peer specialists in an integrated healthcare setting, and from mentoring peer specialists to measuring the success of programs that use peer specialists.

Florida Department of Children and Families and Office of Substance Abuse & Mental Health's Florida Peer Services Handbook (https://nuance.myflfamilies.com/sites/default/files/2022-12/DCF-Peer-Guidance.pdf): This guidebook describes the roles of peer specialists and discusses the benefits of using them. It also addresses adding peers into the behavioral health workforce and provides tips for hiring and supervising peer specialists.

Indiana Association of Peer Recovery Support Services: (https://www.iaprss.org/): This website provides resources for advancing peer recovery support through education, collaboration, and professional development.

Montana's Peer Network (https://mtpeernetwork.org/): This website offers recovery podcasts, peer support services webinars and trainings, and topical resource lists.

Wisconsin Certified Peer Specialists Employer Toolkit (https://facesandvoicesofrecovery.org/wp-content/uploads/2019/07/Wisconsin-Certified-Peer-Specialists-Employer-Toolkit-.pdf): This toolkit reviews the benefits of using peer support services, discusses how to develop a peer workforce, and offers tips on creating a positive workplace for peer specialists.

Using a peer services agreement form sets out what people in recovery receiving PSS can expect of their peer workers and what programs expect of people in recovery. An example of such a form can be found through the PeerConnect Recovery Support Services webpage of the Alano Club of Portland (OR) at https://www.portlandalano.org/peerconnect. The forms can be adapted based on the unique needs of the people and communities served and the types of services provided at a given program.