# Chapter 7—How Family Peer Specialists Can Help Families Affected by Problematic Substance Use

KEY MESSAGES

• Families affect, and are affected by, a family member's problematic substance use, treatment, and recovery. Offering comprehensive care to individuals in recovery means including their families in the process as needed and desired.
• The lived experience of caring for a family member with problematic substance use is a key part of what family peer specialists offer families of people in substance use disorder (SUD) treatment. They have firsthand knowledge about coping with the effects of substance use–related problems on a family.
• Family peer specialists play a key role in helping families access recovery support resources and other services and systems that will be helpful to them during their loved one's treatment and recovery and can help improve quality of life for all family members—including the individual in recovery. Education empowers and enables families to be a source of positivity and strength for their family member with problematic substance use—and for one another. Family peer specialists can educate family members of individuals who have problematic substance use to better understand SUDs, treatment, and recovery.
• Families often know that they need help but don't know how to get it. Family peer specialists in SUD treatment programs can connect them to resources that will enable them to support the individual in recovery, and all family members, in living the healthiest life possible.
• While more programs are implementing family peer support, the impact of and outcomes related to the role of family peer specialists in supporting families of individuals in recovery are still emerging and require additional attention.

Substance use disorders (SUDs) are a major stressor on families, potentially causing significant problems with physical and behavioral health, work and education, finances, housing, social relationships, and the criminal justice system. Families and loved ones may respond with coping mechanisms that can be counterproductive to other family members and the person with the disorder. Family members of a person in or seeking recovery may have needs related to the loved one's treatment, including basic education about SUDs, treatment, and recovery as well as support needs of their own (e.g., instrumental support, such as transportation, or emotional support, such as comfort, care, and help with improving social relationships).

Each family can be viewed as a system, consisting of different members. A change affecting one family member can impact the entire family system. A family member's problematic substance use can create significant challenges for the family system, during treatment and throughout recovery. Therefore, recovery support may be necessary for both the individual who has problematic substance use and the entire family system.

Because problematic substance use can affect the entire family, SUD treatment programs that don't address family members’ needs, or that exclude them from treatment and recovery activities, can make it harder for both the family and the individual in or seeking recovery to get and stay healthy. Just as individuals who have problematic substance use can benefit from working with peer specialists who have lived experience with SUDs, family members of those in or seeking recovery can also learn from other family members who have walked the same path. By drawing on their knowledge and unique lived experience of caring for a family member with an SUD, family peer specialists in SUD treatment programs can be powerful role models and play a key role in providing education, support, and linkages to resources that many family members want and need. However, family peer support is an emerging intervention. Although more programs are implementing these types of supports, the effectiveness of family-based peer support services (PSS) is an area that requires further attention and study.

Chapter 7 is geared toward SUD treatment providers and explains why families of individuals in or seeking recovery might need PSS. The chapter describes how family peer specialists working in an SUD treatment program or related service setting can meet families’ needs by linking them with family-based PSS. This chapter identifies family-focused PSS resources and addresses:

• How family-focused PSS benefit families of people with problematic substance use.
• How family peer specialists can support family members in addressing their individual needs.
• How family peer specialists can engage families in their loved one's SUD treatment, recovery, or both by offering education, support, and linkages to resources.
• The many roles family peer specialists fill and specific services they offer to families of individuals in or seeking recovery.

Chapter 6 provides information on how family members of individuals in or seeking recovery can become family peer specialists and discusses training and certification processes.

This chapter includes brief examples of interactions between peer specialists and individuals in or seeking recovery. These examples are simplified for demonstration purposes and may not reflect the complexities or nuances of actual peer relationships.

RESOURCE ALERT: SUBSTANCE USE DISORDER TREATMENT AND FAMILY THERAPY

The Substance Abuse and Mental Health Services Administration's Treatment Improvement Protocol 39, Substance Use Disorder Treatment and Family Therapy (https://store.samhsa.gov/product/treatment-improvement-protocol-tip-39-substance-use-disorder-treatment-and-family-therapy/PEP20-02-02-012), contains indepth information about problematic substance use, the family system, and recovery support.

## Effects of Problematic Substance Use on the Family

There is no single definition of family. For this Treatment Improvement Protocol, “family” includes the people who the individual in or seeking recovery feels closest to emotionally. Asking individuals who are in or seeking recovery about the people they are closest to, or consider the most important in their lives, can help providers learn more about their unique concept of family. They could name:

• Traditional family members, like blood relatives and extended family (including stepfamily, in-laws, and adopted family members).
• Nontraditional family members (e.g., foster family members, unmarried partners).
• Nonblood relatives or friends (e.g., close friends, godparents, godchildren, members of a shared residential community such as recovery housing).

The individual in or seeking recovery may or may not live under the same roof with the people they think of as family. Providers do not decide who an individual who is experiencing problematic substance use considers family. Family is defined by the individual in or seeking recovery and will be different for each person. In many cases, how the family is addressed depends on who is identified as “family” when the individual enters treatment. Family peer specialists in SUD treatment programs work with many different family members, such as parents of adolescents with problematic substance use, spouses who are not in or seeking recovery, and adult children who continue to be closely involved with their parents into adulthood.

### Families and Recovery From Problematic Substance Use

Families may play a central role in the life of an individual in or seeking recovery.^700^ Substance use–related problems take a significant emotional, social, and financial toll on the relatives and close friends of the more than 46.3 million Americans ages 12 and older with a past-year SUD.^701,702^ People with problematic substance use often have family members who also have issues with substance use, which can make initiating and maintaining their recovery harder. Furthermore, families of people with SUDs or with co-occurring mental and substance use disorders often:

• Provide direct care for their family member.^703,704^
• Help pay for the high cost of SUD treatment, which can be a burden even with health insurance.^705,706^
• Are involved in helping their family member start and remain in treatment.^707^
• Take on roles that their loved one cannot fill because of their problems with substance use (e.g., caring for a child and supporting a significant other).^708,709^
• Experience caregiver-related stress and burdens from looking after their family member with problematic substance use. This stress often places caregivers at an increased risk for chronic medical and psychiatric problems.^710,711,712,713^
• Feel responsible or blamed for their family member's substance use or recovery.^714^
• Feel the need to protect other family members from behaviors related to problematic substance use.^715^
• Feel guilty about blaming or mistrusting their loved one, which can lead to social withdrawal or negatively affect relationships with others—especially their relationship with the individual in recovery.^716,717^
• Feel shame and experience stigma and isolation associated with their loved one's substance use–related problems.^718^

Some family members may have negative attitudes toward SUD treatment and recovery, including not supporting the individual with their recovery^719^ or denying that SUD is a disease.^720,721^ Families also may have poor communication or unhealthy relationships, which can complicate the recovery process.^722,723^ Additionally, family members may have their own views and expectations of what recovery looks like, and their loved one may not be meeting those expectations. Therefore, families may need support to understand that there are multiple pathways to recovery for those with problematic substance use.

Family systems theory helps to explain how families organize themselves through their interactions, including around a loved one's problematic substance use. All members of a family play a role in how the family functions. Families will try to maintain a steady state (or homeostasis) when facing challenges related to problematic substance use.^724^ Understanding the roles members play, including how homeostasis affects family dynamics, can help inform efforts to support the family.

Families can influence a person's problematic substance use, treatment, and recovery.^725^ Family involvement can increase an individual's chances of succeeding at treatment and recovery. Research has shown that couples- and family-based treatments can be effective for individuals recovering from SUDs.^726,727^ For example, family member involvement in treatment plans for adolescents in outpatient SUD treatment can:

• Improve treatment engagement.^728^
• Increase treatment retention.^729^
• Enhance family functioning.^730^
• Reduce short- and long-term substance use.^731,732,733^

RESOURCE ALERT: COMMUNITY REINFORCEMENT AND FAMILY TRAINING

Community Reinforcement and Family Training (CRAFT) is an evidence-based approach to helping spouses, parents, and siblings of people with problematic substance use. It helps family members get the person into SUD treatment while improving their own self-care.^734^ CRAFT has been shown to be effective at helping people with substance use–related problems enter treatment, while reducing depression and other mental strains family members may be experiencing, improving their mental health, and increasing relationship happiness.^735^ The Center for Motivation & Change website (https://motivationandchange.com/family-services/what-is-craft/) contains more information about CRAFT.

## Family Support Needs

Many families need support to manage the stress of having a loved one with substance use–related problems in their lives because:^736^

• Problematic substance use is harmful to all family members’ development and health.
• Problematic substance use can harm intimate family relationships; parent–child bonding; sibling relationships; kinship networks; and family roles, rules, rituals, and relationships.
• SUDs and related problems can be passed down from generation to generation, both genetically and through learned behavior.
• Recovery can be a difficult time for families. Individuals in or seeking recovery may struggle emotionally and physically as they address their problematic substance use. This can destabilize families who don't receive strong support during the process.
• Family members’ physical health may have been neglected for years.
• Family members may have to take on added responsibilities while their loved one is in treatment or focusing on recovery.
• Family members can develop unhealthy behaviors as a result of the stress of a loved one's problematic substance use.

Family members of individuals in or seeking recovery have specific education, skill-building, emotional, resource, and advocacy needs. For instance, partners of people in the early stages of recovery from problematic substance use may:^737^

• Have difficulty adjusting to and expressing feelings about their partner's recovery.^738^
• Experience loneliness and separation (e.g., when the individual in or seeking recovery enters residential treatment).
• Struggle with changes in intimacy and communication with their partner.^739^
• Feel threatened by their partner forming new and emotionally intimate bonds with others in or seeking recovery (e.g., other participants in mutual-help groups) or spending much of their time participating in recovery activities that do not involve the partner.
• Struggle with no longer being the person's only source of support.
• Feel that their partner has made recovery, not the relationship, the primary focus and top priority.
• Feel left out of the recovery process (especially if not invited to participate in services).^740^
• Have difficulty adjusting to various life changes that no longer include shared activities, events, people, or places, and may feel grief associated with these losses or changes.

Addressing unmet needs is critical in helping families connect completely to the recovery process. Family peer specialists support families’ needs by sharing their lived experience with similar problems; knowledge of family-based resources available; and understanding of how to navigate the healthcare, behavioral health, and other service systems. Family peer specialists also must recognize that family dynamics differ among cultural groups. Being culturally responsive ensures that providers are better serving the individual needs of families. (Chapter 3 has more information about cultural responsiveness and peer worker functions, and Chapter 6 has more information about training related to cultural responsiveness.)

FAMILY PEER SPECIALIST WORK SETTINGS

Family peer specialists work in a variety of settings and contexts, including with families involved in the child welfare system and families of adolescents with problematic substance use, among others. For example, a family peer specialist in the child welfare system may serve as an ally to a parent whose child is involved in the system. The family peer specialist may be a parent in recovery who faced a similar situation with their child.^741^ The family peer specialists may help engage the parent in services to improve outcomes for both the parent and their child. Although family peer specialists work in other settings, this chapter focuses on the roles of family peer specialists in SUD treatment programs.

Family peer specialists in SUD treatment programs can fill many roles to meet the needs of families affected by problematic substance use, such as:^742^

• Education/informational support. Family peer specialists give information about available resources to support families, including the purpose of family-focused PSS and how these services can help families.
• Skills development support. Family peer specialists support families in developing skills to better communicate with their loved one with problematic substance use, solve problems, manage crises, cope with stress, and deal with emotional difficulties.
• Emotional support. Family peer specialists assist families in feeling understood, heard, validated, and supported. They listen openly and without judgment, share their experiences, and offer support. They do not lecture or tell families what to do.
• Instrumental support. Family peer specialists assist families in accessing resources for everyday needs, like transportation, child care, respite care, and safe and stable housing.
• Advocacy. Family peer specialists support families who are interested in advocating for and with individuals in or seeking recovery. They can educate families about their rights (especially parental rights in the case of children and adolescents), teach them about substance use–related problems and the power of treatment and recovery, be a voice in the community and speak with local leaders and policymakers, and guide them on working confidently and cooperatively with the individual's healthcare and behavioral health service providers.

Family members have their own separate recovery processes and will need to develop individualized recovery plans that addresses issues such as self-care and boundaries.

Providers shouldn't wait for family members to ask for assistance. However, if a family turns down assistance, their wishes should be respected. Not all family members, even those close to the individual who has problematic substance use, want to participate in all components of recovery. That's okay. Providers can always gently revisit the idea with the family later.

Providers should offer the family linkages to PSS—for example, basic education or informational brochures about such services—or the provider can introduce them to a family peer specialist if one is available. When family members receive support from a family peer specialist, which can happen no matter where their loved one is in their SUD recovery plan, it's important to discuss privacy and confidentiality rights with everyone involved, including the person in or seeking recovery and their family members. People in or seeking recovery have a right to privacy and confidentiality. Some individuals may not want providers or other members of their treatment team to share certain information with their family members. Providers should work to encourage and improve communication among family members, including being assertive, clear, direct, and respectful, as outlined in the Community Reinforcement and Family Training (CRAFT) approach discussed earlier.

Although communication with the family and the clinical team should be closely coordinated, family peer specialists must maintain strict confidentiality in their work with families. Family peer specialists may be inclined to share information with family members that they think may be helpful; however, they should consider each member's need for privacy and confidentiality in these discussions. Family peer specialists should develop a confidentiality agreement with families to clarify informational boundaries and ensure that all parties agree to maintain confidentiality, except in instances where personal safety or the safety of others may be at risk.

IDENTIFYING THE CLIENT: RESPECTING PRIVACY AND OBSERVING CONFIDENTIALITY WHEN WORKING WITH FAMILIES

Family peer specialists work primarily with the family members of the individual who has problematic substance use. Although the goal of family-based PSS is to help the family, these services can indirectly help the individual in recovery as well; however, they are not the family peer specialist's focus. Like those in recovery, all family members have a right to privacy and confidentiality. Some may prefer that family peer specialists not share certain information with the person in recovery. Family members must give the family peer specialist permission to share information with the individual in recovery.

## Educating Families About the Benefits of PSS

Families need information about family-focused PSS to understand how these services can help them. Many people have never heard of PSS and are unaware of their benefits. Learning what family peer specialists in SUD treatment programs do and how their services are used throughout the continuum of care empowers families to commit to supporting the person in or seeking recovery.

Family members may know of family therapy, but they may be unfamiliar with the term “family peer specialist.” Providers can help families understand not only the peer specialist's role in the context of the SUD treatment program, but also the benefits of PSS. Specifically, families need to know that family peer specialists:

• Have lived experience as a partner, parent, or other close relative or friend of a person with problematic substance use.
• May be trained (and in some states certified) in providing family peer support and teaching families the skills to help them with recovery.
• Are supervised by an SUD treatment or recovery services provider.
• Can help navigate the many adult and child systems of care that the family may need to access (e.g., physical health, mental health, substance use, education, criminal justice).
• Know how to access SUD treatment and recovery services.
• Help families identify and link to family-based resources.
• Can support families in developing their own person-driven wellness plans.
• Advocate for recovery and the recovery community and help family members be advocates for themselves and the individual who is recovering from problematic substance use.

Families should know what to expect when working with family peer specialists in SUD treatment programs. Providers should plan to discuss:

• What family peer specialists do.
• What family peer specialists do not do, such as:
  – Provide treatment (e.g., therapy, medication).
  – Tell families what to do.
  – Provide information about an individual in or seeking recovery without their permission.
  – Teach religious doctrine or promote their own religious beliefs.
  – Give medical or legal advice.
• The details of the program and the family-based PSS available within that program. This includes discussing the importance of clear boundaries and letting them know that PSS are offered throughout recovery and are not just a one-time service.

Families should understand that PSS are not always available in SUD treatment programs. These services are available in many other settings, and family-focused peers may provide SUD recovery support in any of these settings, which include:

• Mental health service programs.
• Recovery community organizations (RCOs).
• Hospitals (e.g., emergency departments).
• Problem-solving courts and juvenile justice agencies.
• Child welfare agencies.

Families can connect with family PSS by speaking with the individual in or seeking recovery's treatment provider, peer support provider, case manager, or a local RCO. Families can also contact a national family peer support organization to ask about local services, such as a local RCO. (The appendix at the end of this chapter includes a list of family-based PSS organizations and mutual-help programs.)

MAKING A DIFFERENCE FOR FAMILIES

A 2018 study looked at the activities of 28 family mentors working with more than 780 families experiencing child mistreatment and parental SUD.^743^ The services family mentors provided to families and individuals in recovery included:

• Recovery support, such as:
  – Recovery coaching and encouragement.
  – Education on how to develop daily living skills.
  – Accompanying a parent with an SUD to court.
  – Accompanying the parent in recovery to SUD treatment.
• Services for child safety and well-being, such as:
  – Sober parenting coaching.
  – In-home education about child safety.
  – Accompanying a parent with an SUD on child visitation appointments.
• Personal contact, including face-to-face meetings and phone calls.
• Coordinating services with the parent, including:
  – Following up on community resources and referrals given to the parent.
  – Coordinating child services.
  – Working with the SUD treatment provider and the parent.
• Completing other tasks for the family, like seeking support.

## Family Peer Specialists and PSS for Families

### Benefits of Peer Support for Families

As previously mentioned, the study of PSS for families of individuals in recovery is an emerging field. Robust research on PSS for family members of people with problematic substance use is lacking. Most studies have focused on PSS for family members of people with mental health needs—often for parents of children with mental illness. Though there are differences between PSS for substance use–related problems and services to support mental health, these studies can still provide valuable insights into PSS for problematic substance use. In fact, some of the research includes SUDs among the behavioral health concerns studied. Similarly, there is limited research available on problematic substance use and family recovery. What is known indicates that family members facing these challenges should be approached with compassion and offered resources to support their recovery.

Studies have shown the value of family PSS. For instance, a 2017 study examined the effects of family peer services among nearly 600 members of Learn to Cope (https://learn2cope.org/), a peer-led family support organization for loved ones of people recovering from SUDs (primarily opioid use disorder; OUD).^744^ Researchers found that:

• Members of the organization thought participating in Learn to Cope was moderately helpful for getting their loved one access to and engaged in SUD treatment.
• Visitors to the Learn to Cope website found the online forum helpful for handling, understanding, and learning more about their loved one's SUD.
• Members reported that joining Learn to Cope:
  – Increased their understanding of SUDs.
  – Reduced their feelings of self-blame.
  – Lowered their stress.
  – Improved their coping abilities.
  – Helped them communicate better with loved ones.
• Of the nearly 66 percent of service recipients who reported receiving naloxone training, 86 percent received naloxone training through a Learn to Cope meeting, which they found “very helpful.”
• Members liked that the organization's services:
  – Were informative.
  – Instilled a sense of connectedness and belonging.
  – Demonstrated the value of shared experience.
  – Showed them that they are not alone.
  – Gave them feelings of hope and inspiration.
  – Were an outlet for them to share their emotions and tell their story.
  – Improved their self-esteem and self-worth.

### Challenges of Working With Families

Although the core PSS for families are similar to those for individuals in or seeking recovery (e.g., education, support, linkages to resources), working with families can be challenging for peers who have worked only with those in or seeking recovery. Family peer specialists who learn about potential family challenges ahead of time and have a plan for responding to or preventing such challenges can help keep families involved in family-focused PSS and in their loved ones’ treatment, recovery, or both.

#### Negative Family Dynamics and Unhealthy Relationships

Understanding how an individual in or seeking recovery's family functions (or gets along with one another) is very important. Unhealthy family dynamics can act as a barrier to recovery or increase problematic substance use. They can also prevent families from engaging in family PSS. These include:

• Negative attitudes about SUD treatment and recovery, including a lack of support^745^ and the presence of problematic substance use in other family members.^746^
• Negative attitudes or feelings toward the individual in or seeking recovery (e.g., denying that there's a real problem or that SUD is a disease, blaming themselves or others for the person's problematic substance use, stigma).^747,748^
• Poor communication or unhealthy relationships among family members (e.g., stressful relationships, high-conflict relationships).^749,750^
• A lack of family boundaries.^751,752^
• Disempowering the individual in or seeking recovery or other family members—that is, doing or saying things that support the individual's problematic substance use or make recovery more difficult. This includes making statements like:
  – “Why do you have to totally stop drinking? It's just one glass of wine. What's the big deal?”
  – “You don't really have to go to one of those silly 12-Step meetings tonight, do you? Let's go catch a movie instead. You can go to your meeting next week.”
  – “You don't have a problem. Everybody drinks sometimes. You just don't know how to have fun.”
  – “If you start treatment this weekend, what's the harm in having one last hit for old times’ sake?”
• Destructive or other harmful parenting styles (e.g., open substance use, child abuse or neglect, lack of parental monitoring, and inconsistent communication patterns with children and adolescents).^753,754,755^
• Intimate partner violence.

Positive family relationships can support SUD treatment and recovery and protect against recurrence, thereby improving the well-being of all family members.

Families can learn strategies to improve functioning and overcome unhealthy patterns, even if the individual in or seeking recovery's treatment and recovery are not progressing. Families with traits and dynamics that do support recovery may be willing to participate in family-based PSS. Such recovery-supportive traits include:

• Honesty.^756^
• Having a positive attitude toward treatment.^757^
• Emotional closeness.^758^
• Consistent and reliable support.^759^
• Parental warmth.^760^

Family dynamics can change as a person enters and progresses in SUD treatment and recovery. Families who at first were not receptive to family-based PSS may become more interested in participating as time goes on. Therefore, to successfully engage some families in PSS, providers may need to check in with family members on occasion about their desire for family PSS.^761,762^ Family peer specialists can implement motivational interviewing strategies to help family members resolve their ambivalence about participating.^763^ (More information about motivational interviewing can be found in Chapter 3.)

#### Lack of Education About Substance Use–Related Problems

Families may need basic information about problematic substance use, treatment, and recovery to understand the value of engaging in family-based PSS. Misunderstandings about substance use–related problems and recovery can lead to misconceptions, negative attitudes, and hurtful behaviors that make recovery more difficult. This, in turn, may negatively influence the well-being of the family and their interest in participating in family PSS. Family members who have not been affected by problematic substance use cannot fully understand what it's like to have an SUD or to be in treatment or recovery. They may not understand the value of and need for family-based PSS.

By educating families about problems related to substance use and the difficulties families of individuals in or seeking recovery often face, providers can help families develop a more open, accepting, and tolerant attitude. Families need information about:

• SUDs, including that they are chronic illnesses (not indicators of failed morals or weak character).
• Recovery and its many pathways (including family recovery, and with medications).
• Recovery statistics and stages of personal and family recovery.
• Common myths about problematic substance use.
• The effects of substance use–related problems on the family and the effects of the family on substance use–related problems.
• How families affect SUD treatment and recovery and vice versa.
• The ways in which families can achieve their own recovery from the effects of the individual's problematic substance use.
• How families can unknowingly hurt the individual's recovery.
• Medications to support recovery, including training on naloxone administration.
• Appropriate boundary setting.
• Family crisis survival strategies.

Many people falsely believe that problematic substance use is easy to control and results from lack of willpower. Such attitudes are harmful and may leave individuals in or seeking recovery feeling unsupported, judged, and belittled. To correct or prevent harmful and stigmatizing beliefs, families need to know that:^764,765^

• Using language that doesn't stigmatize an individual or substance use–related issues is an important first step to developing nonjudgmental and understanding attitudes toward individuals in or seeking recovery.
• Problematic substance use differs from person to person in its onset, course, symptoms, and more. No two people will experience their illness, or their recovery, in the same way. Families should not compare their loved ones’ experiences with anyone else's experiences.
• Some SUDs are acute and may respond to treatment quickly, whereas others are more severe, complex, and longer lasting. Yet personal and family recovery is possible across the entire continuum.
• Most substance use–related problems require long-term management, often involving more than one type of treatment. They are not fixed instantly by residential/inpatient treatment or by taking medication alone (although inpatient treatment and medication can be very effective for some people—and for people with opioid use disorder can be lifesaving).
• Recovery is possible for everyone and happens often. A person may experience several recurrences of problematic substance use before they reach long-term recovery. The individual who is experiencing problematic substance use and family members should not give up hope that recovery is possible. Introducing family members to those who have sustained recovery for long periods of time can be encouraging and reinforce that recovery is possible for everyone.
• Recurrences can happen. They can be part of the recovery process and do not mean that the person's recovery efforts have not been successful. Success is defined differently for each individual, just as recovery is self-defined. There are multiple pathways to recovery.
• Family and friends are natural supports and are important to a person's long-term recovery.
• Time and effort are needed to address a family member's substance use–related problems (e.g., health problems, legal issues, child welfare and custody issues). Some problems require help from a variety of professionals, including SUD treatment and mental health service providers.
• Individual and family-based peer support can improve a person's chances of long-term recovery.

FAMILY BENEFITS OF A LOVED ONE's RECOVERY

Family members who recognize the value of recovery are more likely to engage in and support their loved one's use of PSS. Providers can share with families the benefits that other families have enjoyed from their loved one's recovery.

Researchers in the United Kingdom asked more than 1,500 family members of individuals in recovery to describe their experiences of their loved one's SUD recovery.^766^ Results from the Families Living in Addiction and Recovery survey found that families saw many improvements in their finances; family and social life; health; and legal, work, and education situations. Families also saw improvements in their loved one's life as they entered and maintained recovery. Improvements in individuals in recovery included:

• Increases in the likelihood of paying bills.
• Decreases in financial debt.
• Regaining custody of children.
• Reductions in the number of violent behaviors directed toward the family.
• Increases in participation in family activities.
• Better care of health.
• Fewer arrests.
• Decreases in the likelihood of driving while under the influence of alcohol or other intoxicating substances.
• Increases in keeping a job.
• Decreases in the likelihood of getting fired or suspended from work.
• Increases in positive work performance evaluations.

The Substance Abuse and Mental Health Services Administration (SAMHSA) has several resources to help families learn more about substance use–related problems, treatment, and recovery:

• Family Therapy Can Help. This booklet provides information about how family therapy can be useful for people in recovery from mental illness, problematic substance use, or both. (https://store.samhsa.gov/sites/default/files/d7/priv/sma13-4784.pdf)
• What Is Substance Abuse Treatment? A Booklet for Families. This brochure helps family members understand different SUD treatment options and how to access family resources. (https://store.samhsa.gov/product/What-Is-Substance-Abuse-Treatment-A-Booklet-for-Families/SMA14-4126)

More resources are available in Chapter 8.

RESOURCE ALERT: FRIENDS OF RECOVERY–NEW YORK: FAMILY TO FAMILY RECOVERY RESOURCE GUIDE

Friends of Recovery–New York has published a resource guide for families of people with problematic substance use. It explains SUDs, recovery, and how families can help themselves as well as their loved one. The Family to Family Recovery Resource Guide includes basic education, links to online videos, and real-life stories from families of individuals in recovery. Topics include:

• An explanation of SUDs and the concept of addiction.
• Effects of substance use–related problems on the family.
• The importance of self-care for families affected by problematic substance use.
• Recognizing signs of SUDs.
• Recognizing and responding to overdose.
• SUD treatment options.
• Ways to help a loved one access treatment and other recovery services (including PSS).
• Navigating SUD treatment and recovery systems.
• Payment options and ways to access private and public health insurance.

(https://preventioncouncilputnam.org/wp-content/uploads/2017/07/Family_to_Family_Resource_Guide.pdf)

#### Ambivalence About Family-Based PSS

Families of an individual in or seeking recovery may feel isolated or struggle with stigma and shame related to their loved one's problematic substance use. This may contribute to feelings of ambivalence about engaging in family peer services.^767^ Some family members may be unsure if they want family PSS or may not understand how family-based PSS can help them. Working with family members who have mixed feelings about family PSS can be frustrating; however, ambivalence is normal. Many strategies can help families understand the benefits of family-based PSS. The following strategies help prevent initial reluctance and can be used with all family members, regardless of whether they have decided to participate in family PSS:

• Providers shouldn't try to change or “fix” a person who clearly indicates disinterest. Doing so may cause negative or hostile interactions that push the family member further away and strengthen their resistance. Watch for signs of transference, wherein a family member may unconsciously direct their feelings for the individual in or seeking recovery toward the family peer specialist.
• Providers should try to find out why the family member doesn't want to engage in family PSS. Basic education may help them understand problematic substance use and the value of participating in family PSS. A little information can go a long way.
• Providers should keep a warm and nonjudgmental attitude. Whatever mixed or negative feelings family members have toward family PSS, they are likely not about the provider. Such feelings are often about them and their own beliefs and experiences.
• Providers should include family members by asking—not telling—them what their needs are and what services would benefit them most. Providers should not assume that they know the family member's wants and needs better than they do.
• Providers should not push family members. Change can be tough and does not happen overnight. Some family members may need more time to think about the information they receive, especially if they are dealing with longstanding negative beliefs or feelings about problematic substance use.
• Providers should recognize that family members have different needs. Each family member will have their own journey and may benefit from working with their own peer specialist, independent from the family unit. How families choose to work with peer specialists may also evolve over time. Supports should be based on the needs of the family and will not necessarily reflect what the family peer specialists needed in their own recovery.
• Providers should find out what family members may be willing to do and offer options. For instance, would they be willing to talk to a member of a family support group on the phone or virtually rather than go to an in-person family-based support meeting? Discuss other barriers to participating, such as transportation difficulties or childcare needs, along with options for addressing these barriers.
• Providers should offer examples of hope through success stories that show how family PSS have benefited others.
• Providers should focus on those who are ready to receive support. Some people simply do not wish to access PSS. Try different engagement strategies, but if none are successful, move on and work with the family members who do want to participate. Provide families information in an accessible way.
• Providers should reinforce the idea that everyone is responsible for their own recovery. Each family member should focus on their own recovery journey and cannot be responsible for the actions of other members of the family, including the individual in or seeking recovery. Avoid telling family members that “if they don't get well, their loved one will not get well.”

#### Practical Barriers

Practical issues may prevent family peer specialists working in SUD treatment programs from engaging fully with family members of the individual in or seeking recovery. For instance:

• The individual's family might live far away and be unable or unwilling to use telehealth or remote services (e.g., telephone- or web-based family peer support).
• Family members might be hard to reach because they are incarcerated or are experiencing housing insecurity or homelessness.
• Working with family members might not be possible if there are safety concerns, such as an abusive family member in the household.
• Family members may not be able to get to the family peer specialist because they lack transportation, or they feel unsafe traveling to the meeting site.
• Family members may not have access to child care.
• Family members may not have sufficient technology or be comfortable with how to use the technology needed to support ongoing communication or virtual visits with a family peer specialist.
• Family members may lack access to a private space, which can hinder their ability to meet with a family peer specialist and speak freely about their concerns.

If a family peer specialist notes safety concerns among a family they're supporting, the family peer specialist should work with their supervisor to determine how best to support the family and address the issue (e.g., whether to involve law enforcement or child protective services). This includes mandatory reporting for suspected child abuse or neglect.

Family members who are willing to participate but do not live nearby can join meetings and discussions by telephone or using web-based services. Family peer specialists in SUD treatment programs should connect family members who need assistance with child care to available resources in their community.

## Conclusion

Problematic substance use can negatively influence the health and well-being of families, and SUDs often have long-lasting effects on family members of individuals in or seeking recovery. Family members play a big role in their loved one's recovery success. Though the impact of and outcomes related to the role of family peer specialists in supporting families of individuals in or seeking recovery is still emerging and requires additional attention, more programs are implementing family peer support. Family peer specialists in SUD treatment programs help families in crisis get the information, support, and resources they need. This effort can indirectly help the individual in or seeking recovery as well, although family-based PSS focus on the family itself. This work is critical to reducing the occurrence and influence of SUDs throughout communities everywhere. To receive the full benefits a family peer specialist can offer, families need to understand what exactly these services are and how they aid in recovery.

## Appendix

### Case Study

The case study below provides an example of the role of family peer specialists in supporting family members of a loved one with problematic substance use. It illustrates for providers how family peer support can help families that are facing difficulties related to problematic substance use, including strategies for engaging families and key activities offered through family peer support. Providers can use the case study to learn more about how family peer specialists support family members and the types of challenges families may be facing.

The case study highlights key concepts discussed in this chapter:

• Engaging willing and supportive family members in the recovery process gives the individual who is experiencing problematic substance use a better chance of successful recovery.
• Families of individuals in recovery often have unmet needs, whether informational, emotional, instrumental, affiliational, or any combination thereof.
• Family peer specialists have lived experience that gives families of individuals in recovery an opportunity to learn firsthand how best to cope with their loved one's problematic substance use and recovery.

#### How To Approach the Case Study

This case study describes the experience of the mother and the wife of a man, Andrew, who has recently completed inpatient treatment for OUD. His family members are speaking with a family peer specialist at the outpatient treatment program where Andrew attends counseling support groups, sees a psychologist for individual psychotherapy, receives medication treatment for OUD, and meets with a family peer specialist. The story consists of an introduction outlining the family's and Andrew's stories, including presenting concerns and treatment needs; learning objectives; the family–peer dialog; and a summary.

INVOLVING ANDREW's FAMILY IN THE RECOVERY PLAN

Overview

This story illustrates how family peer specialists can engage family members in their loved one's recovery by building rapport and acknowledging the family's struggles. By exploring what the family knows about problematic substance use and recovery, family peer specialists learn what education might be supportive. Questions about support and access to services help family peer specialists determine which linkages to resources to offer the family to address the family's specific needs and wishes.

Andrew's Case History

Andrew is a 28-year-old man with a 10-year history of OUD. About 2 months ago, Andrew entered inpatient withdrawal management and treatment after his wife, Rachel, came home from work to find that he was at the emergency department following an overdose. After completing an inpatient SUD treatment program and receiving buprenorphine, Andrew was released and started intensive outpatient treatment at an opioid treatment program.

Rachel supports his entering treatment, as does his mother, Mrs. Walsh. However, both Rachel and Mrs. Walsh find it difficult to keep track of what types of treatment Andrew is currently receiving, including his prescription for buprenorphine. Andrew's father, Mr. Walsh, has not been involved in Andrew's treatment or recovery and never visited him at the inpatient treatment facility, even though Mrs. Walsh and Rachel visited him every weekend. This situation has caused much tension in the family; Mrs. Walsh feels torn between helping her son and being supportive of her husband's desire to “stay out of it” and “let Andrew handle this like an adult—on his own.” Rachel has grown somewhat distant from her in-laws; she feels hurt that Mr. Walsh hasn't shown more interest in his son's recovery. She and Andrew used to have dinner with his parents every Sunday, and she kept up with the tradition even when Andrew first entered treatment. But she has cancelled the last two Sunday dinners because she feels uncomfortable being around Mr. Walsh.

Andrew mentioned to Rachel that he meets with a peer specialist at the intensive outpatient program he attends. He noted how helpful his peer specialist has been in helping him cope with life outside of treatment. Andrew told Rachel that the program also has family peer specialists to help family members better understand and navigate their loved one's SUD. Rachel and Mrs. Walsh agree to speak with one of the family peer specialists to learn how the family—including Mr. Walsh—can work together to feel better and function better. They also would like to better support Andrew.

Learning Objectives

• To show how family peer specialists can engage an individual in or seeking recovery's family in family-based PSS by building a relationship with them, acknowledging their struggles, and offering hope
• To describe the importance of asking the family of an individual in or seeking recovery about their education, support, and resource needs
• To highlight how family PSS can meet a family's unique needs

Family–Peer Dialog

[Rachel and Mrs. Walsh arrive at the opioid treatment program where Andrew is receiving treatment and recovery services. A receptionist greets them and takes them to a small conference room. In the middle of the room is a circular table with a box of tissues and six chairs. The women sit down next to each other and wait for one of the program's family peer support workers, Scott, to arrive.]

SCOTT: [Opens the door and enters the conference room.] Good morning! I'm Scott—one of the family peer specialists here. [Extends his hand to Rachel and then Mrs. Walsh.] You must be Andrew's wife and mother. It's good to meet you both.

RACHEL: [Shakes his hand.] Nice to meet you.

MRS. WALSH: [Shakes his hand.] Thank you for meeting with us, Scott.

SCOTT: [Pulls up a chair and sits down across from Rachel and Mrs. Walsh.] It's my pleasure. So, Rachel, I understand that Andrew meets with one of our peer specialists and that he told you a little about our family services.

RACHEL: That's right. [Glancing at Mrs. Walsh.] We both wanted to hear more about what you offer and how you might be able to help us.

SCOTT: I'd be happy to walk you through it. We know that families dealing with addiction face a lot of difficulties, and we're here to help however we can. I'm so glad that you two decided to come today. But before we start, I need to talk to you first a little about privacy and confidentiality. Federal laws prevent me from sharing certain information with you about Andrew without his permission—things like any medical information or what is going on with his treatment here.

MRS. WALSH: Okay, that makes sense. [Rachel nods in agreement.]

SCOTT: I also want you to know that Andrew already gave me permission to speak with you both today, so there's no problem there. However, if there is anything we talk about today that you do not want me to share with Andrew, just let me know. Just like he has a right to privacy, so do you two.

RACHEL: We appreciate that, but I don't think we will mind you sharing with him whatever we talk about today.

MRS. WALSH: That's right. But if something comes up, we will be sure to mention it and ask you to keep it private.

SCOTT: That sounds like a good plan. [Turns to Mrs. Walsh.] Why don't you start by telling me a little about your son and his struggles with addiction.

MRS. WALSH: Well, I feel like it all started because Andrew fell in with the wrong crowd during his senior year in high school—almost didn't graduate. As it turns out, not graduating was the least of our worries. He started taking pain pills, then began using heroin. Who knows what else he was doing. Over the last 10 years, it's caused him all sorts of problems. He had to drop out of college. He's been arrested twice. And, as I'm sure you know, he nearly died from an overdose. [Pats Rachel's hand.]

RACHEL: It's been a long road, but I am so glad Andy is finally in treatment. We all had been begging him to do this for years, but he just wouldn't go. I just don't understand why it took something as drastic as almost dying for him to get clean, but I guess it doesn't matter. What matters is that he did.

SCOTT: That's right. You learned that addiction is powerful; however, I hear you saying that you're relieved that Andy is open to treatment now.

RACHEL: Completely. I mean, I can't relate to this at all. I've never had a problem putting down a drink or not smoking a cigarette. But I know that everyone is different.

SCOTT: Everyone's addiction is different. For some people, it's drinks or drugs or pills. For others, it's something else entirely. It wasn't until I started working with other families of people in recovery that I really understood that—the idea that although the substance use–related issues may be different, we all have the same need to be well.

MRS. WALSH: But what he's fighting… I don't have a clue how to help him. If you've never had that problem yourself or known someone who has, how are we supposed to know what to do?

SCOTT: [Smiling.] You're not, for exactly the reason you just said—you've never had to deal with this before. But families who have can be a great resource for helping people like you and Rachel deal with whatever stressors or worries you have about Andrew. In fact, what would each of you say are your biggest concerns about your family or about Andrew right now?

RACHEL: For me, I just want Andy to be healthy and happy. And he seems like he is, at least compared to when he was using. But he's doing so many different things in this program… I don't even know what all he's doing, much less how he is doing in them or if they are working. But I worry that it's all too much at once and that he's going to become overwhelmed and just say, “Forget it. I'm outta here.”

SCOTT: I understand what you mean. We offer a lot of different treatments and services here. And it sounds like Andrew is participating in many things—medication treatment, support groups, individual therapy. It's a lot for you two to keep track of. When families understand about the treatment process, it makes it easier to be a cheerleader and support recovery. That can really increase his chances of staying in recovery and not returning to substance use. [Turns to Mrs. Walsh.] And what about you, Mrs. Walsh? What do you most worry about?

MRS. WALSH: My biggest concern is his future. I worry so much that this drug thing has totally ruined his life. I would never say this to him, of course, but how is he going to get a job with people knowing he's an addict? What is he supposed to tell his future children—“Daddy almost died because he's a druggie”? [Takes a tissue from the box on the table and dabs at both eyes.] What do we say to the neighbors who saw the ambulance take him away? [Sighs.] I just worry, what if he's messed things up so much that he can't have a normal life ever again?

SCOTT: You know, language is a powerful thing. The way we think about and speak about people with problematic substance use can affect how others react. It can be helpful to understand that addiction is no different than a physical illness. Unfortunately, some people still don't see it this way, which I know can make things more difficult.

RACHEL: That's much easier said than done. People are so cruel about this sort of thing. If they know you do drugs, they look at you like you're a monster… like you've ruined your life and are infecting society with your problems, too. No one understands what it's like for us.

SCOTT: [Smiling.] Well, I know it might feel that way, but let me reassure you that that's not true. Many families out there know exactly what you're going through. We can connect you with a family peer specialist who's walked in your shoes before. And as someone who watched a family member struggle with alcoholism for decades and end up not only recovering but going to law school and becoming a drug court attorney, in my opinion, Andrew has not ruined his life. But he needs your support and positive attitude to remind him of this. And I think engaging with a family peer specialist can remind you of this, too.

RACHEL: [Nodding her head and looking over at Mrs. Walsh, who nods back in agreement.] I think that would be really helpful.

MRS. WALSH: [Rolling her eyes.] But I wish you could get my husband to understand all of this.

SCOTT: Well, what does your husband think about Andrew's problematic substance use?

MRS. WALSH: Oh, gosh… I don't even know where to start. I don't know if it's anger or sadness or what, but he won't talk about it. Won't even acknowledge it, hardly. Jeff constantly points out that he started drinking after coming home from his service in Iraq during the Gulf War, but once we had Andrew's older brother, he stopped cold turkey because he knew he had to “be a man” and “get it together” to support his family. I think he thinks Andrew is weak or somehow just not trying hard enough. And I know I'm no doctor, but I just don't see it that way. I see how hard Andrew has worked over the past 2 months, and I feel like… this isn't something he can just turn on and off, like a switch. It's bigger than that. It's like his addiction took over his brain. But Jeff just doesn't see it that way… it breaks my heart. [Stares at her hands folded in her lap and is silent for a few moments, then looks back up at Scott.] Did you know that, as a little boy, Andrew used to dress up in his father's clothes and pretend he was “going to the office, like Dad”? [Smiling, her eyes filling with tears.] He just looks up to his father so much.

SCOTT: I can see that. It sounds like your husband has a lot of strong feelings about Andrew's problematic substance use and perhaps substance use in general. Sometimes when family members don't fully understand addiction, they say or do things that are harsh and hurtful. This is why one of the first things our family peer specialists do is give people some very basic but important information about problematic substance use and recovery. It's critical that everyone understand what their family member is dealing with.

MRS. WALSH: That makes sense. There's so much to learn. I get it all confused. I can't even remember the name of his medication. So, trying to explain it to my husband is impossible when I can barely understand it all myself.

SCOTT: We also offer referrals to local counselors who help families with any problems they are having with anyone connected to a loved one's addiction. Family conflict can really make it hard on a person's recovery—especially when that person really looks up to or wants approval from someone in the family who's behaving in a hurtful way, kind of like what you described with Andrew and your husband.

MRS. WALSH: Well, if you can get Jeff to go to one of those people, that would be a miracle in and of itself. I'd love to see him and Andrew patch things up. Fathers and sons need one another.

SCOTT: [Looking at Rachel.] And those local family counseling services also include family educational sessions. How would you say things are between you and Andrew?

RACHEL: I guess they could be worse, but… [Trails off without finishing her sentence.]

SCOTT: …they could also be better?

RACHEL: [Looks down.] Yes. They definitely could.

SCOTT: Have you and Andrew talked about his addiction at all?

RACHEL: Not really. I mean, we have a little but not like we should, I guess. I wouldn't even know what to say. I don't want to complain and then make him feel like he's a burden or is making me feel all these terrible things.

SCOTT: It sounds like both of you could use more help from other people in the same boat as you. Let me ask you, who do you each turn to when you need help or just want to vent?

[Mrs. Walsh and Rachel look at each other and smile.]

RACHEL: Each other, mostly.

MRS. WALSH: Rachel has been with Andrew since the beginning, so she really understands how this has affected him and what he's been through. I can talk to her in ways I can't talk to my friends. I can't even imagine sharing the personal, private details of all this drama with someone outside the family.

RACHEL: [Nods.] I'm on the exact same page. I don't want any outsiders knowing about our problems. They won't get it anyway, so what's the point in talking to them?

SCOTT: I know that, for many families, there's a real fear about talking with others because, when it comes to addiction, so many people are judgmental and unkind—and uneducated, frankly. But that's another upside to working with family peer specialists. They may technically be “outside the family,” but we're all members of the same family here, in a way. We all understand what it's like to have a family member with addiction. There's no judging or lecturing or any of that.

MRS. WALSH: So, where do we find these people? I've heard of Al-Anon, so I know there are groups for people related to alcoholics. But what about people like Rachel and me? Where do we fit in?

SCOTT: There are support groups just like Al-Anon but for people with family recovering from addiction. And there are other forms of support, too—like one-on-one support services and people to help you with more practical things like, “How do I help my son find a job? Does my husband qualify for disability payments because of his addiction? What if he has surgery and needs to take an opioid medication for pain?”

RACHEL: Wow, you're hitting on things I never even thought of but realize now that I have no clue how to answer!

SCOTT: [Smiling.] That's why we're here. There's no way you could possibly know everything you need to know. Let the people who have walked this path already help you figure that out.

MRS. WALSH: [Looking at Rachel.] I'm willing if you're willing?

RACHEL: [Smiling.] Definitely. Anything to help Andy and our family.

SCOTT: I can introduce you to one of our family support workers right now if you have time. She's been working with families here for several years. And I know her schedule opened up recently, and she's looking to work with a new family. I bet she'd love to meet you both.

MRS. WALSH: I have time now. She sounds lovely.

RACHEL: Me, too. Let's go talk to her. The sooner we can start working with her, the sooner we can help Andy start piecing his life back together.

MRS. WALSH: And piecing our family back together, too.

SCOTT: Great. Why don't you follow me down to her office, and she can tell you how you can get started working together.

Summary

Rachel and Mrs. Walsh met with Scott to learn more about the family PSS offered at the opioid treatment program where Andrew, Rachel's husband and Mrs. Walsh's son, receives treatment for OUD. Scott used several rapport-building techniques to engage them in family peer services, such as asking them questions about their needs, validating their feelings, and explaining how family peer services could be helpful. Scott also used their discussion to offer basic information about problematic substance use and recovery and to tell Rachel and Mrs. Walsh about potential resources for instrumental and emotional support. Rachel and Mrs. Walsh felt that Scott truly heard and understood their concerns, which made them open and willing to accept his offer to engage with a family peer specialist. Rather than give them a name and phone number, Scott walked Rachel and Mrs. Walsh over to the office of a family peer specialist and helped them connect with her in person.

### Resources

#### Family Resources About Peer Support in SUDs

• SAMHSA:
  – Peer Support. This easy-to-understand brochure provides general information on peer support. (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peer-support-2017.pdf)
  – Family, Parent and Caregiver Peer Support in Behavioral Health. This brochure explains the value of peer support in SUD recovery. (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/family-parent-caregiver-support-behavioral-health-2017.pdf)
  – What Are Peer Recovery Support Services? This manual provides indepth information on PSS. (https://store.samhsa.gov/product/What-Are-Peer-Recovery-Support-Services-/SMA09-4454)
• Administration for Children & Families. This division of the Department of Health and Human Services promotes the economic and social well-being of families, children, individuals, and communities. (https://www.acf.hhs.gov/)
• Children and Family Futures. This nonprofit organization provides consultation, training and technical assistance, strategic planning, and evaluation services focused on improving practice and policy at the intersections of child welfare, mental and substance use disorder treatment, and court systems. (https://www.cffutures.org/)
• Friends of Recovery–New York: Family to Family Recovery Resource Guide. This guide includes resources for families of individuals who have problematic substance use and information about addiction, recovery, and how to help people in recovery. (https://preventioncouncilputnam.org/wp-content/uploads/2017/07/Family_to_Family_Resource_Guide.pdf)
• Learn to Cope. This peer-led support network offers education, resources, and hope for families and friends. (https://learn2cope.org/)
• National Alliance on Mental Illness:
  – The Family-to-Family program is a free, eight-session educational program for families, significant others, and close friends. (https://www.nami.org/Support-Education/Mental-Health-Education/NAMI-Family-to-Family)
  – The Family-to-Family class locator assists families with finding a free 8-week course for family caregivers of individuals living with mental illness. (https://www.nami.org/Find-Your-Local-NAMI/Affiliate/Programs?classkey=a1x36000003TN9YAAW)
• National Federation of Families (https://www.ffcmh.org/): This nationwide advocacy organization focuses on bringing lived experience to family support. It provides:
  – Resources for peer support specialists. (https://www.ffcmh.org/resources-peersupport)
  – Resources about family-run organizations. (https://www.ffcmh.org/resources-familyorg)
  – Webinars and presentations about family peer support. (https://www.ffcmh.org/resources-webinars)
• Partnership to End Addiction. This website includes a parent blog, stories of hope from parents of children with problematic substance use, and a parent helpline. (https://drugfree.org/get-support/)

#### Family Resources About SUDs and Recovery

• SAMHSA:
  – Family Therapy Can Help. This booklet provides information about how family therapy can be useful for people recovering from mental illness, problematic substance use, or both. (https://store.samhsa.gov/sites/default/files/d7/priv/sma13-4784.pdf)
  – Finding Quality Treatment for Substance Use Disorders. This factsheet serves as a guide for individuals seeking treatment. It describes three necessary steps to complete before using a treatment center and the five signs of a quality treatment center. (https://store.samhsa.gov/product/Finding-Quality-Treatment-for-Substance-Use-Disorders/PEP18-TREATMENT-LOC)
  – What Is Substance Abuse Treatment? A Booklet for Families. This brochure helps family members better understand different SUD treatment options and how to access family resources. (https://store.samhsa.gov/product/What-Is-Substance-Abuse-Treatment-A-Booklet-for-Families/SMA14-4126)
• Adult Children of Alcoholics® & Dysfunctional Families. This 12-Step mutual-help program is for adult children of people with alcohol use disorder. (https://adultchildren.org/)
• Al-Anon and Alateen. These 12-Step mutual-help programs are for family members, adolescents, and friends of people with alcohol use disorder. (https://al-anon.org/)
• Families Anonymous. This 12-Step mutual-help program is for families and friends of people struggling with problematic substance use or with mental illness. (https://www.familiesanonymous.org/)
• Nar-Anon Family Groups. This 12-Step mutual-help program is for family members of people who are addicted to drugs. (https://www.nar-anon.org/)
• National Association for Children of Addiction. This nonprofit organization offers resources for children, adolescents, and adult children of people who use alcohol and other substances and for families in recovery. (https://nacoa.org/families/)
• National Institute on Drug Abuse: If You Have a Problem with Drugs: For Teens and Young Adults. This website for adolescents and young adults with problematic substance use and their parents answers common questions about drugs and drug problems. (https://archives.nida.nih.gov/publications/step-by-step-guides-to-finding-treatment-drug-use-disorders/if-you-have-problem-drugs-teens-young-adults)
• SMART Recovery® Family & Friends. This program uses SMART Recovery® and CRAFT techniques to explain how families and friends can help their loved one who has problematic substance use. The website provides information about online meetings, a family message board, and links to a handbook and a facilitator manual (both can be purchased for a small fee). (https://www.smartrecovery.org/family/)