# Chapter 6—How To Become a Peer Specialist

KEY MESSAGES

• Peer specialists are becoming an increasingly important part of the substance use treatment workforce, and they provide services in a growing range of settings.
• Peer specialists draw on their lived experience with problematic substance use, behavior change, and recovery—plus their training—to improve outcomes for other people entering or in recovery.
• People interested in becoming peer specialists should understand the potential benefits and challenges of this work to make informed decisions about pursuing this path.
• The peer specialist position can be an end goal, a first step in reentering the general workforce, or a steppingstone in a career in the addiction and recovery fields.
• States have different education and training requirements for peer specialist certification. Obtaining certification has become increasingly important to securing work in this field.
• People who have lived experience with a family member in recovery from problematic substance use can become family peer specialists who work with other families affected by such use.

Peer support services (PSS) have become an important part of health care as the substance use disorder (SUD) treatment field increasingly understands that SUDs are long-term illnesses. Peer workers play a valuable role in supporting people with problematic use to seek, engage in, and maintain recovery and wellness.^619,620^

Peer workers are individuals who use their lived experience with problematic substance use, behavior change, and recovery to provide recovery support to people with problematic substance use. The broad term “peer workers” refers to peers who may be paid or unpaid, with or without formal training, and certified or uncertified. Peer specialists are paid and have training; peer specialists may or may not be certified. Family peer workers, who have experience supporting a loved one who is in or seeking recovery, also work in some treatment programs.

Chapter 6 will help people who are interested in working with people with problematic substance use in an SUD treatment setting understand the benefits and challenges of being a peer specialist. The chapter also discusses the training, certification, and credentialing processes involved in becoming a peer specialist. It offers education, information, and resources on topics such as:

• What a peer specialist does.
• The benefits and challenges of working as a peer specialist.
• The roles, settings, and practice standards of peers who support recovery from problematic substance use.
• The training requirements and skills needed to become a peer specialist.
• The steps to take to become a peer specialist, including how to become a certified peer specialist.

Chapter 6 is for anyone interested in becoming a paid or volunteer peer specialist, especially someone who wants to work as part of an SUD treatment program. A description of Chapter 6 follows:

• The first section explains who peer workers are, what they do, the settings in which they work, and their core practices. This section briefly introduces the roles of peer workers. Chapters 1 and 2 provide more information about PSS and the roles of peer workers.
• The second section helps potential peer specialists decide whether the role is right for them by first describing some general characteristics of peer specialists. It then presents questions to help them explore their own motivations for becoming a peer specialist, which is an important step in seeking this line of work. The section also describes benefits and challenges of being a peer specialist.
• The third section outlines the steps and requirements for becoming a peer specialist. It includes information about education, training, and credentialing.
• The fourth section begins by discussing the principles of family peer support. It then explains the benefits and challenges of serving as a family peer worker supporting families affected by problematic substance use as well as how to become trained, and in some places certified, as a family peer specialist.
• The fifth section presents additional resources on peer specialist training and certification. The chapter appendix includes a number of other resources, including a sample job description and case studies to help potential peer specialists learn more about becoming a peer specialist.

A NOTE ON THE TERM “PROGRAM CLIENT”

This chapter sometimes uses the term “program client” to refer to an individual receiving services at or from an SUD treatment program. A peer worker generally doesn't refer to someone they work with as their “client,” however. That's because the nature of this relationship differs from that between a treatment provider, like an SUD counselor, and a person receiving SUD treatment. Often, a peer worker will refer to someone they work with as a “peer,” which reflects a nonhierarchical relationship involving collaboration, mutual learning, and the shared experience of problematic substance use. Peer workers in an SUD treatment setting also often use the term “participant” to refer to someone they're working with.

## Who Are Peer Workers?

No universal definition of a peer worker exists. Many agencies, organizations, and experts in the SUD treatment and recovery fields have slightly different definitions. For example:

• The Substance Abuse and Mental Health Services Administration (SAMHSA) has described peer workers as people with the lived experience of recovery from an SUD who provide nonclinical, strengths-based support to others experiencing similar challenges.^621^
• William White, a well-known and highly respected writer in the recovery field, has referred to peer workers as “recovery coaches.” He has described recovery coaches as people who are “experientially credentialed” and who “provide outreach to people in need of recovery, assertively link people to professional treatment and to communities of recovery, and provide long-term, stage-appropriate recovery education and support.”^622^

The term “recovery coach” is frequently used in the same sense as the terms “peer worker” or “peer specialist.” These positions differ somewhat from that of the professional recovery coach, which this Treatment Improvement Protocol doesn't cover. Professional recovery coaches have training and experience in coaching and may have certification from a professional coaching organization such as the International Coaching Federation or the International Association of Coaching. Also, professional recovery coaches often work in fee-based private practice and may not be directly involved in the local recovery community.^623^

Confusion persists about the roles of peer specialists, sponsors, and SUD counselors because they overlap somewhat.^624^ But important differences exist between these roles. For example:

• SUD counselors (and other SUD treatment providers, like addictions nurses and clinical social workers):
  – Have specialized educational degrees and clinical training.
  – Are certified and licensed to provide clinical services.
  – Are clinically supervised when working in SUD treatment programs (but not when in solo private practice).
  – Provide SUD-related assessments, diagnoses, and treatments.
• Mutual-help sponsors:
  – Typically work through 12-Step programs like Alcoholics Anonymous® and Narcotics Anonymous.
  – Are always unpaid and unsupervised.
  – Mainly focus on helping their sponsees follow the 12-Step program.
  – Don't need formal training or certification.
• Peer specialists:^625,626,627,628^
  – Have formal training on how to use their lived recovery experience to help others enter or maintain recovery, and often have certification. (The section “Peer Specialist Training and Certification Requirements” contains helpful information and resources on certification.)
  – Provide support to people to help them achieve their recovery goals in the ways they choose. (The different ways that people enter, work on, and achieve recovery are often referred to as “recovery pathways.”)
  – Receive supervision. Depending on the setting and program, peer specialists may have more than one supervisor. Some supervisors have themselves worked as peer specialists.
  – Have many roles and responsibilities, such as working with people seeking or in recovery on building their recovery capital, linking to the recovery community (including mutual-help programs) and other resources, developing and carrying out a recovery plan, advocating for themselves, and navigating healthcare, behavioral health, child welfare, criminal justice, and other systems. (Recovery capital means the internal and external resources available to establish and maintain an individual's recovery, like access to health care, supportive relationships, work/schooling, self-esteem, and safe housing.)
  – Typically serve in an SUD treatment, mental health services, healthcare, social services, corrections, court, or recovery organization setting (although some work may take place in the community).

### What Roles Do Peer Specialists Fill?

Peer specialists working in SUD treatment programs offer nonclinical support and services to help people who experience SUDs and their families engage in and maintain recovery. They can work for pay or volunteer. They may work directly for a treatment program or for an organization that contracts to provide PSS to treatment programs. Their daily responsibilities are broad and require flexibility to allow them to help individuals with a range of physical, emotional, spiritual, and functional recovery needs.

A peer specialist serves as:^629,630^

• A person who offers support, caring, and guidance.
• A resource expert who can link the treatment program's clients to services by providing information and going with them to appointments. Such services include:
  – Housing.
  – Transportation.
  – Child care.
  – Health care.
  – Employment.
  – Education.
  – Social services.
  – Legal aid.
• A motivator or cheerleader (for example, celebrating program clients' achievements).
• A provider of honest feedback to help the individuals they work with develop healthier thoughts and behaviors.
• A role model for recovery and wellness.
• A role model for effectively communicating boundaries.
• A person who supports the individuals they work with in gaining recovery capital and overcoming barriers to recovery.
• An advocate for program clients with their SUD treatment team (such as during staff meetings in which treatment providers discuss cases).
• An advocate for PSS in the local community (by, for example, educating the general public about the importance of these services).
• A key figure in assessing community recovery support needs.

Peer specialists are central to SUD treatment, not an add-on, and can contribute across the continuum of recovery. They do so by:^631,632,633,634^

• Going into the local community to work with people seeking recovery and welcoming them into treatment or the recovery community.
• Modeling recovery and imparting recovery skills to new clients of the treatment program.
• Educating program clients about SUDs and coaching them on using social skills, finding other recovery role models, learning to ask for help, and avoiding or navigating risky situations.
• Accompanying individuals they work with to mutual-help group meetings and participating with them in organized activities.
• Supporting people in sticking with their recovery plans and new healthy behaviors.
• Helping individuals they work with understand how family relationships can affect and be affected by a family member's problematic substance use.
• Checking in with people in longer term recovery to support and encourage them.

#### Workplace Settings

Peer specialists work in many different settings, including, increasingly, SUD treatment programs. These types of settings include:^635^

• Outpatient SUD treatment programs.
• Programs that provide medication for opioid use disorder.
• Inpatient hospital addiction units.
• Partial hospitalization programs.
• Residential treatment programs.

Peer specialists may also work in a variety of other settings, especially settings that provide recovery services. The wide range of settings where potential peer specialists may find PSS include:^636,637^

• Recovery community organizations (RCOs). (Chapter 1 of this Treatment Improvement Protocol [TIP] contains a description of RCOs.)
• Recovery homes/recovery housing.
• College recovery programs.
• High school recovery programs.
• Problem-solving courts.
• Jails and prisons.
• Primary care and other physical health clinics.
• Emergency departments and inpatient medical units.
• Mobile crisis units.
• Harm reduction centers.
• Social services agencies (such as child welfare agencies).
• Homeless shelters.
• Telephone or online PSS programs, including mobile apps.

No matter where peer specialists work, part of the job involves connecting individuals with resources available in the recovery community.

WHAT RESEARCH SAYS ABOUT PEER SPECIALISTS

Do peer specialists actually help people with problematic substance use get better? Although the use of peer specialists to support recovery is relatively new, emerging evidence has found that delivery of PSS is linked to better outcomes for recipients. These improved outcomes include:^638,639,640,641,642,643,644,645,646,647,648^

• Greater rates of abstinence.
• More days abstinent.
• Lower rates of opioid overdose.
• Decreases in substance use.
• Increases in treatment retention.
• Fewer rehospitalizations for mental health or addiction issues.
• Increased success in following SUD treatment plans.
• Increases in housing stability.
• Increases in employment stability.
• Increases in recovery capital.
• Increases in treatment motivation and self-efficacy.
• Decreases in certain symptoms of psychosis, including hallucinations and delusions.
• Quality-of-life improvements.
• Greater access to social supports.
• Less anxiety and tension.

#### Core Practices and Practice Standards of Peer Workers

Peer workers support people with a history of substance use–related problems in working on many aspects of recovery and wellness, such as:^649,650^

• Having hope, motivation, and a positive and realistic outlook on recovery.
• Learning ways to reduce substance use and related problems or to achieve and maintain abstinence from substances, depending on their personal goals.
• Increasing skills to prevent a return to problematic use or any use.
• Developing recovery plans.
• Finding and linking to needed resources.
• Building and keeping healthy, supportive relationships.
• Developing effective coping strategies and problem-solving techniques.
• Having a sense of meaning and purpose in their lives.
• Setting and meeting short- and long-term goals.
• Maintaining good health and well-being and reducing stress by:
  – Eating a healthy diet.
  – Exercising.
  – Taking steps to prevent illness or health problems. (Quitting smoking,^651^ addressing hepatitis C, and keeping up with immunizations are examples of such steps.)
  – Meditating.
  – Developing healthy sleep habits.
  – Putting new problem-solving skills into practice.

The day-to-day practices of peer specialists can range from conducting “street outreach” to people with problematic substance use to organizing recreational activities for people in sustained recovery. Depending on the setting and organization, peer specialists' responsibilities can include:^652,653,654^

• Checking in with people on a treatment program's waiting list.
• Welcoming and helping orient new clients of the treatment program to put them more at ease, introducing them to recovery concepts, and explaining PSS and other services offered.
• Facilitating wellness groups.
• Teaching classes on budgeting and finding employment.
• Coaching individuals on locating resources and navigating healthcare and social service systems.
• Helping connect people to mutual-help groups.
• Accompanying individuals, if requested, to medical and other types of appointments to provide support, especially in first-time situations.
• Documenting delivered peer services (especially by peer specialists whose services could be billed to Medicaid).
• Communicating with the rest of the recovery team on behalf of or alongside a program participant.
• Offering one-on-one emotional support to program participants.
• Helping people transition from one level of SUD care to another.
• Reaching out to program clients who left SUD treatment early.
• Performing recovery checkups with former program clients who were successfully discharged.

The list above provides only a sampling of the many different responsibilities that peer specialists may carry out as part of their daily work. Peer specialists may also educate other organizations and the general public about the treatment program, recovery organization, or other setting where they work or about peer services and recovery generally.

RESOURCE ALERT: MANUALS AND TOOLKITS

Online manuals and toolkits for peer work can give potential peer specialists a sense of the roles, skills, and abilities involved. Such resources also discuss what peer training covers.

The following manuals and toolkits are listed here for information only and cannot be used in place of actual training:

• Cal Voices' Workforce Integration Support and Education (WISE) Program, 2019 Peer Toolkit for Workplace Success (https://bhdp.sccgov.org/sites/g/files/exjcpb716/files/calvoices-2019-peer-toolkit-for-workplace-success-handbook-2019.pdf)
• City of Philadelphia Department of Behavioral Health and Intellectual disAbility Services, Peer Support Toolkit (https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf)
• Florida Department of Children and Families, Office of Substance Abuse & Mental Health, Florida Peer Services Handbook (https://nuance.myflfamilies.com/sites/default/files/2022-12/DCF-Peer-Guidance.pdf)
• McShin Foundation, Recovery Coach Manual for the Substance Use Disorder Recovery Program (https://mcshin.org/wp-content/uploads/2019/07/McShin-RCM_for-web.pdf)
• Southern Plains Tribal Health Board, Peer Support Toolkit (https://sites.utexas.edu/ignitingthesparkofhope/files/2021/06/Peer-Support-Toolkit_Booklet.pdf)

In addition to learning day-to-day practices, peer specialists will also need certain core competencies that will help them follow practice standards. Practice standards describe how they should perform their job to ensure that they are acting in an ethical, respectful, and responsible manner.

Peer specialists should always act in an ethical and appropriate manner, although ethical guidelines and codes of conduct can differ depending on the organization and state. Ethical issues include situations involving potential harm to people seeking help, the peer specialist, the organization through which PSS are being delivered, the larger PSS and SUD field, and the recovery community. Whether harm will be done to any of these people or entities should be the primary consideration when peer specialists face an ethical dilemma. Potential issues include the personal conduct of peer specialists outside of the work arena, conduct in relationships with people seeking PSS, conduct in relationships with other service providers, and the responsibility to report threats to public safety.^655^

The organization a peer specialist works for likely will have a set of policies describing acceptable and unacceptable peer specialist actions. These policies derive from an overall ethical framework that guides ethical decision making. Two national organizations have developed ethical guidelines that other groups have adopted:

• NAADAC, The Association for Addiction Professionals, developed the National Certified Peer Recovery Support Specialist (NCPRSS) Code of Ethics (https://www.naadac.org/ncprss-code-of-ethics).
• The National Association of Peer Supporters offers its National Practice Guidelines for Peer Specialists and Supervisors (https://www.peersupportworks.org/resources/national-practice-guidelines).

Chapter 8 includes additional resources in its “Ethical Guidelines” section.

Part of behaving ethically as a peer specialist means respecting and maintaining appropriate boundaries with the individuals that the peer serves.^656^ Potential peer specialists will learn through training and supervision how to recognize when boundaries could get blurred or crossed—and how to avoid or respond to those situations. Such situations include:^657,658^

• Engaging in nonsexual touching.
• Receiving sexual comments from someone the peer specialist serves.
• Acting on or being influenced by romantic feelings for someone the peer specialist serves.
• Having someone receiving PSS from a peer specialist show romantic feelings for that peer specialist.
• Providing personal services outside those appropriate to the peer support role; examples of inappropriate services are babysitting, carpentry, car repair, and hairstyling.
• Loaning money to someone the peer specialist serves.
• Accepting gifts from someone the peer specialist serves.
• Blurring the line between being friendly and being friends.
• Blurring the line between providing professional recovery support and working on the peer specialist's own personal recovery.
• Inappropriately sharing highly personal information with someone the peer specialist serves, especially early on (for example, sharing in detail one's own experience with trauma with a new program participant who has a trauma history).

## Is Being a Peer Specialist Right for People and Families In Recovery?

Potential peer specialists may wonder what characteristics and skills make a good peer specialist. People with many different personality traits and experiences can succeed in this work. But here are some things to keep in mind when considering this field:

• Effective peer specialists genuinely care about individuals seeking or in recovery. They enjoy connecting with people and often speak about their jobs with enthusiasm. These are important qualities to have to do this kind of work. This might not be the right work for a potential peer specialist if he or she is not a “people person.”
• A healthy peer specialist is an effective peer specialist. The number of years in recovery that a peer specialist has is less important than their current state of health and wellness. A potential peer specialists should be honest with themselves about where they are in their own recovery. If they're still experiencing an SUD or other problematic use, they should focus on getting themselves well before trying to support others. The same advice applies if a potential peer specialist has a serious co-occurring medical or mental disorder that needs addressing, including posttraumatic stress disorder. Learn about the eight dimensions of wellness at https://www.youtube.com/watch?v=tDzQdRvLAfM and in the SAMHSA publication Creating a Healthier Life: A Step-by-Step Guide to Wellness at https://store.samhsa.gov/sites/default/files/d7/priv/sma16-4958.pdf.
• This job can be deeply rewarding, because peer specialists provide a critical service to those seeking or in recovery. However, many peers express disappointment with the relatively low pay they receive.^659^
• People who succeed in the peer specialist role often feel “called” to serve. Peer specialists have a unique set of skills and experiences, attitudes, and desire to help others, and they often see their work as a way to give back to the recovery community.
• Peers need thorough knowledge of local recovery community resources. A peer specialist is knowledgeable about SUD treatment programs, mutual-help programs, recovery housing, RCOs, and other resources in their area. They are willing to invest the time and effort to develop such knowledge.
• Effective peer specialists learn when and how to offer trauma-informed support. People with problematic substance use often have a history of trauma. Because a person's trauma history can affect their ability to cope with stress, including the stress of recovery, peer specialists should have training on working with people who have this kind of personal history.

TRAINING AND WORK LIFE OF PEER SPECIALISTS SUPPORTING PEOPLE WITH OPIOID USE DISORDER

RIZE Massachusetts is a nonprofit organization dedicated to addressing the opioid use disorder (OUD) crisis. In 2018, the organization published findings from a literature review and multistate interviews on the use of recovery coaches in OUD care.^660^ The results help shed light on the training needs and day-to-day activities of peer specialists in SUD treatment and recovery settings. Important findings include the following:

• Of 10 programs surveyed, 3 received at least partial reimbursement for PSS from private insurance.
• The number of full-time peer specialists employed at surveyed OUD programs ranged from 2 to 38.
• Full-time peer specialists worked, on average, 37 to 40 hours per week. Part-time peer specialists' hours ranged from being on call to up to regularly working 29 hours per week.
• Caseloads also differed across programs. Some peer specialists saw 8 to 12 people each; others had about 35 to 55 people on their caseload (for full-time positions).
• Programs typically offered ongoing training for peer specialists as a part of employment. Some trainings were free; others required payment. Hours of training offered ranged from 6 to 40 hours per year.
• All programs reported providing health insurance benefits and paid time off (for example, holidays, vacation days, sick leave) to their recovery coaches.
• Common core duties of peer specialists included being a PSS recipient's:
  – Supporter.
  – Motivator.
  – Facilitator.
  – Advocate.
• Other job roles included supporting people in:
  – Developing and engaging in a recovery plan.
  – Working on problem-solving skills.
  – Connecting to recovery services and resources.
  – Navigating systems of care.
  – Helping people in recovery with practical support, like accessing housing and transportation and applying for public assistance.
• Peer specialists and OUD program directors agreed that peer specialists should place a high importance on three areas:
  – Supporting individuals' desired path to treatment and services rather than trying to force them to seek recovery through one specific pathway
  – Engaging program participants in services, earning their trust, and keeping open lines of communication
  – Maintaining their own self-care, such as through individual mentoring or participating in support groups designed to help peer specialists address self-care needs

Potential peer specialists should explore their motivations for becoming a peer specialist as well as their feelings about what this position can involve. Doing so can help them clarify the strength of their interest and stay committed to the training and the work if they pursue this path. The following questions can be considered:

• What are the potential peer specialist's reasons for wanting to become a peer specialist?
• What does the potential peer specialist hope to get out of this position?
• How does the potential peer specialist feel about working with individuals who may be actively using substances?
• How does the potential peer specialist feel about working with individuals whose recovery pathways differ from their own?
• How does the potential peer specialist feel about being supervised in this position?
• How does the potential peer specialist feel about working with individuals who have histories of trauma? Could this be triggering, and if so, how does the potential peer specialist feel about that?
• How does the potential peer specialist feel about working with individuals with mental disorders?
• How does the potential peer specialist feel about working with someone who has been or is involved in the criminal justice system because of their problematic substance use?
• Is the potential peer specialist accepting of individuals with convictions for other types of crimes?
• How willing (and able) is the potential peer specialist to spend time and money on peer specialist education, training, or both?
• What does the potential peer specialist think this work will be like day to day?
• How might working as a peer specialist make one's life different?
• How might serving as a peer specialist affect one's own recovery? Could it be helpful? Could it be harmful?
• What are the potential peer specialist's current recovery/self-care practices, and how might each affect their ability to perform this role effectively?

### Benefits of Becoming a Peer Specialist

A peer specialist's work has many upsides. It can allow a potential peer specialist to:

• Share the valuable knowledge and lived experience they have gained in their own recovery.
• Show people with problematic substance use, their coworkers, outside professionals and organizations that they interact with, and the general public that recovery is possible for everyone and happens often.
• Enter or reenter the workforce, if they don't have previous or recent employment.
• Develop a variety of skills, such as facilitating meetings and leading classes.
• Start building a career within the PSS field, the larger SUD treatment and recovery field (such as by becoming a certified drug and alcohol counselor or addictions nurse), or a different field.
• Maintain, expand, and deepen relationships within the recovery community.
• Find purpose and meaning in their work.^661^
• Improve their confidence and self-esteem, which can enhance their own recovery and well-being. (However, working as a peer provider is no substitute for doing one's own recovery work.)

Interview-based research has found that peer work:

• Enhanced peers' own recovery.^662^
• Increased peers' self-acceptance.^663^
• Increased peers' confidence.^664^
• Gave peers a sense of accomplishment.^665^
• Decreased stigma in peers' workplaces.^666^

THOUGHTS ON THE INTERVIEW PROCESS

A potential peer specialist will want to know what types of questions they may be asked if interviewing for a peer specialist position so they can reflect on their interest in following this path. It can also help them feel better prepared for an interview. Here are some questions that may be asked during an interview:^667^

• What are some ways that you might motivate or encourage someone?
• How might you use your lived experience to support someone in recovery from problematic substance use?
• What role has peer support played in your own recovery?
• How do you feel about sharing your own story of recovery with those you would serve? When do you think sharing your story might help someone? When might sharing your story not help someone?
• What do you know about this organization?
• Why did you apply for this position?
• How would you define a “peer worker”? What do you think a peer worker's roles are?
• What does “recovery” mean to you?
• How would you handle a situation in which someone you are working with is struggling significantly or is in crisis?
• How would you respond if a person in recovery rejected your suggestions?
• How would you respond if a person in recovery had a recurrence?

Remember that, under the Americans with Disabilities Act (ADA), no one can ask the applicant disability-related questions during their interview. Applicants don't have to answer these questions. Such questions include:

• What medications are you currently taking?
• Are you receiving treatment for your SUD?
• When was the last time you were hospitalized for your substance-related problem?

The ADA's National Network webpage contains more information on how the ADA addresses a history of SUD and recovery at different stages of the employment process. (https://adata.org/factsheet/ada-addiction-recovery-and-employment)

### Challenges Peer Specialists Can Face

Although becoming a peer specialist can be rewarding, potential peer specialists may encounter challenges to getting hired and thriving in the position. Awareness of these possible challenges can help them decide whether they want this type of work. Problems peer specialists might encounter include:^668,669,670^

• Lack of understanding among staff of SUD treatment programs about the purpose of and need for these positions.
• Negative attitudes by coworkers toward peer specialists and their contributions to the organization (for example, not valuing peer specialists' work or lived experience).
• Requirements of state credentialing bodies and hiring organizations, especially regarding education and in-the-field experience. Such requirements may be barriers for people who lack a high school education or a GED or who can't access or make time for the required training and work experience.
• Lack of funding for training and certification fees. People often need to pay for training and certification expenses on their own; however, not everyone can afford to do so.
• Criticism from others in recovery that peer specialists are exploiting their recovery experience. Some people in recovery believe strongly that peer mentoring is part of recovery and should always be provided on a volunteer basis.
• Low pay, insufficient working hours, or both.
• Difficulty getting certified or hired.
• Difficulty getting hired if there is past criminal justice system involvement. How much of a barrier this involvement presents depends on such factors as the nature, number, and recency of any crimes; the state; and the employer. Many peer workers with lived experience in the criminal justice system find success getting hired in forensic and diversionary settings like drug courts, jails, and prisons.^671,672^
• Lack of a recovery orientation at an organizational level and among coworkers.
• Token peer positions. For example, a treatment program might establish peer positions to be able to say it offers PSS, but not provide appropriate supervision, training, and work assignments to the peers.
• Difficulty setting boundaries with someone for whom they are providing PSS. This situation can happen when the peer specialist and the individual already have a connection (for example, they are friends or they know each other from participating in the same treatment program).
• Difficulty setting boundaries with work colleagues. This can happen when, for example, the peer specialist is expected to take on clinical functions or entry-level clerical tasks. Such deviation from the peer role can lead to the peer specialist identifying more with the treatment team and less with program participants, and to exploitation of the peer.
• Few career options or opportunities for advancement within the workplace, if serving as a peer specialist is not the end goal.
• Burnout or stress, which can occur because of, for example:
  – Understaffed programs.
  – The demanding nature of peer support work, including the emotional demands of working closely with individuals with trauma histories.
  – The frequent lack of affordable housing, mental health services, and other resources needed by individuals a peer is working with.
  – A lack of effective supervision and leadership support for the peer position.

## Steps to Becoming a Peer Specialist

The process of becoming a peer specialist can take time and may vary depending on where the potential peer specialist lives and wants to work. Here are steps a potential peer specialist can take to ensure that they're prepared for this role.

Step One: Get informed—Potential peer specialists should seek as much information as possible to ensure that they want to pursue this line of work. This process may include:

• Talking to providers, including peer specialists, in the recovery community about the day-to-day work of peer specialists. (The appendix at the end of this chapter contains case studies that show how such conversations can be helpful.)
• Talking to people in the recovery network, especially anyone who has experience working as a peer, about how the peer specialist role may affect one's own recovery (positively and negatively).
• Attending recovery events in the area, such as recovery fairs. Recovery organizations and treatment programs may have representatives there who can speak to the availability of and requirements for peer specialist positions.
• Talking to a trusted friend or adviser.
• Researching what peer training the state requires for certification by going on the websites for, or calling, the state behavioral health agency or peer specialist certification organization. Doing this research will help the potential peer specialist avoid spending money on training that they don't need or that doesn't meet their state's requirements, and will also let them know the time commitment involved.
• Researching how many peer specialist educational hours the state requires for certification.
• Looking into whether organizations in the area provide scholarships for peer training or certification or both, or provide the needed training in-house as part of internships or peers-in-training positions.
• Researching what types of jobs are available for peers in the area and how many jobs are advertised.
• Reading online job descriptions. These can help give the potential peer specialist an idea of the work to be performed and what employers are looking for in a paid peer specialist, including level of education. A sample job description is included in this chapter's appendix.
• Looking at the salaries/hourly rates and benefits being offered to make sure they meet one's needs.
• Checking whether organizations for peer specialists exist in the state and local area. Such organizations may have helpful information on their websites. They can also be sources of information on any scholarships or other funding available to help pay for peer specialist training, education, and certification. Potential peer specialists may need to become a member to access certain types of information.
• Attending peer conferences and networking events to learn about the peer workforce, the experiences of peers working at different organizations, and the ways peer jobs vary by setting (for example, outpatient clinic, hospital, RCO) to get a sense of what might suit the person best. A potential peer specialist may also be able to learn about how, and for how long, peer positions at different organizations are funded. (Potential peer specialists also should consider asking about this during peer specialist job interviews.)
• Reading Chapter 3 of this TIP.
• Checking out the many online peer resources available, including manuals and toolkits. These resources will give the potential peer specialist an idea of requirements and expectations as well as what the work might be like. YouTube also has videos about the role of peer specialists, including training videos and personal stories.

Step Two: Get involved—Potential peer specialists should search out volunteer opportunities at local RCOs, SUD treatment centers, mental health service centers, or other places providing PSS.

Step Three: Get trained—Training, including work experience, will help ensure that the potential peer specialist develops the necessary knowledge, skills, and attitudes to succeed in the peer position. It also shows future employers that the person takes the job and their professional development seriously. Although many training courses are offered in person, some training may be available online. Potential peer specialists will probably need formal training before an organization will hire them to join their staff. If possible, they should use a training entity that offers work experience hours as well as education hours. Potential peer specialists should build their computer skills as part of this effort.

Step Four: Get certified—Potential peer specialists should research certification requirements in the state (and in other states where the person might seek work) and in the organizations where the person wants to work. For example, some will require a certain number of peer work or volunteer hours, which often must be supervised.^673^ Also, potential peer specialists should determine whether additional education is required and accessible. Certification bodies often have additional requirements, such as passing a written test, completing an application, and getting professional or personal reference letters, or both. Some programs include training and certification as part of the hiring process and cover the costs for peer workers. A potential peer specialist might need to complete an internship before getting certified.

Step Five: Get hired—Potential peer specialists should look for job openings.

• For potential peer specialists who started out by volunteering, they should find out whether the organization has any openings for paid positions, and not get discouraged if nothing is open. Potential peer specialists can communicate their interest in a paid position to their supervisor and continue to work as a volunteer, if they can afford to do so.
• Potential peer specialists should check the website of the state-specific certifying body to see whether it publicizes job openings.
• Potential peer specialists should see whether there is a statewide peer specialist organization that shares job announcements. A potential peer specialist may need to join the organization to obtain its information on job openings.
• Potential peer specialists should use connections in the recovery community to express interest in paid work as a peer provider. Informal networks are a great resource for learning about job openings.
• Potential peer specialists should search traditional job outlets for openings, like job websites (for example, Indeed.com, LinkedIn.com, ZipRecruiter.com) and newspapers as well as the websites and social media posts of SUD treatment programs and recovery organizations. Because the peer role goes by many different names, search on different word combinations, such as “peer specialist,” “peer recovery specialist,” and “peer recovery coach.” Make sure that job openings aren't in the mental health field, which also uses peers.
• Job announcements are also often available through:
  – Peer training organizations.
  – RCOs.
  – Nonprofit organizations.
  – Colleges and universities.
  – Community centers.
  – Faith communities.
  – Mutual-help groups.
  – Outreach events.
  – Senior centers.
  – Youth centers.
  – Treatment alumni groups.
  – Social media platforms.
  – State vocational rehabilitation offices.
• Potential peer specialists should ask whether an organization is hiring, even if an opening isn't listed on the organization's website. People who work there may remember who inquired about job positions if an opening becomes available.

COMMON QUESTIONS ABOUT BECOMING A PEER SPECIALIST

The peer specialist role in SUD treatment is still somewhat new and continues to evolve, so the pathway to finding and getting this type of position can be confusing. Common questions include the following:

• Does the person have to be in recovery to be a peer specialist? To become a certified peer specialist, nearly all states require lived experience with problematic substance use and recovery. Requirements for minimum length of time in recovery vary from state to state but most often are 1 or 2 years.
• Does the person need to have a college degree to become a certified peer specialist? Most states require a high school diploma or GED but not a college degree. Certification requirements can change, so potential peer specialists should check with the certification body for the state where they want to work by calling or going on its website. The Resource Alert “Peer Specialist Training and Certification Programs by State” later in this chapter contains resources with helpful links.
• Does the person have to get certified to be a peer specialist? It depends, but the answer is probably yes. Some organizations that offer PSS have unpaid positions or will hire peer workers in the process of getting trained and certified. If the potential peer specialist is interested in being a volunteer peer specialist, certification is probably not needed. (But they should check with the organization about its rules and requirements.) However, virtually all states now offer peer certification and expect the person to get certified to hold these jobs. Therefore, the person likely will need certification to stay employed as a peer specialist.
• Will becoming a peer specialist help the person in their own recovery? Potential peer specialists should not pursue peer work as a way to advance their own recovery. Although it might help their recovery, it also might not. Peer specialists have described feeling that peer work had positive and negative impacts on their own recovery. Positive influences on recovery included improved knowledge about their own mental health and enhanced self-esteem and self-acceptance. Negative influences included feeling the pressure of being a role model for people seeking or in recovery and feeling triggered by working with people facing similar struggles (for example, experiencing a return of trauma-related symptoms after working with someone who discusses reexperiencing trauma in a nightmare).
• If the potential peer specialist gets Social Security Disability Insurance (SSDI) benefits, can they still be a paid peer specialist? Yes, although they may lose eligibility if their earned income goes over a set limit. This cap on earnings doesn't apply for a time if they participate in a Social Security Administration (SSA) SSDI work incentive program. SSA's Working While Disabled: How We Can Help booklet (https://www.ssa.gov/pubs/EN-05-10095.pdf) and its Ticket to Work page (https://choosework.ssa.gov/about/get-started-today/) contain more information. Potential peer specialists may also want to get free disability benefits counseling to learn more about how working will affect their SSDI and other public benefits. The National Disability Institute's Disability Benefits Counseling Services handout (https://www.nationaldisabilityinstitute.org/wp-content/uploads/2018/11/benefits-counseling-services.pdf) provides valuable details.

### Peer Specialist Training and Certification Requirements

Obtaining certification can help a potential peer specialist get a paid position. Some states and organizations require certification before starting paid work. Certification gives confidence to employers and the public that the person has the expertise needed to deliver PSS. In some cases, SUD treatment programs will hire people in recovery and pay for some or all of the costs of their peer specialist training and credentialing as part of the employment package.

SAMHSA collaborated with federal, state, tribal, and local partners to develop SAMHSA's National Model Standards for Peer Support Certification, covering substance use, mental health, and family and youth peer certifications. The National Model Standards, released in 2023, will accelerate universal adoption, recognition, and integration of the peer workforce across all elements of the healthcare system. The Model Standards can be viewed here: https://www.samhsa.gov/about-us/who-we-are/offices-centers/or/model-standards.

As of this TIP's publication, no single peer certification standard is accepted nationwide; however, national peer certifications do exist. Exhibit 6.1 lists the certification requirements of NAADAC and the International Certification and Reciprocity Consortium (IC&RC). Each has slightly different requirements and steps to certification.

EXHIBIT 6.1. Peer Certification Requirements From NAADAC and IC&RC

Factor | NAADAC
Name of credential | National Certified Peer Recovery Support Specialist
Lived experience required? | Yes
Required years in recovery | Minimum of 2 years (candidate must self-attest to having a minimum of 2 years of recovery from lived experience in substance use and/or co-occurring mental disorders)
Education | High school diploma, GED, or higher. Candidate must submit copy of GED, high school, or higher diploma or transcript.
Training | • Must show proof of earning 60 contact and training hours of peer recovery–focused education and training; • These 60 hours of training must include at least 48 hours of peer recovery–focused training, including education in:; – Documentation.; – Community/family education.; – Case management.; – Crisis management.; – Recovery-oriented systems of care.; – Screening and intake.; – Identification of indicators of substance use and/or co-occurring disorders for referral.; – Service coordination.; – Service planning.; – Cultural awareness, cultural responsiveness, or both.; – Basic pharmacology.; This also must include at least 6 hours of ethics education and training and 6 hours of HIV/other pathogens education and training within the last 6 years.
Work experience | A minimum of 200 hours of direct practice (volunteer or paid) in a peer recovery support environment (supervisor attested)
Other requirements or documents | • Must pass the National Certified Peer Recovery Support Specialist exam; • Must submit a signed statement indicating that the person has read and will adhere to the NAADAC/NCC AP Peer Recovery Support Specialist Code of Ethics; • Must provide two references (at least one professional)
Application fee | $235 (initial application; additional fees for testing and renewal)
Website | https://www.naadac.org/NCPRSS
IC&RC; • IC&RC credentials are administered by jurisdiction-specific boards (for example, country, state, region, military) using competencies and an exam developed by IC&RC. Each board sets its own standards, application processes, timelines, and fees for credentialing. To earn a credential, a potential peer specialist must work with the certification board in their jurisdiction.; • Contact information for all boards appears on IC&RC's Board Directory website (https://internationalcredentialing.org/memberboards). Note that this information is subject to change.; • The IC&RC website has information about peer recovery credentials (https://internationalcredentialing.org/creds/pr) and a study guide and other materials for exam preparation (https://internationalcredentialing.org/examprep).

As of this TIP's publication, nearly all states have training and certification programs, although the majority of these states offer a single, integrated certification for peers in the substance use recovery field and peers in the mental health recovery field.

State certification programs have different requirements on training, supervised peer work experience (paid or volunteer), and lived experience. Certifying bodies also differ from state to state. For example, some states have certification boards, some use third parties, and some certify peers through the state behavioral health agency.^674^

RESOURCE ALERT: PEER SPECIALIST TRAINING AND CERTIFICATION PROGRAMS BY STATE

• The SAMHSA-funded Peer Recovery Center of Excellence in 2023 published the updated Comparative Analysis of State Requirements for Peer Support Specialist Training and Certification in the United States (available through https://peerrecoverynow.org/about/coe-products.aspx), which provides an overview of peer training and certification requirements across U.S. states, compares and analyzes those requirements, and lists online resources by state. The center also has an online state certification directory at https://peerrecoverynow.org/resource-library/state-certification-database/.
• SAMHSA's Bringing Recovery Supports to Scale Technical Assistance Center Strategy compiled the State-by-State Directory of Peer Recovery Coaching Training and Certification Programs by searching the Internet to supplement information from state certification boards for SUD professionals, state mental health and SUD authorities, sources identified by IC&RC, local and statewide RCOs, and Faces & Voices of Recovery. It lists certification requirements for peers in all 50 states and Washington, DC (https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Directory-of-Peer-Recovery-Coaching-Training-and-Certification-Programs_8_26_2020.pdf).
• Doors to Wellbeing, a program of the Copeland Center for Wellness and Recovery, offers an online state-by-state database of certification requirements for peer specialists (https://copelandcenter.com/peer-specialists).
• The National Association of State Alcohol and Drug Abuse Directors Member Directory provides links to websites for state and territory Single State Agencies for SUD treatment and prevention, where a potential peer specialist can find information about certification of peer specialists in their state (https://nasadad.org/ssa-web-sites/).

Note: Some of the resources above also include certification information for mental health peer specialists.

Some states offer reciprocal credentials, meaning that peer specialists in other states with qualifying credentials could potentially move to and work in those states with reciprocity arrangements.^675^ IC&RC hosts a webpage that describes the reciprocity process for peer specialists holding the IC&RC peer recovery credential (https://internationalcredentialing.org/reciprocity).

If a potential peer specialist has a history of criminal justice system involvement, this won't necessarily keep them from becoming certified and working as a peer specialist. Recognition is growing that such lived experience can help peers better understand, relate to, and work with people seeking or in recovery who have criminal justice system involvement too. However, some states require criminal background checks or self-disclosure of criminal history as part of the certification process. Depending on the state and the category of offense, a criminal history could be grounds for denying an application for certification as a peer specialist, either permanently or for a number of years. Some states make these determinations on a case-by-case basis.

Examples of the types of convictions that can be disqualifying include the following:^676,677,678,679,680^

• Murder
• Manslaughter
• Assault
• Sexual offense
• Domestic violence
• Child abuse or neglect
• Elder abuse or neglect
• Kidnapping
• Stalking
• Arson
• Burglary

Potential peer specialists should research their state's requirements, then check the hiring requirements of the organizations where they want to work if they have specific employers in mind. Not all state certifying bodies have criminal history–related information available on their public-facing websites.^681^ Also, keep in mind that state laws in this area can and do change.

## Becoming a Family Peer Specialist

Few people understand the difficulty of dealing with a family member's problematic substance use as well as members of similarly affected families. In recent years, the role of family peer specialist has emerged as a way to provide PSS to family members of people with substance use–related problems. Family peer specialists gain their lived experience by participating in their own recovery and wellness journeys as a result of a loved one's substance use–related problems. Drawing on their knowledge and lived experience of caring for those family members, family peer specialists can support other families in similar circumstances and provide education and linkages to resources to individual family members.^682,683^

### Principles of Family Peer Support

Family peer specialists have lived experience as a family member of a person in recovery. Before becoming qualified to work with families, family peer specialists must learn the core principles of family-based PSS. This knowledge helps support the use of services that are safe, effective, respectful, and ethical. High-quality family peer support reflects the following standards and values:^684,685,686,687^

• Individualized services: Family peer specialists don't use the cookie-cutter approach of offering the same services in the same ways to all families. They tailor support to the specific needs of each family and family member.
• Connectedness: Family peer specialists focus on helping families engage with and use services, resources, and support from other families, rather than just helping them access these tools.
• Respectful and culturally responsive services: Family peer specialists should have an open and nonjudgmental attitude that honors rather than objects to differences in viewpoints, opinions, or cultural outlooks.
• Skill-based approaches: Family peer specialists teach, mentor, and coach families on how to build the necessary skills to help themselves and family members in or seeking recovery during their recovery journeys.
• Knowledge-based techniques: Family peer specialists help educate families and answer questions to help them make informed decisions.
• Engagement: Family peer specialists work closely with families to ensure that they feel knowledgeable, confident, and supported.
• Solution-focused support: Although some families find it helpful to vent about their problems and frustrations, family peer specialists help them try to find solutions to their difficulties.
• Person-driven support: Family peer specialists support affected family members by helping them develop a wellness plan based on their own personal needs and goals. The plan reflects the idea that all affected family members have their own wellness journey, regardless of where the person in or seeking recovery is in their recovery journey.
• Outcome-based services: Rather than focusing on problems and weaknesses, family peer specialists offer families hope and encouragement, help them identify their unique strengths and resiliencies, and support them as they find solutions and work toward positive outcomes.
• Expanded opportunities: Family peer specialists help families get involved in the recovery community at multiple levels, such as through local or national recovery events.
• Advocacy: Family peer specialists teach families how to stand up for their own rights and the rights of the individual in or seeking recovery. They also promote recovery to the local community, providers, and policymakers.

FAMILY PEER SPECIALISTS: WHAT PEOPLE IN RECOVERY NEED TO KNOW

Research shows that when supportive loved ones are involved in a person's SUD treatment, recovery, or both, that person has a better chance of stopping their addiction and maintaining long-term recovery.^688,689^ But many people in recovery won't have heard about family-based PSS and will probably have questions about what it means to have a family peer specialist working with their family. People in recovery who are unfamiliar with family peer support need to know that:^690^

• People are more likely to succeed in treatment or recovery when supportive family members are involved in their care.^691^ Family support—whether emotional, instrumental, or both—can go a long way in helping someone feel cared for and encouraged through the ups and downs of recovery.
• Family peer specialists do for families what peer specialists do for individuals in recovery—offer education, support, and resources. Their job is to give families the tools and information they need to better function, meet their own needs, and understand what their loved one is going through and how to help.^692^
• Family peer specialists don't provide treatment to families. However, if a family could benefit from treatment, such as family or couples counseling, family peer specialists can refer them to treatment and answer questions about that service.
• Family members have a right to seek clinical and nonclinical recovery support, regardless of the actions or preferences of their loved one. PSS can benefit anyone who has been directly or indirectly affected by substance use–related problems. (Note that there may be limitations on minors receiving PSS, depending on state laws and organizational policies about parental or guardian consent.)
• Family peer specialists don't force services onto families. If a family isn't interested in working with a family peer specialist, that's all right. Family specialists respect the choices families make but ensure that the family knows how to reach them in case family members change their minds.
• A person in recovery may at some point want to consider including a family peer specialist in their care team to strengthen their recovery support network. Before including a family peer specialist in their care team, the person in recovery should carefully discuss any privacy or other concerns with their own peer specialist. (If the individual doesn't have a peer specialist, they should discuss the idea with another member of their care team, like a counselor or case manager.)
• As a best practice, family peer specialists encourage the person in recovery and family members to be open with one another but don't share anything with the family that the person in recovery doesn't want shared. Similarly, family peer specialists don't share anything with the person in recovery that the family doesn't want shared. This includes medical, mental health, legal, and treatment-related information. The person in recovery has the right to privacy, and family peer specialists should respect that privacy. Before the start of services and treatment, family peer specialists will review confidentiality guidelines with family members and the person seeking recovery to make sure everyone is on the same page.

### Qualifications

Family peer specialists are qualified nonclinical providers trained and supervised to make sure they:

• Have the necessary skills and education to effectively help affected families.
• Offer services that are:
  – Person centered.
  – Strengths based.
  – Trauma informed.
  – Culturally responsive.
• Follow rules and guidelines for ethical behavior.
• Have the required certification that reflects their experience, training, and supervision (where available—not all states offer family-specific peer certification).

#### Lived Experience

Having lived experience with supporting a person in or seeking recovery is important for family peer specialists. This experience helps family peer specialists empathize with the experiences of other families of individuals in or seeking recovery. It also means that family peer specialists have personal knowledge of how to address the problems families face and can offer ideas for how to cope with their struggles. Because of this lived experience, family peer specialists serve as role models for other families and offer living proof that families touched by problematic substance use can recover. Entities that certify family peer specialists typically require them to have lived experience.

#### Training

Training to become a family peer specialist usually includes a combination of:

• In-person or web-based training courses, lectures, or seminars offered through local, regional, national, or online training programs. Some states include family recovery support specialist training as part of their peer support training (for example, Arizona, Colorado [in 2020]).^693^
• Volunteer or paid work experience as a family peer specialist.

Training isn't only critical to making sure family peer specialists understand how to perform this type of work, it also helps them understand how to provide support that is family driven, trauma informed, and culturally responsive.

#### Supervision

Most states require that family peer specialists be supervised, and all state and national certification programs require that family peer specialists receive supervision as part of the certification process.^694,695^ Supervision is often provided by someone licensed and qualified in the area of substance use or mental health, such as a psychologist, counselor, or social worker. Supervision helps family peer specialists build and improve peer support skills while ensuring that services are of the highest quality possible.

Supervision also protects and guides the family peer specialist when facing challenging situations like working with reluctant family members or answering medical or legal questions. A supervisor steps in when a family member asks the family peer specialist to do something beyond their scope of training, abilities, or certification. This will help keep the family peer specialist from accidentally doing or saying something that could negatively affect the family or themselves.

#### Certification

Because family peer support is an emerging practice, family-specific peer support certification is not yet widely available. Some states' peer specialist certification programs allow family members to qualify as peers, but don't offer a separate certification. Fewer states offer family-specific certification.^696,697^ Exhibit 6.2 lists which states offer family peer specialist certification.

EXHIBIT 6.2. Family Peer Specialist Certification

SAMHSA's Bringing Recovery Supports to Scale Technical Assistance Center Strategy prepared the State-by-State Directory of Parent Peer Support Training and Certification Programs, which lists information on family peer worker certification programs for states that had them as of 2020 (https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Parent-Peer-Support-Training-Directory_2020.pdf).

Family peer support is an emerging practice. Although more programs have begun implementing these types of supports, information about the role continues to evolve and requires further examination.

Some states offer a peer specialist certification that includes family members as peers. Fewer states offer credentialing that is separate from other peer specialist certifications and specific only to family members. States that currently offer this type of certification include the following:

State (name of certification) | For Further Information
Colorado (Peer and Family Specialist) | https://coprovidersassociation.org/certifications/peer-family-specialist-certification/
Idaho (Certified Peer and Family Support Specialists) | https://healthandwelfare.idaho.gov/Medical/MentalHealth/PeerSpecialistsFamilySupportPartners/tabid/2935/Default.aspx
New York (Certified Recovery Peer Advocate–Family) | http://www.asapnys.org/certified-recovery-peer-advocate-family/
New York (Family Peer Advocate) | https://www.ftnys.org/training-credentialing/family-peer-advocate-credential/
Pennsylvania (Certified Family Recovery Specialist) | https://www.pacertboard.org/cfrs
Utah (Certified Peer Support Specialist) | https://sumh.utah.gov/education/certification/peer-support
Wisconsin (Parent Peer Specialist) | https://www.wicps.org/parent-peer-specialist/

Currently, the National Federation of Families offers the only national family peer specialist certification, but it differs from the family peer specialist certification described above. The National Federation of Families certification is for parents or caregivers of children and emerging adults with emotional, developmental, behavioral, substance use, or mental disorders. Information about the certification is available online (https://www.ffcmh.org/certification).

## Conclusion

The peer specialist position can be a rewarding career choice for individuals wanting to help others recover from SUDs and achieve health and wellness. People and families who are interested in becoming peer specialists should continue to educate themselves on the benefits as well as the challenges of working in this capacity. They should make sure they understand their motivations and expectations. Also, potential peer specialists can familiarize themselves with the certification requirements for the state or states where they might want to work and look at the qualifications and duties listed in online peer specialist jobs posted by the types of organizations that interest them.

Peer specialists make up an increasingly important part of the SUD treatment and recovery workforce, and the settings where they work continue to expand. Positions in the emerging field of PSS offer plenty of opportunity to learn, to contribute, and to grow.

## Appendix

### Peer Specialist Functions and Responsibilities

Sample Functions:

• Providing vision-driven hope and encouragement, supporting people in their recovery, and assisting them in connecting to the recovery community
• Providing opportunities for individuals receiving services to direct their own recovery process (self-determination) and acting as an advocate for people served
• Working with individuals one-on-one and in groups to provide recovery training, and reaching out to individuals who use SUD services in the local community
• Sharing personal recovery experiences and developing authentic peer-to-peer relationships
• Offering instruction and support to help people develop the skills they need to facilitate their individual recovery
• Informing people served of available service options and choices while promoting the use of natural supports and resources within the local community
• Providing peer mentoring and support for individuals who are receiving SUD services
• Assisting individuals in navigating the SUD services system and in achieving resiliency and recovery as defined by the person

Sample Responsibilities:

• Assisting in the orientation process for people who are new to receiving services for substance use and/or co-occurring disorders
• Proactively contacting individuals to ensure they are making a successful transition to community integration and continuing their progress toward recovery goals
• Supporting individuals in seeking to connect/reconnect with family, friends, and significant others and in learning how to improve or eliminate unhealthy relationships
• Providing education and advocacy within the local community that promotes awareness of SUDs, while reducing misconceptions, prejudices, and discrimination
• Keeping treatment team informed about individuals' strengths, accomplishments, and obstacles in relation to their recovery goals
• Completing all required documentation in a timely, legible manner
• Educating professional staff about the recovery process and the damaging role that stigma can play in undermining recovery
• Visiting community resources with people using services to assist them in becoming familiar with potential opportunities
• Facilitating the transition from a professionally directed service plan to a self-directed recovery plan
• Modeling personal responsibility, self-advocacy, and hope by drawing on one's recovery story, as appropriate
• Ensuring confidentiality of individuals' information
• Assessing emergency situations, notifying supervisor or appropriate clinical and administrative personnel of actual or potential problems
• Exhibiting a nonjudgmental approach, effective listening, good eye contact, and positive interactions

Source: Adapted with permission.^698^ Job descriptions and materials collected by P. Swarbrick and P. Nemec, 2011, The Transformation Center (Boston, MA), and Collaborative Support Programs of New Jersey. Edited by Achara Consulting; adapted from job descriptions and materials from Pennsylvania, North Carolina, Recovery Innovations of Arizona, Florida Peer Network Inc., the Transformation Center (Boston, MA), and Collaborative Support Programs of NJ.

### Sample Job Description for a Peer Support Specialist

Summary: The Peer Support Specialist works with program participants onsite and in the local community to provide recovery support. Peer Support Specialists provide individual and group support in multiple settings and provide referrals for resources like housing, clothing/food, and overdose prevention/naloxone training. They also provide educational outreach to providers and community groups.

Job Responsibilities:

• Providing individual recovery support on a regular basis
• Facilitating recovery support groups
• Connecting program participants to community-based resources
• Assisting program participants in finding community services to meet basic needs
• Empowering program participants by supporting them in identifying and removing barriers to their recovery
• Supporting program participants in developing a self-directed plan for advancing their recovery
• Working with program participants on acquiring daily living skills, such as taking the bus
• Advocating for program participants and helping them develop self-advocacy skills
• Completing all required documentation clearly and on time
• Assisting in planning and conducting recreational activities for program participants
• Coaching program participants on problem-solving techniques and coping skills
• Accompanying program participants to appointments, meetings, and other activities, while maintaining ethical boundaries and communication with supervisor
• Providing outreach to and follow-up with nonresidential program participants where they live or in the community
• Providing community outreach
• Maintaining contact by phone/text/email with program participants after they leave the program to provide support and encouragement
• Communicating effectively and respectfully with all program participants and coworkers and with community partners
• Maintaining positive relationships
• Completing all trainings as assigned
• Completing additional duties and responsibilities as assigned

Qualifications: To perform this job successfully, one must be able to perform each essential duty satisfactorily:

• Demonstrating an understanding of, and belief in, the recovery process
• Being a person with lived recovery experience, with a minimum 2 years of continuous recovery
• Having positive communication skills
• Having the ability to maintain confidentiality
• Having the ability to relate to people from diverse backgrounds
• Being 21 years old or older

Education and/or Experience:

• High school diploma or GED required
• Associate's degree or higher preferred
• State-certified Recovery Coach or working to complete this within 6 months of hire
• Understanding of local community resources and recovery-oriented systems of care model

Certificates, Licenses, Registrations: Must have a valid driver's license, registration, positive driving record, and proper auto insurance (provide a copy to the manager)

Other Skills and Abilities:

• Knowledge of basic crisis intervention and motivational interviewing techniques
• Ability to act as an advocate for the needs of the individual

Physical Demands: The physical demands described here are representative of those that must be met by an employee to successfully perform the essential functions of this job. Reasonable accommodations may be made to enable individuals with disabilities to perform the essential functions.

• While performing the duties of this job, the employee is regularly required to stand, walk, use hands, feel objects and/or controls, talk, hear, and smell.
• The employee frequently must be able to reach with hands and arms, climb or balance, stoop, kneel, crouch, and sit.
• The employee may need to lift up to 25 pounds.

Work Environment: The work environment characteristics described here are representative of those an employee encounters while performing the essential functions of this job. Reasonable accommodations may be made to enable individuals with disabilities to perform the essential functions.

Source: Adapted from material in the public domain^699^ and available for free online (https://rizema.org/wp-content/uploads/2019/01/UMass-Recovery-Coach-Report.pdf).

### Additional Resources

• The Academy for Addiction Professionals Blog. Features a posting on “A Day in the Life: Peer Support Specialist” (https://www.addictionacademy.com/2017/08/a-day-in-the-life-peer-support-specialist/)
• SAMHSA's Bringing Recovery Supports to Scale Technical Assistance Center Strategy (BRSS TACS). Offers an extensive list of video trainings (pre-2019) on many aspects of PSS (https://www.samhsa.gov/brss-tacs/video-trainings)
• BRSS TACS. Offers a list of certification requirements for all 50 states and the District of Columbia, as of 2018 (https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Directory-of-Peer-Recovery-Coaching-Training-and-Certification-Programs_8_26_2020.pdf)
• Doors to Wellbeing Peer Specialists Database. Features a searchable database of program descriptions and certification requirements of peer specialist programs in each state (https://copelandcenter.com/peer-specialists)
• IC&RC. Includes information about the certification process for their peer recovery credential (https://internationalcredentialing.org/creds/pr)
• NAADAC. Includes information about the certification process for becoming a national certified peer recovery support specialist (https://www.naadac.org/NCPRSS)
• National Association of State Alcohol and Drug Abuse Directors Member Directory. Provides links to state and territory Single State Agencies for SUD treatment and prevention where potential peer specialists can find information about certification of peer specialists in their state (https://nasadad.org/ssa-web-sites/)

#### Case Studies

##### How To Approach the Case Studies

These case studies contain the stories of two people in recovery who are thinking about becoming peer specialists. Each story consists of an introduction outlining the person's story (including recovery history), learning objectives for readers, a dialog, and a summary.

The two stories incorporate key concepts discussed in this chapter:

• The first case study demonstrates the importance of knowing why someone would want to become a peer specialist and what motivates them to seek this work.
• The second case study shows how a person in recovery interested in becoming a peer specialist learns about the nuts and bolts of entering this field from a current peer specialist.
• Both case studies also touch on some of the rewards and challenges of being a peer specialist.

CASE STUDY 1—SARAH: EXPLORING MOTIVATION FOR SEEKING WORK AS A PEER SPECIALIST

Overview

This story illustrates how providers can be a valuable source of information and support for people interested in becoming peer specialists. Such discussions can help people interested in these jobs explore their own motivations and desires about this line of work.

The story begins when Sarah, who is in recovery, seeks out a counselor, Paul, at the local SUD treatment program she attends. Although Sarah isn't Paul's client, she knows him, is comfortable speaking with him, and trusts his opinion. She also knows that, before becoming a counselor, Paul worked as a peer specialist at the treatment program. She has an interest in peer work and decides she would benefit from speaking with Paul about how to become a peer specialist.

Sarah's Case History

Sarah is a 31-year-old African American woman with a 10-year history of alcohol and opioid use disorders. She has been in recovery for 2 years, including 1 month of inpatient SUD treatment and nearly 2 years of outpatient SUD treatment. Since entering recovery, she has developed a strong support system that includes her boyfriend of 5 years, two sisters, and a number of close friends, some of whom are also in recovery.

Sarah still regularly attends the outpatient SUD program, where she participates in many different social sober activities, including recovery-related workshops led by peer specialists, job training seminars, and 12-Step meetings. From time to time, she does volunteer work for recovery activities held by the treatment program, like helping organize an annual National Recovery Month celebration event every September and leading computer training classes.

As a result of her positive experiences volunteering and working with peer specialists on her own recovery, Sarah has started thinking about becoming a peer specialist herself.

Objectives for Case Study 1

The objectives are:

• To illustrate how, by speaking with Paul, Sarah can explore her personal reasons for wanting to work as a peer specialist.
• To show the ways in which providers can offer important insights into why a person might (or might not) want to become a peer specialist as well as information about the job itself.
• To highlight how Paul offers Sarah encouragement while also challenging her to think about peer work in ways she hadn't before.

Person in Recovery–Provider Dialog

[Sarah arrives at the treatment center first thing in the morning. She knocks on Paul's office door, which is open slightly. Paul is sitting at his desk, reading through email on his computer.]

PAUL: Oh, hi, Sarah. Come on in.

[Sarah enters Paul's office and takes a chair facing him.]

SARAH: Morning. I hope I'm not bothering you too early.

PAUL: No, not at all. Just clearing out my inbox. [Paul smiles.] So, yesterday you said that you wanted to meet with me this morning. What's going on? Is everything alright?

SARAH: Yeah, everything is good. I just wanted to talk to you a little about the peer services here.

PAUL: Sure. Do you have some suggestions about them?

SARAH: No, I actually wanted to talk to you because I've been thinking about things, and I think I might want to try to become a peer specialist. Like, do what those folks do, help out those of us who come here. That kind of thing.

PAUL: Ah, I gotcha. Well, I think that's a really great goal, and I also think you'd be good at it.

SARAH: [Smiles.] Thanks!

PAUL: But I think it's important that you're really clear with yourself about why you want to do this kind of work. Let's start with this, though: How do you think of peer specialists? Who are they, and what do they do?

SARAH: Well, I know that they help people get in recovery and stay that way, and that they're all people in recovery, too.

PAUL: In a very basic sense, yes, that's true. Peer specialists do support people who are thinking about or in recovery, and most of them are in recovery themselves. There's a lot more to it than that though. What are your reasons for wanting to do this job?

SARAH: Well … I don't know. I mean, I know I want to help people with problems like I had.

PAUL: Okay, that's fair. But there are lots of ways to help people get or stay in recovery that don't involve being a peer provider. So, what is it about peer work specifically that interests you?

[Sarah is silent while she thinks over Paul's question. He waits quietly and patiently, without making her feel rushed.]

SARAH: Well, you know how my brother had his problems with pills, and that caused him to overdose? That was probably the worst time in my life. I mean, my whole family fell apart after he died. Our mom lost it … wouldn't get out of bed or take care of my sisters and me or anything. And Pops had to quit his job to stay home to take care of Mom. And since I've been coming here, working with the peers and everything, I just feel like … if my brother had had something like that in his life when he was trying to kick the pills, he probably could have made it. He didn't, though … and I just don't want any other family to go through what ours did.

PAUL: You know, I knew you had a family member who had struggled with addiction, but I didn't know it was your brother. And I didn't know that you lost him to an overdose. That sounds like a terrible time for you and your family, Sarah.

SARAH: Yeah, it was.

PAUL: How do you think losing your brother might help you reach other people?

SARAH: Um … Well, I think it might help because you can't really understand what it's like to lose someone until you do, you know? I mean, it's not the kind of thing you can just teach someone about. You either know it or you don't. And when you feel that pain … just having someone else who really gets it helps you not feel so alone and so sad.

PAUL: You're right, and I think it's really wonderful that you want to try to reach people like your brother and turn your loss into something positive. Why else do you think you might enjoy or be good at peer work?

SARAH: [Thinks for a minute.] You know how I teach those computer classes here every other Tuesday? I really like it.

PAUL: Yes, I've heard that you've become quite the computer whiz. What do you enjoy about teaching the classes?

SARAH: I'm not totally sure. I mean, I like teaching people things that they can use. And with the computers, that was something I didn't really know about until I came here and took the classes too. So, when people in the class ask questions or get upset because they can't figure something out, I feel like I get it because I was there too.

PAUL: You know, that's actually a really important part of being an effective peer specialist—being able to understand what it's like to struggle and having experienced some of the same things. Because you've walked in their shoes, you really know where people in recovery are coming from. And that also makes your input very valuable, because they know that you understand.

SARAH: [Nods her head.] I guess it's sort of like when I was in the hospital program for my pills and my drinking. There was a girl there, a peer specialist, who worked with all of us who were getting treatment. She taught me about recovery and what the hospital program could do for me. And I actually listened to her more than I did the doctors, because sometimes I felt like they didn't really get it. They're just talking at you and telling you what to do because that's their job or whatever. But this woman I worked with … she didn't talk to me like that. She really listened and explained things in a way that helped me get it. And I knew she understood because she had been through the program too.

PAUL: Let me ask you—how are you as far as staying connected with people? Because being a peer specialist means really keeping in close touch with the folks you work with—not like therapy, which can sometimes be a “touch and run” type of job that only lasts for a certain amount of time. How do you feel about staying connected to people, even if they aren't grateful, or don't do things the way you would do them. Will you be okay with that?

SARAH: Well, I made a lot of friends when I started my recovery 2 years ago, and we're all still fighting our own fight. They don't all come here. But we all text each other and whatnot. We have coffee and talk about our families and what's going on. Even though we do recovery our own way, we keep in touch because we want to keep that closeness. Like, I do Alcoholics Anonymous, but one of my girls who also has problems with drinking does her own thing with her church. And that's fine. I don't get on her case because she has to do recovery her own way, and she doesn't get on my case. So, I don't think I would have a hard time keeping in touch with people even if they weren't doing things the way I am.

PAUL: That's great to hear. Having an open and flexible attitude is an important part of this job. So, you've named several experiences that you think might help you in this role. What about challenges you might face?

SARAH: What do you mean?

PAUL: I mean, sometimes the things that we think will help us reach out to others actually can make it harder for us. How might your brother's death make it hard for you to work with others in recovery?

SARAH: Well … [stares at the floor for a minute] I hadn't really thought about it like that. I guess it would be hard if I was working with someone who also lost their brother. Like, someone whose story is a lot like mine. I could see myself just wanting to get outta there because it would be too much.

PAUL: That's not unusual—to work with others in recovery whose stories trigger our own negative feelings of pain or anger or sadness. And that's partly why all of our peer specialists are supervised, so they can discuss how to react in those situations and how to handle those feelings.

SARAH: Or maybe if I am working with someone who ends up overdosing like Michael did … that would be so awful. I don't even know what I would do. [She takes a tissue from Paul's desk and wipes her eyes.]

PAUL: I can tell that losing your brother was really traumatic for you. If you're going to be a peer specialist, you will be working with people who also have experienced loss or other traumas. It might help for you to talk with a counselor about how to deal with your own feelings about losing Michael and about what it would be like helping other people who have experienced trauma. A supervisor can help you with the work side of things, like what to say or do in those situations, but your supervisor can't really be your therapist and help with the emotions of it all, you know?

SARAH: [Nods.] Yeah, I get it.

PAUL: And just like a supervisor isn't a therapist to you, you can't be a therapist to the people in recovery that you'd be supporting.

SARAH: [Nods.] I saw my counselor for more than a year, and it was totally different than the work I did with the woman at the hospital program or with the peers here. It was more … I don't know … it was more like talking to a doctor.

PAUL: Yes, the two roles are really different. Therapy is a type of treatment. Peer work is about using your knowledge of recovery and your personal experiences to support others with their recovery and connect them to resources. It's not a clinical role. It's not your job to diagnose or treat someone. And as a peer specialist, you're not giving people directions or telling them what to do. Instead, you're saying, “These are some different things that have worked for other people.” So that also makes it a little different from, say, when you go to the doctor for a problem and they tell you, “Here's what you need to do.” Does that make sense?

SARAH: It does. I don't think I want to be a therapist anyway—no offense. [Both laugh.]

PAUL: None taken. You certainly don't have to become one. I started out as a peer specialist, and that ended up helping me get into counseling, which was what I wanted to do. It's not a requirement. Not everyone wants to take that path, and that's totally fine.

SARAH: Good to know. I wasn't sure if there would be any pressure or whatever … like, if I become a peer specialist, would I have to keep going? Is that bad if I'm not into that?

PAUL: Not at all! Peer providers offer really valuable services apart from what doctors and therapists and social workers offer. You can make a big difference in a lot of people's lives without becoming a treatment provider. And I think your reasons for seeking this kind of work are good ones. With the right training, I think you'll really succeed in this role.

SARAH: [Smiles.] That means a lot to me, thanks. Now when you say training … I mean, what exactly do I have to do?

PAUL: Well, no matter where you work, you'll have to be trained to make sure you perform the role correctly and ethically. For instance, if you're interested in being a peer specialist here, we have all peer specialists get sixty hours of training.

SARAH: Sixty? Wow. That's a lot.

PAUL: It is. But it's important that you get trained right so you can do your job well.

SARAH: No, I get it. That makes sense. How long will that take me though? And what does it cost? Wait—would I have to go back to school? I know that Sean—do you know Sean? He didn't go to college, and he's been a peer specialist here for something like five years.

PAUL: You're right. Sean is a really effective peer specialist, and he doesn't have a college degree. Whether or not you will need one depends on where you work. Here, it isn't needed.

SARAH: Okay, that's good. I mean, I definitely don't mind training and taking whatever courses you guys might offer. There's no way I can spend all that money or time on college right now, though.

PAUL: I understand.

SARAH: So, what do I need to do next?

PAUL: [Looks at his watch.] I hate to cut our talk short, but I have a client I need to meet with. Why don't we meet again in a few days, and I can walk you through one of our peer specialist job ads. That way, you can better understand the role of peer specialists here, what we expect from them, and what you need to do to get one of these jobs—including the amount of time it will take and how much it might cost. We can also talk about certification.

SARAH: Okay, that sounds good. Wait—certification?

PAUL: [Smiling.] Don't worry—it's not as scary as it sounds. I can explain everything and give you some useful resources, like websites to look at and manuals to read.

SARAH: Oh, okay. That all sounds good. I'm really glad I came to talk to you about this. I mean, I guess I hadn't thought a lot about why I wanted to do this. It was just something that seemed like a good idea.

PAUL: No problem at all. I'm glad you came to talk to me too. Knowing why you want to do something can be just as important as knowing how to do it. When you understand what is driving you, you will feel a sense of purpose. You're not just taking this job because it's something to do with your time. You're doing it because it is meaningful to you in some way. And that means you will be more likely to stay committed to the training and the work, especially when things get tough.

SARAH: Yeah, that's true. I see now that peer work really is something I want to do, not just, like you said, a way to kill time or get paid or whatever. I actually feel more excited about this now, even though I know it will be hard work getting everything in place and finding a job.

PAUL: I'm happy to help, and I hope you keep me updated on how things are going. Now let's look at our schedules and see what works for meeting again later this week.

Summary

Sarah came to Paul to learn more about becoming a peer specialist. Rather than jumping straight into how to enter this line of work, Paul first helped Sarah explore her personal reasons for seeking a peer specialist position. He helped her think about how her own experiences might affect her work in both positive and negative ways. In doing so, Paul was also able to provide some basic yet important information about certain aspects of peer work, such as the need for supervision, how peer work differs from therapy, and what training might be needed. By asking questions, Paul helped Sarah think about this line of work in a meaningful and personal way. Although Sarah will still need to learn more about the nuts and bolts of how to become a peer specialist, her conversation with Paul helped her better understand whether this step is right for her.

CASE STUDY 2—SAM: USING PEER SPECIALISTS AS A SOURCE OF INFORMATION AND SUPPORT

Overview

This story describes a conversation between Sam, who is in long-term recovery and is interested in seeking work as a peer specialist at a residential or outpatient treatment center, and Robert, a peer specialist at the outpatient clinic Sam attends. Sam has a long and positive history with recovery services and formal treatment. He knows that becoming a peer specialist would be a good role for him. But he isn't sure what steps he needs to take or how to enter the field. He meets with Robert to learn firsthand the ins and outs of becoming a peer specialist.

Sam's Case History

Sam is a 64-year-old White man who has been in recovery from stimulant use disorder for 35 years. He also has a diagnosis of bipolar I disorder, for which he takes medication. Sam had inpatient SUD treatment followed by intensive outpatient treatment for both disorders. This included individual and group therapy and psychoeducation classes, which lasted about a year. Five years ago, Sam went through a bitter divorce, and although he did not return to stimulant use, he felt like he was close to having a recurrence. Sam feared that he might use again if he faced another stressful situation in the future, so he started seeing a psychologist, Dr. Ross, at a community mental health services and SUD treatment clinic. He continued to see Dr. Ross over the past 5 years but reduced the frequency of his visits to once a month.

Dr. Ross recently began working at a nonprofit SUD treatment clinic, where Sam now sees her. The clinic has peer specialists on staff, and Sam has read a handout about their services. Sam tells Dr. Ross during a therapy session that he'd like to become more active in the recovery community and learn how to become a peer specialist himself, now that he is doing well in recovery from SUD. She suggests that he sit down with a peer specialist at the clinic, Robert, to learn about Robert's experiences in becoming a peer specialist. She arranges for Sam to come by the clinic when he's off work and Robert has some time to meet with him.

Objectives for Case Study 2

The objectives are:

• To show how peer specialists can help others learn firsthand how to enter this line of work.
• To illustrate how encouragement from peer specialists can help people interested in the position feel empowered and supported.

Person in Recovery–Peer Dialog

[Dr. Ross and Sam walk down the hall to Robert's office. When they arrive, the office door is open. Robert is sitting at his desk, typing on his computer.]

DR. ROSS: [Knocks gently on the door frame.] Knock, knock! [Robert looks up, sees Dr. Ross, and smiles at her.] Here we are. Are you finishing something up?

ROBERT: Just typing up some notes. There, I'm done. [Smiling at Sam.] Please, come in and have a seat. [Robert gestures at two empty chairs across from his desk. Sam sits down in one of the chairs.]

DR. ROSS: Robert, I want you to meet Sam, the gentleman I was telling you about who might be interested in becoming a peer specialist. [Turning toward Sam.] Sam, this is Robert. He's been a peer specialist at this clinic for about ten years and now he also supervises other peer specialists. He'll be a great resource for you.

ROBERT: Good to meet you, Sam.

SAM: You as well. Thanks for making time to talk with me.

DR. ROSS: Well, I'll leave you two to it. Sam, I'll see you in a month?

SAM: Sounds good. Thanks, Dr. Ross.

[Dr. Ross leaves, pulling the door behind her so Sam and Robert can have some privacy.]

ROBERT: So, Sam, Dr. Ross tells me that you might be interested in becoming a peer specialist. I think that's excellent!

SAM: Well, I've been at this recovery thing for a long time now—almost thirty-five years. And it definitely hasn't been easy. I never would have been able to do it without the support of my doctors and the recovery community.

ROBERT: I'm glad to hear that you've had good support.

SAM: I guess that's partly why I want to look into becoming a peer specialist. I know how tough it can be and that none of us get through this alone. And even when things are going well, a slip can be right around the corner. That almost happened to me … [Sam pauses and looks away for a few seconds.] But thanks to Dr. Ross and the other staff here, including the peer specialists, I was able to keep that from happening. I swear, I wake up every day so grateful. I just feel like, if I can help even one person stop using and move forward with their lives … well, I think I'd really like that.

ROBERT: That's really powerful, Sam. You sound like you've learned some important lessons throughout your recovery and are very motivated to start this type of work.

SAM: Oh, I am. I can't start soon enough. Problem is, I don't even know where to start. I was hoping you could tell me a little about how you got to where you are and what I need to do to get there too.

ROBERT: Of course. You know, when I was just starting out, it would have been really helpful to talk to another peer worker so I could get the inside scoop, but I never thought of it myself and no one on my recovery team suggested it. So I'm really glad Dr. Ross said something to you about this and that you're open to talking with me.

SAM: Me too. The inside scoop sounds great. So where do I need to begin?

ROBERT: Well, I think the first thing is to learn about the job and make sure it's really what you want to do. But it sounds like you're already familiar with peer specialists' work and know this is something you're interested in.

SAM: Yep. No problem there.

ROBERT: Well, when I was trying to figure things out, I didn't really know what the steps were, so I just decided to see if I could start volunteering as a peer worker. I knew the recovery community organization I attended at the time used peer workers, so I asked one of the administrators I knew there if I could start volunteering. She said yes, and that was that.

SAM: So that's basically all I have to do? Just get some volunteer hours under my belt? That doesn't sound too bad. I work part-time, so I should be able to swing that.

ROBERT: [Laughs.] Well, no, this was more than fifteen years ago. Back then, we didn't know as much about peer workers and why what they do is so important. It wasn't as clear how exactly to get into this kind of work. You sort of had to figure it out on your own and go from there. Nowadays, nearly every state has some sort of certification for peer specialists, and a lot of clinics like ours can bill Medicaid for their services. That has really changed the process. It's much more clearly defined now because we have to make sure peer workers have the necessary training and experience.

SAM: Ah. I was sort of hoping that was all there was to it. [Laughs.] So, does that mean I shouldn't look for volunteer work?

ROBERT: No, I actually think that would still be helpful. It's a way to learn on the job, so to speak. And you will need to have some paid or unpaid peer work experience before you can get certified anyway. But even if you don't get certified, doing volunteer work is still an excellent way for you to learn whether or not you really enjoy this job and how to handle the day-to-day responsibilities. I highly recommend it.

SAM: I hear you. It sounds like certification is a big part of this, right?

ROBERT: Well, yes and no. It could be optional depending on where you want to work. A lot of places will want you to get certified, especially if they're billing to Medicaid.

SAM: I see. Well, I was thinking I could just skip all that certification stuff. I feel like I'm too old to be taking tests and going back to school. [Laughs.]

ROBERT: Are you kidding me? You're never too old to stop learning! [Laughs.] I know it sounds like a pain, but you can do it. And when you love what you do, you don't mind putting in the work. When I got certified, I had to get sixty hours of classroom training. I also needed five hundred hours of in-person experience working with people who have substance use disorders and twenty-five hours of supervision.

SAM: Five hundred hours? Man, that's a lot! This is going to be more work than I thought. [Sam looks disappointed.]

ROBERT: I know it seems like it, but don't let that get you down. Look, it's a marathon, not a sprint—just like recovery, right? It doesn't happen overnight—it's a journey. Even though I had to put in all those hours for training and work experience, by the time I got certified and was interviewing for jobs, I was very well prepared. I knew what to expect on the job, and the places that interviewed me all said they were impressed with my knowledge and service.

SAM: Well, when you put it that way, I guess it's not so bad. I guess I thought it was more like, take this test and go get hired. So, where do I go to get this training?

ROBERT: There's an agency within the state health department that certifies peer specialists. I'll give you the web address so you can look up the certification requirements and fees and see what training information it has. I can tell you that Nikki in our business office keeps a listing of peer specialist trainings in this county and the next county over. We can stop by her office on your way out and get that from her.

SAM: That'd be great—thanks.

ROBERT: A couple of other tips: Some places with peer specialists will pay for the cost of the training needed for certification. Our clinic does. Also, you should go online and look up job descriptions for peer specialist positions in this area, to see what sort of qualifications and experience different places require.

SAM: You know, the last time I was job hunting, I just opened up the newspaper. I guess that's not really how things work nowadays, huh? So it sounds like I need to get more comfortable with the Internet. I can do that—I'm sure my nephew can help me out. But you know what kind of worries me? Job interviewing. I've worked at the same place for so long that I haven't gone on a job interview in years.

ROBERT: [Smiling.] I actually have a printout of some questions you might be asked during an interview for a peer specialist position. I can share that with you. In fact, if you want, before you start job hunting, you and I could practice together, like role-playing. That way you can practice your answers.

SAM: Man, that would be great. I'd really appreciate that.

ROBERT: The other thing I'd do when you're ready to start job hunting is ask around and talk to people in the recovery community.

SAM: You mean like networking?

ROBERT: Exactly. That was how I found my first job as a peer specialist. I had mentioned something to a social worker at the recovery community organization where I was volunteering, and she had a colleague in a nearby city whose organization was looking to hire a team of peer specialists. One thing led to another, and within about a month, I had my first paid position in peer services.

SAM: That's great that it came together so easily. I hope it's like that with me.

ROBERT: Well, like I said, this is a process. Focus on learning what you need to learn to do your job well and help others. And remember to look after yourself while you're doing the training and the job hunting.

SAM: Thanks again, man. I can't tell you how much this helps. And hearing it from you makes me feel like I really can do this, because I know you were in my shoes at one point too.

ROBERT: It's no problem, really. I'm happy to share whatever knowledge I can. And maybe one day after you've been doing this awhile, you can do the same thing for someone else too! Now, let's go see Nikki about that listing of trainings.

Summary

Sam came to Robert to get firsthand advice about how to get a job as a peer specialist. Rather than just walking through the steps or giving Sam some handouts, Robert shared his personal story about what he did. He also linked Sam to peer recovery resources and offered to help him use these resources (for example, role-playing a job interview, helping Sam look up websites). Throughout their conversation, Robert offered words of encouragement and support to help Sam stay motivated and feel confident in his ability to complete the steps needed to become a peer specialist, especially when Sam seemed to feel overwhelmed. He also validated Sam's worries but helped him reframe his fears in a more positive light. By making the conversation personal and collaborative, Robert helped make their discussion a meaningful and useful experience for Sam.