# Chapter 5—Supervision of Peer Specialists

KEY MESSAGES

• Peer supervisors serve as a vital bridge between peer specialists and nonpeer staff.
• Peer supervisors can help peer specialists maintain healthy boundaries and ethical guidelines that are appropriate for peer support work.
• Peer supervisors can help nonpeer staff understand the peer role and the value peer workers bring to a program.
• As part of their role, peer supervisors should model recovery principles for peer and nonpeer staff.
• Peer specialists sometimes receive inappropriate assignments outside their scope of work. Peer supervisors need to advocate for peer specialists to ensure they have meaningful and appropriate work.
• Supervisors should help program administrators and human resources staff write peer specialist job descriptions, in part to avoid role confusion and role drift.
• Peer supervision can be performed by an experienced peer provider or treatment provider. Or a peer can receive dual supervision from some combination of an experienced peer provider, a treatment provider, and an administrator. Supervision can take place individually and in groups.

Across behavioral health settings, the use of peer support services (PSS) is rapidly expanding, including services that address substance use disorders (SUDs). Key factors that propel this growth include a paradigm shift from acute to long-term disease management, greater focus on recovery-oriented approaches, and more widespread approval of Medicaid reimbursement for peer services across states.^529,530,531^ Given the rapid expansion of PSS, the field needs supervisors who are knowledgeable about peer workers and who embrace a recovery-oriented, strengths-based, trauma-informed approach to supervision.

This chapter uses different terms to refer to different kinds of peers. Peer workers may volunteer their time or be paid. Like many people who work in “supporting” or mutual-help roles,^532,533^ peer workers often benefit from helping others. For example, peer work can benefit those who do it by increasing their knowledge, enhancing their self-esteem, and renewing their commitment to recovery.

The terms used in this chapter to refer to peers include:

• Peer worker: Refers broadly to all types of peers who provide SUD recovery support, regardless of whether they have received training or certification and whether they are paid or volunteer. Peer workers may or may not work in professional settings or as part of formal SUD treatment and recovery services. The term peer provider has the same meaning.
• Peer specialist: Applies to peers with some training, including those working in paid capacities, whether certified or not
• Certified peer specialist: Indicates a peer who has received certification or credentialing to provide PSS

Exhibit ES.1 in the Executive Summary includes full definitions of these and other terms readers will encounter in this chapter and throughout this Treatment Improvement Protocol (TIP).

Supervisors of peer workers play a vital role in integrating PSS into traditional SUD treatment programs and in establishing role clarity for peer workers and nonpeer staff. Supervisors educate and support peer specialists on how best to operate within the treatment setting (e.g., SUD treatment programs, recovery community organizations, primary care organizations, and emergency departments [EDs]), which may be unfamiliar to them. At the same time, supervisors help nonpeer staff (i.e., administrative and clinical staff) understand the peers’ recovery support work and its benefits to individuals in or seeking recovery, the organization, and the community.

Supervision may be delivered by peer and nonpeer supervisors, or a combination of both. To the extent possible, peer workers providing support to individuals in SUD treatment programs should receive supervision specifically from a supervisor who has personal lived experience with recovery and a history of working as a peer specialist.

Supervisors oversee administrative tasks while supporting skills development, maintenance of boundaries, and professional development. To deliver peer supervision effectively, supervisors need to commit to understanding peer services and the difference between clinical and peer supervision. Supervisors promote and advocate for peer specialists in the organization and in the community.^534,535^

Chapter 5 discusses key elements and challenges of supervising peer specialists. Chapter 5 is for peer supervisors in SUD treatment settings. It is organized into three sections:

• The first section describes the basics of supervising peer specialists.
• The second section addresses peer supervisor competencies.
• The third section discusses challenges of supervising peer specialists in treatment settings and offers solutions to these challenges.

## Basics of Supervising Peer Specialists

The use of peer specialists in SUD treatment, other behavioral health service settings, and other environments has increased rapidly. This growth has created a need to ensure that peer specialists have adequate support and supervision to fulfill their duties.

In some ways, supervising peer specialists does not differ from supervising other behavioral health service staff. A supervisor's primary roles are:

• Working with peer specialists and other staff to ensure the health and safety of individuals in or seeking recovery.
• Helping peer specialists provide quality services to individuals in or seeking recovery.
• Ensuring peers understand their ethical responsibilities and stay within their scope of practice.
• Facilitating peer specialists’ professional development and effective practice.

The key difference is that clinical supervision focuses on helping counselors develop clinical knowledge and skills like assessment, diagnosis, and treatment planning, whereas supervision of peer specialists focuses on helping them develop and apply recovery support knowledge and skills. Supervisors help peer specialists effectively support individuals in or seeking recovery such as by working with people to develop recovery plans and access recovery capital, while also helping peer specialists maintain appropriate boundaries and engage in self-care so as not to jeopardize peer specialists’ own recovery journeys.^536,537^

RESOURCE ALERT: ESSENTIAL KNOWLEDGE FOR SUPERVISORS

Effective delivery of supervision requires a need to initially invest in understanding PSS, particularly if the supervisor doesn't have a history of lived experience. In learning about the history, competencies, ethics, and responsibilities related to PSS and the roles of peer workers, supervisors also will demonstrate to peer and nonpeer staff that they value PSS within the organization. The following links provide information in several essential core areas:

Integrating Peers into Treatment Programs in New York City: An In-depth Guide for Substance Use Disorder Treatment Providers (www1.nyc.gov/assets/doh/downloads/pdf/mh/peers-treatment-programs.pdf)

Meaningful Roles for Peer Providers in Integrated Healthcare: A Guide (casra-meaningful-roles-for-peer-providers-in-integrated-healthcare-toolkit-11-13-14.pdf)

Value of Peers, 2017 (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/value-of-peers-2017.pdf)

SAMHSA's Core Competencies for Peer Workers in Behavioral Health Services (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/core-competencies_508_12_13_18.pdf)

National Certified Peer Recovery Support Specialist (NCPRSS) Code of Ethics (https://www.naadac.org/assets/2416/nccap-peer-recovery-support-specialist-code-of-ethics-final06-22-16.pdf)

The National Association of Peer Supporters’ National Practice Guidelines for Peer Specialists and Supervisors (https://www.peersupportworks.org/wp-content/uploads/2021/07/National-Practice-Guidelines-for-Peer-Specialists-and-Supervisors-1.pdf)

Peer Recovery Coaching Standards for Professional Practice (https://www.iaprss.org/wp-content/uploads/2023/05/PRC-Standards-for-Practice-Publication.pdf)

Candidate Guide for the IC&RC Peer Recovery Examination, including the four domains (advocacy, ethical responsibility, mentoring and education, and recovery/wellness support) and corresponding tasks (https://internationalcredentialing.org/resources/Candidate%20Guides/PR_Candidate_Guide.pdf)

Chapter 1 includes a brief history of PSS in SUDs. In addition, peer supervisors are encouraged to consult individual states for their codes of ethics and certification requirements for peer specialists. Resources are available in this chapter in the “Certifications” section and in the Resource Alert “Certification Programs and Resources.”

Ideally, supervision of peer specialists would include:^538,539,540,541^

• Creating a supportive environment in which peer specialists feel empowered to develop the capacity to build and apply skills. Supervisors should recognize the individual experiences of each peer, help them use that experience to work with individuals in or seeking recovery, and expand their knowledge by providing ongoing guidance and training.
• Promoting a stimulating environment that involves questioning, reflective practice, and understanding ethical and boundary issues between the peer specialist and the individuals in or seeking recovery, their family members, or other colleagues. Supervisors should talk with peer specialists about their impressions, concerns, and questions about their daily work to uncover growth and training opportunities, as well as potential challenges. During staff meetings, supervisors can encourage peer specialists to share about their work. (Case Study #1: “Ethical Issues” and the Resource Alert “Professional Development Trainings for Peer Specialists” provide more information on boundary issues and training.)
• Helping peer specialists identify strengths and areas for growth and set goals to develop and strengthen skills and abilities. Supervisors should acknowledge the peer workers’ successes, work with them to identify areas where they can improve, and help them locate trainings or other resources to support their growth.
• Conveying to nonpeer colleagues and the program at large that peer workers have an important role. Supervisors should model recovery, educate nonpeers about the work peer workers perform, and highlight the successes of peer workers in staff meetings.
• Holding regular, scheduled group meetings. In addition to meetings that include nonpeer staff, supervisors should consider holding peer-only meetings to ensure time for focusing on the unique challenges of their role. In some instances, it may be helpful to encourage connections to other professional peers outside the organization as well. Also, some states have requirements for the frequency of individual and group supervision.
• Helping peer specialists maintain and expand their own recovery experience. Supervisors need to understand how peers’ job duties (e.g., outreach to people who are actively using substances or who have experienced trauma) may place them at risk of return to use. Supervisors should make a plan to check in with peer specialists to assess their recovery journeys, help them balance their work with individuals in or seeking recovery, and sustain their own recovery.
• Giving consistent, constructive feedback in one-on-one meetings and actively requesting feedback from peer specialists. Supervisors should hold regular meetings in which peer specialists know they will receive honest and helpful critiques and can offer their ideas and suggestions to improve the program.

Peer supervisors serve as liaisons in the treatment setting. Peer supervisors:^542^

• Act as go-betweens for peer specialists and the administration, helping the former adapt to the organization's work culture and the latter better understand peers’ value to the organization.
• Convey information between administration and peer specialists on policies, program procedures, trainings, and changes within the organization.
• Act as go-betweens for peer workers and their nonpeer colleagues, negotiating any issues that arise because of the newness of the position, nonpeer unfamiliarity with the role, and similar causes.
• Communicate with individuals in or seeking recovery about recovery plans and coordinate their care with peer specialists and nonpeer staff.
• Oversee peer specialists’ relationships with the individuals in or seeking recovery they work with, and supporting the peers in their recovery, while helping them navigate any boundary issues that arise with their support work.

Supervisors’ involvement at so many junctions makes it essential that they engage with their supervisees regularly and remain mindful of the dual roles that peers occupy—as both individuals in recovery and as members of a treatment program for other individuals in or seeking recovery.

Whereas supervision is not the same as recovery support, supervisors can deliver supervision supportively. In interviews of peer workers receiving supervision from nonpeer supervisors, the supervisor's attitude was considered the most important element in determining whether peer workers viewed supervision as effective or detrimental.^543^ Peer workers described common positive supervisor attitudes as the ability to show respect and communicate nonjudgmentally.

CASE STUDY #1: ETHICAL ISSUES

Participant complains about peer specialist's level of self-disclosure about eating disorder and sex work.

Gina is a certified peer specialist working in an inpatient SUD treatment center that uses peer–participant working agreements.* Gina engages in individual recovery coaching, facilitates peer-run groups, and maintains the weekly All Recovery Meeting. Gina is in sustained recovery from SUD and binge eating disorder. She is also a survivor of sex trafficking.

One of Gina's participants left a message on the treatment center's voicemail complaining about Gina's coaching. The participant said that she feels uncomfortable when hearing about Gina's experience as a sex worker or her past eating disorder issues. The participant said, “I've never had to do that, and I don't plan to. Why do I have to hear about this or her eating issues?” The supervisor calls Gina to her office and asks her about her use of disclosure during coaching. Gina says that she avoids oversharing but does often use her full experience when discussing resilience with individuals in or seeking recovery.

Considerations

In what ways does Gina's use of self-disclosure potentially harm or benefit participants?

Has Gina explored her motives? Did she disclose more than was wise in an effort to prove that these aspects of her life experience help qualify her for her peer role? Did she have the participant's best interests in mind?

Lived experience of mental and substance use disorders is a prerequisite for authentic peer work, and some degree of disclosure is good practice. But should the program institute self-disclosure guidelines for the peer employees? For all employees? When can peer specialists appropriately disclose more of their stories beyond mental and substance use disorders (e.g., sex work, domestic violence, HIV status, criminal justice involvement)?

Possible Resolution

Gina and her supervisor agree to address level of disclosure in the peer–individual in recovery working agreement. Some guidelines within the agreement may specify disclosing certain types of lived experiences only when the individual first discloses a similar experience.

Her supervisor should take the opportunity to discuss how to make informed decisions about self-disclosure. Possible suggestions include that she initially think about the motive behind her self-disclosure and whether she believes that it would help the individual before sharing the information. Her supervisor should emphasize that self-disclosure is an important tool for peer providers. In Gina's case, it involves not only her history of mental and substance use disorders, but how she uses coping skills, supports, and her strengths.

* A working agreement is a list of mutual expectations agreed on by the peer worker and the individual in recovery when they initiate a peer support relationship.

### Supervisor Requirements and Training Needs

Peer specialists need skilled, recovery-oriented supervisors.^544^ Specific training for supervisors will enhance their ability to support peer specialists.^545^ The Substance Abuse and Mental Health Services Administration's (SAMHSA) Bringing Recovery Supports to Scale Technical Assistance Center Strategy (BRSS TACS) program prepared a self-assessment for supervisors of peer workers: https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/guidelines-peer-supervision-2-self-assessment-cp9.pdf. This assessment tool gives supervisors an opportunity to reflect on their supervision knowledge, skills, and learning needs specific to the supervision of peer specialists working in their program. Other BRSS TACS resources for supervising peer workers can be found at https://www.samhsa.gov/brss-tacs/about (under “BRSS TACS Spotlight”).

Each state holds different requirements for those who supervise peers. As of 2019, 15 states required either a certified or licensed provider and/or an individual who held at least a master's degree.^546^ Another 15 states required supervisors with certification or license to have some formal education, including completion of high school or an associate's or bachelor's degree. Several states don't have any requirements, and others allow a broad range of providers to supervise peers.

In addition to 10 Model Standards on general peer support certification, SAMHSA's National Model Standards for Peer Support Certification includes a standard with several recommendations for peer supervisor certifications (see Model Standard #11: Peer Supervision) at https://www.samhsa.gov/about-us/who-we-are/offices-centers/or/model-standards.

RESOURCE ALERT: GUIDES FOR SUPERVISION OF PEER WORKERS

These resources provide guidance and tools for peer supervisors:

• National Practice Guidelines for Peer Specialists and Supervisors (https://www.peersupportworks.org/wp-content/uploads/2021/07/National-Practice-Guidelines-for-Peer-Specialists-and-Supervisors-1.pdf)
• Peer Recovery Support Webinars (https://www.naadac.org/peer-recovery-support-webinars)
• Peer Support Toolkit (https://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf) [Refer to Module 4: Supervision and Retention.]
• Supervisor Guide: Peer Support Whole Health and Wellness (https://www.peersupportworks.org/wp-content/uploads/2021/05/Supervisor-Guide-to-Peer-Support-Whole-Health-and-Wellness-c-2013.pdf)
• SAMHSA's Supervision of Peer Workers Presentation (BRSS TACS) (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/guidelines-peer-supervision-4-ppt-cp5.pdf)
• SAMHSA's Supervision of Peer Workers Brochure (BRSS TACS) (https://www.samhsa.gov/sites/default/files/brss-tacs-peer-worker-supervision.pdf)
• Utah Supervisor Guide for Peer Support (https://dsamh.utah.gov/wp-content/uploads/2020/09/Utah-Peer-Support-Supervisor-Guide-3-9-2020.pdf [Readers may need to search on the document's title for an updated URL.])
• Magellan Health Services’ Course, Effective Supervision of Peer Specialists (https://alphacarecms.magellanhealth.com/training2/peersupport/magellanmodule7/main.htm)
• Strategies for Effective Peer Supervision (2018) (https://soundcloud.com/resourcesforintegratedcare/how-behavioral-health-organizations-can-advocate-for-peers-2018)
• DIMENSIONS: Peer Support Program Toolkit (https://www.bhwellness.org/toolkits/Peer-Support-Program-Toolkit.pdf)
• Peer Integration and the Stages of Change ToolKit (https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf)

### Peer Supervision Formats

#### Group Supervision

The primary formats of peer supervision are group and individual supervision. Group supervision involves other peer specialists from the same organization or setting. It provides an opportunity to solidify role clarity,^547^ as the supervisor and peers discuss current support efforts with individuals in or seeking recovery as well as their own recovery journeys. Regular (usually weekly) group meetings offer a good way to:

• Provide information (e.g., training opportunities, changes in policy and procedures, agency announcements, community resources).
• Promote team cohesiveness, decrease isolation in role, and gain support from others in similar roles.
• Share knowledge about individuals in or seeking recovery and discuss ways to support their recovery processes.
• Provide collaborative learning experiences and practice skills with each other.
• Receive feedback from other peers and learn how they handle different scenarios with individuals in or seeking recovery.

Peer supervision can promote open discussion and help peers work out issues unique to their role within the program. Incorporating new peer specialists into group supervision meetings as soon as possible will provide them with immediate support and guidance. In addition to peer supervision, staff meetings—involving both peer specialists and clinical staff—provide an opportunity to define, coordinate, and honor the contributions of everyone. Team meetings enable the entire staff to learn from each other, understand each other's roles and responsibilities, coordinate care, and reinforce the value of peer specialists’ roles in the care of a person in or seeking recovery.

A 12-week study in an outpatient treatment facility found that weekly group supervision of peer workers, along with an individual supervisory meeting after 6 weeks, adequately prepared peers for successful delivery of services and resulted in significant decreases in substance use by those receiving PSS.^548^ Another study of supportive group supervision for peer workers showed significant increases in self-efficacy—not only in their work, but also in their own recovery.^549^

#### Individual Supervision

Individual supervision is the second way to supervise peer specialists. Individual supervision allows peer specialists to examine in greater detail their interactions with individuals in or seeking recovery and to receive more support and guidance from an experienced colleague. Such meetings work better when regularly scheduled^550^ and held in addition to—rather than instead of—group supervision. As soon as peers begin work, supervisors should ensure that they understand the expectations, procedures, and schedule for formal supervision.

For some peers, this will be their first time participating in formal supervision in a work environment. This means that the first step of individual supervision should be educating peer specialists about the purpose of supervision, how supervisors will use it, and what it consists of. Sometimes supervisors will initiate supervision outside of scheduled sessions. However, peer workers should understand that they can always go to their supervisor if they have concerns or questions (e.g., emergencies and unanticipated events potentially affecting the delivery of services by the program).

The initial supervision session is an opportunity to discuss expectations and responsibilities of both the supervisor and the peer specialist. Supervisors need to review documentation guidelines, documentation samples, and common pitfalls in completing documentation. Subsequent supervision sessions should include check-ins to determine how the peer specialist is doing and if any questions or problems have come up since the previous session.

The following elements can go into individual supervision:

• Discussing current concerns or questions regarding their interactions with individuals in or seeking recovery
• Asking for feedback about how they see their role as a peer specialist within the organization
• Brainstorming approaches in providing peer recovery support using the peer specialist's strengths and experience
• Reviewing their documentation, as needed, and discussing intervention strategies and available community resources
• Developing and discussing their professional development goals, including training goals, while serving as a resource and source of encouragement in achieving these goals
• Discussing and trying to resolve ethical dilemmas (e.g., issues around boundaries, confidentiality)
• Discussing what has gone well since the last session, asking for examples, and celebrating their success
• Communicating any changes in program policies and procedures or upcoming learning opportunities
• Setting an agenda and time for the next session

SAMPLE CONTENT FOR PSS DOCUMENTATION

• Name of individuals in or seeking recovery, location and duration of service, type of service (e.g., telephone contact), date, and time
• Brief narrative of how PSS connects with the person's plan for recovery care
• Objectives and goals addressed by the service
• Interventions, services, and resources provided
• Outcome (e.g., person's response to the intervention) and next steps

Individual supervision should not turn into “hallway supervision,” where spur-of-the-moment conversations with a peer specialist take the place of regular, scheduled, and documented supervision.^551^ Such discussions likely focus on immediate issues only at the expense of addressing developmental issues, such as how best to use peer specialists’ strengths and skills. An analysis of supervisory methods for peer workers found that unscheduled individual supervision can hurt job performance because it gives peers limited opportunities to develop in their peer recovery role.^552^ That said, supervisors should assure peer workers that they can request help or supervision at nearly any time while on the job. Supervisors can create a welcoming environment by informally checking in outside of scheduled supervision and expressing interest in peers’ day-to-day experiences.

Exhibit 5.1 shows strategies that promote supportive, strengths-based supervision.

EXHIBIT 5.1. Strategies for Supportive, Strengths-Based Supervision of Peer Support Staff^553^

Supervision Strategy | Examples
Routinely providing support in a structured setting, focused on the strengths of peer support staff | • Tailoring language to include supportive words and phrasing. For example, supervisors should always consider the tone and content of notes and reminders that they leave for peer support staff members, to ensure the reminders do not come across as punitive.
Using peer support supervision sessions to model the skills that peer staff need to work successfully with individuals in or seeking recovery | • Working with peer support staff members to develop individualized goals that are tied to identified strengths, and address weaknesses; • Encouraging peer support staff in the use of effective, person-centered approaches to develop and enact individualized recovery plans with participants
Building confidence by using supervisory sessions to discuss and role-play strategies for dealing with challenging situations | • Reviewing past situations and potential situations that peer support staff members may experience, and discussing resources and strengths the peer support staff members can draw from to address those situations; • Role-playing potentially challenging conversations that peer support staff members may experience with individuals in or seeking recovery
Using supervisory sessions to maintain trust and detect issues early | • Providing space in each supervisory session to listen to any needs or concerns peer support staff members wants to raise; • Asking explicitly about workload to assess feasibility; • Providing opportunities to discuss self-care

## Supervision Competencies

Although many publications cover supervising treatment providers, little guidance exists on supervising peer workers. Because peers perform fundamentally different work than treatment providers, supervisors cannot simply apply the principles of clinical supervision to supervising peer staff (the text box below provides more information on avoiding traditional models of supervision).

Substance Use Disorder Peer Supervision Competencies, a report funded by the Oregon Health Authority, provides useful guidance on supervising peer workers.^554^ The report has four sections: recovery-oriented philosophy, providing education and training, facilitating quality supervision, and performing administrative duties. Each competency provides a checklist to help supervisors assess their current level of competency and determine their additional training needs. The recovery-oriented philosophy section can help lay the organizational groundwork for effectively supervising peer specialists and adopting a more recovery-oriented approach to SUD care.

Another resource, provided by the Indiana Family & Social Services Administration titled Supervision Competencies for Effective and Ethical Peer Recovery Coach Supervision^555^ also provides helpful information for supervisors. This concise document covers 10 competencies supervisors should possess to ensure peers provide effective care and also maintain their own individual recovery.

AVOID TRADITIONAL MODELS OF CLINICAL SUPERVISION

“I think the greatest mistake that could be made in guiding the delivery of [peer-based recovery support services] would be to assume that traditional models of clinical supervision within addiction treatment can be indiscriminately applied to the supervision of P-BRSS [peer-based recovery support services] delivery. If that occurs, peers providing recovery support services will be turned into little more than junior counselors and the potential vitality of that role and the broader role of community in long-term recovery will be lost.”^556^ —William L. White

The section on recovery-oriented philosophy encompasses five foundational competencies:^557^

• Competency 1: Understands peer roles. The supervisor grasps SUD peer recovery roles, functions, and responsibilities through peer training, lived recovery experience, and behavioral health work experience.
• Competency 2: Demonstrates recovery orientation. The supervisor supports and understands the philosophy of recovery promotion, recovery management, and recovery-oriented systems of care. The core recovery-oriented philosophy includes:
  – Instilling hope.
  – Reinforcing appropriate self-disclosure.
  – Respecting mutuality.
  – Using person-first language.
  – Promoting self-determination.
  – Encouraging empowerment.
  – Fostering independence.
  – Using a strengths-based approach.
  – Addressing stigma and oppression.
  – Providing support appropriate to the individual's recovery stage.
  – Engaging in advocacy.
  – Embracing many pathways and styles of recovery.

On the last point, note that the principle of many pathways is not always carried out in practice, and many treatment programs may only support specific pathways to recovery. This must be explained to individuals in or seeking recovery so they are fully aware of their treatment and can agree to the specific pathway provided. Both the supervisor and peer specialist must be able to explain the rationale and intent of the treatment program's philosophy and recovery approach. They also must make clear that other pathways are available and offer information on where to obtain them.

• Competency 3: Models principles of recovery. The supervisor models and supports recovery principles and a recovery-oriented philosophy across roles: as a provider, as a supervisor, and as a part of the organization.
• Competency 4: Supports meaningful roles. The supervisor embraces the value of lived experience and supports and advocates for meaningful peer roles. The supervisor discourages the use of peers in other roles that diminish the value of their work. The supervisor supports role clarity and discourages the use of peers in work activities that are outside of the peer's education, training, and experience.
• Competency 5: Recognizes the importance of addressing trauma, social inequity, and healthcare disparity. The supervisor understands and incorporates trauma-informed care in interactions with peers, individuals in or seeking recovery, and the organization. The supervisor recognizes and integrates practices that promote social and healthcare equity, including trauma-informed care for those who have historically experienced trauma through oppression (e.g., certain underserved racial, ethnic, and cultural groups; people with physical or cognitive disabilities; people who have SUDs; members of the LGBTQ+ community; people experiencing poverty or homelessness).

CASE STUDY #2: RECOVERY SUPPORT IN AN UNFAMILIAR SETTING

Peer specialist asks about providing support appropriate for those initiating or questioning their need for help.

Erin is a certified peer specialist who has just started to work in a hospital ED. She conducts individual peer coaching at admission, helps individuals in or seeking recovery navigate to appropriate resources, and does telephone recovery support after discharge. She spent the past 3 years at a nonprofit recovery community center working with people who were already committed to their recovery.

Erin goes to her supervisor, concerned that she may not have the background to work in a setting with so many patients who question whether they have SUDs or need help. In her previous job, most people that she worked with wanted to maintain their recovery, and she helped them strengthen that motivation. She says that motivating people to initiate recovery is another story. Erin lacks experience in coaching people not yet committed to recovery.

Considerations

How much does Erin know about the stages of change and the importance of establishing rapport, supporting the individual, and providing education in early recovery?

What are Erin's strengths that might help others who are uncertain about their need for help? How could she use these strengths to help those questioning their need to address their SUD?

Has Erin had an opportunity to follow another peer specialist within the setting to learn different ways of connecting with individuals in acute settings?

Did Erin receive sufficient orientation and guidance in how best to meet role expectations?

Possible Resolution

Surveys show that job shadowing is a valuable interactive training tool for peer specialists.^558^ After talking with Erin, her supervisor pairs her with another experienced peer specialist for the following week to help with her transition and orientation to the ED setting. Erin's supervisor also discovers that her peer training did not cover stages of change. The supervisor registers Erin for a webinar on this topic. Erin's supervisor also checks in on Erin's well-being and emphasizes the importance of activities that support her recovery during this transition.

## Challenges and Solutions

The principles that guide the daily practice of recovery also guide the daily practice of supervising peer workers: hope, mutuality, honesty, respect, person-first orientation, multiple pathways of recovery, support appropriate for the stage of change, and a strengths-based approach. Supervisors should model and promote recovery principles. This means demonstrating a belief in the capacity for people to change—motivating peer workers, encouraging any with ongoing struggles, and celebrating peers’ successes.

If a supervisor's workplace has not fully committed to a recovery orientation, the supervisor should model recovery principles—not just for peer workers and individuals in or seeking recovery, but also for administrators and other staff.

Common challenges of supervising peer workers in SUD treatment settings include:

• Providing a recovery-oriented framework for supervision.
• Establishing role clarity.
• Integrating peer workers with other staff.
• Supporting professional and career development.
• Providing a career pathway.
• Dealing with personnel turnover.
• Having insufficient resources to train, retain, or hire peer specialists.

### Providing a Recovery-Oriented Framework for Supervision

Peer supervisors have multiple roles and responsibilities, which can make their jobs complex. Some duties differ from those of traditional clinical supervision. Peer supervisors model recovery principles, promote healthy self-care by their supervisees, and help prevent role drift. Clinical supervisors do the same, while balancing program and peer worker needs and helping to match peer expertise with an individual's needs. Exhibit 5.2 highlights one framework for understanding the roles of peer supervisors.

EXHIBIT 5.2. Peer Supervisor Roles and Responsibilities^559^

Administrative

• Orienting and assigning staff
• Delegating and coordinating work
• Reviewing and assessing job performance
• Coaching staff on administrative functions
• Connecting and coordinating with other staff, treatment providers, and community resources
• Helping peer staff with time management

Developmental

• Assessing peer staff strengths
• Identifying the knowledge and skills needed to perform all job functions
• Providing learning resources and ongoing training (e.g., training in ethical conduct)
• Providing opportunities for professional and leadership development
• Linking learning resources and skill building to situations arising from recovery support work with individuals in or seeking recovery
• Educating all staff on the peer worker's role in recovery support

Supportive

• Advocating for peer workers
• Encouraging and affirming peer workers
• Recognizing the peer workers’ efforts and successes
• Offering perspective and providing a safe place for peer workers to express frustrations
• Promoting peer worker self-care
• Creating opportunities for peer workers to connect with other peer providers

The complexity of supervisory roles has led to various approaches. In one approach, known as cosupervision, peer workers are supervised by two supervisors: one deals with the administrative tasks of the role (e.g., scheduling, assigning work duties, managing workloads), while the other supervisor focuses on developmental skills and supportive roles (e.g., providing training, reviewing ethical principles and practical applications, supporting self-care).^560^

With cosupervision, supervisors need to coordinate their assigned responsibilities and communicate with each other regularly. If not, joint supervision may cause confusion and misunderstanding and make peers’ work more frustrating.^561^ Regular meetings between the two supervisors to discuss priorities and concerns can prevent these issues.

Newly hired peer specialists may not have experience with working in the setting. They may be apprehensive about how best to interact with individuals in or seeking recovery and staff, fulfill responsibilities outlined in their job description, and access resources for individuals in or seeking recovery. Helping peers work with people while managing their own recovery necessitates the use of regular group and individual supervision.

THE SPIRIT OF MOTIVATIONAL INTERVIEWING IN SUPERVISING PEER SPECIALISTS

Motivational interviewing (MI) is a respectful, person-centered therapeutic technique^562^ supervisors can use with supervisees and a powerful tool to model listening and interaction skills for peer specialists. MI is consistent with the recovery-oriented principles of self-determination, empowerment, and a strengths-based focus. MI has the potential to foster strong supervisory relationships, address supervisee anxiety and ambivalence, and provide nonjudgmental, supportive feedback to supervisees.^563^

MI is a strengths-based approach that reinforces a recovery-oriented framework in supervision. The latest version of MI describes four processes that represent the way MI commonly works to help individuals in or seeking recovery change substance use behaviors, but MI can also be applied in a supervisory relationship to help build rapport, provide support, and structure guidance. These four processes are:^564^

• Engaging: Expressing empathy through reflective listening, acknowledging ambivalence about behavior change, and avoiding arguing
• Focusing: Working collaboratively on setting an agenda and staying on task
• Evoking: Eliciting change talk (i.e., desire, ability, reasons, need to change) by asking open questions and using reflective listening
• Planning: Respecting the person's desired goals for change and working together to identify specific steps to achieve those goals

The four processes reflect several core MI skills one can remember through the acronym OARS:^565^

• Open-ended questions
• Affirmations
• Reflective listening
• Summaries

The four processes and the core skills of MI can help supervisors:

• Engage peer specialists.
• Focus their supervision meetings.
• Respectfully elicit from peers their understanding of how they can change their behavior and interactions with the individuals they support to help those individuals achieve their recovery goals.
• Work collaboratively with peer specialists to create a professional development plan that enhances their confidence and competence as peer providers.

One study exploring how supervisors in a treatment setting used MI in their relationships with supervisees reported that the most common MI skills and processes supervisors practiced were OARS and evoking change talk.^566^

Applying MI as a peer supervisor requires training and coaching in MI processes and core skills. Advanced training and practice in MI will ensure that the supervisor is not only using MI with fidelity, but also effectively modeling and coaching peer specialists on the spirit of MI principles with individuals in or seeking recovery.

SAMHSA's TIP 35, Enhancing Motivation for Change in Substance Use Disorder Treatment (https://store.samhsa.gov/product/TIP-35-Enhancing-Motivation-for-Change-in-Substance-Use-Disorder-Treatment/PEP19-02-01-003), and the Advisory, Using Motivational Interviewing in Substance Use Disorder Treatment (https://store.samhsa.gov/product/advisory-using-motivational-interviewing-substance-use-disorder-treatment/pep20-02-02-014) contain more information and practical guidance on MI.

### Establishing Role Clarity

Issues with role clarity can come up in peers’ relationships with individuals in or seeking recovery and their coworkers. Peer specialists’ dual identity as individuals in or seeking recovery and providers is a strength, but it can cause confusion about their roles.^567^ Many programs may not have the same level of experience integrating peer positions into their programs as they do with more traditional and well-defined roles, such as counselors and psychiatrists. Further, there may be overlap or similarities in the duties carried out by peer workers and the duties of social workers and case managers.

In workplace surveys, peer workers, treatment providers, and administrative staff in behavioral health settings often say they lack clarity about peer roles.^568,569,570^ Nonpeer workers report that they struggle to understand the role of peer workers and how best to use and include them.^571^

Peer workers often find the lack of clarity frustrating,^572,573^ and supervisors must pay special attention to the issue, because it can lead to strain and role drift. (The section “Minimizing Role Drift” later in this chapter provides more information.) In a study of role clarity among behavioral health peers, the availability of supervision was the strongest predictor of role clarity in this workforce.^574^

Supervisors can use several approaches with peers (and other staff) to address peer role clarity. These approaches include:

• Maintaining detailed job descriptions by creating, reviewing, and regularly updating them.
• Minimizing role drift.
• Engaging peer specialists in meaningful work.

### Maintaining Job Descriptions

Role confusion can result from poorly defined roles and expectations. A clearly written job description, with concrete duties and competencies spelled out, can contribute to role clarity by:

• Helping orient peer specialists to the expectations of their role.
• Helping integrate peer specialists appropriately into the workplace.
• Guiding peer specialists’ day-to-day work activities.
• Giving peer specialists something to point to if they are asked to perform inappropriate duties (e.g., duties outside their expertise, menial tasks not in their job description).

Research supports the need for thorough job descriptions for peer specialist positions.^575^ In one representative study, peer specialists and their supervisors expressed frustration with the lack of formal definition of the peer role. Some supervisors reported not knowing what training peer specialists had and what work they could do.^576^

In interviews with peer workers in a hospital setting, researchers found that physicians often asked peer workers to see patients who were actively suicidal or in the middle of psychotic episodes. One peer worker reported that physicians treated peer workers like a “magic sobriety wand.”^577^ There have also been reports of physicians seeking medical input from peers about buprenorphine treatment.

A good peer specialist job description includes these components:

• Job title. It should be succinct and clear.
• Duties and responsibilities. This section should clearly lay out the peer specialist's daily, weekly, and monthly duties and tasks.
• Relationships among staff. In addition to a description, this section should have an accompanying organizational chart that shows who supervises peer specialists and how other staff positions relate to theirs.
• Qualifications and requirements. This section specifies, as applicable, licensure, certification, training, experience, education requirements, and role restrictions.
• Knowledge, skills, and abilities (KSAs). This section should clearly state how each KSA relates to the job peer specialists perform.
• Ethical expectations. This section should spell out procedures for an ethical decision-making process, responsibility for reporting ethical concerns to the supervisor and/or credentialing agency (as applicable), and unethical behavior that would initiate disciplinary action.
• Description of the program the peer will be entering. This section will give the peers a clear understanding of what they can expect should they be hired, and include such items as the organization's treatment philosophy, mission statement, and structure.

A sample peer specialist job description appears in the Appendix of Chapter 6 of this TIP. (The Chapter 6 section “Core Practices and Practice Standards of Peer Workers” also contains examples of peer activities that could be relevant for peer job descriptions for programs.) Supervisors can find several other sample job descriptions here: https://rizema.org/wp-content/uploads/2019/01/UMass-Recovery-Coach-Report.pdf. Chapter 4 of this TIP discusses job descriptions and administrators’ and human resource staff's involvement in drafting them.

Supervisors need to meet with new peer workers and review their job description in detail to ensure that they understand what is expected of them and to confirm their buy-in.^578^ Supervisors should revisit the job description with peer workers regularly, updating it as necessary so that it accurately reflects the work assigned to them. Reviewing the peer job description 6 months after their start date and again during an annual review is a good idea, although greater or lesser duration between reviews may sometimes be appropriate. Supervisors can also discuss expectations, as necessary, in informal conversations with their peer workers.

ORIENTING NEW PEER SPECIALISTS

Peer specialists operate in many different environments—some clinical (e.g., opioid treatment programs, hospital behavioral health units, EDs) and some more recovery focused (e.g., recovery housing, recovery communities). Newly hired peer specialists may not have experience in the supervisor's particular setting. Therefore, the supervisor should give them a thorough orientation to the setting where the peer specialist works. In addition to covering practical matters—such as building access and use of computers, phones, and email—this orientation should include:

• Face-to-face introductions to everyone the peer will work with directly, including key colleagues.
• An explanation of the program's guiding principles, mission, treatment philosophy, and values.
• An organizational chart with clear lines of communication and reporting.
• A review of program policies and procedures.
• A review of job description and documentation requirements.
• An orientation to community recovery support services.
• An opportunity to shadow another peer specialist in the setting, if possible.

A thorough orientation can help reduce the strain on peer specialists and ease their integration onto a new team.

Researchers have developed Mentorship for Addiction Problems, a 4-week training orientation for peer mentors helping people in SUD treatment. The training consists of 1-hour sessions twice a week for 4 weeks. This training covers:^579,580^

• Understanding clinic policy and procedures (e.g., interacting with the system).
• Understanding peers’ roles as mentors (e.g., boundaries, ethics).
• Helping individuals in or seeking recovery maintain abstinence.
• Undertaking self-care.
• Maintaining abstinence while working as a peer.
• Responding to crises (e.g., suicidal ideation, homicidal ideation).
• Managing mental issues experienced by individuals in or seeking recovery.
• Being sensitive to diversity.

### Minimizing Role Drift

Role drift occurs when a peer worker takes on or is assigned responsibilities that fall outside the scope of the peer worker's practice. When peer workers attempt to take on clinical tasks at a treatment program or use language that may be too technical for the particular individuals in or seeking recovery they are working with, they risk drifting away from the role of peer worker^581^ (e.g., giving people advice about medicines). Subsequently, peers may lose touch with individuals in or seeking recovery or not relate to them as effectively. In addition, they may begin providing services outside of their scope, which can create liability issues and violate ethics.

Role drift also happens when peer workers interact with individuals in or seeking recovery more like friends or sponsors than as members of care teams. This type of role drift can become a particular problem for peer workers previously treated in the same program where they now provide PSS. They may now work with people they know from treatment groups, which can make acting solely in a peer role especially difficult.

Supervisors need to encourage peer workers to “stay in their lane” to keep them from drifting into acting as friends, sponsors, counselors, or healthcare providers to individuals in or seeking recovery.^582^ Supervisors should determine how best to help peer workers use their wealth of recovery-related knowledge and experience in an authentically peer role, which can be challenging in certain environments, where peers are used as cost-cutting mechanisms to replace the social service workforce and fill in systemic gaps. Supervisors should avoid using clinical jargon, and periodically discuss the peer worker's typical daily work activities to help identify role drift—either imposed by others or adopted by the peer.

When role drift occurs, supervisors must work with the peer to identify the problem and explore options for a course correction. (Case Study #3 includes an example of role drift.) These discussions provide a natural opportunity to revisit the peer's responsibilities and the consequences of role drift, and to enlist the peer worker in strategies to recognize and correct role drift. Regular individual and group supervision makes it possible to discuss and explore role drift before it happens.

The guidance about “staying in one's lane” applies both to peer workers and also to supervisors, who must avoid acting as counselor, sponsor, or friend. When supervisors need to help a peer worker move back to the appropriate “lane,” they should consider mentioning any issues they might have had with staying in one's lane and what they did to resolve them.^583^ By establishing common ground, supervisors can help the peer worker identify and correct role issues.

CASE STUDY #3: STAYING IN ONE's LANE

Peer specialist leads discussion on pros and cons of certain medications, based on personal experience; psychiatrist on team expresses concern.

Jesse is a certified peer specialist in an opioid treatment program (OTP). He helps individuals in or seeking recovery navigate community resources, leads discussion groups on general topics, and provides telephone recovery support for participants and alumni. Jesse is in sustained recovery from opioid use disorder and has been stable for the past 3 years on buprenorphine. He gets treatment in an office-based opioid treatment (OBOT) program setting. Jesse was once an individual in or seeking recovery at the OTP where he works, taking a daily methadone dose. Jesse chose to transition to buprenorphine after 1 year on methadone.

The OTP psychiatrist contacted Jesse's supervisor after hearing that Jesse led a group discussion on the pros and cons of methadone versus buprenorphine. Although Jesse kept most of his remarks neutral, he did say that he was grateful that he had changed medications. He also said that he plans to taper completely by the end of his fifth year of recovery. The psychiatrist expressed worry that Jesse could influence medical decisions that should be between a prescriber and an individual in or seeking recovery. The supervisor discusses the situation with the OTP director, who asks the supervisor to have a talk with Jesse.

Considerations

How could Jesse's actions potentially harm or benefit individuals in or seeking recovery?

What was Jesse's motive for discussing this topic? Does he have a bias against methadone? Did he just want to help the participants?

Does Jesse understand the ethical principle of working only within his area of expertise?

Jesse is not a treatment provider, but his recovery experience is valuable. How can Jesse best use his history as an OTP and OBOT participant while avoiding role drift? Are team roles clearly stated? Do clinical and peer staff ever co-lead group discussions on topics where their expertise overlaps?

Possible Resolution

Jesse and his supervisor brainstorm peer group topics for a 12-week cycle. Jesse, naturally, leads most of the brainstorming meeting as the peer recovery expert. They identify several recovery topics that intersect with other staff roles and responsibilities and develop a plan to include the psychiatrist and others on the treatment team during the group session and share their expertise on these specific topics. The treatment team members’ rapport and knowledge of each other's roles will increase with each session. Indeed, having “multidisciplinary group supervision” (i.e., including nonpeer staff) has proven helpful when discussing medical issues as well as examining integration of peer staff onto the team.

ROLE STRAIN IN PEER SPECIALISTS

Role strain, also referred to as role stress, occurs when peer specialists encounter competing demands within one role. It is “any physical or psychological strain experienced by an individual who needs greater abilities or resources than those that are available in order to perform the role.”^584^ For example, peer specialists may have far too many responsibilities or a large caseload that hampers their ability to provide PSS effectively. They may be the only peer specialist in the organization, limiting their ability to obtain support. Further, in meeting their responsibilities, in advocating for individuals in or seeking recovery, or in providing recovery-oriented care, peer specialists may face conflicts with other staff who are not knowledgeable about recovery support services.^585,586^

Role strain can lead to a decrease in the peer specialist's self-care and recovery activities. The peer specialist begins to believe it is too much effort to follow through with their own recovery support because they don't have enough energy after work. They may feel the need to work beyond their scheduled hours at the expense of other personal commitments. They may express a concern that if they don't take on the responsibility, no one will.

The peer specialist may adopt a “them versus us” stance toward other staff or assume staff responsibilities outside of their job description to feel a part of the agency. They may begin to use clinical language and step further away from recovery-oriented principles within the setting to increase their connection with clinical staff.

Role strain can occur in any job. Supervisors need to help peer specialists in recognizing and reflecting on how they manage stress in their role. Supervisors should create opportunities to discuss strategies for addressing specific circumstances that heighten role strain and elicit the peer specialist's strengths in finding solutions within their professional life, while supporting their recovery.

#### Engaging Peer Specialists in Meaningful Work

Problems with role clarity also arise when other staff ask peer specialists to perform administrative or support tasks that do not involve working with individuals in or seeking recovery, such as picking up coffee for coworkers or doing copying for billing staff. Supervisors are responsible for ensuring that other staff members treat peer specialists professionally and give them significant, appropriate, and rewarding work that makes use of their experience and training.

Supervisors are also responsible for ensuring that peer specialists understand that their work reflects program goals and contributes to achieving the organization's mission. Such discussions will help ensure that the outcomes expected of peer specialists align with that mission and each peer specialist's job description.

Supervisors should avoid the convenience of treating all peer specialists as generalists. Instead, they should strive to understand each peer specialist's strengths and background.^587^ For example, based on their lived experience, some peer specialists may be especially suited to help individuals in or seeking recovery from using a specific substance, or multiple substances, or who have co-occurring mental and substance use disorders. Other peers may be more familiar with the child welfare or criminal justice systems.

The consensus panel recommends that, to the extent possible, peer workers should have the lived experience of the population of individuals they will work with (e.g., a program that treats individuals with HIV who are in or seeking recovery should try to engage a peer worker with HIV). The more supervisors know about their peer workers’ lived experience and expertise, the better they and their program will be able to match individuals in or seeking recovery with peer workers.

Peer worker roles may depend on the state or states where their program operates. Some states limit peer workers to supporting individuals in or seeking recovery in navigating health systems and steering them toward local social services. Others permit peer workers to perform coaching services. Likewise, the setting in which peers work (e.g., ED, residential treatment facility, outpatient SUD treatment program) will shape the services they provide.

Supervisors need to learn and understand relevant federal and state regulations affecting PSS and which services are appropriate for their setting. Supervisors must be aware that introducing peer services into an SUD treatment environment can begin or speed up a shift toward a more recovery-focused orientation. (Chapter 4 of this TIP includes a discussion of cultural change when introducing PSS to the organization.) Supervisors are responsible for helping peers integrate into the workplace and enhancing peer and nonpeer staff cooperation in support of individuals in or seeking recovery.

RESOURCE ALERT: PEER RECOVERY CENTER OF EXCELLENCE

SAMHSA's Peer Recovery Center of Excellence is a peer-led national center that provides training and technical assistance related to PSS. It serves as a resource for individuals, organizations, and systems working toward the successful implementation of the peer support model of recovery across settings. Enhancing the professionalization of peers through workforce development is one of the center's four core areas of focus (https://www.samhsa.gov/peer-recovery-center-of-excellence).

### Integrating Peer Workers With Other Staff

A key task for supervisors is facilitating the integration of the organization's peer workers and other treatment staff. This integration can ease competition, conflict, confusion, and tension.^588^ A study of factors contributing to the successful integration of behavioral health service peer workers gave the most weight to peers’ perceptions of how well their supervisors understood peer work.^589^

Several studies attribute the tension that sometimes arises between peer workers and nonpeer staff to ambiguity about the peers’ role within the setting.^590,591,592^ In a survey of behavioral health service providers, some nonpeer agency staff viewed peers as unprofessional and unable to deal with the stress of the job, and as a way for the agency to save money by paying lower wages.^593^ Peer workers described experiences in which nonpeer staff invalidated their role, questioned their integrity, and corrected them in front of others.^594^ When peer workers were surveyed nationally, 64 percent witnessed or experienced discrimination and stigma from nonpeer staff.^595^

Across settings, peer workers often face the challenge of not being accepted as valued staff members.^596^ If peers don't feel accepted and respected by nonpeer staff because of their recovery status or lack of professional credentials, supervisors need to address nonpeer staff perceptions through education to dispel any misinformation. For example, clinical staff may be unaware that peer specialists receive training on ethics, including confidentiality and boundaries, while pursuing certification and receiving supervision.

In studies about peer worker roles, peers stated that their lived experience with problematic substance use and recovery translated into empathy and an easy rapport with individuals in or seeking recovery that nonpeer staff envied—but peer workers also reported feeling that nonpeer staff resented them because they lacked professional training and credentials.^597,598^ Peers sometimes found that nonpeer staff believed peers’ lived experience meant they knew about aspects of treatment and recovery they had not actually seen or gone through. In situations in which friction or misunderstanding exists between peers and nonpeers, supervisors should assume the role of a liaison, helping each group understand the perspectives and capacities of the other. Staff members need to understand that the peers’ value lies in the lived experience of behavior change and the ability to be a “translator” between the clinical world and the individual in or seeking recovery's world. Additionally, staff need to know that not valuing or respecting peers can be detrimental to the program as a whole.

Supervisors want to promote mutual respect between peers and nonpeers by treating peer specialists as experts on recovery who can educate nonpeer staff on the challenges of recovery and on how to relate to people at various stages of recovery.^599^ This can be achieved by emphasizing that peer specialists are a vital part of treatment and recovery and by explaining to program staff that peer specialists benefit the program by improving outcomes, enhancing access to community resources, encouraging engagement in treatment and recovery activities, and instilling hope in individuals in or seeking recovery. Understanding that peer specialists’ lived experience is at the core of their valuable contributions to the program will build nonpeers’ trust in and appreciation of the peers’ work.^600^

Supervisors can also improve peer–nonpeer staff working relationships by:

• Eliciting feedback from peer specialists during all-staff meetings.
• Modeling social integration by inviting peers and nonpeers to lunch together.
• Holding team-building activities for the entire staff.

RESOURCE ALERT: SAMHSA's WORKING DEFINITION OF RECOVERY: 10 GUIDING PRINCIPLES OF RECOVERY

SAMHSA developed a working definition and set of principles for recovery. When working with peer workers and other staff, supervisors need to understand, adopt, model, and reinforce recovery-oriented principles (https://store.samhsa.gov/sites/default/files/d7/priv/pep12-recdef.pdf).

### Supporting Professional and Career Development

The increasing presence of peer workers in behavioral health services calls for the development of career opportunities for them.^601,602^ Because of the relative newness of PSS in SUD treatment, the structure and supports that would enable peer specialists to have a career (not just a job) is still developing. (Chapter 4 includes a more thorough discussion of career pathways for peer specialists.)

Often, programs without enough work to employ one full-time peer or a few part-time peers may use only volunteer peers. This lack of full-time work can lead to ad hoc use of peers that ebbs and flows with funding or demand. Such practices may seem to benefit a program's bottom line, but they have several drawbacks:

• Peer specialists may not be treated like professionals.
• Peer specialists may be treated as an afterthought, rather than as valued, vital members of a team.
• Nonpeer workers may undervalue peer specialists’ involvement if management treats peers as contingent employees.
• Peer specialists have little chance to grow and advance in their work without secure employment.
• Peer specialists may not receive consistent supervision or training.
• The program itself will be less stable and effective if PSS are not consistent.
• Peer specialists may experience role strain in attempting to deliver PSS in a limited time or capacity.
• Quality and continuity of care may suffer.

A synthesis of 27 studies on the experience of peer workers in behavioral health services outlines the drawbacks of hiring only part-time or temporary peer workers.^603^ The most frequently reported aspect of the peer worker experience concerned low pay and few hours. Peer workers equated few hours with decreased chances to interact with nonpeer staff, including supervisors and administrators. Peer workers felt that this hampered their integration into treatment teams. Other studies highlight that peer workers face not only low pay but overtime work, without compensation, and high caseloads.^604,605^ Peer workers equated low pay with a lack of respect, job dissatisfaction, and job instability.

Although funding for both peer specialists and those who supervise them continues to evolve,^606^ well-paid, stable, and consistent employment for peer specialists would avoid these drawbacks. Such working conditions are currently a goal, rather than a reality, for most programs and peer specialists. However, supervisors can advocate for more hours and better pay for peer specialists, and they can help ensure that peer specialists become fully integrated into treatment teams, regardless of their hours and pay.

Many peer specialists view their jobs as a route back into employment and a chance for advancement. Supervisors should advocate with program management for peer specialists to receive career development support comparable to that available to other employees. Creating formal career paths for peers enhances their integration into the organization and reinforces the message that peers are valued for their contributions. The presence of career opportunities will help to demonstrate the program's commitment to peer specialists and stabilize peer roles in the SUD treatment field.

Peer specialists vary widely in educational background. Although some may not have finished high school, others have graduate school training. Supervisors should adopt a strengths-based approach when establishing professional development plans for peer specialists. They should support certifications, education, and training, and communicate with peer specialists about upcoming opportunities within the organization and community. Supervisors can recommend online and print resources to support peer specialists as they expand their knowledge and skills. Supervisors also can investigate local options for education and training, and consider having the program reimburse peers’ expenses, in full or in part. Peer specialists who receive more hours of training, including supervision, to support their role are more satisfied with their jobs.^607^ This increase in morale often leads to better job performance as well.

#### Certifications

Currently, states have a range of certification requirements for peer specialists seeking certification. These requirements may include but are not limited to passing an exam, participating in trainings, or obtaining formal or continuing education. The type and hours of training, education, and work-related experience vary across states. A high school diploma or GED is generally the highest level of formal education required for certification; however, it's best to check with the organization to see if it requires further education. States that require an exam have established their own requirements and use exams from NAADAC, the Association for Addiction Professionals, or the International Certification & Reciprocity Consortium (IC&RC). (The Resource Alert “Certification Programs and Resources” contains more information about certification.)

Many certifications are recognized by individual states but are overseen by a private credentialing board, making reciprocity more difficult to achieve. Reciprocity among all states that certify peer specialists would further enhance the position's professionalization and stability. As of the publication of this TIP, 28 states and the District of Columbia offer reciprocity through IC&RC. However, that still means nearly half of the states don't have uniform, transferrable credentials for peer specialists.^608^

Additionally, not all states who participate in the IC&RC will accept a credential from another IC&RC state. In light of this, SAMHSA in 2022 and 2023 collaborated with federal, state, tribal, and local partners to develop SAMHSA's National Model Standards for Peer Support Certification, covering substance use, mental health, and family and youth peer certifications. The National Model Standards will accelerate universal adoption, recognition, and integration of the peer workforce across all elements of the healthcare system. The Model Standards can be viewed here: https://www.samhsa.gov/about-us/who-we-are/offices-centers/or/model-standards.

RESOURCE ALERT: PROFESSIONAL DEVELOPMENT TRAININGS FOR PEER SPECIALISTS

Numerous professional development resources are available to support peer specialists’ interests, needs, and goals. The following resources address a few relevant issues that may appear in supervision:

• Cultural Humility Primer: Peer Support Specialist and Recovery Coach Guide to Serving and Supporting Diverse Individuals and Their Recovery Journeys (https://attcnetwork.org/sites/default/files/2020-11/Peer%20Primer%20FINAL.pdf)
• Supporting Recovery from Opioid Use: A Peer's Guide to Person-Centered Care (https://attcnetwork.org/centers/northwest-attc/product/supporting-recovery-opioid-use-peers-guide-person-centered-care)
• Peer Support Provider—Walking the Tightrope Between Helping Others & Maintaining Your Own Wellness (https://www.mirecc.va.gov/visn1/docs/products/Peer_Support_Provider_Self-Care_Presentation.pdf)
• Compensating for Systems Failures: The Transformation of the Community Health Worker/Peer Recovery Specialist Roles during COVID-19 Webinar (https://www.youtube.com/watch?v=8WV5Qx2tYZo)

Supervisors can support peer specialists’ professional development as well as agency qualification for certain funding and reimbursement by helping peers achieve and maintain certification. Certifications create an opportunity for peer specialists to transfer their credentials when they leave a position. Certification is a positive step in the professionalization of peer specialists and helps bring more stability to their employment situation. Supervisors should familiarize themselves with their state's requirements for certified peer specialists.

RESOURCE ALERT: CERTIFICATION PROGRAMS AND RESOURCES

These resources provide descriptions of certification programs and resources across states and nationally.

• The SAMHSA-funded Peer Recovery Center of Excellence: Comparative Analysis of State Requirements for Peer Support Specialist Training and Certification in the United States (https://peerrecoverynow.org/about/coe-products.aspx)
• The SAMHSA-funded Peer Recovery Center of Excellence: State Certification Directory (https://peerrecoverynow.org/resources/state-certifications.aspx)
• SAMHSA/BRSS TACS’ State-by-State Directory of Peer Recovery Coaching Training and Certification Programs (https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Directory-of-Peer-Recovery-Coaching-Training-and-Certification-Programs_8_26_2020.pdf)
• Texas Institute for Excellence in Mental Health: Peer Specialist Training & Certification Programs: National Overview 2016 (https://sites.utexas.edu/mental-health-institute/files/2017/01/Peer-Specialist-Training-and-Certification-Programs-A-National-Overview-2016-Update-1.5.17.pdf)
• NAADAC: National Certified Peer Recovery Support Specialist Certification (https://www.naadac.org/NCPRSS)
• International Certification & Reciprocity Consortium's Board Directory (https://internationalcredentialing.org/memberboards/)

#### Ongoing Training and Advancement

Peer workers’ ongoing training should include formal training, on-the-job mentoring, and continuing education.^609^ Training requires commitment of the organization's resources. The supervisor's program can help peers develop professionally by, for example, allowing time for more experienced peer workers or peer supervisors to mentor and train less experienced peer workers, providing paid time off for peer workers to travel for trainings, and underwriting the cost of their continuing education.

The mode of training can help determine how well peer workers adapt to their jobs and how satisfied they are with the work. One study of peer specialists revealed that the more time they spend in self-study or independent study, including video-based training, the less satisfied they are with their job training and the less they feel their role is clearly defined by their supervisor. The authors encouraged programs employing peer specialists to use job shadowing and other interactive training methods, as opposed to self-study methods. These methods are not only more satisfying, they may also increase role clarity, another important predictor of job satisfaction among peer specialists.^610^

RESOURCE ALERT: RESOURCES FOR ONGOING PEER WORKER TRAINING AND LEARNING

• The Peer Recovery Center of Excellence hosts monthly Communities of Practice calls for peer recovery support specialists and those who supervise them. (https://peerrecoverynow.org/training/communities-practice.aspx)
• SAMHSA hosts video trainings on PSS (pre-2019). (https://www.samhsa.gov/brss-tacs/video-trainings#peer-support)
• The core curriculum list on page 39 of the University of Colorado School of Medicine's DIMENSIONS: Peer Support Program Toolkit (https://www.bhwellness.org/toolkits/Peer-Support-Program-Toolkit.pdf) and SAMHSA's Core Competencies for Peer Workers in Behavioral Health Services (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/core-competencies_508_12_13_18.pdf) contain ideas on training topics.
• The Resource Alert “Manuals and Toolkits” in Chapter 6 of this TIP contains further information.

Some peer workers may require training to expand their knowledge of medications for opioid or alcohol use disorder and to address negative attitudes they may have about individuals who take these medications in their recovery journey, or about programs that dispense the medications. Additional areas for continued training that can help peer workers improve their performance and efficacy and enable them to further their careers may include:

• Harm reduction strategies, such as syringe services programs.
• Overdose reduction strategies, such as naloxone training and education, including the newer, stronger formulations (the Resource Alert “Establishing PSS for Overdose Response: A Toolkit for Health Departments” contains more information).
• Engagement strategies, such as motivational interviewing techniques.
• Emerging evidence-based practices to help individuals in or seeking recovery.
• Emerging laws and regulations concerning recovery.
• Any changes or updates to organizational policies.
• Emerging technological trends concerning behavioral health (e.g., mobile apps, telehealth).
• An understanding of the importance of person-first, nonstigmatizing language.
• An understanding of the concepts of diversity, equity, and inclusion.
• A deeper understanding of cultural responsiveness.
• Continued education in trauma-informed care.
• Any changes or updates to the treatment community, resources, and/or landscape in the area where the peer specialist works.

RESOURCE ALERT: ESTABLISHING PSS FOR OVERDOSE RESPONSE: A TOOLKIT FOR HEALTH DEPARTMENTS

The National Council for Mental Wellbeing has released a toolkit that contains resources, tools, concrete steps, and examples informed by the most current research to help organizations enhance their PSS with overdose response education and initiatives. The toolkit can be found at (https://www.thenationalcouncil.org/wp-content/uploads/2022/03/Establishing-Peer-Support-Services-for-Overdose-Response-Toolkit-7-March-2022-Final.pdf) (https://www.thenationalcouncil.org/wp-content/uploads/2023/03/Establishing-Peer-Support-Services-for-Overdose-Response-Toolkit-7-March-2022-Final.pdf).

#### Providing a Career Pathway

The lack of a career pathway for peer workers is a problem for the entire behavioral health field. Peer workers often cite lack of opportunity for advancement as a cause of job dissatisfaction.^611^ Some peer workers leave their jobs and the field as a result. Some peer workers obtain a professional credential and move on to other roles in the behavioral health field. Others want to remain peer workers, while still making progress up a career ladder.

Consider establishing a clear career pathway for peer workers who aspire to advance in their profession, to bring stability to the peer worker role, and contribute to peer workers’ job satisfaction and retention in their program.^612,613^

The most common career ladder for peer specialists has only two steps: the position of peer specialist and the position of peer supervisor. A four-state study found that although some larger behavioral health service providers had multistep career ladders for peer workers in the behavioral health field, most did not.^614^

TRANSITIONING FROM PEER SPECIALIST TO PEER SUPERVISOR

Some states and organizations have clearly defined steps and criteria for peer specialists who are interested in advancing to supervisory roles. The following guidelines from the Ohio Department of Mental Health and Addiction Services (OHMAS) provide a useful example.

• Training required: 4-hour supervisory training. Registration is available online: https://www.eventbrite.com/e/ohiomhas-online-peer-recovery-supporter-supervision-training-tickets-159118113561
• Certification requirements^615^:
  – [The peer specialist needs…] experience delivering peer services in behavioral health over a cumulative period of 2 years, has completed the 16 hours of online learning administered or designated by the department, and has completed the 4-hour supervising peer training administered or designated by the department.
  – (1) To obtain peer supporter certification, individuals will submit a complete and compliant application, including the following documentation:
    • Proof of a minimum of 40 hours of department-approved competency-based peer services training or 3 equivalent years formal, verifiable experience providing behavioral health peer services pursuant to Rule 5122-29-15 of the Administrative Code
    • A high school diploma, a GED certification, or similar secondary education from outside of the United States
    • Documentation of passing the department peer supporter exam, or an exam administered or designated by the department
    • Proof that certified peer supporters have read and understood the code of ethics at initial certification and every certification renewal thereafter
    • The results of a bureau of criminal investigation and Federal Bureau of Investigation criminal records check conducted within 1 year of submission
  – (2) Completion of 16 hours of online learning administered or designated by the department

Important: Certifications expire after a 2-year period. For certification renewal, supervisors must complete all the steps outlined in Rule 5122-29-15.1.

Lastly, OHMAS stipulates that the potential supervisor must:

• Have a thorough understanding of and belief in recovery.
• Believe sharing lived experience is helpful.
• Be available for regular supervision.
• Supervise no more than five certified peer recovery supporters.

#### Having Insufficient Resources To Train, Retain, or Hire Peer Specialists

Lack of funds or other resources can make it unfeasible for some treatment programs to hire peer specialists directly as staff. An alternative is to contract out with recovery community organizations or similar entities and use peers on a consultant basis. Such arrangements can be beneficial for all parties involved, as programs can integrate the support of peer workers into their service offerings despite their lack of resources, while peer workers can receive valuable work experience and access to a broader network of other peers who can provide support, education, guidance, and even supervision.

## Conclusion

PSS is a growing field in behavioral health, as demonstrated by the expansion of diverse peer roles, settings, reimbursement, and professionalism. According to the 2020 National Survey of Substance Abuse Treatment Services, approximately 63 percent of SUD treatment facilities offered mentoring or PSS.^616^ As of 2018, 27 states allowed Medicaid peer support reimbursement for individuals who had SUDs.^617^

With this growth, the field faces challenges in how best to integrate and support PSS, including the provision of ongoing professional development, supervision, and role clarity.^618^ Peer supervisors have important roles to serve in SUD treatment programs—as advocates and guides for peer specialists, as facilitators in integrating peer services, as models of recovery principles, and as promoters of ethical decision making and healthy boundaries.