# Chapter 4—Why and How To Integrate the Peer Specialist Position Into Substance Use Disorder Treatment Programs

KEY MESSAGES

• Peer workers’ unique roles and activities contribute to client engagement, satisfaction, retention, and success.
• Peer workers typically have different training, perspectives, and approaches than clinical staff.
• Research evidence shows improved outcomes for people in recovery who receive peer support services (PSS) for substance use disorders (SUDs).
• SUD treatment programs can hire peer workers directly or contract for delivery of PSS from recovery community organizations and other recovery entities.
• Expanded reimbursement of—and more federal grant funding available for—PSS have provided new opportunities for delivering them.
• Successful integration of the peer specialist position requires leadership by administrators.
• Learning from organizations that have already integrated the peer specialist position can ease the transition.
• Establishing a career pathway for peer workers can help with their job satisfaction and retention.
• Administrators can play a role in sustaining PSS by documenting and communicating the benefits of these services.

Substance use disorders (SUDs) are now commonly recognized as requiring a continuum of services to support the best possible outcomes.^396^ During recovery, individuals with one or more SUDs gain an understanding of the nature of their SUDs and come to think of themselves as taking control of their recovery and their lives, not as lacking control over their problematic substance use.

Peer workers’ lived experience with problematic substance use, behavior change, and recovery makes them uniquely suited to support people in recovery as the latter undertake inner exploration and build recovery supports. Peer workers “can offer strong personal connections and earnest encouragement and hope.”^397^ Having lived experience can make them more relatable than other professional staff at SUD treatment programs, including SUD counselors, case managers, social workers, and prescribing clinicians. Peer workers can “speak the same language” as people seeking or in recovery and act as “interpreters” between them and clinical staff.^398^

This Treatment Improvement Protocol does not cover the work of peer specialists in the mental health field.

Although more research on peer support services (PSS) for SUDs is needed, many studies have already demonstrated that PSS can improve SUD treatment outcomes.^399^ And by expanding the behavioral health service workforce, peer workers can help fill the service gap caused by the growing need for SUD care.^400,401^ Peers can also help treatment programs better address the ongoing nature of recovery, in part by connecting program clients to people and resources in the local recovery community.

Although this TIP covers incorporating PSS into SUD treatment programs, PSS offered by these programs should be thought of as supplementing and not replacing PSS offered by recovery community organizations (RCOs) and recovery community centers (RCCs). These types of community-based organizations have decades-long experience providing PSS, which form an organic, core part of their mission. And these organizations are central settings for people to work on recovery before, during, after, or in place of treatment. Adding PSS to SUD treatment settings not only strengthens a community's SUD treatment and recovery infrastructure, but also helps people with SUD transition smoothly from treatment to community-based recovery support. This chapter's “RCOs and RCCs” Resource Alert has more information on these organizations.

Despite the need and evidence for PSS, many treatment programs may require a significant cultural shift when creating positions for peer workers. Some nonpeer staff may view peer workers as unqualified, prone to recurrence of use, or likely to have dual or prior relationships with program clients—and therefore may resist offering PSS. Even programs that have committed to a recovery orientation may face challenges in integrating peer workers into a clinical environment. Integrating peer workers successfully requires investing time and resources into ensuring that they become a valued and well-understood part of a treatment program,^402^ something that has been done by programs across the country.

Chapter 4 of this Treatment Improvement Protocol (TIP) discusses how administrators can successfully integrate and sustain the services that peer workers provide. The chapter is organized as follows:

• The first section briefly describes different service models for integrating the peer specialist position.
• The second section gives background on PSS for SUDs—including a brief discussion of their history and peer worker settings, roles, and activities—and reviews the benefits of offering PSS.
• The third section covers introducing peer workers into SUD treatment program settings, looking at such topics as assessing organizational readiness, writing job descriptions, and interviewing candidates for peer worker jobs.
• The fourth section discusses workforce development and retention, with an emphasis on ongoing training and career ladders.
• The fifth section addresses PSS sustainability.
• The sixth section briefly discusses ensuring access to peer services.

This chapter does not cover implementing family PSS. Information on this emerging category of PSS appears in Chapter 7 of this TIP.

SUD treatment program administrators make up the primary audience for Chapter 4; however, administrators of other services (e.g., social services) may find aspects of this chapter useful, particularly if they are considering PSS for the first time.

Exhibit ES.1 in the Executive Summary highlights key terms used in this and other chapters.

A NOTE ON THE TERM “CLIENT”

This chapter uses the term “client” to refer to an individual receiving services from an SUD treatment program. A peer worker generally doesn't refer to someone they work with as their “client,” however. That's because the nature of this relationship differs from that between a treatment provider, like an SUD counselor, and a person receiving SUD treatment. Often, a peer worker will refer to someone they work with as a “peer,” which reflects a nonhierarchical relationship involving collaboration, mutual learning, and the shared experience of problematic substance use. Peer workers in an SUD treatment setting also sometimes use the term “participant” to refer to someone they're working with.

## Service Models for Integrating the Peer Specialist Position

Different models exist for incorporating the peer specialist position into SUD treatment programs. Some programs hire peer specialists directly. Others contract with an entity like an RCO or an RCC to provide PSS and peer supervision.^403^ Yet others may use both models at the same time. Another option involves piloting the use of PSS by first contracting with an RCO or an RCC for their delivery, while developing and putting in place the policies and practices needed to directly employ peer specialists.^404^

RESOURCE ALERT: RCOs and RCCs

RCOs and RCCs are invaluable resources for information, training, and partnership for SUD treatment programs interested in introducing the peer specialist position. RCOs are local, typically nonprofit organizations that support people with problematic substance use in achieving long-term recovery through a range of activities that can include PSS, advocacy in the community, and public education about recovery. Not all RCOs have a physical location. RCOs are led and staffed mainly by people in recovery. An RCC, a type of RCO, is a physical place where people in recovery, and people who want to be in recovery, can meet, get PSS and other support, and participate in activities like computer workshops and game nights.^405^

Faces & Voices of Recovery (https://facesand (https://facesandvoicesofrecovery.org/) https://facesand (https://facesandvoicesofrecovery.org/)), an organization whose mission includes increasing the number and capacity of these organizations, can provide useful contacts and information. An interactive map of RCOs and RCCs that belongs to Faces & Voices of Recovery's Association of Recovery Community Organizations is available at https://facesandvoicesofrecovery.org/arco/arco-members-on-the-map/.

## PSS: Background and Benefits

### History

People working to recover from problematic substance use have long provided help to their peers in the same situation. In the United States, such support has always been at the core of 12-Step and other mutual-help programs for people with such use. Other types of recovery communities that began forming in the last quarter of the 20th century, like RCOs, recovery residences, and collegiate recovery programs, have also always had peer-to-peer support at the heart of their missions.^406^

Alongside this more general type of peer support, formal PSS delivered by peer workers to people with problematic substance use have emerged and become increasingly widespread in the past 20 years. The Substance Abuse and Mental Health Services Administration (SAMHSA) seeded this growth with funding for peer services in two important grant programs.^407,408,409^

The Centers for Medicare & Medicaid Services (CMS) began allowing Medicaid reimbursement for PSS (with certain conditions) in 2007, encouraging further growth. Increased insurance coverage for SUD treatment (including through certain provisions in the Affordable Care Act), the expansion of Medicaid in some states,^410^ and coverage of PSS for SUDs by more state Medicaid programs^411^ have also contributed to the spread of PSS.

In recent years, the opioid epidemic has driven much of the expansion of PSS for SUDs. For example, SAMHSA's State Targeted Response to the Opioid Crisis, State Opioid Response, and Medication-Assisted Treatment–Prescription Drug and Opioid Addiction programs raised the visibility of PSS and helped make PSS more available.

By 2020, 63 percent of the SUD treatment facilities responding to an annual SAMHSA survey on SUD services reported that they offered peer support or mentoring.^412^

### SUD Treatment Settings With Peer Specialists

Many different types of SUD treatment settings use peer specialists, including:^413^

• Outpatient treatment programs.
• Intensive outpatient programs.
• Residential treatment programs.
• Inpatient hospital programs.
• Partial hospitalization programs.
• Opioid treatment programs.
• Office-based opioid treatment programs.
• Medically supervised withdrawal facilities.

Other settings outside of dedicated SUD treatment programs that may offer PSS include hospital emergency departments (EDs), inpatient hospital units, mobile and other crisis units, primary care practices, harm reduction settings (e.g., syringe services programs), social service and child welfare agencies, recovery residences, high school and collegiate recovery programs, first responder agencies, and criminal justice agencies (e.g., problem-solving courts, parole/probation departments, prisons, jails).^414^

RCOs and RCCs typically offer PSS in house and may provide PSS through arrangements with SUD treatment facilities, as already noted; they may provide these services for other settings as well.

Faces & Voices of Recovery has an accreditation arm, the Council on Accreditation of Peer Recovery Support Services (CAPRSS), that accredits organizations and programs offering PSS, including SUD treatment programs. CAPRSS publishes a resource book to aid in achieving accreditation.^415^ More information on CAPRSS can be found at https://caprss.org/. The resource book, which also discusses why to become accredited, is available at https://www.manula.com/manuals/caprss/accreditation/main/en/topic/preface. Administrators are encouraged to review the resource book's standards for peer programs.

### Peer Worker Roles and Activities

Peer workers perform many nonclinical roles that fill in gaps or enhance traditional SUD treatment services. Their roles vary by setting, but commonly involve:

• Conducting community and street outreach.
• Serving as a role model.
• Providing education.
• Providing recovery support.
• Advocating for people in recovery and coaching them on advocating for themselves.
• Acting as a resource navigator.

Understanding appropriate peer worker roles and activities and the nature of the relationship between peers and the individuals they work with is vital for effectively integrating the peer position. For example, having peer workers undertake activities of a behavioral health technician (like conducting urine screens or room or body searches) would put them in a directive, monitoring role that goes against the essence of peer work. Chapters 2 and 3 of this TIP discuss peer roles and responsibilities.

Peer workers provide four types of recovery support: emotional support, informational support, instrumental support (practical help), and affiliational support (help making social connections). The table below gives typical examples of peer worker activities along the SUD continuum of care, using an extended framework adapted from Facing Addiction in America: The Surgeon General's Report on Alcohol, Drugs, and Health.^416^ In many cases, sample activities listed for a given stage are also appropriate for other stages. For example, giving one-on-one emotional support and providing coaching on the recovery process can take place at any stage.

Stage | Sample Peer Worker Activities^417,418,419,420^
Treatment Engagement or Harm Reduction | • Conducting street outreach to areas where people with problematic substance use may gather (e.g., parks, syringe services programs; • Providing naloxone kits and training; • Providing peer coaching on entering treatment to overdose patients in EDs; • Conducting “inreach” to people in prisons and jails preparing for reentry to connect them with SUD treatment on their release
Inpatient Treatment^421^ | • Giving emotional support by talking with patients one-on-one; • Helping patients navigate healthcare, criminal justice, and child welfare systems, as needed; • Accompanying patients on off-unit activities (e.g., meals, outside breaks, off-unit visits); • Providing patients’ perspectives to other care team members, while observing confidentiality requirements
Residential Treatment | • Leading wellness classes; • Leading parenting classes; • Coaching program clients on the recovery process
Partial Hospitalization and Intensive Outpatient Treatment | • Distributing public transportation passes to program clients for SUD appointments; • Helping program clients find mutual-help program sponsors; • Making “warm handoffs” (direct introductions) to providers or peer workers at next level of care
Outpatient Treatment (including opioid treatment programs and office-based opioid treatment programs) | • Offering pretreatment support to individuals on waiting lists (in person, by phone, or via telehealth); • Helping conduct intake, including introducing new program clients to recovery concepts and PSS; • Conducting recovery planning with program clients; • Accompanying program clients to medical appointments; • Working with program clients on applying for jobs and social services; • Supporting program clients transitioning out of specialty SUD treatment by connecting them in advance with RCOs/RCCs and/or mutual-help programs (if desired by clients)
Post–Specialty–Treatment Recovery (recovery maintenance) | • Conducting recovery check-ins (in person, by phone, or via telehealth); • Holding substance-free social and recreational activities for program alumni; • Facilitating recovery support groups; • Leading computer skills workshops

As several activities in the above table show, peer workers not only provide services linked to an individual's current stage of care but can also support their transition to the next stage of care and to the local recovery community, including RCOs and RCCs where available.^422,423^

As the table also shows, some peer worker activities take place away from the treatment setting. Peer workers affiliated with RCOs, RCCs, and other recovery support organizations have long provided support out in the community to people in or seeking recovery. Peer workers in some SUD treatment programs offering PSS do so as well.

Note that the list of peer activities above is neither exhaustive nor prescriptive. Programs should create a variety of PSS that meet their needs and those of their clients, and periodically assess community needs and PSS offerings to determine whether to add or change programming.

### Technology-Assisted PSS

The COVID-19 pandemic sped up the already growing use of digital technologies in PSS. The expanded use of technologies in delivering PSS requires developing best practices. Considerations include:^424^

• General technology literacy.
• Available equipment.
• Ways to use technologies (e.g., downloading apps, sending text messages, entering survey data).
• Organization policies and regulatory compliance.
• Privacy and confidentiality issues, including appropriate spaces for delivering virtual PSS.
• Processes for handling crises through digital communication.

In the early months of the COVID-19 pandemic, a publication for addiction professionals conducted an informal review of the expanded use of technology-assisted peer support in PSS programs across the country. Five key practices emerged:^425^

• Using the phone as the central tool. Most PSS programs increased their use of both smartphone and traditional telephone services during the pandemic. Peer specialists checked in with program clients by phone and texts to let them know about virtual resources, such as online or video-based support meetings and classes. Programs also expanded peer-staffed call-in lines for noncrisis calls and established new emergency phone numbers for clients to reach their peer workers.
• Using communication platforms preferred by participants. PSS programs chose their platforms for ease of use, security, and user preference.
• Engaging people in new ways, using virtual peer-led support groups. Videoconferencing attracted new participants not seen in face-to-face meetings; the virtual setting reduced geographic, transportation, and other barriers to participation. Online peer recovery group meetings also allowed facilitators to multitask during discussions by answering questions and sharing resources via the chat function.
• Providing clear guidelines for technology use. Peer specialists moderated virtual meetings, setting group agreements and managing group dynamics, and they needed guidelines for communication etiquette and confidentiality in this new setting. Programs used encrypted forms of technology when possible, and they reviewed and revised guidelines to ensure that staff protected participant privacy when posting to public forums.
• Promoting technology-based PSS through online resource pages and social media. People new to recovery may have challenges finding out where and how to access technology-assisted PSS. Programs promoted their technology-assisted PSS in resource pages on their websites, links on their social media feeds, and blog posts. They also posted self-directed learning courses to address information needs.

RESOURCE ALERT: TELEHEALTH AND SUDs

Administrators implementing PSS will need to determine the role of telehealth in delivering these services. This SAMHSA evidence-based resource guide to telehealth for SUD treatment reviews relevant literature and research findings, examines emerging and best practices, discusses gaps in knowledge, and identifies challenges and strategies for implementation: Telehealth for the Treatment of Serious Mental Illness and Substance Use Disorders (https://store.samhsa.gov/product/telehealth-for-treatment-serious-mental-illness-substance-use-disorders/PEP21-06-02-001).

### How PSS Benefit People With Problematic Substance Use

The evidence linking PSS for problematic substance use to better outcomes continues to grow, although this area of research is relatively new and more studies are needed. Improved outcomes for people with problematic substance use include:^426,427,428,429,430,431,432,433,434,435,436^

• Increases in treatment retention.
• Increases in treatment motivation and general self-efficacy.
• Better adherence to SUD treatment plans.
• Greater rates of abstinence.
• Decreases in substance use.
• Lower rates of overdose for people with opioid use disorder.^437^
• Fewer rehospitalizations for addiction issues.
• Less anxiety and tension.
• Increases in housing, employment, and educational stability.
• Greater access to social supports.

Research also suggests that delivering PSS benefits the peer worker.^438^ Serving in this role can validate positive changes made and strengthen peer workers’ connections and identification with the recovery community.^439^

### How Peer Workers Can Benefit Treatment Programs

Peer workers will most obviously benefit programs—and, by extension, their client population—by expanding and enhancing program services. Peer workers can, for example:

• Help put new program clients at ease by being the ones to welcome and orient them.
• Engage program clients in recovery planning.
• Make staff resources go further or expand programming by helping to run groups appropriate to the peer role (e.g., life-skills groups).
• Perform supportive roles and tasks^440^ not undertaken by clinicians, like accompanying individual program clients to medical appointments or their first mutual-help group meeting.

Peer workers add value to a program by:^441^

• Directly filling gaps in the continuum of SUD care, including engagement in long-term recovery activities.
• Connecting program clients to no-barrier recovery resources (like RCOs) before, during, or after specialty treatment.
• Emphasizing long-term recovery over acute, episodic care.
• Showing people seeking or in recovery, and the community as a whole, that the program values the recovery process and people in recovery.
• Letting program clients work with someone who can inspire hope in them, serve as a role model, and “speak their language.”

Peer workers can strengthen an organization's financial standing by increasing client retention and satisfaction.^442^ And because peer workers often maintain supportive contact with individuals who have completed treatment, some individuals may as a result choose to return to the same organization should they need additional treatment.

Treatment programs can highlight improved outcomes resulting from PSS when seeking grant funding or private donations. Peer workers can also help a program increase its visibility in the local community and strengthen connections with partner organizations that might refer clients.

Peer workers can help assess community needs, local drug trends, local resources, and service delivery gaps—especially if they come from the communities an organization serves. They can also contribute the perspective of the population served, a valuable voice to have in care team meetings and other planning meetings.

### The Right Time for Integrating the Peer Specialist Position

Advances in the understanding of recovery and changes in healthcare delivery models have opened doors for PSS to grow. The expanding body of promising research results on PSS for SUDs gives programs wanting to provide these services a strong rationale for doing so. Increased insurance coverage for SUD treatment and growth in the number of state Medicaid programs covering PSS have provided new pathways for reimbursement of these services, which previously may have been out of reach. Telehealth and technology-based PSS are also expanding the ways in which PSS are available to people recovering from or otherwise affected by problematic substance use.

## Introducing PSS Into SUD Treatment Program Settings

This section will provide tools and tips for introducing PSS into treatment programs as well as suggestions on how to address challenges that can arise during this process. Most of the discussion will focus on directly hiring peer workers, but much will also apply to contracting for peer workers.

### Shifting the Organizational Culture

PSS are a key ingredient for effective SUD care, not just an add-on service. Still, even if an organization has a recovery orientation, its leadership should prepare for the possibility of pushback from some existing staff when beginning to integrate peer workers. This is especially true if an organization recently adopted a recovery orientation and is still making that transition.

Some nonpeer staff may experience culture shock as PSS join the service offerings, and even those who fully accept the concept of PSS may have difficulty incorporating peer workers into their customary workflow or negotiating conflicts and disagreements with specific peer workers (as could happen with the introduction of other new positions and personnel).

Introducing PSS requires commitment to a recovery orientation and recovery principles throughout the organization, starting at the top. Program leadership must see PSS as consistent with the cultural values and recovery orientation of the organization, and must believe that PSS will add value to the program. On a practical level, administrators need to:^443^

• Understand the specifics of why and how to introduce PSS.
• Clearly explain these specifics to nonpeer staff ahead of time.

When introducing PSS, administrators should inform existing staff that peer workers provide essential, not supplementary, services.^444^ Staff should also be told that the peer position will complement, not replace, existing positions, and that peer workers can undertake some responsibilities that may not be within the scope of practice of existing staff. Administrators need to keep in mind, and advise staff, that adopting a recovery orientation requires more than adding peer workers to existing treatment processes.^445^ Administrators should also consider assigning appropriate chapters in this TIP as background reading for the phase-in.

Administrators can take several other steps to lay the groundwork for introducing PSS successfully. Early on, they can get advice from leadership at programs that have already introduced peer workers, and directly from peer workers themselves, including specifics on what the peer staff do and how this benefits the program and program clients. Seeing a program in operation, and hearing from peer staff and from program staff who helped implement PSS, can also open the door to peer-to-peer information sharing between programs. Programs that have already implemented PSS may also have relevant training materials that they can provide.

Administrators can also contact the appropriate SAMHSA Regional Office (https://www.samhsa.gov/about-us/who-we-are/regional-offices) or SAMHSA-funded Addiction Technology Transfer Center Network (https://attcnetwork.org/centers/selection) for help locating treatment programs that have implemented PSS.

RESOURCE ALERT: PEER SUPPORT TOOLKITS

• The Philadelphia Department of Behavioral Health and Intellectual disAbility Services has created a toolkit specifically for organizations incorporating peer workers into new roles. It covers why and how to add peer services, and how to prepare the organizational culture. The Peer Support Toolkit is available at https://dbhids.org/peer-support-toolkit/.
• This Veterans Health Administration toolkit on peer workers discusses why and how to hire them and gives tips on training, supervising, and building organizational support for them: Peer Specialist Toolkit: Implementing Peer Support Services in VHA (https://www.mirecc.va.gov/visn4/docs/Peer_Specialist_toolkit_Final.pdf).
• The New York State Office of Alcoholism and Substance Abuse Services released a toolkit that provides indepth information on training and program integration. Although tailored to New York, it also contains information applicable across all states. The Peer Integration and the Stages of Change ToolKit is available at https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf.
• The National Council for Mental Wellbeing has published Establishing Peer Support Services for Overdose Response: A Toolkit for Health Departments. Although the toolkit focuses on harm reduction to prevent and respond to opioid overdose, it contains checklists and resource lists useful for introducing PSS in other contexts. It is available through https://www.thenationalcouncil.org/program/tools-for-overdose-prevention/.

### Championing PSS

Administrators should be among the first and strongest champions for PSS within an organization. They should work to develop early allies among other nonpeer staff. They should also enlist the help of any supervisors or other members of the program's leadership who understand and support peer services and use these allies to help prepare other nonpeer staff for the introduction of peer workers. Like-minded program leadership and staff could form a workgroup to plan the rollout of PSS, including developing:

• Realistic goals and objectives.
• Job descriptions for peer workers.
• Plans for supervision.
• Revisions to the organizational chart to reflect the new position and new reporting lines.
• Onboarding plans.
• A defined implementation plan.
• Action steps to achieve the plan.

Studies of peer workers in behavioral health service settings show that peer workplace satisfaction depends to a significant extent on administrators’ and supervisors’ understanding of peer workers’ responsibilities.^446,447,448^ These findings suggest that before introducing PSS, administrators and supervisors must fully comprehend the roles that peer workers will fill and must stay involved in the process of integrating peer workers after they are hired.

An all-staff meeting would provide a good opportunity to explain the coming changes, the roles peer workers will play, the benefits to the program and its clients, and the expectations for nonpeer staff. Staff could ask questions, which would establish a sense of transparency about the new services and set a pattern of openness about peer workers and their roles.

Administrators should consider holding smaller team- or department-specific meetings during which allies on staff can lead discussions on specific questions. Conducting anonymous surveys to collect feedback on staff's knowledge, perceptions, concerns, and expectations about PSS will help administrators identify and address any issues early on.

New skills and attitudes need reinforcement. To ensure that the cultural change represented by introducing PSS moves forward successfully, administrators should make available training, technical assistance, and coaching to support implementation. Emphasizing the relevance of PSS to the mission of the program and demonstrating leadership's commitment through trainings will help peer integration succeed.^449,450^

### Assessing Readiness

Before a program hires or contracts for peer workers, its leadership should conduct a readiness assessment of the program and existing staff. The New York City Department of Health and Mental Hygiene's guide for integrating peer workers includes several tools for assessing organizational readiness for PSS (https://www1.nyc.gov/assets/doh/downloads/pdf/mh/peers-treatment-programs.pdf).^451^

The “Organizational Characteristics Indicating Readiness To Hire Peer Workers” text box provides an example of a checklist for evaluating an organization's readiness to integrate PSS; administrators can revise it to suit their situation. The “DEIA” Resource Alert includes resources for incorporating diversity, equity, inclusion, and accessibility (DEIA) considerations into the organizational assessment and workforce planning.

ORGANIZATIONAL CHARACTERISTICS INDICATING READINESS TO HIRE PEER WORKERS

Organizational values

• A recovery-oriented mission
• Defined peer roles that are permanent with secure funding
• Clear job descriptions for peer workers
• Equitable wages and benefits packages for peer workers

Policies and practices

• Policies and practices aligned with recovery-oriented values
• Clear confidentiality policies and practices
• Clear policies regarding relationships and personal boundaries
• Inclusive hiring policies and practices
• Policies that ensure regular communication among staff members
• Policies that ensure routine performance evaluations that reflect the peer worker's role

Staff knowledge and attitudes

• Staff believe that recovery is possible for everyone
• Staff are knowledgeable about the benefits of peer support
• Staff continue to develop their knowledge and understanding of peer support
• Staff address their own prejudices about people with behavioral health conditions

Supervision and support

• Organization ensures the provision of regular supervision
• Supervision is recovery-oriented and trauma-informed
• Supervisors know how to use reasonable accommodations for colleagues with disabilities

Source: Reprinted with permission. ^ 452 ^

Administrators should enlist supportive people in leadership to help assess the knowledge and attitudes of others on staff. Administrators should also communicate to nonpeer staff about the various ways the peers will work with clients and staff and their anticipated contributions to client outcomes.^453^

In assessing readiness and preparing to introduce peer workers, administrators may find it useful to map the intake and service delivery workflows currently used, especially if this hasn't been done recently. The resulting flowcharts can be used to determine how peer workers will fit into the work of the program and what changes in workflow will be required for existing staff. Adding peer workers to the flowcharts will clearly show both the peer workers and existing staff how clients move through the organization and who is involved in each stage of SUD care.

Exhibit 4.1 shows a hypothetical division of responsibilities among an SUD counselor, a case manager, and a peer specialist at an outpatient treatment program. The exhibit doesn't aim to prescribe exactly which duties each professional should undertake. Rather, it provides an example of how administrators should try to clarify responsibilities across staff members as well as how the peer specialist's work complements that of the other two staff members.

EXHIBIT 4.1. Division of Responsibilities Among Three Outpatient Staff Members^454,455,456^

SUD Counselor

• Orients client on the treatment program and next steps
• Conducts screening and comprehensive assessment
• Assesses client's readiness for treatment
• Reviews treatment options with client
• Develops treatment plan with client, with input from other staff; regularly updates and shares plan with care team
• Describes and links to other care team members, mutual-help resources (e.g., Alcoholics Anonymous^®^, Narcotics Anonymous)
• Provides individual and group counseling
• Educates client on SUDs and, as needed, co-occurring disorders
• Does planning with client to avoid recurrence of use, with input from other staff
• Provides family support and education
• Conducts crisis counseling
• Tracks and reports on client's progress in treatment
• Develops continuing care plan for client upon treatment completion or discharge

Case Manager

• Coordinates service planning for client
• Refers client to and communicates with outside clinical service providers
• Refers client to job services
• Helps client make plans to continue education
• Reviews client recovery plan with peer specialist and other staff
• Helps link client to supportive resources responding to social determinants of health (e.g., housing, food, financial security)
• Helps client resolve benefits and entitlements issues (e.g., with Social Security, Medicaid)
• Keeps family informed about client treatment progress, as appropriate
• Advocates for client with law enforcement, the courts, and the client's employer(s), as needed
• Takes part in admission and discharge planning if client needs inpatient care

Peer Specialist

• Provides outreach and engages with client at first point of contact
• Helps educate client on community resources and provides linkages to access these resources
• Develops recovery plan with client and monitors progress
• Models recovery skills and shares recovery-oriented lived experience
• Helps client engage in services, shares client perspective with clinical staff
• Provides emotional support to client, including in the community^457^
• Helps client navigate health, social service, and justice systems, as needed
• Coaches client on self-advocacy
• Accompanies client to medical appointments, mutual-help group meetings, housing interviews, as needed
• Holds recovery social activities
• Supports client during and after transitions in care
• Connects client to local RCO

RESOURCE ALERT: DEIA

A diverse program workforce that reflects the populations served will enrich an SUD treatment program and increase its effectiveness. The following resources provide useful guidance on DEIA considerations:

• Diversity, Equity, and Inclusion (DEI) Organizational Assessment Tools: A Resource Guide (https://heller.brandeis.edu/iere/pdfs/dei_organizational_assessment_tools.pdf). The instruments included in the guide “outline a set of dimensions through which DEI is assessed, with specific indicators to reflect the extent to which DEI is put into practice.”
• National Association of Addiction Treatment Providers (NAATP) Diversity, Equity, Inclusivity & Belonging Resources (https://www.naatp.org/resources/dei). This website, updated regularly, provides a wealth of resources, including links to the NAATP DEIB organizational assessment tool, webinars, videos, manuals, a blog, research, and other publications that can help with learning and implementing DEIB best practices.
• SAMHSA's SSI/SSDI Outreach, Access, and Recovery (SOAR) DEI Resources webpage (https://soarworks.samhsa.gov/article/dei-resources)

Peer workers who engage in community-based work with program clients may require more time offsite than other staff members. Program managers need to keep this aspect of peers’ work in mind when peers’ duties are coordinated with those of intake, clinical, and other staff.

Administrators should also assess whether program safety policies and procedures adequately cover the sort of offsite work that peer workers do, including home visits. Such steps include having set times for checking in by phone or text message and identifying safe public locations for meetings with program clients in the community. Additional suggestions can be found in the “Risk Assessments and Controls for Peers Who Work in Homes/Community” section of the New York State Office of Addiction Services and Supports’ Peer Integration and the Stages of Change ToolKit (https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf).

When developing policies for peer workers, administrators should treat recurrence of problematic substance use as a human resources issue. If peer workers experience a recurrence of use, they should receive support and guidance as outlined by treatment program policies and state and national guidelines.

Administrators may want to use a peer services agreement form that sets out what program clients receiving PSS can expect of their peer workers and what the program expects of these clients. An example of such a form can be found via the PeerConnect Recovery Support Services webpage of the Alano Club of Portland (OR) at https://www.portlandalano.org/peerconnect. Administrators should consider adapting the form based on the unique needs of the people and communities served and the types of services provided by their programs.

### Identifying Funding

Funding sources for PSS vary by state, setting, and clients’ insurance status. Many state Medicaid programs reimburse for PSS for SUDs,^458^ although states decide which eligible services are covered and the service delivery model. To be Medicaid reimbursable by CMS, the PSS and the peer workers who provide them must meet federal requirements pertaining to documentation, care coordination, supervision, and training and credentialing.^459,460^ Administrators should contact their state Medicaid agency for more information.

As previously noted, SAMHSA grants to states have been and remain an important source of funding for PSS.^461^ Some states also use dedicated funds or general revenues to help support PSS. State behavioral health authorities (https://www.samhsa.gov/sites/default/files/ssa-directory.pdf) and local behavioral health authorities can be helpful sources of information. Administrators should also contact any private health insurance plans accepted to see whether they reimburse for PSS.^462^ Administrators whose programs are part of a large healthcare organization should find out whether it pays for PSS. Foundations and other private sources may help support PSS. Administrators should also review the “Sustainability” section below for additional discussion of funding possibilities.

### Training Nonpeer Staff

Nonpeer staff members need training on PSS-related topics before an organization introduces the peer specialist position.^463,464^ For example, staff, including supervisors, need to understand the training that peer specialists have probably received before they arrive at a program. Most states require somewhere between 40 and 84 hours of training.^465^ Covered topics may include:^466,467^

• Building office skills, including computer use and recordkeeping for behavioral health.
• Collaborating with and handling resistance from nonpeer coworkers.
• Understanding the fundamentals of SUDs.
• Understanding recovery concepts, setting recovery goals, and doing recovery planning with people who have problematic substance use.
• Understanding trauma and its impact on people seeking or in recovery.
• Linking people with substance use–related problems to resources.
• Setting boundaries with the people they work with on recovery.
• Following ethics guidelines.
• Understanding laws and policies on confidentiality.
• Communicating effectively.
• Promoting their own self-care and wellness.
• Becoming familiar with the Americans With Disabilities Act.
• Understanding the spirit and philosophy of motivational interviewing.

Nonpeer staff members also need to understand the roles that peer workers will assume, to help avoid role confusion and role drift. Other training topics for nonpeer staff typically focus on:

• The culture clashes that can prevent integration, and how to resolve them.
• Reassurance that peer workers will understand the importance of relevant laws and regulations, such as those on the confidentiality of individuals’ SUD treatment records.

### Arranging for Supervision of Peer Workers

As part of introducing PSS, administrators should arrange for supervision for the peer workers. Someone who supervises peer workers needs to have a recovery outlook. A supervisor with experience working as a peer is ideal.

In addition to addressing the administrative aspects of supervising employees, a peer supervisor should support peer workers in maintaining a work–life balance. Such support will help peer workers avoid role drift and practice self-care. Chapter 5 of this TIP has more information on supervising peer specialists.

Some treatment programs use cosupervision, where one supervisor handles the administrative aspects of the role and the other supports peer workers in their professional development and knowledge acquisition and helps them address ethical questions, boundary concerns, and any role confusion.^468^ Treatment programs that contract with RCOs or other entities for PSS delivery often arrange for the contractor organization to provide the professional/supportive supervision. The Chapter 5 section “Providing a Recovery-Oriented Framework for Supervision” provides more information on cosupervision.

In addition to committing to a recovery-oriented approach, anyone supervising peers must understand:

• Peer workers’ roles.^469^
• Ethical issues that can arise with peer work.
• State licensing and certification requirements for peer workers,^470^ including the training received.

Nonpeer supervisors of peer specialists should receive training on such peer-specific topics as peer specialists’ roles and applicable codes of ethics. Chapter 5's “Guides for Supervision of Peer Workers” Resource Alert and “Supervision Competencies” section have more information.

The 2007 CMS guidance allowing Medicaid reimbursement for PSS requires supervision of peer staff by “a competent mental health professional” as defined by the state.^471^ State definitions of this term vary widely. If a state's Medicaid program reimburses for SUD PSS and a treatment program plans to bill Medicaid for PSS delivered to clients with this coverage, administrators need to check with the state Medicaid office on the types of professionals permitted to serve as peer supervisors. (In many states, supervisors of peer specialists whose services are billed to Medicaid must be licensed clinicians, which underscores the need for ensuring peer supervisors’ understanding of peer worker roles, values, training, and contributions.^472,473^)

Chapter 8 includes additional resources on supervising peer staff.

### Setting Hiring Objectives for Direct Employees

When introducing PSS for the first time, programs should try to hire more than one peer. Having a single peer potentially isolates that individual if other staff don't provide professional support, and puts the future of peer services at the program at risk if that one person does not work out. Also, SAMHSA's Expert Panel on Equipping Behavioral Health Systems and Authorities To Promote Peer Specialist/Peer Recovery Coaching Services emphasized the importance of regular contact with other peer workers who are in similar roles.^474^ Ideally, peer workers should have other peer workers with whom they can discuss their job-related experiences, ideas, and challenges.^475^

Administrators need to know whether their state has a single integrated certification for mental health peer specialists and peer specialists working in the substance use field, or whether the certifications are separate. Planning and activities for hiring peers need to reflect that the program seeks peers in the substance use treatment field and not mental health peers.

Diversity is an important goal when hiring peer workers. Because shared experiences form the foundation of peer support, a program should try to match program clients with peer workers who share as similar an experience as possible. This principle of shared experience should also be followed regarding the characteristics and demographics of the populations an organization serves. Administrators may want to begin developing their peer workforce by recruiting locally; for example, by offering paid internships.

If a program treats populations for whom English is not their first language, an effort should be made to hire peer staff who speak their preferred language.^476^ If a program treats populations with high rates of HIV infection, hiring peer workers who are living with HIV is advisable. If a program serves a significant number of veterans, the peer workers hired should ideally include veterans. LGBTQ+ peer workers or peer workers with a physical disability or a co-occurring condition such as depression or bipolar disorder may have special insights they can share with program clients who are similar in these respects. Peer workers with a criminal history may better understand, relate to, and work with people seeking or in recovery who have a criminal history.^477,478^

RESOURCE ALERT: STATE PEER SPECIALIST TRAINING AND CERTIFICATION REQUIREMENTS

• SAMHSA's Bringing Recovery Supports to Scale Technical Assistance Center Strategy in 2020 compiled the State-by-State Directory of Peer Recovery Coaching Training and Certification Programs, available at https://c4innovates.com/brsstacs/BRSS-TACS_State-by-State-Directory-of-Peer-Recovery-Coaching-Training-and-Certification-Programs_8_26_2020.pdf.
• The 2023 Comparative Analysis of State Requirements for Peer Support Specialist Training and Certification in the United States, published for SAMHSA by the Peer Recovery Center of Excellence and available through https://peerrecoverynow.org/about/coe-products.aspx, provides links to training and certification information by state in the section “State Website Data Sources.” The center also has an online state certification directory at https://peerrecoverynow.org/resources/state-certifications.aspx.
• Doors to Wellbeing, a program of the Copeland Center for Wellness and Recovery, also offers an online state-by-state database of certification requirements for peer specialists (https://copelandcenter.com/peer-specialists).
• The National Association of State Alcohol and Drug Abuse Directors Member Directory provides links to websites for state and territory Single State Agencies for SUD treatment and prevention, where administrators can find information about certification of peer specialists in their state (https://nasadad.org/ssa-web-sites/).

The state peer specialist credentialing organization may have resources available to help with the objectives discussed above. (The resources in “Resource Alert: State Peer Specialist Training and Certification Requirements” have information on state credentialing bodies.) Local RCOs may also have helpful resources.

### Setting a Compensation Package

Surveys of peer workers and analysis by researchers consistently point to low pay as a major source of job dissatisfaction and a barrier to peer worker retention.^479,480,481^ In a survey of more than 500 peer workers, only 46.8 percent of respondents reported feeling that their pay was consistent with the pay of others who perform similar kinds of work but do not have lived experience.^482^

To attract and retain a strong peer worker staff, programs should:

• Pay peer workers a fair wage.
• Provide benefits (e.g., health insurance, paid time off, sick leave, access to an employee assistance program).
• Permit them to work full time if they wish to (but human resources staff should be upfront with peer worker candidates and employees that higher income could affect any public benefits they might receive^483^).

The Peer Support Toolkit developed by the Philadelphia Department of Behavioral Health and Intellectual disAbility Services offers this guidance:

Peer support staff should be offered a competitive salary and the same opportunities as other staff for raises and promotions. When designing job descriptions and pay scales, ensure that the pay scale for peer positions is comparable to that of positions with similar qualifications. For example, if your qualifications and roles for peer staff are comparable to those of case managers, the salary ranges of the two positions should be similar. Looking at pay scales and job descriptions of current staff can help you develop job descriptions that clearly differentiate the roles of peer workers and nonpeer staff.

Also consider benefits such as a flexible work schedule. Many peer staff are scheduled to work 25–40 hours a week. However, the job often demands that peer workers work additional hours, often outside of normal business hours. The reality of peer support positions should be reflected in policies and procedures on overtime pay, flexible work hours, or flex time.^484^

The Peer Support Toolkit further recommends providing mileage reimbursement for travel done in personal vehicles as part of peer work in the community.

To accomplish these goals, administrators need to carefully explore how many peer workers their program can afford to hire. It is preferable, for many reasons, to hire fewer peer workers and provide them with full-time hours as well as pay and benefits comparable to those of other staff.

Programs may seek to stretch their budget by using part-time peer workers. But limited work hours give peer workers fewer chances to interact with nonpeer staff. Peer workers report that gaining the trust and respect of their colleagues leads to job satisfaction,^485^ and this process may be more difficult for part-timers.

### Writing Job Descriptions

The more care taken in developing clear job descriptions for peer positions, the better chance a program has of successfully incorporating peer worker positions. Poorly defined peer job descriptions can lead to role confusion and organization-wide misunderstandings about the duties of peer workers, making it hard for them to succeed and integrate into the workplace.^486^

A program needs a clear vision for the roles peer workers will fill before leadership and human resources staff write the job description. A decision should also be made on whether the job description mentions opportunities for advancement. The job description must be written in such a way that it clearly applies to peer specialists in the substance use field, not the mental health field. Administrators may want to consult with other SUD treatment programs that employ peer specialists, reviewing their peer job descriptions and discussing how the job descriptions helped or hurt the process of hiring and integrating peer workers.

With the approval of human resources, the rest of the staff should have an opportunity to look over the draft job description before it is finalized. Allowing nonpeer staff to become familiar with these details will help smooth the process of incorporating PSS, and nonpeer staff may have input that will improve the job description.

How Can Organizations Incorporate Both Volunteer Peer Workers and Paid Peer Workers?^487,488^

Organizations may want to consider adding volunteer peer workers to supplement the work done by paid peer providers. Individuals in recovery may be interested in volunteering as peer workers to:

• Make a difference in the lives of other people in or seeking recovery.
• Put their existing experience and knowledge to use.
• Stay active in the behavioral health field.
• Take a step toward entering or reentering the general workforce.
• Accrue supervised volunteer hours to fulfill state requirements for becoming a certified peer specialist (in those states that require experience hours for certification and count volunteering toward these hours).^489^

Volunteers may want to work flexible and limited hours.

Organizations can have volunteer peer workers handle important activities that don't involve carrying a caseload and that require less training and specialized education than functions assigned to paid peer specialists (including Medicaid-billable services). For example, volunteers can:

• Help clients fill out applications for social service programs.
• Make reminder or follow-up calls.
• Welcome prospective clients visiting in person.
• Update community resource guides.
• Help run holiday and recreational activities.

More pointers on adding volunteer peer worker positions are on pages 42–43 of the Peer Support Toolkit published by the Philadelphia Department of Behavioral Health and Intellectual disAbility Services (http://dbhids.org/wp-content/uploads/1970/01/PCCI_Peer-Support-Toolkit.pdf) and pages 17–18 of the Peer Integration and the Stages of Change ToolKit published by the New York State Office of Addiction Services and Supports (https://oasas.ny.gov/system/files/documents/2019/08/PeerIntegrationToolKit-DigitalFinal.pdf).

The job description should specify whether applicants need to hold state certification or be in the process of getting certified. Although no single universally recognized credentialing body for peer specialists exists in the United States, the International Certification & Reciprocity Consortium (IC&RC; https://internationalcredentialing.org/creds/pr) and NAADAC, The Association for Addiction Professionals (https://www.naadac.org/ncprss), both offer certification recognized by multiple states. Administrators can refer to these organizations’ websites for details on certification requirements and should confirm that their state recognizes a given certification. (IC&RC credentials are administered by state-specific boards. Each board sets its own standards, application processes, timelines, and fees for credentialing. To earn a credential, a peer specialist candidate must work with the certification board in their state.)

In 2022 and 2023, SAMHSA collaborated with federal, state, tribal, and local partners to develop SAMHSA's National Model Standards for Peer Support Certification, which covers substance use, mental health, and family and youth peer certifications. The National Model Standards will accelerate universal adoption, recognition, and integration of the peer workforce across all elements of the healthcare system.

Each standard was written based on the needs of the peer workforce and the people they serve. SAMHSA is strongly encouraging states to consider adopting the Model Standards to strengthen the peer workforce and expand certification reciprocity across states. The National Model Standards can be viewed here: https://www.samhsa.gov/about-us/who-we-are/offices-centers/or/model-standards. Ten of the Standards apply to peer specialists and one applies to supervisors of peer specialists. The Standards’ recommendations on the certification process and certification requirements cover topics such as training, work experience, background checks, and ethics.

Administrators interested in incorporating peer specialists into their programs should familiarize themselves with the Model Standards and stay up to date on their state's peer specialist and peer supervisor certification requirements.

In addition to the required credentials, the job description should include the following components:

• Job title. It should be succinct and clear. (Consistent use of the title is important to avoid confusion within an organization and when promoting PSS offerings to partners and the public.)
• Duties and responsibilities. This section should clearly lay out the peer specialist's daily, weekly, and monthly duties and tasks.
• Relationships among staff. In addition to a description, this section should have an accompanying organizational chart that shows who supervises the peer specialist and how this position relates to other staff positions.
• Qualifications and requirements. This section specifies, as applicable, licensure, certification, training, experience, education requirements, and role restrictions.
• Knowledge, skills, and abilities (KSAs). This section should clearly state how each KSA relates to the job the peer specialist performs.
• Ethical expectations. This section should spell out procedures for an ethical decision-making process, responsibility for reporting ethical concerns to the supervisor, and unethical behavior that would initiate disciplinary action.
• Description of the program the peer will be entering. This section needs to give the peer a clear understanding of what they can expect should they be hired. It should include the organization's treatment philosophy, mission statement, and structure.

Below are questions for administrators to ask themselves before posting a peer specialist job and interviewing candidates. (Answers may depend on the requirements of the state where an organization operates.)

• Must applicants be certified peer specialists or be eligible for certification?
• Will the program require peer workers to have a minimum length of time in recovery? If so, does the job description clearly state this requirement? Asking applicants to disclose their time in recovery can be problematic, so any staff member who will conduct interviews needs to understand current state and federal restrictions around such queries.
• What open-ended questions will be asked to invite applicants to discuss their recovery journeys, what recovery means to them, and why they feel they are a good fit for the position?
• How will the program address criminal history (keeping in mind state and federal employment laws and regulations related to criminal histories)?

Program leadership and human resources personnel must actively support and enforce the expectations and the boundaries of the peer role laid out in the job description. Other peer staff should join in this process as much as possible.

The job description should be viewed as a living document. As peer workers become established in the program, the job description should be updated to reflect any changes in the peer role. It should also be updated to reflect any changes in the needs of the population the program serves. When updating the job description, administrators should get feedback on it from peer staff, to ensure accuracy.

### Recruiting

Most states now have infrastructure for credentialing peer workers for SUD PSS. Administrators can check with their state's credentialing agency on services that it may offer for placing trained peer workers. It may also have a job bank for posting job listings, as may any statewide peer worker associations.^490^ Credentialed peer specialists can often be found through the local recovery community. A program can advertise for peer workers at every level of training through online job sites, social media sites, and postings on its own website.

Some programs hire people in recovery who are in the process of getting trained and certified (sometimes called peers-in-training).^491,492^ This approach will work best if a program already has credentialed peer specialists who can supervise the newly hired peers-in-training. (Supervision can be one of the biggest hurdles to overcome in getting newly trained peer specialists the work hours needed for credentialing.) Programs will sometimes pay for some or all of the costs of peer workers’ training and credentialing.

HIRING PROGRAM ALUMNI AS PEERS^493^

An organization may choose to hire program alumni, but it is not obligated to do so. Program leadership should weigh the pros and cons before making this decision. Alumni know the program and its views on treatment and recovery well. However, some staff may have trouble accepting alumni as members of care teams. Alumni may need additional supervision to establish and maintain their new role with any program clients whom they got to know while in treatment, to prevent role confusion.

Before hiring peers, an administrator should determine whether organizational stakeholders and nonpeer staff feel comfortable working with treatment program alumni. New policies or protocols can ease some of the concerns staff may have about hiring program alumni. For example, if an organization has multiple treatment programs, it could assign peers only to treatment programs in which they did not participate. An organization can also impose a waiting period for hiring alumni as peers. Alumni hires can receive extra training and supervision focused on avoiding role confusion and maintaining boundaries with any program clients they know from the treatment program.

### Interviewing

Exhibit 4.2 can serve as a starting point for developing an interview process for peer workers. It contains sample interview questions and scenarios to help determine how candidates would respond to complicated situations. Interviewers should be reminded that it is illegal to ask interviewees what medications they take or when they last had a drink. Also, during interviews, candidates should be informed how, and for how long, the peer position is funded.

Once hired, peer workers can provide insights on the hiring process for other peer workers. They can develop interview questions, select interviewees, and interpret information given during the interview.

EXHIBIT 4.2. Interviewing Peer Worker Candidates

Peer Worker Interview Questions

• How did you hear about our peer program?
• Why are you interested in serving as a peer?
• What are you hoping to get out of being a peer at this organization?
• What training, work, or volunteer experience have you had in recovery services?
• What does recovery mean to you, and what role does recovery play in your daily life?
• How can you help people who are struggling with alcohol or drug use?
• What do you think is the most important part of peer support services?
• Are you comfortable sharing some of your personal story with program participants, when appropriate? What is an example of when you might share your story?

Peer Worker Interview Scenarios

• You are accompanying a person in recovery to a doctor's appointment. Alcoholics Anonymous^®^ is crucial in this person's recovery; he keeps asking whether you are really in recovery, because you haven't surrendered to a higher power. How would you respond?
• As a new employee, you had check-in meetings with your supervisor every week. After 2 months, you started meeting less frequently. You would like to continue meeting weekly. How would you talk to your supervisor about this?
• You occasionally meet with a program participant for goal-setting meetings outside of the office. The participant has started asking you to hang out after your sessions. You consider canceling these meetings because you don't want to give the participant the wrong idea. How would you try to set healthy boundaries between yourself and the participant?

Source: Adapted with permission. ^ 494 ^

### Preparing an Orientation for Peer Workers

For newly hired or contracted peers to get off to a good start, they need a thorough orientation. Chapter 5 discusses developing an orientation program in more detail.

Even if new peer workers have completed the state's training and certification program, they will probably need additional training to make an organization's introduction of PSS proceed as smoothly as possible. For example, new peer workers should job shadow members of the SUD care team to better understand different roles and the program's workflow.^495^

### Ensuring Respect of the Peer Worker Role

To have a truly successful PSS program, nonpeer staff members also need to feel committed to recovery principles and empathic toward people in recovery, including peer workers. (The SAMHSA webpage “Recovery and Recovery Support” at https://www.samhsa.gov/find-help/recovery summarizes recovery principles.) However, studies have found that peer workers in the field can face stigma in their organizations, especially when PSS are new.^496,497,498^ For example, peer workers report being excluded from activities and functions, or from after-work socializing.^499^

Staff should use inclusive language, focusing on recovery and strengths, when talking with or referring to their peer colleagues. Two different ways to ask for input on a local treatment facility show the difference between language that respects or disrespects peer workers. Asking a peer colleague, “Were you treated at that facility?” emphasizes the peer's past as someone with an SUD. Asking instead, “What can you tell me about that facility?” invites the peer to share an informed opinion and includes the peer in the work of the program in a respectful way. (In a recovery-oriented organization, clinical staff also use strengths-based language when discussing program clients.)

Some staff may question peer workers’ qualifications and professionalism, or they may feel defensive about their own professional turf.^500,501^ Such attitudes conflict with a recovery orientation and with the rationale for introducing peer workers: that PSS form an integral, unique, and vital aspect of SUD treatment and that a program with a recovery orientation is incomplete without them.

RESOURCE ALERT: EMPLOYING AND INTEGRATING PEERS

Cal Voices’ Workforce Integration Support and Education program provides this useful resource to help programs with recruiting, hiring, incorporating, and evaluating peer workers: Employer Toolkit—Implementing Essential Organizational Changes To Successfully Integrate Peers (https://15d85744-5333-41e2-91ff-18e506035f98.filesusr.com/ugd/44a48f_97fd3e1daf754ed3b3646388dfb043b9.pdf). The toolkit is organized around 11 core competencies organizations should have to ensure the success of PSS. The toolkit also includes a sample job listing and description, a checklist of peer onboarding procedures, and a sample peer evaluation form.

NAADAC and the Great Lakes Addiction Technology Transfer Center in 2020 collaborated on the Peer Recovery Support series of free webinars, which cover such topics as building a successful culture in an organization; hiring, onboarding, and integration; and supervision and management. Downloadable resources from the webinars are at https://www.naadac.org/peer-recovery-support-webinars.

Once peer workers are on board, administrators should consider giving them the opportunity to educate nonpeer staff on their work. Two studies found that such activities lead nonpeer staff to have greater appreciation for and trust in peer workers’ contributions. The first, a survey, reported on a training by mental health peer workers for nonpeer staff on recovery principles and the peer role.^502^ The other described information sessions on criminal justice populations that peer workers facilitated for nonpeer staff.^503^

To foster mutual learning and teamwork, members of the multidisciplinary care team that peers will work with can in turn discuss their roles and functions with the peers.

Administrators can help ensure respect for the peer role by visibly supporting the peers on their staff.

## Workforce Development and Retention

A survey of almost 600 peer specialists found that 57 percent expected to remain in that role permanently, and another 25 percent for at least 3 years.^504^ These findings suggest that many peer workers have a firm commitment to their field. However, to help keep peer workers prepared for and engaged in their jobs—and to retain them—organizations need to provide them with a sense of community, ongoing training, and opportunities for career advancement, in addition to fair pay and pay increases.

### Develop a Community of Peer Workers

Regular peer-only staff meetings can help new peer workers become accustomed to a program and their roles in it. Such meetings can also help build the peer team's morale and cohesion.

If no community of peer workers exists in the workplace, the consensus panel recommends holding a regular telephone or videoconference call with peer workers from various programs. Administrators can participate in arranging and facilitating such meetings or calls to help peer workers succeed in their roles. A local RCO may be able to assist with organizing such a peer support networking opportunity.

As of 2023, the Peer Recovery Center of Excellence hosts monthly communities of practice calls for peer support specialists and those who supervise them. Participants in the calls engage in sharing, networking, and mutual learning on topics relevant to the peer workforce. The schedule appears at https://peerrecoverynow.org/training/communities-practice.aspx.

Building a community of peers isn't a substitute for having a peer worker feel part of the SUD care team.

### Promote Ongoing Training

Peer workers’ ongoing training should include formal training, on-the-job coaching, and continuing education.^505^ Training requires commitment of organizational resources. A program can help its peer workforce develop professionally by:

• Allowing time for more experienced peer workers or peer supervisors to train less experienced peer workers.
• Providing paid time for peer workers to travel for and attend trainings.
• Underwriting the cost of peers’ continuing education.
• Holding education sessions on topics of mutual interest with peer workers and other professional staff, which can also build teamwork. (The bulleted list of training topics later in this section offers examples.)

Any training should be relevant to the peers’ work.

The mode of training can help determine how well peer workers adapt to their jobs and how satisfied they are with the work. One study of peer specialists revealed that the more time they spend in self-study or independent study, including video-based training, the less satisfied they are with their job training and the less they feel their role is clearly defined by their supervisor. The authors encouraged agencies with peer specialists to use job shadowing and other interactive training methods instead of self-study methods. Not only are interactive methods more satisfying, but they may increase role clarity, another important predictor of job satisfaction among peer specialists.^506^

RESOURCE ALERT: RESOURCES FOR ONGOING PEER WORKER TRAINING

• SAMHSA video trainings on PSS (pre-2019) are at https://www.samhsa.gov/brss-tacs/video-trainings#peer-support.
• Ideas for ongoing training topics may be found in the core curriculum list on page 39 of the University of Colorado School of Medicine's DIMENSIONS: Peer Support Program Toolkit (https://www.bhwellness.org/toolkits/Peer-Support-Program-Toolkit.pdf) and in SAMHSA's Core Competencies for Peer Workers in Behavioral Health Services (downloadable from at https://www.samhsa.gov/brss-tacs/recovery-support-tools/peers/core-competencies-peer-workers).
• Items in “Resource Alert: Manuals and Toolkits” in Chapter 6 of this TIP also contain training topic ideas.

As with other staff in the behavioral health field, some peer workers may require targeted training to increase their knowledge of medications for opioid or alcohol use disorder and to address negative attitudes they may have about individuals who take these medications to support their recovery.

Additional areas for continued training include:

• Multiple pathways to recovery, including with medications.
• Harm reduction strategies, such as syringe services programs.
• Overdose reduction strategies, such as naloxone training and education, including on the newer, stronger naloxone formulations.
• Engagement strategies, such as motivational interviewing techniques.
• Emerging evidence-based practices to help people seeking and in recovery.
• New laws and regulations concerning recovery.
• Changes or updates to organizational policies.
• Emerging technological trends concerning behavioral health (e.g., mobile apps, telehealth).
• An understanding of the importance of person-first, nonstigmatizing language.
• An understanding of recovery messaging: how to describe recovery concepts, the recovery experience, and the language of recovery, including to stakeholders and the general public.
• An understanding of the language that encompasses the concept of DEIA.
• A deeper understanding of cultural responsiveness.
• Trauma-informed care.
• Any changes or updates to local treatment and recovery resources, including new mutual-help groups.

### Provide a Career Pathway

Despite growth in the use of PSS, the lack of a career pathway for peer workers is a problem for the entire behavioral health field. Peer workers often cite lack of opportunity for advancement as a cause of job dissatisfaction.^507^ Some peer workers leave their jobs and the field as a result.^508^

The most common career ladder for peer specialists has only two steps: the position of peer specialist and the position of peer supervisor. A four-state study found that although some larger behavioral health service providers had multistep career ladders for peer workers in the behavioral health field, most did not.^509^ And as noted in the “Arranging for Supervision of Peer Workers” section in this chapter, many states require clinicians to supervise peer specialists who provide services billed to Medicaid, which limits career prospects for peer specialists working for SUD treatment programs in these states unless the programs employ a cosupervision model involving qualified peer specialists.

Some peer workers obtain a professional credential and move on to other roles in the behavioral health field. Others want to remain peer workers while still making progress up a career ladder. For those who aspire to advance in their profession, administrators can consider establishing a clear career pathway to bring stability to the peer worker role and to contribute to peer workers’ job satisfaction and retention.^510,511^ For example, as of this writing, Ventura County (CA) Behavioral Health has three peer specialist levels: Peer Specialist I (trainee), Peer Specialist II (journey level), and Peer Specialist III (lead level). Required qualifications, responsibilities, and compensation increase with each level.^512^

Another approach to support peer worker career development and advancement would be to establish compensation levels for peer roles based on length of time on the job and satisfactory performance evaluations.

The expert panel, however, noted the need for caution when establishing a career ladder. Career pathways that professionalize or establish a hierarchy for peer workers can have a downside: some loss of the peers’ ability to relate one-on-one to program participants. This essential element of peer work—the “peerness” of the role—may disappear if peer workers become stratified or fully incorporated into the professional structures of the behavioral health field. Being aware of this tension may help administrators and peers balance potentially conflicting goals.

THE DEPARTMENT OF VETERANS AFFAIRS’ PEER WORKER CAREER LADDER

The Department of Veterans Affairs (VA) has a multilevel career ladder for its large SUD and mental health peer workforce. Paid VA peer worker positions range from Peer Support Apprentice to Lead Peer Specialist.

The VA's peer apprentice position allows noncertified peer support providers to work in a training role under close supervision while completing their certification.^513^ Peer apprentices must become certified by a state-approved agency or a VA-approved not-for-profit training vendor within a year of their initial appointment as an apprentice.^514^ The apprentice position doesn't have promotion potential, but a peer apprentice may, if qualified, apply for a permanent peer specialist position.

The entry-level peer specialist position is at the General Schedule (GS)-6 grade level. As of 2022, the VA's peer career ladder has four more grade levels, with the GS-10 grade level as the highest.^515^ The GS-10 Lead Peer Specialist position entails such duties as determining training needs for and coaching peer team members. The VA also has GS-11 supervisory peer specialist positions, which are open to qualified VA peer specialists.^516^

Eligibility for peer apprentice and specialist positions is limited to veterans with at least 1 year in recovery. VA peer job descriptions can be found by searching on “peer” at https://www.vacareers.va.gov/.

## Sustainability

Several factors contribute to sustaining the role of PSS in an organization. Internally, the most important factor is that the entire staff—administrators, supervisors, nonpeer staff, and peer workers—consider PSS an integral part of the program's services. A program staff that has a unified commitment to peer services will help sustain those services.

Another way to sustain PSS is to create institutional memory from the outset through good recordkeeping. Such steps include saving peer worker position descriptions and documenting standard operating procedures that show how peer workers fit into the program's ongoing work.

Testimonials from recipients of PSS make up yet another important resource for sustainability. (A related discussion is in the “PSS Evaluation, Marketing, and Advocacy” section below.) Such accounts should be shared not just with potential funders but also with other program staff.

### Funding

Funding shapes the stability and sustainability of services in SUD treatment. “While Medicaid now pays for peer services in many states, sustainable funding remains an issue—grants, contracts, and other time-limited funding still make up a significant percentage of the funding for peer workers and peer services.”^517^ Also, certain types of SUD treatment programs may not be eligible for Medicaid reimbursement under some state Medicaid programs,^518^ and some state Medicaid programs reimburse only for mental health peer services.^519^

Programs may hire or contract for peer workers when they have the resources to do so, then discontinue PSS when the funding disappears. For PSS to receive consistent funding, both program leadership and current and potential funders must see those services as a valuable part of the SUD care and recovery process.

SUD treatment programs in nonprofit, local government, or tribally run behavioral health service agencies may want to work with their parent agencies to look into the Certified Community Behavioral Health Clinic (CCBHC) model as a potential funding mechanism for PSS, especially where the client population is largely low income. Funding support may come through Medicaid; independent state programs; or, at the time of this publication's printing, SAMHSA grants.^520^ Medicaid uses a prospective payment system for CCBHC services provided to Medicaid beneficiaries, with states choosing a daily or a monthly fixed rate.^521^

CCBHCs must provide, either directly or through contracted partner organizations, a specified range of behavioral health services as well as primary care screening and monitoring and care coordination.^522^ More information on CCBHCs’ goals, funding, and requirements can be found at https://www.samhsa.gov/certified-community-behavioral-health-clinics, https://www.ncsl.org/state-legislatures-news/details/the-value-of-certified-community-behavioral-health-clinics, and https://www.thenationalcouncil.org/program/ccbhc-success-center/ccbhc-overview/. An overview of how CCBHCs can collaborate with RCOs on providing PSS is at https://www.thenationalcouncil.org/wp-content/uploads/2022/03/110920_CCBHC_Peer_Services_Mtg_Toolkit-2.pdf.

Another emerging model for integrating primary care and behavioral health services that also offers funding support for PSS is the Medicaid health home. Health homes are designed to provide integrated care plus long-term services and supports for Medicaid populations with complex needs.^523^

As of late 2022, not all states had created Medicaid health homes. Of those states that had chosen to do so, some limited the eligibility for health homes to Medicaid beneficiaries who have SUDs, or opioid use disorder only, or mental and substance use disorders, or serious mental illness only.^524^ Health homes focused on behavioral health conditions have become known as behavioral health homes.

Although PSS aren't explicitly named as one of the six core services that behavioral health homes must provide, peer specialists may deliver some of these core services, and peer activities are included in a document for CMS on best practices for SUD-focused health homes.^525^ One payment option for Medicaid health homes is a per-member per-month payment to programs to cover the required core services.^526^ Medicaid health homes are discussed in more detail at https://www.medicaid.gov/resources-for-states/medicaid-state-technical-assistance/health-home-information-resource-center/index.html.

### PSS Evaluation, Marketing, and Advocacy

One of the best ways for gaining support for PSS—from current and potential funders, stakeholders, and the community at large—is gathering and sharing information that demonstrates the value of these services. To solidify and bolster support, administrators should consider collecting and sharing information on PSS effectiveness to the degree resources allow. Some possibilities include:

Utilization metrics. How have peer specialists affected client retention? No-show rates? Use of hospital services?

Outcome metrics. What effect have PSS had on program clients’ ability to find and maintain employment? Have PSS reduced clients’ involvement in illegal activity?^527^

Qualitative surveys. Organizations can survey staff members—both peer and nonpeer—about their experience with PSS and include positive comments in materials presented to help secure funding or community buy-in. (Any criticisms in the surveys can help guide improvements in PSS.)

Likewise, organizations can survey program clients about their experiences working with peer workers. (Again, negative comments could provide valuable course corrections for programs’ PSS.) Maintaining a file with the strongest, most compelling comments from the surveys for use (with permission) in materials presented to funders, stakeholders, and the community is a good idea.

Storytelling. A sample of stories about how PSS have helped clients, told from their perspectives (anonymously, of course), could impress funders and others in a position to help sustain those services. Particularly powerful are stories of former clients who needed help and now help others on the path to recovery. Avenues for sharing this information include social media, organizations’ websites, and community education sessions.

Advocacy for PSS in the community, whether undertaken by program leadership or peer staff, can help stakeholders understand the importance of—and encourage them to prioritize funding to—these services. Peer workers make some of the best ambassadors for PSS support, especially if they have experience speaking in public about recovery.

## Ensuring Access to PSS

Administrators in other treatment programs that have already adopted PSS may provide insights about navigating the sustainability challenges that can come with adopting PSS. State provider associations may offer good contacts.

If a program can't implement PSS by employing or contracting for peer workers, leadership shouldn't give up on making these important services accessible to clients. Instead, the program could connect clients with PSS by building strong linkages with organizations and agencies that already provide these services, such as RCOs, so that program staff can readily refer clients to these resources. Linkages may require or work better with memorandums of understanding, memorandums of agreement, qualified service organization agreements, or release of information forms to facilitate communication and referral (Question 3 at https://www.samhsa.gov/about-us/who-we-are/laws-regulations/confidentiality-regulations-faqs describes a Qualified Service Organization Agreement).

## Conclusion

Given the shift away from acute-care models of SUD treatment, the need for peer-provided services will increase.^528^ Several trends in SUD treatment delivery make this a good time to initiate PSS. Insurance companies and CMS are increasingly willing to reimburse for the services that peer workers provide. Evolving attitudes about recovery from SUDs focus on chronic, long-term care, rather than acute, one-time interventions.

Peer workers can work in many traditional SUD treatment settings (e.g., outpatient programs, residential treatment programs, hospital addiction units) and become integrated into the workflow in many ways (e.g., outreach and orientation, recovery care planning, continuing care).

Incorporating PSS may represent a cultural shift for treatment organizations. Administrators can help prepare staff for peer services by talking with programs that have successfully implemented them and by working with stakeholders in the community to determine their expectations.

Preparing both incoming peer workers and the existing nonpeer staff for a cultural change will help ensure peer workers’ success in their new positions. Steadfast support of peer workers from program leadership will also help them become an accepted, effective part of an organization.