# Chapter 1—Introduction to Peer Support Services for People With Substance Use–Related Problems

KEY MESSAGES

• Recovery from substance use–related problems is not only possible but likely, given proper resources and support. Incorporating the peer specialist position into substance use disorder (SUD) treatment programs can help clients achieve long-term recovery by maximizing their access to support, resources, and education on SUDs and by connecting them to the recovery community.
• Peer specialists’ training and lived experience with problematic substance use, behavior change, and recovery equip them to engage and work with SUD treatment program clients in unique ways.
• Peer workers reflect principles of recovery, serve many roles, and provide a range of services in diverse settings, including SUD treatment settings.
• Evolving ways of delivering peer support services can increase treatment programs’ engagement with otherwise hard-to-reach people with substance use–related problems.

This Treatment Improvement Protocol (TIP) focuses on peer support services (PSS) provided to people seeking or receiving treatment for problematic substance use, especially from specialized substance use disorder (SUD) treatment programs. PSS enhance SUD treatment services by making it possible for people with SUDs to work with nonclinical professionals who have lived experience with problematic substance use, behavior change, and recovery and, in many cases, special training and certification. These professionals—peer workers—develop and deliver a range of recovery supports designed to improve clients’ treatment experiences and outcomes and their ability to follow their chosen recovery path before, during, and after treatment.

This TIP is intended to educate treatment providers and program administrators about:

• Who peer workers are and what they do.
• Why the role peers play and the supports they provide are important.
• How peers and PSS can be successfully incorporated into SUD treatment programs.

This TIP does not cover the work of peer specialists in the mental health field.

To the extent possible, SUD treatment programs should incorporate peer positions to best support clients. Programs can do so by hiring peer workers directly or contracting for PSS with organizations like recovery community organizations (RCOs). RCOs are independent nonprofit organizations governed, led, and staffed mainly by people in recovery. These organizations typically carry out advocacy activities, educate the community about recovery, conduct outreach programs, and provide PSS.^15^ Some RCOs don't have a physical location, and some have mobile units. RCOs and recovery community centers (RCCs, a type of RCO) are central sites for:,^16,17^

• Recovery support group meetings.
• PSS delivery (such as life skills training, housing, and employment search and support).
• Education on naloxone (opioid overdose reversal medication).
• Precrisis support, including crisis planning and linking to crisis care.^18^
• Postcrisis support, including companionship and digital support.^19^
• Recovery-focused social networking.
• Advocacy.
• Volunteer activities.

Chapter 4 contains more information on partnering with RCOs for the delivery of PSS.

Although this TIP focuses on integrating the peer position and PSS into SUD treatment programs, PSS offered by SUD treatment programs do not replace PSS provided by RCOs and RCCs. Instead, they supplement the PSS provided by RCOs and RCCs. These types of organizations have decades-long experience offering PSS, which are an organic and core part of their mission, and they are central settings for people to work on recovery before, during, after, or, for some people, in place of specialty SUD treatment. Expanding PSS from recovery settings to SUD treatment settings not only strengthens the overall SUD treatment and recovery ecosystem, but also helps people transition seamlessly from treatment to broader community supports like RCOs and RCCs.

TERMS FOR PEER WORKERS

Peer workers are known by many names, including recovery specialist, peer mentor, peer navigator, peer provider, recovery coach, peer support provider, peer specialist, certified peer specialist, recovery support navigator, recovery support specialist, wellness coach, or health navigator.

This TIP uses the following titles (Exhibit ES.1 in this TIP's Executive Summary contains detailed definitions):

• Peer worker and peer support provider refer broadly to all types of peers who provide support for recovery from problematic substance use (except for those in mutual-help organizations), regardless of whether they have received training or certification or whether they work in a clinical or nonclinical setting.
• Peer specialist applies to peers with some training, including those working in professional capacities, whether certified or not.
• Certified peer specialist indicates a peer who has received certification or credentialing to provide PSS.

SUD treatment programs interested in incorporating peer worker positions, and people interested in becoming peer workers, can use this TIP as a resource for understanding:

• PSS.
• The roles and responsibilities of peer workers in the SUD treatment and recovery process.
• Steps for integrating the peer specialist position into SUD treatment programs.
• Best practices for supervising peer specialists in SUD treatment settings.
• The steps necessary to enter the SUD-focused peer support workforce.

Chapter 1 presents an overview of PSS provided to individuals seeking or already in recovery from problematic substance use. The chapter describes the many settings of PSS, and its benefits and challenges, and lays the groundwork for information and concepts presented in later chapters. Learning about the roles, training, and activities of peer workers will help show treatment providers, administrators, and supervisors how offering PSS can enhance an SUD treatment program's services and outcomes.

Chapter 1 reviews:

• The benefits of PSS.
• The role of peer workers in SUD treatment and recovery.
• Settings for PSS.
• The integration of peer positions into SUD treatment settings.
• Background and concepts.
• Diversity, equity, and inclusion.
• Evolving ways to deliver PSS.
• The challenges of providing PSS within SUD treatment programs.

Exhibit ES.1 in the Executive Summary of this TIP contains definitions of key terms used in this and other chapters.

TYPES OF SUD TREATMENT PROGRAMS

This TIP focuses on introducing the peer worker position into specialty SUD treatment programs. Specialty SUD treatment includes:^20^

• Outpatient treatment programs.
• Intensive outpatient programs.
• Residential treatment programs.
• Inpatient hospital programs.
• Opioid treatment programs.
• Office-based opioid treatment programs.
• Medically supervised withdrawal.^*^

The TIP also looks at peer work conducted in other clinical settings providing SUD treatment and care, such as hospital emergency departments and primary care practices.

* Medically supervised withdrawal does not by itself typically lead to recovery, but it can serve as a first step in treatment and recovery, especially for more severe alcohol and benzodiazepine use disorders.^21^

A NOTE ON THE TERM “CLIENT”

This chapter uses the term “client” to refer to an individual receiving services at or from an SUD treatment program. A peer worker generally doesn't refer to someone they work with as their “client,” however. That's because the nature of this relationship differs from that between a treatment provider, like an SUD counselor, and a person receiving SUD treatment. Often, a peer worker will refer to someone they work with as a “peer,” which reflects a nonhierarchical relationship involving collaboration, mutual learning, and the shared experience of problematic substance use. Peer workers in an SUD treatment setting also often use the term “participant” to refer to someone they're working with.

## Benefits of PSS

Emerging research supports using PSS to help meet the needs of people in SUD treatment. Studies with a range of designs, including randomized trials, have explored using PSS to address SUDs. Evidence suggests that PSS can help:^22,23^

• Increase treatment motivation and engagement.
• Increase treatment retention.
• Increase adherence to SUD treatment plans.
• Improve relationships with treatment providers, family members, and social supports.^24,25^
• Increase general self-efficacy.^26,27^
• Improve people's transitions between different stages of SUD care.^28^
• Increase satisfaction with the overall treatment experience.^29^
• Reduce recurrence rates.

Peer workers can enable SUD treatment programs to:

• Expand and enhance their service offerings.
• Add the lived experience perspective to care team discussions.
• Have a more person-centered approach to care.
• Maintain better contact with people awaiting treatment (e.g., because of limited availability of appointments or inpatient/residential beds), through reminder calls and communications on SUD education, treatment preparation, and other topics.^30^
• Better link program participants to the recovery community.
• Better link program participants to social, vocational, housing, and other services and resources that they need. (Such linkages especially help people with unfavorable social determinants of health [SDOH]; SDOH are “the conditions in the environments where people are born, live, learn, work, play, worship, and age that affect a wide range of health, functioning, and quality-of-life outcomes and risks.”^31^)
• Improve communication with program participants, through peer workers’ ability to build rapport with them through shared experience and to “speak their language.”
• Reduce stigma within the treatment team against people with a history of problematic substance use.
• Maintain contact with and provide support to former program participants after time-limited treatment ends.

Chapter 4 discusses additional ways SUD treatment programs can benefit by offering PSS.

## Role of Peer Workers in SUD Treatment and Recovery

Peer workers fill a key role in the SUD treatment workforce—a workforce that faces ever-increasing demands. Increasingly, peer workers are paid or contract staff, although some volunteer.

The main role of a peer worker is to provide recovery support to people who are seeking or in recovery. For example, peer workers:

• Share their personal “lived experience” stories of recovery to motivate and inspire the individuals they work with and their families as well as the community.
• Provide a role model for and motivate individuals in, considering, or seeking recovery.
• Support individuals in creating strengths-based recovery plans.
• Coach individuals on working toward their recovery-specific goals as well as general life goals, within multiple recovery pathways.
• Educate the people they work with and the community at large about substance use–related problems and recovery.
• Link individuals to resources like housing, work, education, transportation, and child care.
• Help individuals draw on and increase their recovery capital (i.e., the quantity and quality of internal and external resources available to someone to initiate and sustain recovery from problematic substance use).
• Work with individuals to build their relationship skills and enhance their social support networks.
• Impart a powerful message of hope to people with substance use–related problems.^32^
• Provide an example of healthy recovery lifestyles.
• Help people seeking recovery get connected to community-based recovery groups and recovery-supportive places in their area.

Peer workers also collaborate with others on the care team and build connections with the recovery community, social service agencies, local businesses, and other resources.

Peer workers provide recovery support services by using their training and drawing selectively on their lived experience. They acquired this lived experience as individuals who have achieved behavior change and recovery from problematic substance use,^33,34^ or as family members or significant others of people who have had problematic substance use. Peers’ firsthand experiences provide unique insights into how to support others in SUD treatment and recovery.^35,36^

Increasingly, peer workers have state-approved, peer-specific training and certification. Organizations providing PSS often require peer workers to have, or be working toward, certification as a condition of employment.

FORMAL PEER SUPPORT AND MUTUAL-HELP PEER SUPPORT: A BRIEF COMPARISON

Peer support has long been an important part of recovery and is the foundation of mutual-help programs. In these programs, participants support each other's recovery from substance use–related problems. Such mutual help isn't learned through training courses or supervision and isn't regulated, licensed, or otherwise certified. Anyone who attends mutual-help programs can provide this support (consistent with program principles and practices).^37^ This support differs from the formal peer support increasingly offered by SUD treatment programs (the focus of this TIP) and pioneered by RCOs and RCCs, which remain major providers of PSS.

A peer specialist delivering formal peer support has, or should have, clearly defined practice boundaries, job duties, and supervision requirements. Delivery of formal peer support requires training and, often, certification. And unlike mutual-help peers (including sponsors), peer specialists provide a wide range of services in a wide range of clinical and nonclinical settings. However, peer specialists often link people in SUD treatment to mutual-help groups^38^ and may themselves be past or active mutual-help group members.

Chapter 6 contains a more detailed comparison in its “Who Are Peer Workers?” section.

Peers’ activities and responsibilities differ from those of nonpeer providers. For example:^39,40^

• Unlike a clinician providing SUD treatment, peer workers don't diagnose, assess for, or treat SUDs.
• Unlike a mental health clinician, peer workers don't diagnose or provide counseling on mental disorders. They don't refer to their support services as “counseling” or “therapy.”
• Unlike a behavioral health technician, peer workers don't collect urine or other bodily samples for testing or conduct room or body searches for substances.
• Unlike a primary care provider, peer workers don't diagnose medical conditions or offer medical advice or treatment.

Here are some real-world examples of how peer workers’ roles become operationalized in SUD treatment programs:

• Certified peer specialists facilitate a virtual non-12-Step mutual-help group for individuals taking medication for SUDs. The group is free and anonymous.^41^
• Certified peer specialists make follow-up calls and check-ins between program clients’ formal treatment sessions to provide support, encouragement, and connection as well as to provide reminders about upcoming events, meetings, or appointments.
• PSS are regularly included in the discharge referral plan for program clients with executive functioning issues, to increase the likelihood that these clients will attend continuing care appointments and recovery programming.

RESOURCE ALERT: ROLE OF PEER WORKERS IN ADDRESSING THE OVERDOSE CRISIS

Peer workers fill a key role in the SUD treatment workforce—a workforce that faces ever-increasing demands, particularly as the United States continues to experience an epidemic of drug overdose deaths. PSS provide a much-needed expansion of the continuum of care available to address opioid use disorder and other SUDs, while also improving recovery outcomes.

In 2022, the National Council for Mental Wellbeing published Establishing Peer Support Services for Overdose Response: A Toolkit for Health Departments. Although the toolkit is especially relevant for integrating PSS in emergency departments, postoverdose response teams, and mobile outreach teams, it contains useful tips and resources on PSS generally. (https://www.thenationalcouncil.org/wp-content/uploads/2022/03/Establishing-Peer-Support-Services-for-Overdose-Response-Toolkit-7-March-2022-Final.pdf)

THE ROLE OF FAMILY PEER SPECIALISTS IN SUPPORTING FAMILIES AFFECTED BY PROBLEMATIC SUBSTANCE USE

Families directly affect and are affected by a family member's problematic substance use, including their treatment and recovery. Problematic substance use creates significant stress for families in such areas as physical and behavioral health, work and education, finances, and social relationships. Other family members often have needs related to their loved one's treatment and recovery, along with needs of their own. Therefore, recovery support is necessary for not only the individual in or seeking recovery, but also for their entire family.

Family peer specialists can assist families in crisis in getting the information, support, and resources they need. These individuals draw on their knowledge and unique lived experience of caring for a family member with problematic substance use to serve as role models and provide a variety of supports for families. Family peer specialists’ work includes:^42^

• Offering families education and information, including ways to develop skills to better communicate, solve problems, and manage stress.
• Providing ongoing emotional support.
• Helping families access resources for everyday needs.
• Encouraging families to advocate for and with individuals in or seeking recovery.

While family peer specialists can indirectly help the individual in or seeking recovery, family-based peer services focus on the family itself.

Programs are increasingly offering family peer support; however, the field is still emerging and requires additional attention. Chapters 6 and 7 provide more information about the work of family peer specialists, particularly in SUD treatment programs.

## Settings for PSS

Although this TIP focuses on incorporating the peer specialist position into SUD treatment programs, peer specialists serve in many other settings. Knowing about these other settings is useful for:

• SUD treatment providers (including peers) seeking to connect clients to recovery-oriented organizations, especially those with PSS.
• SUD treatment programs seeking to connect with entities using PSS that may refer clients for treatment.
• Peer specialists seeking to connect with others in their field and to pursue professional growth and development.

In addition to RCOs and RCCs, other recovery-oriented settings that typically or often provide PSS include:^43,44^

• Recovery residences, which provide safe housing and opportunities to build social and leadership skills. Most are self-supporting and operate via democratic principles of self-governance (https://www.recoveryanswers.org/resource/recovery-residences/).
• Recovery schools, which include recovery high schools (https://recoveryschools.org/) and collegiate recovery programs (https://collegiaterecovery.org/) that support young people in recovery in academic settings. These programs may offer scholarships, recovery housing, on-campus recovery support groups, recovery coaching, academic mentoring, and substance-free social activities.
• Recovery-friendly workplaces, which are employers with supportive policies and practices for employees in recovery (https://www.opioidlibrary.org/featured_collection/recovery-friendly-workplaces/).
• Recovery cafés, which are spaces where people in recovery can socialize and support each other in a substance-free setting (https://recoverycafenetwork.org/).
• Recovery ministries, which include recovery and recovery-friendly houses of worship, recovery-focused worship services and workshops, recovery pastoring, and mutual-help groups sponsored by houses of worship.^45^

PSS can also be found in:

• Recovery fitness centers and organizations, such as the nonprofit organization The Phoenix.^46^
• Harm reduction agencies, such as syringe services programs.^47^
• Criminal justice settings (e.g., problem-solving courts, pretrial release programs, parole/probation departments, prisons, and jail reentry programs)^48^
• First responder settings^49,50^
• Social service agencies.

## Integration of Peer Positions Into SUD Treatment Settings

In recovery-oriented SUD treatment programs, peer workers play an important role on the staff. They are visible and actively involved with the treatment program's clients and with the program's treatment providers.

Integrating the peer worker position into SUD treatment programs aligns with many programs’ needs or goals to:

• Increase engagement and retention in and adherence to treatment, for better initial and sustained health outcomes.
• Inform people starting treatment about the multiple pathways to recovery.
• Connect individuals with recovery resources early on in treatment.
• Provide more information and support to people transitioning between levels of SUD care.
• Provide support to people transitioning from inpatient SUD treatment to the community and ongoing care.
• Shift from an acute, episodic model of SUD treatment to a long-term, recovery-oriented model.

Exhibit 1.1 lists the defining features of PSS that focus specifically on supporting people with SUDs in their recovery and on supporting their friends and family members.

EXHIBIT 1.1. Defining Features of SUD-Focused PSS^51,52,53^

Essential elements:

• Nonclinical services that engage, educate, and support people with substance use–related problems
• Delivery by individuals who have experience with recovery from problematic substance use
• Interactions that involve—on the part of the peer worker—effective listening and storytelling, strengths-based guidance, and the recognition that recovery exists in a cultural context and has many pathways

Purpose/functions and associated services/activities:

• Engagement: Promote a visible and accessible community presence through outreach and collaboration
• Education: Share knowledge and information about multiple pathways of recovery
• Social support^54^ (Exhibit 2.1 in Chapter 2 contains details on the four types of recovery support.)

RESOURCE ALERT: LEARN MORE ABOUT PSS

These products published by or for the Substance Abuse and Mental Health Services Administration contain more information on PSS:

• What Are Peer Recovery Support Services? (https://store.samhsa.gov/product/What-Are-Peer-Recovery-Support-Services-/SMA09-4454)
• List of peer support resources (https://www.samhsa.gov/brss-tacs/recovery-support-tools/peers)
• Peers Supporting Recovery From Substance Use Disorders (https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peers-supporting-recovery-substance-use-disorders-2017.pdf)
• Peer Recovery Support: Evolving Roles and Settings: A Literature Review (https://peerrecoverynow.org/wp-content/uploads/PeerRecoverySupport-LiteratureReview_Final-Nov2021.pdf)
• Comparative Analysis of State Requirements for Peer Support Specialist Training and Certification in the United States (https://peerrecoverynow.org/about/coe-products.aspx)

## Background and Concepts

### History of PSS

In the mid-19th century, concerns about alcohol problems and the promotion of sobriety as a societal value set the stage not only for the beginnings of SUD treatment in the United States, but also for a range of sobriety-based mutual-help societies, including the Washingtonian Society and the Sons of Temperance.^55,56,57^ Alcoholics Anonymous® (AA), the first 12-Step program and the most well-known mutual-help program, began a century later. Secular and culturally oriented alternatives to AA, Narcotics Anonymous, and other 12-Step programs have developed over time^58,59^ These organizations include LifeRing Secular Recovery,^60^ Secular Organizations for Sobriety (SOS),^61^ Self-Management and Recovery Training (SMART) Recovery®,^62^ Wellbriety,^63^ and Women for Sobriety.^64^

In 1998, the Substance Abuse and Mental Health Services Administration (SAMHSA) initiated the Recovery Community Support Program (RCSP) to support RCOs in their outreach, policy, and education efforts. By 2001, RCSP began more fully integrating PSS modeled after mutual-help activities that characterized AA and other popular 12-Step programs.^65^ Guidance to states issued by the Centers for Medicare & Medicaid Services (CMS) in 2007 on covering PSS under Medicaid,^66^ the Affordable Care Act of 2010, federal legislation addressing the opioid epidemic, other federal initiatives, and recent support from state and local government programs, advocacy organizations, service providers, and other stakeholders have further increased access to PSS.^67,68,69^

### Expanding Definitions of Recovery

Growing acceptance of SUDs as chronic conditions^70^ (much like hypertension, diabetes, or asthma) is transforming the behavioral health field's concept of what it means to have an SUD and what kinds of support people need to address SUDs successfully. The idea of recovery predates the rise of specialty SUD treatment^71^ and is central to peer work and to mutual-help programs like AA and SMART Recovery®^72^.

Working definitions of recovery began to emerge in the literature in the mid-2000s and have been evolving ever since.^73,74,75^ Some definitions focus exclusively on stopping substance use (abstinence). Other definitions extend the concept of recovery to encompass reducing substance use. And some definitions include harm reduction, which recognizes the benefits to the individual of lessening substance use–related risks by, for example, using opioid overdose reversal medication and safer injection practices.^76^ Recovery expert William White included the idea that recovery needs to be actively managed over time.^77^ Nearly all definitions mention making personal changes that promote long-term well-being and support improved quality of life.^78^

After receiving significant stakeholder and public input, SAMHSA in 2012 published 10 guiding principles of recovery and a working definition of recovery that describes it as “a process of change through which individuals improve their health and wellness, live a self-directed life, and strive to reach their full potential.”^79^ The SAMHSA definition undergirds a shared recovery language. SAMHSA in 2012 also set forth four major dimensions of a life in recovery: health, home, purpose, and community.

The definition, principles, and dimensions apply to recovery from mental or substance use disorders, or both. Exhibit 1.2 summarizes SAMHSA's 10 principles.

EXHIBIT 1.2. SAMHSA's 10 Guiding Principles of Recovery

Recovery is a multifaceted process that may look different from one person to the next. The principles emphasize that recovery:

• Is an outgrowth of hope.
• Is person driven and focused on an individual's strengths, needs, and wishes.
• Occurs in many ways, via many paths, and in many forms. There truly is no one “right” way to find, establish, and maintain recovery.
• Is holistic, addressing not just a person's substance use problems but also their physical, emotional, social, and spiritual wellness.
• Includes support from one's peers and other allies.
• Is achieved, at least in part, through one's personal relationships and social network.
• Is shaped and supported by one's culture, values, traditions, and beliefs.
• Requires services and treatments responsive to one's current situation and history of trauma.
• Is built on individual, family, and community strengths, supports, responsibilities, and resources.
• Promotes self-respect, dignity, and self-acceptance.

Source: Image reprinted from material in the public domain. ^ 80 ^

## Recovery Capital

The concept of recovery capital has shifted the thinking about what people with substance use–related problems might need to achieve recovery. “Recovery capital” refers to the quantity and quality of resources available to individuals to initiate and sustain their recovery from problematic substance use. Resources may be internal (e.g., physical health, financial wellness) or external (e.g., social relationships, community, and cultural support), and they can grow.^81,82^ Recovery capital reflects a core belief that everyone has strengths and that building on those strengths is key to achieving and maintaining recovery. Supporting people in identifying, harnessing, and increasing their recovery capital underlies much of what peer workers do.

### Recovery Planning

Recovery planning is largely driven by the program client,^83^ and the focus is future-, wellness-, and sustainability-oriented, although immediate needs and tasks are also addressed. Such planning, which the individual should undertake with the support of a peer worker, includes identifying the individual's recovery capital, needs, and goals, and then brainstorming actions to take. The result of this process is a recovery plan setting out the individual's short- and longer term recovery, wellness, and life goals, with realistic, prioritized steps for working toward them. Ideally, the recovery plan should include SMART goals: Specific, Measurable, Achievable, Relevant, and Time Bound.

Like recovery itself, recovery planning is a continuing and dynamic process. The recovery plan will need revisiting and revising as the individual builds their recovery capital and meets or changes goals, or if new challenges or barriers arise.^84^

Chapter 3 contains more information on recovery plans, including differences between recovery planning and treatment planning.

WHAT IS A RECOVERY-ORIENTED SYSTEM OF CARE?

This TIP will in places refer to a recovery-oriented system of care (ROSC), which is a multisystem, strengths-based, person-centered continuum of care in which a menu of coordinated supports is tailored to individuals’ needs and chosen recovery pathways.^85^ A ROSC's self-defined network can include SUD treatment programs, RCOs, primary healthcare organizations, prevention services, allied service systems, other types of organizations, and individuals. Although an SUD treatment program can offer PSS without becoming part of a ROSC, taking this step can help clients receive better coordinated services and more holistic care.

## Diversity, Equity, Inclusion, and Accessibility

The concept of diversity, equity, inclusion, and accessibility (DEIA) stresses the value and importance of accepting and supporting people of all races, sexual orientations, genders, abilities, religions, ages, and socioeconomic backgrounds, equally and with fair treatment for each person.^86,87^ The components of DEIA are defined as follows:

• Diversity: The characteristics and experiences, both seen and unseen, that make everyone unique^88^
• Equity: Ensuring fair access to opportunities and resources, while taking into consideration individuals’ barriers or privileges and eliminating systemic barriers and privileges^89^
• Inclusion: The actions taken to understand, embrace, and leverage the unique identities and perspectives of all individuals so that all feel welcomed, valued, and supported^90^
• Accessibility: Facilities, information, technology, programs, and services designed so that all people, including people with disabilities, can fully and independently access and use them^91^

SAMHSA's seventh principle of recovery—stating that recovery is shaped and supported by one's culture, values, traditions, and beliefs—reflects the importance of DEIA in treatment and recovery support services.^92^

Peer support services provide an opportunity for SUD treatment programs to promote an inclusive atmosphere in which people with diverse backgrounds and life experiences feel welcome, and to improve clients’ engagement with recovery resources.

Peer workers may have things in common (e.g., age, ethnicity, family experience, gender, sexual orientation, gender identity, co-occurring disorders, prior justice system involvement) with the program participants they support. These shared characteristics and experiences can enhance program participants’ feelings of alliance, trust, confidence, and safety^93,94^ and can increase treatment engagement and other positive outcomes.

The commitment to DEIA involves administrators and supervisors and extends throughout the organization. It includes hiring peer workers who are:

• Representative of the communities the program serves.
• Culturally responsive to program participants.
• Able to provide culturally appropriate PSS in one or more languages spoken by the populations the program serves (besides English).
• Culturally knowledgeable about available resources, including those outside their personal recovery experiences and supports.
• Committed to their own self-awareness and willing to explore any implicit bias around their own cultural identity.

DEIA is a complex, nuanced, and quickly evolving set of concepts. The importance of incorporating DEIA considerations into the delivery of PSS, and behavioral health services more generally, cannot be overstated. However, it is outside the scope of this TIP to provide an indepth discussion of the many facets of DEIA and the ways in which they intersect with, and affect, substance use, recovery, and the services and service systems people seeking recovery may rely on for support.

The consensus panel recommends that peer workers, their supervisors, program administrators, and other SUD treatment program staff engage in ongoing education and professional development activities to strengthen their understanding of and commitment to DEIA. Programs should allow staff to undertake these activities during working hours.

The following Resource Alert provides some useful starting points for learning more about DEIA in the context of peer support and recovery from problematic substance use.

RESOURCE ALERT: TOOLS FOR LEARNING MORE ABOUT DEIA

The concept of DEIA is a rapidly developing and increasingly vital model of care for behavioral health service settings. The following resources will allow peer workers to explore the topic of DEIA more fully and examine the importance of a culturally responsive and informed approach to substance use–related services.

DEI Mission and Definitions

This webpage, produced by Thrive Behavioral Health in Rhode Island, provides expanded definitions of the terms “diversity,” “equity,” and “inclusion” that may be useful to programs and individuals wanting to implement these concepts in their services. (https://www.thrivebhri.org/about-us/diversity-equity-inclusion/dei-mission-and-definitions)

National Association of Addiction Treatment Providers® (NAATP)—Diversity, Equity, Inclusivity, & Belonging (DEIB) Webinars and Events

This webpage features links to recent NAATP webinars on DEIB-related topics, including implementing DEIB, understanding the importance of antiracism in treatment environments, and working with individuals from LGBTQ+ populations. Free webinar videos and related PowerPoint presentations are available on the page. (https://www.naatp.org/resources/dei/webinars-events)

North Star Guide for Recovery Leaders

Faces & Voices of Recovery provides this overview of the key elements for committing to an antiracism stance in a treatment environment. The document focuses on representation and culture shift, advocacy, education, and accountability, with metrics for measuring progress. (https://facesandvoicesofrecovery.org/wp-content/uploads/2021/06/Race-Equity-in-Recovery-North-Star-final-2.pdf)

RESPECT Model

Originally developed in 2002,^95^ this tool helps peer workers and treatment providers remember the key factors to ensure that they engage with people seeking recovery in a culturally and linguistically responsive manner. (https://thinkculturalhealth.hhs.gov/assets/pdfs/resource-library/respect-model.pdf)

## Evolving Ways To Deliver PSS

In recent years, the ways in which peer workers connect with and support people with problematic substance use have expanded. For example, the rapid growth of telehealth, especially during the COVID-19 pandemic, has increased the reach of peer workers. Now they provide PSS to individuals and families who might have difficulty accessing in-person services because of transportation and other barriers,^96^ and they can interact more frequently with the people they already work with.

Although telehealth presents unique challenges, peer workers can successfully fulfill their roles and functions when working virtually.^97^ For example, a 2021 study showed that web-based psychoeducation and peer support for adults with problematic alcohol use led to improved quality of life and reduced alcohol use and craving, symptoms meeting criteria for alcohol use disorder, and use of other substances.^98^ A 2021 pilot study of a peer-supported app for veterans to use to self-manage unhealthy alcohol consumption found that participant feedback on the integration of the app with weekly peer specialist phone support was “uniformly positive.”^99^ The feedback highlighted such benefits of peer involvement as general emotional support, coaching on navigating the app, sharing of lived experience, and encouragement of ongoing use of the app.

Although peer workers have long met with individuals in the community, mobile PSS, with one or more peers working as part of a team, have also become more prevalent. (“Mobile” in this sense refers to using vehicles.) Examples of mobile services that may incorporate PSS include:

• Mobile opioid treatment.
• Mobile outreach programs.
• Mobile crisis units.^100^
• Postoverdose response teams.^101^

## Challenges of Providing PSS Within SUD Treatment Programs

PSS form an increasingly common and important part of the SUD treatment system; however, offering PSS can still have its challenges. For example:

• Sustainable funding for PSS needs the attention of program leadership. Greater availability of grant funding, Medicaid coverage, and even private health insurance reimbursement has made funding PSS more viable. Still, programs need to budget for PSS carefully and be prepared to look to different funding sources, to offer clients a strong PSS component^102^ and to provide fair and stable compensation to peer workers.
• Peer workers can feel confused or unclear about their exact roles and job duties (as can their supervisors and colleagues and program administrators). Developing clearly defined job descriptions that spell out peer workers’ roles can help avoid role strain and role drift. So can educating other staff about peer workers’ roles and providing peer workers with good supervision by individuals who understand the peer worker role.
• Lack of role clarity can lead to ethical and boundary issues. Organizations can address these issues in job descriptions and training for peer workers and other staff, and through peer supervision. Organizations should also have clear ethical guidelines for peer workers, and train peer workers on them to help ensure that the peers operate within their scope of practice.
• SUD treatment program staff may not recognize the value of incorporating PSS into their programs. Organizations aiming to offer PSS should train other program staff on the benefits of PSS to clients.
• Once on the job, peer workers may still experience a lack of acceptance by SUD treatment program staff and a lack of appropriate compensation. This can lead to job dissatisfaction and retention problems among peer workers.^103^ Program leadership needs to ensure respect and fair pay for the peer worker role.

RESOURCE ALERT: MOBILE APPLICATIONS SUPPORTING RECOVERY

Multiple mobile applications (apps) have been developed to support people in their recovery journeys. These apps can supplement the work that people in recovery do with peers and other members of an SUD care team. However, many apps need further study to determine whether they effectively support recovery.^104^

Helpful mobile app features include:

• Educational exercises.
• Motivational messages.
• Messaging functions that allow individuals to connect with others who have lived experience with SUD recovery.
• Accountability support groups or support meeting locators.
• Privacy-enabled dashboards for communication with treatment team members, including peer specialists.
• Journaling to track thoughts, feelings, stressors, substance use triggers, and ways to manage those triggers.
• Clocks, timers, or counters to track abstinence.

Pear reSET^®^ and reSET-O^®^, free apps developed by Pear Therapeutics, were the first prescription apps for SUDs approved by the Food and Drug Administration. Pear reSET® and reSET-O® are suitable for individuals ages 18 and older in outpatient SUD treatment or otherwise under the supervision of a clinical provider. Both apps provide cognitive-behavioral therapy to support other clinical treatment approaches for SUDs, such as contingency management and the use of medication to support recovery. A study suggested that clients who used the app would be more likely to stay in treatment and achieve or maintain abstinence than clients receiving standard care.^105^

The Connections App offers support through a variety of features, including moderated virtual support group meetings and discussion groups, appointment reminders, and 24/7 peer support. One study of the app showed that people who used it after leaving residential treatment for alcohol use disorder reported significantly fewer risky drinking days than those who did not.^106^

SAMHSA's TIP 60, Using Technology-Based Therapeutic Tools in Behavioral Health Services, contains information about technology-based tools. (https://store.samhsa.gov/product/TIP-60-Using-Technology-Based-Therapeutic-Tools-in-Behavioral-Health-Services/SMA15-4924)

Source: Image reprinted with permission from https://peartherapeutics.com/products/reset-reset-o/.

## Conclusion

Peer workers play an important and ever-growing role in supporting individuals with problematic substance use in initiating and sustaining recovery. Integrating the peer worker position into SUD treatment programs and allied service systems and collaborating with community-based recovery organizations can increase clients’ chances of successful treatment and recovery outcomes. Likewise, family members can help loved ones succeed in SUD treatment and recovery by encouraging their use of PSS. Peer services offered by SUD treatment programs supplement PSS provided by RCOs and RCCs.

To integrate the peer worker position into SUD treatment programs successfully, program staff must understand the benefits of PSS and the training and roles of peer workers. Administrators must clearly define the peer position within the program; demonstrate professional respect for the people in these positions and the valuable work they do; and provide for PSS-specific supervision.

The following chapters provide an overview of peer workers’ roles when working with people seeking treatment for or in recovery from problematic substance use; a description of the essential knowledge, values, and skills needed by peer workers; guidance for SUD treatment program administrators and supervisors on implementing PSS; discussion of the considerations and processes involved in becoming a peer specialist; and information on the benefits of family PSS.