# Chapter 3F: Medical Management of Patients Taking OUD Medications in Hospital Settings

Chapter 3F guides the management of patients taking OUD medications in hospital settings. The audience is healthcare professionals in emergency, general medical, surgical, psychiatric, and obstetric units.

Patients with opioid use disorder (OUD) who present to emergency departments (EDs) or are admitted to hospitals for acute medical or psychiatric care can benefit from medication to treat OUD in the hospital setting. During acute medical illness, patients experiencing consequences of opioid use may be motivated to change.^393^ Hospital-based providers can take this opportunity to initiate long-term medication maintenance.^394,395^

Unfortunately, less than one-quarter of patients with an opioid-related hospitalization are offered Food and Drug Administration-approved medication for OUD within 30 days of discharge.^396^ Patients who already take OUD medication may also present to the hospital. Thus, a broad understanding of how to manage their OUD medication during hospitalization is necessary.

The keys to effective patient management in general hospital settings are:

• Balancing medication for OUD with other medical concerns (e.g., surgery, pain management) during hospitalization.
• Careful management after discharge.
• Seamless transfer to opioid treatment via an opioid treatment program (OTP) or office-based opioid treatment (OBOT) provider after discharge.

## Hospitalized or ED Patients Taking Medication for OUD

Buprenorphine, methadone, and naltrexone may be ordered in EDs or inpatient hospital units. It's essential for the patient to continue receiving OUD medication while hospitalized.

### Pain Management

Pain management for hospitalized patients who take OUD medication is a key element of medical management. Discuss pain management and engage in a shared decision-making process with patients being treated for OUD with buprenorphine, methadone, or naltrexone. Patients may have strong preferences and opinions about pain and use of opioid analgesics for pain treatment. Some patients may want to avoid opioid analgesics. For others, inadequately treated pain may be a trigger for illicit drug use. Involve primary care pain specialists and addiction treatment providers in discussing options for managing OUD medication and pain during patient hospitalization.

### Buprenorphine

The hospital team will need to manage buprenorphine for patients who present to the ED or are hospitalized on buprenorphine maintenance. Physicians in inpatient settings can legally order buprenorphine without a waiver if a patient is admitted primarily for other medical reasons.^399^ Key medication management strategies include:

• Obtaining written consent to contact the patient's providers, including:
  - Primary care provider.
  - Buprenorphine prescriber.
  - Pharmacy.
• Confirming the patient's outpatient buprenorphine dose by:
  - Checking prescribing records.
  - Contacting the prescriber or pharmacy.
  - Examining recent prescription bottles.
  - Checking the prescription drug monitoring program database before administering buprenorphine.
• Providing the usual daily dose to the patient, once that dose is confirmed.
• Ensuring the patient's outpatient prescriber understands the reason for any missed visits.
• Informing the patient's outpatient prescriber that the patient may test positive for opioids if treated with opioid analgesics while in the hospital.
• Maintaining contact with the patient's prescriber, especially when a buprenorphine dose change is considered and in discharge planning.

Patients with pain may continue their buprenorphine while in the hospital. For mild-to-moderate pain, dividing the patient's usual buprenorphine dose three times per day (TID) may provide sufficient pain relief.^400^ In some cases, increased buprenorphine dose may be appropriate. For moderate-to-severe pain, additional analgesia will be necessary. Two approaches to consider:

1. Continue buprenorphine treatment and use full agonist opioids for added pain relief. Because of the partial blockade caused by buprenorphine, higher-than-usual doses of opioids will probably be required for pain relief. Fentanyl, hydromorphone, and morphine have relatively high binding affinities for the mu-opioid receptor and are most likely to displace buprenorphine from receptors and provide improved analgesia. Once the painful condition has improved, if mild-to-moderate pain persists, buprenorphine can be divided TID to manage residual pain. This approach is usually successful and allows the patient to remain stable on buprenorphine.
2. Discontinue buprenorphine upon hospitalization and use full agonist opioids to treat pain and prevent withdrawal. This approach avoids the blockade effect of buprenorphine on the mu-opioid receptors but leaves the patient vulnerable to a return to illicit opioid use. It may be useful if the first approach does not achieve adequate pain control.^401^ Consider a consult by an addiction medicine, psychiatric, or pain management provider if appropriate and available.

Pregnant women on buprenorphine can continue buprenorphine through their labor. Labor pain for pregnant patients on buprenorphine can be managed effectively with epidural analgesia or intravenous opioids. Spinal anesthesia is effective in patients on buprenorphine; patients can receive general anesthesia if needed.^402^

Perioperative pain management of patients on buprenorphine requires further study, but multiple approaches have been found effective. Most patients can continue buprenorphine through the operative period. Treat postoperative pain with regional anesthesia, nonopioid pain management, or full agonist opioids. Remember that higher doses are likely to be necessary. Some data suggest that buprenorphine divided TID may even be as effective as morphine for postoperative pain control.^403^ Alternatively, buprenorphine can be discontinued 72 hours before a planned surgery and restarted after resolution of acute postoperative pain. The risk of this approach is that it leaves the patient vulnerable to a return to use of illicit opioids.^404^

### Methadone

The hospital team will need to manage methadone for patients who present to the ED or are hospitalized on methadone maintenance treatment. This includes pregnant women. Generally, only physicians in OTPs can order methadone to treat OUD. However, physicians in an inpatient setting can legally order methadone administration to patients admitted primarily for other reasons.^405^

Contact the patient's OTP directly to confirm the outpatient methadone dose, the last day of dose administration, and whether the patient was dispensed take-home doses (and how many doses) after the last dose administration at the OTP. This is to avoid double dosing and to avoid providing a full dose to a patient who hasn't been to the OTP for several days. Notify the OTP of the patient's admission and discharge so that OTP staff is aware of:

• The patient's upcoming missed visits.
• Medications received during hospitalization.
• Medications prescribed at discharge.

Patients in pain should receive their full usual daily dose of methadone, barring contraindications. This is their baseline dose and should not be considered a dose for pain management.

The expert panel for this Treatment Improvement Protocol (TIP) recommends restarting buprenorphine before discharge when possible, with a proper handoff between inpatient and outpatient providers.

They'll need pain medication in addition to their usual methadone dose. If their condition is painful enough to require opioids, prescribe short-acting opioids as scheduled, not as-needed, treatment. Because these patients are already opioid tolerant, they'll likely require higher doses of opioids than patients without tolerance.^406^ However, as with any patient, use nonopioid multimodal pain management when possible to minimize reliance on opioids and maximize pain control.^407^

CLINICAL CAUTION

##### Do Not Rely Solely on Patient Self-Report of Methadone Dosage

Do not administer the methadone dose based on patient self-report of OTP enrollment and methadone dose; get OTP confirmation. This is important because doses above 30 mg can be lethal if the patient is not currently receiving methadone treatment and has relatively low tolerance to opioids. If it's not possible to confirm the patient's methadone dose because the OTP is closed on nights or weekends and has no emergency contact, up to 20 mg per day can be administered to treat opioid withdrawal symptoms, but monitor for signs of opioid intoxication. If the patient shows no signs of sedation or opioid intoxication 3 to 4 hours after the initial dose and continues to display symptoms of withdrawal, an additional 5 mg to 10 mg may be safe to administer.

It is important to tell patients who receive take-home doses that they should not take their own medication while in the hospital. They will receive methadone from the treatment team. Patients can be asked to lock their take-home medications with their other valuables. It is also important to monitor these patients closely after the initial and subsequent methadone administration in the hospital. Some patients who receive take-home doses do not take their entire dose every day, so they may display signs of intoxication or frank overdose if the hospital staff gives them the full dose.

### Naltrexone

Patients taking oral naltrexone for OUD treatment may continue naltrexone when admitted to the hospital if they do not have and are not at risk for developing a painful condition requiring opioid analgesia. Oral naltrexone provides full blockade of opioid receptors for up to 72 hours. Extended-release injectable naltrexone (XR-NTX) provides measurable naltrexone levels for 1 month or longer. Thus, managing acute pain in patients taking XR-NTX is complicated.

In patients who have taken naltrexone, manage severe pain intensively via nonopioid approaches, such as regional anesthesia or injected nonsteroidal anti-inflammatory drugs.

Naltrexone blockade can be overcome with very high doses of opioids, but patients must be closely monitored for respiratory depression in a setting with anesthesia services. This is especially true upon discontinuation of oral naltrexone, which dissociates from opioid receptors.

## Hospitalized or ED Patients Not Taking Medication for OUD

Patients with OUD who present to the ED or are admitted to the hospital for an acute medical problem may benefit from initiating medications for OUD during their hospitalization. A thoughtful and respectful discussion of treatment options and patient-centered provision of medication can be a critical entry point into care. Research supports the efficacy of initiating either buprenorphine or methadone during acute hospital stays^408,409^ and starting patients on buprenorphine in the ED.^410^

### Buprenorphine Induction in the Hospital Setting

Patients admitted to the hospital for medical conditions incident to OUD can undergo medically supervised withdrawal or receive buprenorphine maintenance treatment during their inpatient stay.^411^ It is important to adequately address opioid withdrawal because hospital patients may otherwise sign out against medical advice or use illicit opioids in the hospital. Buprenorphine can also be initiated for maintenance treatment if there is a system in place that allows smooth and reliable discharge to an outpatient buprenorphine prescriber. Unlike methadone, a several-day delay between discharge and the first visit to the outpatient provider is acceptable for stable patients, as long as sufficient medication is provided until the patient begins outpatient treatment. The prescription for medication to be taken outside the hospital must be written by a prescriber with a buprenorphine waiver. If there is no prescriber with a waiver, it is possible to have a patient return to the hospital ED or a clinic within the hospital to have the buprenorphine dose administered by a physician (who does not need to be waivered) for up to 3 days.

To provide continuity of care at discharge, use these strategies:

• Develop and maintain a network of local buprenorphine prescribers and other drug treatment providers.
• Discharge patients directly to a specific outpatient prescriber for stabilization and maintenance after inpatient buprenorphine induction.
• Send discharge information directly to the outpatient prescriber, including treatment course, medications administered, and medications prescribed.

To initiate buprenorphine during hospitalization:

• Confirm that there are no contraindications to buprenorphine before initiation.
• Discontinue opioids for pain management only when no longer needed and the patient is stable enough to tolerate withdrawal.
• Wait for patients to develop opioid withdrawal symptoms.
• Initiate buprenorphine treatment.
• Individualize buprenorphine dosing.
• Follow the dosing guidance found in Chapter 3D of this TIP.

A clinical trial found that starting buprenorphine in the ED to treat OUD was more effective in linking patients to buprenorphine treatment in the community than were two other approaches without medication.^412^ When patients presented in opioid withdrawal, they received 8 mg of buprenorphine in the ED. Patients who were not in withdrawal received a detailed self-medication guide and were provided buprenorphine for an unobserved home induction. In both cases, patients were given sufficient buprenorphine to take 16 mg per day at home until they could see an outpatient prescriber within 72 hours. Close follow-up with an outpatient buprenorphine prescriber was critical for dose stabilization and ongoing medication management.

### Methadone Induction in the Hospital Setting

Offer to treat hospitalized patients in opioid withdrawal with methadone (or buprenorphine) maintenance if they can continue the medication in an OTP seamlessly after discharge. Do not start patients on methadone maintenance in the hospital without a clear follow-up plan. Form relationships with local OTPs that allow discharging of patients directly into methadone maintenance treatment.

RESOURCE ALERT

##### Telehealth Tools for the Treatment of OUD

The Substance Abuse and Mental Health Services Administration and other federal agencies have developed numerous resources to guide healthcare professionals in their use of telehealth and telemedicine approaches for OUD. These resources include information on:

• Guidance on the use of telemedicine in OTPs (https://store.samhsa.gov/product/Federal-Guidelines-for-Opioid-Treatment-Programs/PEP15-FEDGUIDEOTP).
• The policies that must be put in place (to comply with the Controlled Substances Act) by physicians who wish to use telehealth in treating patients with buprenorphine for OUD under the Drug Addiction Treatment Act of 2000. Federal (and sometimes state) restrictions apply, which can be reviewed by accessing 21 USC § 802 (www.gpo.gov/fdsys/pkg/USCODE-2011-title21/pdf/USCODE-2011-title21-chap13-subchapI-partA-sec802.pdf).
• Centers for Medicare and Medicaid guidance on telehealth (www.cms.gov/Medicare/Medicare-General-Information/Telehealth/index.html).
• Challenges and opportunities in using telehealth for rural populations (https://store.samhsa.gov/product/In-Brief-Rural-Behavioral-Health-Telehealth-Challenges-and-Opportunities/SMA16-4989).
• How certified community behavioral health clinics can use telehealth approaches to expand their services (www.samhsa.gov/section-223/care-coordination/telehealth-telemedicine).

The TIP expert panel urges providers not to force patients to withdraw from opioid agonist treatment in the hospital, especially if they have acute illness, pain, or a mental illness.

Inpatient methadone inductions should follow the same “start low, go slow” principles that outpatient inductions do (see Chapter 3B of this TIP). The initial dose should be from 10 mg to 20 mg per day. Increase slowly by 5 mg every few days in response to symptoms of opioid withdrawal and level of sedation at the peak plasma level 2 to 4 hours after dosing.

### Naltrexone Induction in the Hospital Setting

Consider XR-NTX initiation for patients who complete withdrawal in the hospital and are opioid free for 7 days (short acting) and up to 14 days (long acting). Only do so if:

• There are no contraindications (such as the need for opioid analgesia).
• The patient prefers it after a risk/benefit discussion that covers alternative treatments.
• There are available follow-up opportunities for ongoing medication maintenance upon discharge.

No published data indicate this approach's effectiveness.

If a patient desires and gives informed consent for medically supervised withdrawal and XR-NTX initiation while in the hospital, a first dose of naltrexone can be given before discharge. As with other medications for OUD, discharge coordination is critical. Hospitals that develop XR-NTX induction protocols need to have a clear discharge plan in place for patients who will then need to continue treatment in the outpatient setting. Patients should be advised about the risk of overdose if return to opioid use occurs after discontinuing treatment.

## Medical Management Plan

The key to effective treatment is to involve patients and all treating healthcare professionals in developing a comprehensive plan for managing treatment with OUD medication during and after hospitalization. This plan should include:

• Strategies for pain management (if required).
• In-hospital dosing procedures.
• Postdischarge coordination of care with outpatient programs and outpatient providers.

This plan ensures effective pain relief as well as continuity of ongoing care for patients taking medication for OUD.^413^

## Notes

1 Department of Health and Human Services. (2016). The opioid epidemic: By the numbers. Washington, DC: Author.
2 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved April 28, 2021, from www.samhsa.gov/data/
3 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
4 Weiss, A. J., Elixhauser, A., Barrett, M. L., Steiner, C. A., Bailey, M. K., & O'Malley, L. (2017, January). Opioid-related inpatient stays and emergency department visits by state, 2009-2014. HCUP Statistical Brief No. 219. Rockville, MD: Agency for Healthcare Research and Quality.
5 Agency for Healthcare Research and Quality. (2020). Rate of opioid-related ED visits per 100,000 population. Retrieved April 28, 2021, from www.hcup-us.ahrq.gov/faststats/OpioidUseMap?setting=ED
6 American Society of Addiction Medicine. (2011). Definition of addiction. Chevy Chase, MD: American Society of Addiction Medicine. Retrieved January 5, 2018, from www.asam.org/resources/definition-of-addiction
7 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
8 Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
9 Substance Abuse and Mental Health Services Administration. (2016). Pocket guide: Medication-assisted treatment of opioid use disorder. HHS Publication No. (SMA) 16-4892PG. Rockville, MD: Substance Abuse and Mental Health Services Administration.
10 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
11 Kreek, M. J., Borg, L., Ducat, E., & Ray, B. (2010). Pharmacotherapy in the treatment of addiction: Methadone. Journal of Addictive Diseases, 29(2), 200–216.20407977
12 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
13 World Health Organization. (2015). 19th WHO model list of essential medicines. Geneva, Switzerland: Author.
14 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
15 Sees, K. L., Delucchi, K. L., Masson, C., Rosen, A., Clark, H. W., Robillard, H., … Hall, S. M. (2000). Methadone maintenance vs 180-day psychosocially enriched detoxification for treatment of opioid dependence: A randomized controlled trial. JAMA, 283(10), 1303–1310.10714729
16 Nielsen, S., Larance, B., Degenhardt, L., Gowing, L., Kehler, C., & Lintzeris, N. (2016). Opioid agonist treatment for pharmaceutical opioid dependent people. Cochrane Database of Systematic Reviews, 2016(5), 1–61.
17 Stoller, K. B., Stephens, M. A. C., & Schorr, A. (2016). Integrated service delivery models for opioid treatment programs in an era of increasing opioid addiction, health reform, and parity. Retrieved October 16, 2017, from www.aatod.org/wp-content/uploads/2016/07/2nd-Whitepaper-.pdf
18 Comer, S. D., Sullivan, M. A., Yu, E., Rothenberg, J. L., Kleber, H. D., Kampman, K., … O'Brien, C. P. (2006). Injectable, sustained-release naltrexone for the treatment of opioid dependence: A randomized, placebo-controlled trial. Archives of General Psychiatry, 63(2), 210–218.16461865
19 Krupitsky, E., Nunes, E. V., Ling, W., Illeperuma, A., Gastfriend, D. R., & Silverman, B. L. (2011). Injectable extended-release naltrexone for opioid dependence: A double-blind, placebo-controlled, multicentre randomised trial. Lancet, 377(9776), 1506–1513.21529928
20 Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. A., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.
21 American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
22 Lee, J. D., McDonald, R., Grossman, E., McNeely, J., Laska, E., Rotrosen, J., & Gourevitch, M. N. (2015). Opioid treatment at release from jail using extended-release naltrexone: A pilot proof-of-concept randomized effectiveness trial. Addiction, 110(6), 1008–1014.25703440
23 Leslie, D. L., Milchak, W., Gastfriend, D. R., Herschman, P. L., Bixler, E. O., Velott, D. L., & Meyer, R. E. (2015). Effects of injectable extended-release naltrexone (XR-NTX) for opioid dependence on residential rehabilitation outcomes and early follow-up. American Journal on Addictions, 24(3), 265–270.
24 Sullivan, M. A., Garawi, F., Bisaga, A., Comer, S. D., Carpenter, K., Raby, W. N., … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 91(2-3), 289–292.17681716
25 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
26 World Health Organization. (2015). 19th WHO model list of essential medicines. Geneva, Switzerland: Author.
27 Jaffe, J. H., & O'Keeffe, C. (2003). From morphine clinics to buprenorphine: Regulating opioid agonist treatment of addiction in the United States. Drug and Alcohol Dependence, 70(2 Suppl.), S3–S11.12738346
28 Department of Health and Human Services. (2021, April 28). Practice guidelines for the administration of buprenorphine for treating opioid use disorder. HHS Notice, 86 Fed. Reg. 22439. Retrieved May 21, 2021, from www.federalregister.gov/documents/2021/04/28/2021-08961/practice-guidelines-for-the-administration-of-buprenorphine-for-treating-opioid-use-disorder#:~:text=The%20Practice%20Guidelines%20for%20the%20Administration%20of%20Buprenorphine,counseling%20and%20other%20ancillary%20services%20%28i.e.%2C%20psychosocial%20services%29
29 Ling, W., Casadonte, P., Bigelow, G., Kampman, K. M., Patkar, A., Bailey, G. L., … Beebe, K. L. (2010). Buprenorphine implants for treatment of opioid dependence: A randomized controlled trial. JAMA, 304(14), 1576–1583.20940383
30 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
31 Kinlock, T. W., Gordon, M. S., Schwartz, R. P., Fitzgerald, T. T., & O'Grady, K. E. (2009). A randomized clinical trial of methadone maintenance for prisoners: Results at twelve-months post-release. Journal of Substance Abuse Treatment, 37(3), 277–285.19339140
32 McKenzie, M., Zaller, N., Dickman, S. L., Green, T. C., Parihk, A., Friedmann, P. D., & Rich, J. D. (2012). A randomized trial of methadone initiation prior to release from incarceration. Substance Abuse, 33(1), 19–29.22263710
33 Gordon, M. S., Kinlock, T. W., Schwartz, R. P., O'Grady, K. E., Fitzgerald, T. T., & Vocci, F. J. (2017). A randomized trial of buprenorphine for prisoners: Findings at 12-months post-release. Drug and Alcohol Dependence, 172, 34–42.28107680
34 Vocci, F. J., Schwartz, R. P., Wilson, M. E., Gordon, M. S., Kinlock, T. W., Fitzgerald, T. T., O'Grady, K. E., & Jaffe, J. H. (2015). Buprenorphine dose induction in non-opioid-tolerant pre-release prisoners. Drug and Alcohol Dependence, 156, 133–138.26409751
35 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
36 Binder, T., & Vavrinková, B. (2008). Prospective randomised comparative study of the effect of buprenorphine, methadone and heroin on the course of pregnancy, birthweight of newborns, early postpartum adaptation and course of the neonatal abstinence syndrome (NAS) in women followed up in the outpatient department. Neuro Endocrinology Letters, 29(1), 80–86.18283247
37 Fajemirokun-Odudeyi, O., Sinha, C., Tutty, S., Pairaudeau, P., Armstrong, D., Phillips, T., & Lindow, S. W. (2006). Pregnancy outcome in women who use opiates. European Journal of Obstetrics & Gynecology and Reproductive Biology, 126(2), 170–175.16202501
38 Stimmel, B., & Adamsons, K. (1976). Narcotic dependency in pregnancy. Methadone maintenance compared to use of street drugs. JAMA, 235, 1121–1124.946208
39 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
40 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
41 American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711.
42 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
43 American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711.
44 American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
45 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2). CD002207.
46 Lee, J. D., Nunes, E. V., Jr., Novo, P., Bachrach, K., Bailey, L., Bhatt, S., … Rotrosen, J. (2018). Comparative effectiveness of extended-release naltrexone versus buprenorphine-naloxone for opioid relapse prevention (X:BOT): A multicentre, open-label, randomised controlled trial. Lancet, 397(10118), 309–318.
47 Tanum, L., Solli, K. K., Latif, Z. E., Benth, J. S., Opheim, Α., Sharma-Haase, K. … Kunoe, N. (2017). The effectiveness of injectable extended-release naltrexone vs daily buprenorphine-naloxone for opioid dependence: A randomized clinical noninferiority trial. JAMA Psychiatry, 74(12), 1197–1205.29049469
48 Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
49 Sees, K. L., Delucchi, K. L., Masson, C., Rosen, Α., Clark, W., Robillard, H. … Hall, S. M. (2000). Methadone maintenance vs 180-day psychosocial enriched detoxification for treatment of opioid dependence: A randomized controlled trial. JAMA, 283(10), 1303–1310.10714729
50 Weiss, R. D., Potter, J. S., Fiellin, D. Α., Byrne, M., Connery, H. S., Dickinson, W. … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
51 Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. Α., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.
52 Gowing, L., Ali, R., White, J. M. & Mbewe, D. (2017). Buprenorphine for managing opioid withdrawal. Cochrane Database of Systematic Reviews, 2017(2). CD002025.
53 Degenhardt, L., Randall, D., Hall, W., Law, M., Butler, T., & Burns, L. (2009). Mortality among clients of a state-wide opioid pharmacotherapy program over 20 years: Risk factors and lives saved. Drug and Alcohol Dependence, 705(1-2), 9–15.
54 Hser, Y. I., Huang, D., Saxon, A. J., Woody, G., Moskowitz, A. L., Matthews, A. G. & Ling, W. (2017). Distinctive trajectories of opioid use over an extended follow-up of patients in a multisite trial on buprenorphine + naloxone and methadone. Journal of Addiction Medicine, 77(1), 63–69.
55 Novick, D. M., Salsitz, Ε. Α., Joseph, H. & Kreek, M. J. (2015). Methadone medical maintenance: An early 21st-century perspective. Journal of Addictive Diseases, 34(2-3), 226–237.26110221
56 Fiellin, D. Α., Moore, Β. Α., Sullivan, L. E., Becker, W. C., Pantalon, M. V., Chawarski, M. C., … Schottenfeld, R. S. (2008). Long-term treatment with buprenorphine/naloxone in primary care: Results at 2-5 years. American Journal on Addictions, 17(2), 116–120.
57 Krupitsky, E., Nunes, E. V., Ling, W., Gastfriend, D. R., Memisoglu, Α., & Silverman, B. L. (2013). Injectable extended-release naltrexone (XR-NTX) for opioid dependence: long-term safety and effectiveness. Addiction, 108(9), 162–1637.
58 Kreek, M. J., Levran, O., Reed, B., Schlussman, S. D., Zhou, Y., & Butelman, E. R. (2012). Opiate addiction and cocaine addiction: Underlying molecular neurobiology and genetics. Journal of Clinical Investigation, 722(10), 3387–3393.
59 Volkow, N. D., Koob, G. F., & McLellan, A. T. (2016). Neurobiologie advances from the brain disease model of addiction. New England Journal of Medicine, 374(4), 363–371.
60 Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., … Bilangi, R. (2009). Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
61 Senay, E. C., Dorus, W. & Thornton, W. (1977). Withdrawal from methadone maintenance: Rate of withdrawal and expectation. Archives of General Psychiatry, 34(3), 361–367.843188
62 Sigmon, S. C., Dunn, K. E., Saulsgiver, K., Patrick, M. E., Badger, G. J., Heil, S. H., … Higgins, S. T. (2013). A randomized, double-blind evaluation of buprenorphine taper duration in primary prescription opioid abusers. JAMA Psychiatry, 70(12), 1347–1354.24153411
63 Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
64 Fullerton, C. Α., Kim, M., Thomas, C. P., Lyman, D. R., Montejano, L. B., Dougherty, R. H., … Delphin-Rittmon, M. E. (2014). Medication-assisted treatment with methadone: Assessing the evidence. Psychiatric Services, 65(2), 146–157.24248468
65 Weiss, R. D., Potter, J. S., Fiellin, D. Α., Byrne, M., Connery, H. S., Dickinson, W. … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
66 Amato, L., Davoli, M., Minozzi, S., Ferroni, E., Ali, R., & Ferri M. (2013). Methadone at tapered doses for the management of opioid withdrawal. Cochrane Database of Systematic Reviews, 2013(2). CD003409.
67 Weiss, R. D., Potter, J. S., Fiellin, D. A., Byrne, M., Connery, H. S., Dickinson, W., … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
68 Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., & Bilangi, R. (2009). Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
69 Amato, L., Minozzi, S., Davoli, M., & Vecchi, S. (2011). Psychosocial and pharmacological treatments versus pharmacological treatments for opioid detoxification. Cochrane Database of Systematic Reviews, 2011(9). CD005031.
70 Nunes, E. V., Gordon, M., Friedmann, P. D., Fishman, M. J., Lee, J. D., Chen, D. T., … O'Brien, C. P. (2018). Relapse to opioid use disorder after inpatient treatment: Protective effect of injection naltrexone. Journal of Substance Abuse Treatment, 85, 49–55.28473233
71 Satoh, M., & Minami, M. (1995). Molecular pharmacology of the opioid receptors. Pharmacology & Therapeutics, 68(3), 343–364.8788562
72 Akbarali, H. I., Inkisar, A., & Dewey, W. L. (2014). Site and mechanism of morphine tolerance in the gastrointestinal tract. Neurogastroenterology and Motility, 26(10), 1361–1367.25257923
73 Bodnar, R. J. (2017). Endogenous opiates and behavior, 2015. Peptides, 88, 126–188.28012859
74 Johnson, R. E., Strain, E. C., & Amass, L. (2003). Buprenorphine: How to use it right. Drug and Alcohol Dependence, 70(Suppl.), S59–S77.12738351
75 Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 2011(2). CD001333.
76 Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
77 Kreek, M. J., Borg, L., Ducat, E., & Ray, B. (2010). Pharmacotherapy in the treatment of addiction: Methadone. Journal of Addictive Diseases, 29(2), 200–216.20407977
78 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
79 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
80 Degenhardt, L., Randall, D., Hall, W., Law, M., Butler, T., & Burns, L. (2009). Mortality among clients of a state-wide opioid pharmacotherapy program over 20 years: Risk factors and lives saved. Drug and Alcohol Dependence, 105(1-2), 9–15.19608355
81 Metzger, D. S., Woody, G. E., McLellan, A. T., O'Brien, C. P., Druley, P., Navaline, H., … Abrutyn, E. J. (1993). Human immunodeficiency virus seroconversion among intravenous drug users in-and out-of-treatment: An 18-month prospective follow-up. Journal of Acquired Immune Deficiency Syndromes, 6(9), 1049–1056.8340896
82 Ball, J. C., & Ross, A. (1991). The effectiveness of methadone maintenance treatment. New York, NY: Springer Verlag.
83 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2). CD002207.
84 Walsh, S. L., & Strain, E. C. (2006). Pharmacology of methadone. In E. C. Strain & M. L. Stitzer (Eds.), The treatment of opioid dependence (pp. 59–76). Baltimore, MD: John Hopkins University Press.
85 Mallinckrodt Pharmaceuticals. (2017). Label: Methadose - methadone hydrochloride concentrate; Methadose sugar-free-methadone hydrochloride concentrate. Retrieved January 9, 2018, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=808a9d0b-720b-4034-a862-5122ff514608
86 Walsh, S. L., & Strain, E. C. (2006). Pharmacology of methadone. In E. C. Strain & M. L. Stitzer (Eds.), The treatment of opioid dependence (pp. 59–76). Baltimore, MD: John Hopkins University Press.
87 Payte, J. T., & Zweben, J. E. (1998). Opioid maintenance therapies. In A. W. Graham, T. K. Schultz, & B. B. Wilford (Eds.), Principles of addiction medicine (pp. 557–570). Chevy Chase, MD: American Society of Addiction Medicine.
88 Eap, C. B., Buclin, T., & Baumann, P. (2002). Interindividual variability of the clinical pharmacokinetics of methadone: Implications for the treatment of opioid dependence. Clinical Pharmacokinetics, 41(14), 1153–1193.12405865
89 Mallinckrodt Pharmaceuticals. (2017). Label: Methadose - methadone hydrochloride concentrate; Methadose sugar-free-methadone hydrochloride concentrate. Retrieved January 9, 2018, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=808a9d0b-720b-4034-a862-5122ff514608
90 Oda, Y., & Kharasch, E. D. (2001). Metabolism of methadone and levo-alpha-acetylmethadol (LAAM) by human intestinal cytochrome P450 3A4 (CYP3A4): Potential contribution of intestinal metabolism to presystemic clearance and bioactivation. Journal of Pharmacology and Experimental Therapeutics, 298(3), 1021–1032.
91 Eap, C. B., Buclin, T., & Baumann, P. (2002). Interindividual variability of the clinical pharmacokinetics of methadone: Implications for the treatment of opioid dependence. Clinical Pharmacokinetics, 41(14), 1153–1193.12405865
92 Eap, C. B., Buclin, T., & Baumann, P. (2002). Interindividual variability of the clinical pharmacokinetics of methadone: Implications for the treatment of opioid dependence. Clinical Pharmacokinetics, 41(14), 1153–1193.12405865
93 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
94 Federal opioid treatment standards, 42 CFR § 8.12 (2015).
95 Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.
96 Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
97 Food and Drug Administration. (2016, March). FDA Drug Safety Communications, FDA urges caution about withholding opioid addiction medications from patients taking benzodiazepines or CNS depressant: Careful medication management can reduce risks. Retrieved January 3, 2018, from www.fda.gov/downloads/Drugs/DrugSafety/UCM576377.pdf
98 Lintzeris, N., & Nielsen, S. (2010). Benzodiazepines, methadone and buprenorphine: Interactions and clinical management. American Journal on Addictions, 19(1), 59–72.
99 Bart, G., Wyman, Z., Wang, Q., Hodges, J. S., Karim, R., & Bart, B. A. (2017). Methadone and the QTc interval: Paucity of clinically significant factors in a retrospective cohort. Journal of Addiction Medicine, 11(6), 489–493.28863009
100 Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.
101 Bednar, M. M., Harrigan, E. P., & Ruskin, J. N. (2002). Torsades de pointes associated with nonantiarrhythmic drugs and observations on gender and QTc. American Journal of Cardiology, 89(11), 1316–1319.
102 Al-Khatib, S. M., LaPointe, N. M. A., Kramer, J. M., & Califf, R. M. (2003). What clinicians should know about the QT interval. JAMA, 289(16), 2120–2127.12709470
103 Martin, J. A., Campbell, A., Killip, T., Kotz, M., Krantz, M. J., Kreek, M. J., … Wilford, B. B. (2011). QT interval screening in methadone maintenance treatment: Report of a SAMHSA expert panel. Journal of Addictive Diseases, 30(4), 283–306.22026519
104 Bazett, H. C. (1997). An analysis of the time-relations of electrocardiograms. Annals of Noninvasive Electrocardiology, 2(2), 177–194.
105 Martin, J. A., Campbell, A., Killip, T., Kotz, M., Krantz, M. J., Kreek, M. J., … Wilford, B. B. (2011). QT interval screening in methadone maintenance treatment: Report of a SAMHSA expert panel. Journal of Addictive Diseases, 30(4), 283–306.22026519
106 Mallinckrodt Pharmaceuticals. (2015). Methadose™ dispersible tablets, 40 mg (Methadone hydrochloride tablets for oral suspension USP), CII - Generic products. Retrieved October 16, 2017, from https://dailymed.nlm.nih.gov/dailymed/archives/fdaDrugInfo.cfm?archiveid=8731
107 Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.
108 Krantz, M. J., Martin, J., Stimmel, B., Mehta, D., & Haigney, M. C. (2009). QTc interval screening in methadone treatment. Annals of Internal Medicine, 150(6), 387–395.19153406
109 Bart, G., Wyman, Z., Wang, Q., Hodges, J. S., Karim, R., & Bart, B. A. (2017). Methadone and the QTc interval: Paucity of clinically significant factors in a retrospective cohort. Journal of Addiction Medicine, 11(6), 489–493.28863009
110 Pani, P. P., Trogu, E., Maremmani, I., & Pacini, M. (2013). QTc interval screening for cardiac risk in methadone treatment of opioid dependence. Cochrane Database of Systematic Reviews, 2013(6). CD008939.
111 Martin, J. A., Campbell, A., Killip, T., Kotz, M., Krantz, M. J., Kreek, M. J., … Wilford, B. B. (2011). QT interval screening in methadone maintenance treatment: Report of a SAMHSA expert panel. Journal of Addictive Diseases, 30(4), 283–306.22026519
112 Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.
113 Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.
114 Jones, H. E., Dengler, E., Garrison, A., O'Grady, K. E., Seashore, C., Horton, E., … Thorp, J. (2014). Neonatal outcomes and their relationship to maternal buprenorphine dose during pregnancy. Drug and Alcohol Dependence, 134, 414–417.24290979
115 Cleary, B. J., Reynolds, K., Eogan, M., O'Connell, M. P., Fahey, T., Gallagher, P. J., … Murphy, D. J. (2014). Methadone dosing and prescribed medication use in a prospective cohort of opioid-dependent pregnant women. Addiction, 108(4), 762–770.
116 Kaltenbach, K., Holbrook, A. M., Coyle, M. G., Heil, S. H., Salisbury, A. L., Stine, S. M., … Jones, H. E. (2012). Predicting treatment for neonatal abstinence syndrome in infants born to women maintained on opioid agonist medication. Addiction, 107(Suppl. 1), 45–52.
117 Food and Drug Administration. (2016, March). FDA Drug Safety Communication: FDA warns about several safety issues with opioid pain medicines; requires label changes.
118 McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.
119 Martin, J., Zweben, J. E., & Payte, J. T. (2014). Opioid maintenance treatment. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), The ASAM principles of addiction medicine (5th ed., pp. 759–777). Philadelphia, PA: Wolters Kluwer Health.
120 Saxon, A. J., & Miotto, K. (2011). Methadone maintenance. In P. Ruiz & E. Strain (Eds.), Lowinson and Ruiz's substance abuse: A comprehensive textbook (5th ed., pp. 419–436). Philadelphia, PA: Wolters Kluwer Health.
121 McCance-Katz, E. F., Rainey, P. M., Jatlow, P., & Friedland, G. (1998). Methadone effects on zidovudine disposition (AIDS Clinical Trials Group 262). Journal of Acquired Immune Deficiency Syndromes and Human Retrovirology, 18(5), 435–443.9715839
122 World Health Organization. (2009). Guidelines for the psychosocially assisted pharmacological treatment of opioid dependence. Geneva, Switzerland: WHO Press.
123 American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711.
124 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
125 U.S. Preventive Services Task Force. (2019). Final Recommendation Statement on Human Immunodeficiency Virus (HIV) Infection: Screening. Retrieved June 11, 2019, from www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/human-immunodefìiency-virus-hiv-infection-screening
126 Centers for Disease Control and Prevention. Testing Recommendations for Hepatitis C Virus Infection. October 15, 2015. Retrieved from www.cdc.gov/hepatitis/hcv/guidelinesc.htm
127 Centers for Disease Control and Prevention. (2016). Viral hepatitis. Retrieved December 1, 2017, from www.cdc.gov/hepatitis/hbv/bfaq.htm
128 Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
129 McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.
130 Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
131 Jones, H. E. (2004). Practical considerations for the clinical use of buprenorphine. Science and Practice Perspectives, 2(2), 4–20.18552728
132 Vocci, F. J., Schwartz, R. P., Wilson, M. E., Gordon, M. S., Kinlock, T. W., Fitzgerald, T. T., … Jaffe, J. H. (2015). Buprenorphine dose induction in non-opioid-tolerant pre-release prisoners. Drug and Alcohol Dependence, 156, 133–138.26409751
133 Kinlock, T. W., Gordon, M. S., Schwartz, R. P., & O'Grady, K. E. (2008). A study of methadone maintenance for male prisoners: 3-month postrelease outcomes. Criminal Justice and Behavior, 35(1), 34–47.18612373
134 Martin, J., Zweben, J. E., & Payte, J. T. (2014). Opioid maintenance treatment. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), The ASAM principles of addiction medicine (5th ed., pp. 759–777). Philadelphia, PA: Wolters Kluwer.
135 Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
136 Center for Substance Abuse Treatment. (1993). State methadone treatment guidelines. HHS Publication No. (SMA) 93-1991. Rockville, MD: Substance Abuse and Mental Health Services Administration.
137 Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.
138 Gowing, L., Ali, R., Dunlop, A., Farrell, M., & Lintzeris, N. (2014). National guidelines for medication-assisted treatment of opioid dependence. Retrieved January 4, 2018, from www.health.gov.au/sites/default/files/national-guidelines-for-medication-assisted-treatment-of-opioid-dependence.pdf
139 Leavitt, S. B., Shinderman, M., Maxwell, S., Eap, C. B., & Paris, P. (2000). When “enough” is not enough: New perspectives on optimal methadone maintenance dose. Mount Sinai Journal of Medicine, 67(5-6), 404–411.11064491
140 Payte, J. T. (2002). Opioid agonist treatment of addiction. Slide presentation at ASAM Review Course in Addiction Medicine.
141 Leavitt, S. B. (2003). The methadone dose debate continues. Addiction Treatment Forum, 12(1), 13.
142 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
143 Benmebarek, M., Devaud, C., Gex-Fabry, M., Powell Golay, K., Brogli, C., Baumann, P., … Eap, C. B. (2004). Effects of grapefruit juice on the pharmacokinetics of the enantiomers of methadone. Clinical Pharmacology and Therapeutics, 76(1), 55–63.15229464
144 Drozdick, J., III, Berghella, V., Hill, M., & Kaltenbach, K. (2002). Methadone trough levels in pregnancy. American Journal of Obstetrics and Gynecology, 187(5), 1184–1188.12439500
145 Leavitt, S. B., Shinderman, M., Maxwell, S., Eap, C. B., & Paris, P. (2000). When “enough” is not enough: New perspectives on optimal methadone maintenance dose. Mount Sinai Journal of Medicine, 67(5-6), 404–411.11064491
146 Hallinan, R., Ray, J., Byrne, A., Agho, K., & Attia, J. (2006). Therapeutic thresholds in methadone maintenance treatment: A receiver operating characteristic analysis. Drug and Alcohol Dependence, 81, 129–136.16026938
147 Stine, S. M., & Kosten, T. R. (2014). Pharmacologic interventions for opioid dependence. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), The ASAM principles of addiction medicine (5th ed., pp. 745–758). Philadelphia, PA: Wolters Kluwer.
148 Drozdick, J., III, Berghella, V., Hill, M., & Kaltenbach, K. (2002). Methadone trough levels in pregnancy. American Journal of Obstetrics and Gynecology, 187(5), 1184–1188.12439500
149 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
150 Food and Drug Administration. (2008). Methadose™ oral concentrate. Retrieved October 16, 2017, from www.accessdata.fda.gov/drugsatfdadocs/label/2008/017116s021lbl.pdf
151 Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
152 Stitzer, M. L., Iguchi, M. Y., & Felch, L. J. (1992). Contingent take-home incentive: Effects on drug use of methadone maintenance patients. Journal of Consulting and Clinical Psychology, 60(6), 927–934.1460154
153 Gwin Mitchell, S., Kelly, S. M., Brown, B. S., Schacht Reisinger, H., Peterson, J. A., Ruhf, A., … Schwartz, R. P. (2009). Uses of diverted methadone and buprenorphine by opioid-addicted individuals in Baltimore, Maryland. American Journal on Addictions, 18(5), 346–355.
154 Vlahov, D., O'Driscoll, P., Mehta, S. H., Ompad, D. C., Gern, R., Galai, N., & Kirk, G. D. (2007). Risk factors for methadone outside treatment programs: Implications for HIV treatment among injection drug users. Addiction, 102(5), 771–777.17506154
155 Timko, C., Schultz, N. R., Cucciare, M. A., Vittorio, L., & Garrison-Diehn, C. (2016). Retention in medication-assisted treatment for opiate dependence: A systematic review. Journal of Addictive Diseases, 35(1), 22–35.26467975
156 Woody, G. E., Kane, V., Lewis, K., & Thompson, R. (2007). Premature deaths after discharge from methadone maintenance: A replication. Journal of Addiction Medicine, 1(4), 180–185.21768955
157 Sordo, L., Barrio, G., Bravo, M. J., Indave, I., Degenhardt, L., Wiessing, L., Ferri, M., & Pastor-Barriuso, R. (2017). Mortality risk during and after opioid substitution treatment: Systematic review and meta-analysis of cohort studies. BMJ, 357, j1550.28446428
158 Gibson, A., Degenhardt, L., Mattick, R. P., Ali, R., White, J., & O'Brien, S. (2008). Exposure to opioid maintenance treatment reduces long-term mortality. Addiction, 103(3), 462–468.18190664
159 Schwartz, R. P., Highfield, D. A., Jaffe, J. H., Brady, J. V., Butler, C. B., Rouse, C. O., … Battjes, R. J. (2006). A randomized controlled trial of interim methadone maintenance. Archives of General Psychiatry, 63(1), 102–109.16389204
160 Yancovitz, S. R., Des Jaríais, D. C., Peyser, Ν. P., Drew, E., Friedmann, P., Trigg, Η. L. & Robinson, J. W. (1991). A randomized trial of an interim methadone maintenance clinic. American Journal of Public Health, 87(9), 1185–1191.
161 Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
162 Martin, W. R., Jasinski, D. R. & Mansky, P. A. (1973). Naltrexone, an antagonist for the treatment of heroin dependence: Effects in man. Archives of General Psychiatry, 28(6), 784–791.4707988
163 Sullivan, Μ. Α., Garawi, F., Bisaga, Α., Comer, S. D., Carpenter, K., Raby, W. N. … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 97(2-3), 289–292.
164 American Society of Addiction Medicine. (2015). National practice guideline for the use of medications in the treatment of addiction involving opioid use. Retrieved December 1, 2017, from www.asam.org/docs/default-source/practice-support/guidelines-and-consensus-docs/asam-national-practice-guideline-supplement.pdf?sfvrsn=24
165 Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, Α. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 2011(2), 1–45. doi:10.1002/14651858.CD001333.pub3
166 Alkermes. (2015). Vivitrol. Retrieved May 21, 2017, from http://medlibrary.0rg/lib/rx/meds/vivitr0l/page/6
167 Krupitsky, E., Nunes, E. V., Ling, W., Illeperuma, Α., Gastfriend, D. R., & Silverman, B. L. (2011). Injectable extended-release naltrexone for opioid dependence: A double-blind, placebo-controlled, multicentre randomised trial. Lancet, 377(9776), 1506–1513.21529928
168 Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. Α., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.
169 Krupitsky, E., Nunes, E. V., Ling, W., Illeperuma, Α., Gastfriend, D. R., & Silverman, B. L. (2011, April 30). Injectable extended-release naltrexone for opioid dependence: A double-blind, placebo-controlled, multicentre randomised trial. Lancet, 377(9776), 1506–1513.21529928
170 Lee, J. D., Nunes, E. V., Jr., Novo, P., Bachrach, K., Bailey, G. L., Bhatt, S., … Rotrosen J. (2018). Comparative effectiveness of extended-release naltrexone versus buprenorphine-naloxone for opioid relapse prevention (X:BOT): A multicentre, open-label, randomised controlled trial. Lancet, 397(10118), 309–318.
171 Tanum, L., Solli, K. K., Latif, Z. E., Benth, J. S., Opheim, Α., Sharma-Haase, K. … Kunoe, N. (2017). The effectiveness of injectable extended-release naltrexone vs daily buprenorphine-naloxone for opioid dependence: A randomized clinical noninferiority trial. JAMA Psychiatry, 740(2), 1197–1205.
172 Meyer, M. C., Straughn, A. B., Lo, M. W., Schary, W. L., & Whitney, C. C. (1984). Bioequivalence, dose-proportionality, and pharmacokinetics of naltrexone after oral administration. Journal of Clinical Psychiatry, 45(9 Pt 2), 15–19.
173 Alkermes. (2015). Vivitrol (naltrexone for extended release injectable suspension) 380 mg/vial. Retrieved January 9, 2018, from www.vivitrol.com/content/pdfs/prescribing-information.pdf
174 Alkermes. (2015). Vivitrol (naltrexone for extended release injectable suspension) 380 mg/vial. Retrieved January 9, 2018, from www.vivitrol.com/content/pdfs/prescribing-information.pdf
175 Meyer, M. C., Straughn, A. B., Lo, M. W., Schary, W. L., & Whitney, C. C. (1984). Bioequivalence, dose-proportionality, and pharmacokinetics of naltrexone after oral administration. Journal of Clinical Psychiatry, 45(9, Pt. 2), 15–19.
176 Bigelow, G. E., Preston, K. L., Schmittner, J., Dong, Q., & Gastfriend, D. R. (2012). Opioid challenge evaluation of blockade by extended-release naltrexone in opioid-abusing adults: Dose-effects and time-course. Drug and Alcohol Dependence, 723(1-3), 57–65.
177 Tetrault, J. M., Tate, J. P., McGinnis, Κ. Α., Goulet, J. L., Sullivan, L. E., Bryant, K. … Fiellin, D. A. (2012). Hepatic safety and antiretroviral effectiveness in HIV-infected patients receiving naltrexone. Alcoholism: Clinical and Experimental Research, 36(2), 318–324.
178 Comer, S. D., Mannelli, P., Alam, D., Douaihy, Α., Nangia, N., Åkerman, S. C., … Sullivan, Μ. Α. (2020). Transition of patients with opioid use disorder from buprenorphine to extended-release naltrexone: A randomized clinical trial assessing two transition regimens. American Journal on Addictions, 29(4), 313–322.
179 Bisaga, Α., Mannelli, P., Yu, M., Nangia, N., Graham, C. E., Tompkins, D. Α., … Sullivan, M. A. (2018). Outpatient transition to extended-release injectable naltrexone for patients with opioid use disorder: A phase 3 randomized trial. Drug and Alcohol Dependence, 187, 171–178.29674251
180 Comer, S. D., Mannelli, P., Alam, D., Douaihy, Α., Nangia, N., Åkerman, S. C., … Sullivan, Μ. Α. (2020). Transition of patients with opioid use disorder from buprenorphine to extended-release naltrexone: A randomized clinical trial assessing two transition regimens. American Journal on Addictions, 29(4), 313–322.
181 Jones, H. E., Kaltenbach, K., Heil, S. H., Stine, S. M., Coyle, M. G., Arria, A. M., … Fischer, G. (2010). Neonatal abstinence syndrome after methadone or buprenorphine exposure. New England Journal of Medicine, 363(24), 2320–2331.
182 Mozurkewich, E. L., & Rayburn, W. F. (2014). Buprenorphine and methadone for opioid addiction during pregnancy. Obstetrics and Gynecology Clinics of North America, 41(2), 241–253.24845488
183 Alkermes. (2015). Vivitrol. Retrieved October 16, 2017, from http://medlibrary.org/lib/rx/meds/vivitrol/page/6
184 Bisaga, A., Mannelli, P., Yu, M., Nangia, N., Graham, C. E., Tompkins, D. A., … Sullivan, M. A. (2018). Outpatient transition to extended-release injectable naltrexone for patients with opioid use disorder: A phase 3 randomized trial. Drug and Alcohol Dependence, 187, 171–178.29674251
185 Comer, S. D., Mannelli, P., Alam, D., Douaihy, A., Nangia, N., Akerman, S. C., … Sullivan, M. A. (2020). Transition of patients with opioid use disorder from buprenorphine to extended-release naltrexone: A randomized clinical trial assessing two transition regimens. American Journal on Addictions, 29(4), 313–322.
186 Sullivan, M., Bisaga, A., Pavlicova, M., Choi, C. J., Mishlen, K., Carpenter, K. M., … Nunes, E. V. (2017). Long-acting injectable naltrexone induction: A randomized trial of outpatient opioid detoxification with naltrexone versus buprenorphine. American Journal of Psychiatry, 174(5), 459–467.
187 Tetrault, J. M., Tate, J. P., McGinnis, K. A., Goulet, J. L., Sullivan, L. E., Bryant, K., … Fiellin, D. A. (2012). Hepatic safety and antiretroviral effectiveness in HIV-infected patients receiving naltrexone. Alcoholism: Clinical and Experimental Research, 36(2), 318–324.
188 Crowley, T. J., Wagner, J. E., Zerbe, G., & Macdonald, M. (1985). Naltrexone-induced dysphoria in former opioid addicts. American Journal of Psychiatry, 142(9), 1081–1084.
189 Miotto, K., McCann, M., Basch, J., Rawson, R., & Ling, W. (2002). Naltrexone and dysphoria: Fact or myth? American Journal on Addictions, 11(2), 151–160.
190 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
191 National Library of Medicine. (2014). NALTREXONE HYDROCHLORIDE - naltrexone hydrochloride tablet, film coated DAILY MED. Retrieved October 16, 2017, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=06ff2d5a-e62b-4fa4-bbdb-01938535bc65
192 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
193 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
194 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
195 U.S. Preventive Services Task Force. (2019). Final Recommendation Statement on Human Immunodeficiency Virus (HIV) Infection: Screening. Retrieved January 11, 2020, from www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/human-immunodeficiency-virus-hiv-infection-screening
196 Centers for Disease Control and Prevention. Testing Recommendations for Hepatitis C Virus Infection. October 15, 2015. Retrieved January 11, 2020, from www.cdc.gov/hepatitis/hcv/guidelinesc.htm
197 Centers for Disease Control and Prevention. (2016). Viral hepatitis. Retrieved October 16, 2017, from www.cdc.gov/hepatitis/hbv/bfaq.htm
198 Nunes, E. V., Krupitsky, E., Ling, W., Zummo, J., Memisoglu, A., Silverman, B. L., & Gastfriend, D. R. (2015). Treating opioid dependence with injectable extended-release naltrexone (XR-NTX): Who will respond? Journal of Addiction Medicine, 9(3), 238–243.25901451
199 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
200 Sigmon, S. C., Bisaga, A., Nunes, E. V., O'Connor, P. G., Kosten, T., & Woody, G. (2012). Opioid detoxification and naltrexone induction strategies: Recommendations for clinical practice. American Journal of Drug and Alcohol Abuse, 38(3), 187–199.
201 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
202 Comer, S. D., Mannelli, P., Alam, D., Douaihy, A., Nangia, N., Akerman, S. C., … Sullivan, M. A. (2020). Transition of patients with opioid use disorder from buprenorphine to extended-release naltrexone: A randomized clinical trial assessing two transition regimens. American Journal on Addictions, 29(4), 313–322.
203 Sullivan, M. A., Bisaga, A., Mariani, J. J., Glass, A., Levin, F. R., Comer, S. D., & Nunes, E. V. (2013). Naltrexone treatment for opioid dependence: Does its effectiveness depend on testing the blockade? Drug and Alcohol Dependence, 133(1), 80–85.23827259
204 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
205 Kosten, T. R., Morgan, C., & Kleber, H. D. (1992). Phase II clinical trials of buprenorphine: Detoxification and induction onto naltrexone. NIDA Research Monograph, 121, 101–119.1406906
206 Bisaga, A., Sullivan, M. A., Glass, A., Mishlen, K., Pavlicova, M., Haney, M., … Nunes, E. V. (2015). The effects of dronabinol during detoxification and the initiation of treatment with extended release naltrexone. Drug and Alcohol Dependence, 154, 38–45.26187456
207 Sigmon, S. C., Bisaga, A., Nunes, E. V., O'Connor, P. G., Kosten, T., & Woody, G. (2012). Opioid detoxification and naltrexone induction strategies: Recommendations for clinical practice. American Journal of Drug and Alcohol Abuse, 38(3), 187–199.
208 Sullivan, M., Bisaga, A., Pavlicova, M., Choi, C. J., Mishlen, K., Carpenter, K. M., … Nunes, E. V. (2017). Long-acting injectable naltrexone induction: A randomized trial of outpatient opioid detoxification with naltrexone versus buprenorphine. American Journal of Psychiatry, 174(5), 459–467.
209 Sullivan, M., Bisaga, A., Pavlicova, M., Choi, C. J., Mishlen, K., Carpenter, K. M., … Nunes, E. V. (2017). Long-acting injectable naltrexone induction: A randomized trial of outpatient opioid detoxification with naltrexone versus buprenorphine. American Journal of Psychiatry, 174(5), 459–467.
210 Bisaga, A. (2015). Implementing antagonist-based relapse prevention treatment for buprenorphine-treated individuals. Providence, RI: Providers' Clinical Support System for Medication-Assisted Treatment.
211 Shearer, J., Wodak, A. D., & Dolan, K. A. (2007). Evaluation of a prison-based naltrexone program. International Journal of Prisoner Health, 3(3), 214–224.
212 Adi, Y., Juarez-Garcia, A., Wang, D., Jowett, S., Frew, E., Day, E., … Burls, A. (2007). Oral naltrexone as a treatment for relapse prevention in formerly opioid-dependent drug users: A systematic review and economic evaluation. Health Technology Assessment, 11(6), iii–iv, 1-85.
213 Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
214 Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 2011(2), 1–45.
215 Ling, W., & Wesson, D. R. (1984). Naltrexone treatment for addicted health-care professionals: A collaborative private practice experience. Journal of Clinical Psychiatry, 45(9 Pt. 2), 46–48.
216 Washton, A. M., Gold, M. S., & Pottash, A. C. (1984). Successful use of naltrexone in addicted physicians and business executives. Advances in Alcohol and Substance Abuse, 4(2), 89–96.6524509
217 Sullivan, M. A., Rothenberg, J. L., Vosburg, S. K., Church, S. H., Feldman, S. J., Epstein, E. M., … Nunes, E. V. (2006). Predictors of retention in naltrexone maintenance for opioid dependence: Analysis of a Stage I trial. American Journal on Addictions, 15(2), 150–159.
218 Sullivan, M. A., Garawi, F., Bisaga, A., Comer, S. D., Carpenter, K., Raby, W. N., … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 91(2-3), 289–292.17681716
219 Sullivan, M. A., Garawi, F., Bisaga, A., Comer, S. D., Carpenter, K., Raby, W. N., … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 91(2-3), 289–292.17681716
220 American Society of Addiction Medicine. (2017). Sample treatment agreement. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-treatment-agreement30fa159472bc604ca5b7ff000030b21a.pdf?sfvrsn=0
221 Alkermes. (2013). Patient counseling tool: VIVITROL (naltrexone for extended-release injectable suspension. Retrieved January 9, 2018, from www.vivitrolrems.com/content/pdf/patinfo-counseling-tool.pdf
222 Alkermes. (2015). Key techniques to reduce severe injection site reactions: VIVITROL (naltrexone for extended release injectable suspension) intramuscular injection. Retrieved January 9, 2018, from www.vivitrolrems.com/content/pdf/patinfo-injection-poster.pdf
223 Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
224 Caldiero, R. M., Parran, T. J., Adelman, C. L., & Piche, B. (2006). Inpatient initiation of buprenorphine maintenance vs. detoxification: Can retention of opioid-dependent patients in outpatient counseling be improved? American Journal on Addictions, 15(1), 1–7.
225 Weiss, R. D., Potter, J. S., Fiellin, D. A., Byrne, M., Connery, H. S., Dickinson, W., … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
226 Fiellin, D. A., Moore, B. A., Sullivan, L. E., Becker, W. C., Pantalon, M. V., Chawarski, M. C., … Schottenfeld, R. S. (2008). Long-term treatment with buprenorphine/naloxone in primary care: Results at 2-5 years. American Journal on Addictions, 17(2), 116–120.
227 Edelman, E. J., Chantarat, T., Caffrey, S., Chaudhry, A., O'Connor, P. G., Weiss, L., … Fiellin, L. E. (2014). The impact of buprenorphine/naloxone treatment on HIV risk behaviors among HIV-infected, opioid-dependent patients. Drug and Alcohol Dependence, 139, 79–85.24726429
228 Sullivan, L. E., Moore, B. A., Chawarski, M. C., Pantalon, M. V., Barry, D., O'Connor, P. G., Fiellin, D. A. (2008). Buprenorphine/naloxone treatment in primary care is associated with decreased human immunodeficiency virus risk behaviors. Journal of Substance Abuse Treatment, 35(1), 87–92.17933486
229 Auriacombe, M., Fatséas, M., Dubernet, J., Daulouède, J. P., & Tignol, J. (2004). French field experience with buprenorphine. American Journal on Addictions, 13(Suppl. 1), S17–S28.
230 Degenhardt, L., Randall, D., Hall, W., Law, M., Butler, T., & Burns, L. (2009). Mortality among clients of a state-wide opioid pharmacotherapy program over 20 years: Risk factors and lives saved. Drug and Alcohol Dependence, 105(1-2), 9–15.19608355
231 Herget, G. (2005). Methadone and buprenorphine added to the WHO list of essential medicines. HIV/AIDS Policy and Law Review, 10(3), 23–24.
232 Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
233 Orexo US. (2016). Zubsolv (buprenorphine and naloxone) sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from www.zubsolv.com/wp-content/uploads/2015/01/ZubsolvFullPrescribingInformation.pdf
234 BioDelivery Sciences International. (2018). Bunavail (buprenorphine and naloxone buccal film): Highlights of prescribing information. Retrieved April 28, 2021, from www.accessdata.fda.gov/drugsatfdadocs/label/2018/205637s016lbl.pdf
235 BioDelivery Sciences International. (2018). Bunavail (buprenorphine and naloxone buccal film): Highlights of prescribing information. Retrieved April 28, 2021, from www.accessdata.fda.gov/drugsatfdadocs/label/2018/205637s016lbl.pdf
236 Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, from www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
237 Roxane Laboratories. (2015). Buprenorphine and naloxone sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=713db2c6-0544-4633-b874-cfbeaf93db89
238 Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, from www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
239 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
240 Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, from www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
241 Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
242 Orexo US. (2015). Zubsolv (buprenorphine and naloxone) sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from www.zubsolv.com/wp-content/uploads/2015/01/ZubsolvFullPrescribingInformation.pdf
243 Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, from www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
244 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
245 Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
246 Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
247 Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
248 Amass, L., Kamien, J. B., & Mikulich, S. K. (2001). Thrice-weekly supervised dosing with the combination buprenorphine-naloxone tablet is preferred to daily supervised dosing by opioid-dependent humans. Drug and Alcohol Dependence, 61(2), 173–181.11137282
249 Schottenfeld, R. S., Pakes, J., O'Connor, P., Chawarski, M., Oliveto, A., & Kosten, T. R. (2000). Thrice-weekly versus daily buprenorphine maintenance. Biological Psychiatry, 47(12), 1072–1079.10862807
250 Walsh, S. L., Preston, K. L., Stitzer, M. L., Cone, E. J., & Bigelow, G. E. (1994). Clinical pharmacology of buprenorphine: Ceiling effects at high doses. Clinical Pharmacology and Therapeutics, 55(5), 569–580.8181201
251 Elkader, A., & Sproule, B. (2005). Buprenorphine: Clinical pharmacokinetics in the treatment of opioid dependence. Clinical Pharmacokinetics, 44(7), 661–680.15966752
252 Kuhlman, J. J., Jr., Levine, B., Johnson, R. E., Fudala, P. J., & Cone, E. J. (1998). Relationship of plasma buprenorphine and norbuprenorphine to withdrawal symptoms during dose induction, maintenance and withdrawal from sublingual buprenorphine. Addiction, 93(4), 549–559.9684393
253 Indivor. (2016). Label: Suboxone - buprenorphine hydrochloride, naloxone hydrochloride film, soluble. Retrieved January 9, 2018, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=8a5edcf9-828c-4f97-b671-268ab13a8ecd
254 Marsch, L. A., Bickel, W. K., Badger, G. J., & Jacobs, E. A. (2005). Buprenorphine treatment for opioid dependence: The relative efficacy of daily, twice and thrice weekly dosing. Drug & Alcohol Dependence, 77(2), 195–204.15664721
255 Jones, J. D., Sullivan, M. A., Vosburg, S. K., Manubay, J. M., Mogali, S., Metz, V., & Comer, S. D. (2015). Abuse potential of intranasal buprenorphine versus buprenorphine/naloxone in buprenorphine-maintained heroin users. Addiction Biology, 20(4), 784–798.25060839
256 Walsh, S. L., Nuzzo, P. A., Babalonis, S., Casselton, V., & Lofwall, M. R. (2016). Intranasal buprenorphine alone and in combination with naloxone: Abuse liability and reinforcing efficacy in physically dependent opioid abusers. Drug and Alcohol Dependence, 162, 190–198.27012435
257 Indivior. (2017). Sublocade (buprenorphine extended-release) injection: Full prescribing information. Retrieved December 18, 2017, from www.accessdata.fda.gov/drugsatfdadocs/label/2017/209819s000lbl.pdf
258 Elkader, A., & Sproule, B. (2005). Buprenorphine: Clinical pharmacokinetics in the treatment of opioid dependence. Clinical Pharmacokinetics, 44(7), 661–680.15966752
259 Zhang, W., Ramamoorthy, Y., Tyndale, R. F., & Sellers, E. M. (2003). Interaction of buprenorphine and its metabolite norbuprenorphine with cytochromes p450 in vitro. Drug Metabolism and Disposition: The Biological Fate of Chemicals, 31(6), 768–772.12756210
260 McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.
261 Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
262 Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
263 Selden, T., Ahlner, J., Druid, H., & Kronstrand, R. (2012). Toxicological and pathological findings in a series of buprenorphine related deaths. Possible risk factors for fatal outcome. Forensic Science International, 220(1-3), 284–290.22565115
264 Hakkinen, M., Launiainen, T., Vuori, E., & Ojanpera, I. (2012). Benzodiazepines and alcohol are associated with cases of fatal buprenorphine poisoning. European Journal of Clinical Pharmacology, 68(3), 301–309.21927835
265 Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
266 Toce, M. S., Burns, M. M., & O'Donnell, K. A. (2017). Clinical effects of unintentional pediatric buprenorphine exposures: Experience at a single tertiary care center. Clinical Toxicology (Philadelphia, Pa.), 55(1), 12–17.
267 Saxon, A. J., Ling, W., Hillhouse, M., Thomas, C., Hasson, A., Ang, A., … Jacobs, P. (2013). Buprenorphine/naloxone and methadone effects on laboratory indices of liver health: A randomized trial. Drug and Alcohol Dependence, 128(1-2), 71–76.22921476
268 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
269 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
270 Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
271 Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
272 Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
273 Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
274 Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
275 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
276 Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
277 Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
278 Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
279 Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
280 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
281 Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetic, 54(8), 837–849.
282 Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
283 Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
284 Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
285 Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
286 Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
287 Strain, E. C., & Lofwall, M. R. (Eds.). (2008). Buprenorphine. The American Psychiatric Publishing textbook of substance abuse treatment (4th ed.). Arlington, VA: American Psychiatric Publishing.
288 Walsh, S. L., June, H. L., Schuh, K. J., Preston, K. L., Bigelow, G. E., & Stitzer, M. L. (1995). Effects of buprenorphine and methadone in methadone-maintained subjects. Psychopharmacology, 119(3), 268–276.7675960
289 Strain, E. C., Preston, K. L., Liebson, I. A., & Bigelow, G. E. (1995). Buprenorphine effects in methadone-maintained volunteers: Effects at two hours after methadone. Journal of Pharmacology and Experimental Therapeutics, 272(2), 628–638.
290 Rosado, J., Walsh, S. L., Bigelow, G. E., & Strain, E. C. (2007). Sublingual buprenorphine/naloxone precipitated withdrawal in subjects maintained on 100mg of daily methadone. Drug and Alcohol Dependence, 90(2-3), 261–269.17517480
291 Walsh, S. L., June, H. L., Schuh, K. J., Preston, K. L., Bigelow, G. E., & Stitzer, M. L. (1995). Effects of buprenorphine and methadone in methadone-maintained subjects. Psychopharmacology, 119(3), 268–276.7675960
292 Jones, H. E., Dengler, E., Garrison, A., O'Grady, K. E., Seashore, C., Horton, E., … Thorp, J. (2014). Neonatal outcomes and their relationship to maternal buprenorphine dose during pregnancy. Drug and Alcohol Dependence, 134, 414–417.24290979
293 Cleary, B. J., Reynolds, K., Eogan, M., O'Connell, M. P., Fahey, T., Gallagher, P. J., … Murphy, D. J. (2014). Methadone dosing and prescribed medication use in a prospective cohort of opioid-dependent pregnant women. Addiction, 108(4), 762–770.
294 Kaltenbach, K., Holbrook, A. M., Coyle, M. G., Heil, S. H., Salisbury, A. L. Stine, S. M., … Jones, H. E. (2012). Predicting treatment for neonatal abstinence syndrome in infants born to women maintained on opioid agonist medication. Addiction, 107(Suppl. 1), 45–52.
295 McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.
296 Center for Substance Abuse Treatment. (2004). Clinical guidelines for the use of buprenorphine in the treatment of opioid addiction. Treatment Improvement Protocol (TIP) Series 40. HHS Publication No. (SMA) 04-3939. Rockville, MD: Substance Abuse and Mental Health Services Administration.
297 Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
298 McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., DiFrancesco, R., Friedland, G., … Rainey, P. M. (2007). Interaction between buprenorphine and atazanavir or atazanavir/ritonavir. Drug and Alcohol Dependence, 91(2-3), 269–278.17643869
299 Bruce, R. D., & Altice, F. L. (2006). Three case reports of a clinical pharmacokinetic interaction with buprenorphine and atazanavir plus ritonavir. AIDS, 20(5), 783–784.16514314
300 Vergara-Rodriguez, P., Tozzi, M. J., Botsko, M., Nandi, V., Altice, F., Egan, J. E., … Fiellin, D. A. (2011). Hepatic safety and lack of antiretroviral interactions with buprenorphine/naloxone in HIV-infected opioid-dependent patients. Journal of Acquired Immune Deficiency Syndromes, 56(Suppl. 1), S62–S67.21317596
301 McCance-Katz, E. F., Moody, D. E., Prathikanti, S., Friedland, G., & Rainey, P. M. (2011). Rifampin, but not rifabutin, may produce opiate withdrawal in buprenorphine-maintained patients. Drug and Alcohol Dependence, 118(2-3), 326–334.21596492
302 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
303 McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., DiFrancesco, R., Friedland, G., … Rainey, P. M. (2007). Interaction between buprenorphine and atazanavir or atazanavir/ritonavir. Drug and Alcohol Dependence, 91(2-3), 269–278.17643869
304 McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., DiFrancesco, R., Friedland, G., … Rainey, P. M. (2007). Interaction between buprenorphine and atazanavir or atazanavir/ritonavir. Drug and Alcohol Dependence, 91(2-3), 269–278.17643869
305 Bruce, R. D., Moody, D. E., Altice, F. L., Gourevitch, M. N., & Friedland, G. H. (2013). A review of pharmacological interactions between HIV or hepatitis C virus medications and opioid agonist therapy: Implications and management for clinical practice. Expert Review of Clinical Pharmacology, 6(3), 249–269.23656339
306 Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
307 Bruce, R. D., Moody, D. E., Altice, F. L., Gourevitch, M. N., & Friedland, G. H. (2013). A review of pharmacological interactions between HIV or hepatitis C virus medications and opioid agonist therapy: Implications and management for clinical practice. Expert Review of Clinical Pharmacology, 6(3), 249–269.23656339
308 Gruber, V. A., Rainey, P. M., Moody, D. E., Morse, G. D., Ma, Q., Prathikanti, S., … McCance-Katz, E. F. (2012). Interactions between buprenorphine and the protease inhibitors darunavir-ritonavir and fosamprenavir-ritonavir. Clinical Infectious Diseases, 54(3), 414–423.22100576
309 Bruce, R. D., Moody, D. E., Altice, F. L., Gourevitch, M. N., & Friedland, G. H. (2013). A review of pharmacological interactions between HIV or hepatitis C virus medications and opioid agonist therapy: Implications and management for clinical practice. Expert Review of Clinical Pharmacology, 6(3), 249–269.23656339
310 McCance-Katz, E. F., Moody, D. E., Morse, G. D., Friedland, G., Pade, P., Baker, J., … Rainey, P. M. (2006). Interactions between buprenorphine and antiretrovirals. I. The nonnucleoside reverse-transcriptase inhibitors efavirenz and delavirdine. Clinical Infectious Diseases, 43(Suppl. 4), S224–S234.17109309
311 McCance-Katz, E. F., Moody, D. E., Morse, G. D., Friedland, G., Pade, P., Baker, J., … Rainey, P. M. (2006). Interactions between buprenorphine and antiretrovirals. I. The nonnucleoside reverse-transcriptase inhibitors efavirenz and delavirdine. Clinical Infectious Diseases, 43(Suppl. 4), S224–S234.17109309
312 Bruce, R. D., Winkle, P., Custodio, J., Yin, X., Rhee, M., Andrews, J., … Ramanathan, S. (2012, September). Pharmacokinetics of cobicistat-boosted elvitegravir administered in combination with methadone or buprenorphine/naloxone. Paper presented at the 52nd Interscience Conference on Antimicrobial Agents and Chemotherapy, San Francisco, CA.
313 McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., & Rainey, P. M. (2010). Lack of clinically significant drug interactions between nevirapine and buprenorphine. American Journal on Addictions, 19(1), 30–37.
314 McCance-Katz, E. F., Moody, D. E., Smith, P. F., Morse, G. D., Friedland, G., Pade, P., … Rainey, P. (2006). Interactions between buprenorphine and antiretrovirals. II. The protease inhibitors nelfinavir, lopinavir/ritonavir, and ritonavir. Clinical Infectious Diseases, 43(Suppl. 4), S235–S246.17109310
315 Bruce, R. D., Altice, F. L., Moody, D. E., Lin, S. N., Fang, W. B., Sabo, J. P., Friedland, G. H. (2009). Pharmacokinetic interactions between buprenorphine/naloxone and tipranavir/ritonavir in HIV-negative subjects chronically receiving buprenorphine/naloxone. Drug and Alcohol Dependence, 105(3), 234–239.19726139
316 Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
317 Isenberg, D., Wong, S. C., & Curtis, J. A. (2008). Serotonin syndrome triggered by a single dose of Suboxone. American Journal of Emergency Medicine, 26(7), 840.e3-840.e5.
318 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
319 Soyka, M. (2013). Buprenorphine use in pregnant opioid users: A critical review. CNS Drugs, 27(8), 653–662.23775478
320 Saxon, A. J., Ling, W., Hillhouse, M., Thomas, C., Hasson, A., Ang, A., … Jacobs, P. (2013). Buprenorphine/naloxone and methadone effects on laboratory indices of liver health: A randomized trial. Drug and Alcohol Dependence, 128(1-2), 71–76.22921476
321 Vergara-Rodriguez, P., Tozzi, M. J., Botsko, M., Nandi, V., Altice, F., Egan, J. E., … Fiellin, D. A. (2011). Hepatic safety and lack of antiretroviral interactions with buprenorphine/naloxone in HIV-infected opioid-dependent patients. Journal of Acquired Immune Deficiency Syndromes, 56(Suppl. 1), S62–S67.21317596
322 U.S. Preventive Services Task Force. (2019). Final Recommendation Statement on Human Immunodefciency Virus (HIV) Infection: Screening. Retrieved January 11, 2020, from_ www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/human-immunodeficiency-virus-hiv-infection-screening
323 Centers for Disease Control and Prevention. Testing Recommendations for Hepatitis C Virus Infection. October 15, 2015. Retrieved January 11, 2020, from www.cdc.gov/hepatitis/hcv/guidelinesc.htm
324 Centers for Disease Control and Prevention. (2016). Viral hepatitis. Retrieved October 16, 2017, from www.cdc.gov/hepatitis/hbv/bfaq.htm
325 Lofwall, M. R., & Havens, J. R. (2012). Inability to access buprenorphine treatment as a risk factor for using diverted buprenorphine. Drug and Alcohol Dependence, 126(3), 379–383.22704124
326 Bazazi, A. R., Yokell, M., Fu, J. J., Rich, J. D., & Zaller, N. D. (2011). Illicit use of buprenorphine/naloxone among injecting and noninjecting opioid users. Journal of Addiction Medicine, 5(3), 175–180.21844833
327 Moratti, E., Kashanpour, H., Lombardelli, T., & Maisto, M. (2010). Intravenous misuse of buprenorphine: Characteristics and extent among patients undergoing drug maintenance therapy. Clinical Drug Investigation, 30(Suppl. 1), 3–11.
328 Braeburn Pharmaceuticals. (2016). Probuphine (buprenorphine) implant: Full prescribing information. Retrieved October 16, 2017, from www.accessdata.fda.gov/drugsatfdadocs/label/2016/204442Qrig1s000lbl.pdf
329 Braeburn Pharmaceuticals. (2016). Probuphine (buprenorphine) implant: Full prescribing information. Retrieved October 16, 2017, from www.accessdata.fda.gov/drugsatfdadocs/label/2016/2Q4442Orig1s000lbl.pdf
330 Center for Substance Abuse Treatment. (2004). Clinical guidelines for the use of buprenorphine in the treatment of opioid addiction. Treatment Improvement Protocol (TIP) Series 40. HHS Publication No. (SMA) 04-3939. Rockville, MD: Substance Abuse and Mental Health Services Administration.
331 Walley, A. Y., Alperen, J. K., Cheng, D. M., Botticelli, M., Castro-Donlan, C., Samet, J. H., & Alford, D. P. (2008). Office-based management of opioid dependence with buprenorphine: Clinical practices and barriers. Journal of General Internal Medicine, 23(9), 1393–1398.18592319
332 Gunderson, E. W., Wang, X. Q., Fiellin, D. A., Bryan, B., & Levin, F. R. (2010). Unobserved versus observed office buprenorphine/naloxone induction: A pilot randomized clinical trial. Addictive Behaviors, 35(5), 537–540.20106601
333 Lee, J. D., Vocci, F., & Fiellin, D. A. (2014). Unobserved “home” induction onto buprenorphine. Journal of Addiction Medicine, 8(5), 299–308.25254667
334 American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
335 Providers Clinical Support System for Medication Assisted Treatment. (2013, November). PCSS Guidance. Retrieved December 18, 2017, from http://pcssmat.org/wp-content/uploads/2014/02/PCSS-MATGuidanceBuprenorphineInduction.Casadonte.pdf
336 Tompkins, D. A., & Strain, E. C. (2011). Buprenorphine in the treatment of opioid dependence. In P. Ruiz & E. C. Strain (Eds.), Substance abuse. A comprehensive textbook (5th ed., pp. 437–446). Philadelphia, PA: Wolters Kluwer.
337 Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/pdfs/prescribing-information.pdf
338 Strain, E. C. (2006). Clinical use of buprenorphine. In E. C. Strain & M. L. Stitzer (Eds.) The treatment of opioid dependence (pp. 230–252). Baltimore, MD: Johns Hopkins University Press.
339 Rich, J. D., McKenzie, M., Dickman, S., Bratberg, J., Lee, J. D., & Schwartz, R. P. (2011). An adverse reaction to buprenorphine/naloxone induction in prison: A case report. Addictive Disorders and Their Treatment, 10(4), 199–200.22121339
340 Vocci, F. J., Schwartz, R. P., Wilson, M. E., Gordon, M. S., Kinlock, T. W., Fitzgerald, T. T., … Jaffe, J. H. (2015). Buprenorphine dose induction in non-opioid-tolerant pre-release prisoners. Drug and Alcohol Dependence, 156, 133–138.26409751
341 Tompkins, D. A., & Strain, E. C. (2011). Buprenorphine in the treatment of opioid dependence. In P. Ruiz & E. C. Strain (Eds.), Substance abuse: A comprehensive textbook (5th ed., pp. 437–446). Philadelphia, PA: Wolters Kluwer.
342 Rosado, J., Walsh, S. L., Bigelow, G. E., & Strain, E. C. (2007). Sublingual buprenorphine/naloxone precipitated withdrawal in subjects maintained on 100mg of daily methadone. Drug and Alcohol Dependence, 90(2-3), 261–269.17517480
343 Zubieta, J., Greenwald, M. K., Lombardi, U., Woods, J. H., Kilbourn, M. R., Jewett, D. M., Johanson, C. E. (2000). Buprenorphine-induced changes in mu-opioid receptor availability in male heroin-dependent volunteers: A preliminary study. Neuropsychopharmacology, 23(3), 326–334.10942856
344 Hser, Y., Saxon, A. J., Huang, D., Hasson, A., Thomas, C., Hillhouse, M. … Ling, W. (2014). Treatment retention among patients randomized to buprenorphine/naloxone compared to methadone in a multi-site trial. Addiction, 109(1), 79–87.23961726
345 American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711.
346 Debelak, K., Morrone, W. R., O'Grady, K. E., & Jones, H. E. (2013). Buprenorphine + naloxone in the treatment of opioid dependence during pregnancy-initial patient care and outcome data. American Journal on Addictions, 22, 252–254.
347 Wiegand, S. L., Stringer, E. M., Stuebe, A. M., Jones, H., Seashore, C., & Thorp, J. (2015). Buprenorphine and naloxone compared with methadone treatment in pregnancy. Obstetrics & Gynecology, 125, 363–368.25569005
348 American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
349 Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
350 Chavoustie, S., Frost, M., Snyder, O., Owen, J., Darwish, M., Dammerman, R., & Sanjurjo, V. (2017). Buprenorphine implants in medical treatment of opioid addiction. Expert Review of Clinical Pharmacology, 10(8), 799–807.28571505
351 Hser, Y. I., Huang, D., Saxon, A. J., Woody, G., Moskowitz, A. L., Matthews, A. G., & Ling, W. (2017). Distinctive trajectories of opioid use over an extended follow-up of patients in a multisite trial on buprenorphine + naloxone and methadone. Journal of Addiction Medicine, 11(1), 63–69.27898496
352 Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., Bilangi, R. (2009). Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
353 Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
354 American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
355 Henry-Edwards, S., Gowing, L., White, J., Ali, R., Bell, J., Brough, R., … Quigley, A. (2003). Clinical guidelines and procedures for the use of methadone in the maintenance treatment of opioid dependence. Publication approval number: 3263 (JN 7616).
356 World Health Organization. (2009). Guidelines for the psychosocially assisted pharmacological treatment of opioid dependence. Geneva, Switzerland: WHO Press.
357 Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., Bilangi, R. (2009). Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
358 Food and Drug Administration. (2017, May). Appropriate use checklist: Buprenorphine-containing transmucosal products for opioid dependence. Silver Spring, MD: Author.
359 American Society of Addiction Medicine. (2017). Sample treatment agreement. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-treatment-agreement30fa159472bc604ca5b7ff000030b21a.pdf?sfvrsn=0
360 Food and Drug Administration. (2017). FDA Drug Safety Communication: FDA urges caution about withholding opioid addiction medications from patients taking benzodiazepines or CNS depressants: Careful medication management can reduce risks. Retrieved December 18, 2017, from www.fda.gov/Drugs/DrugSafety/ucm575307.htm
361 Lintzeris, N., & Nielsen, S. (2010). Benzodiazepines, methadone and buprenorphine: Interactions and clinical management. American Journal on Addictions, 19(1), 59–72.
362 Lintzeris, N., & Nielsen, S. (2010). Benzodiazepines, methadone and buprenorphine: Interactions and clinical management. American Journal on Addictions, 19(1), 59–72.
363 Liebschutz, J. M., Crooks, D., Herman, D., Anderson, B., Tsui, J., Meshesha, L. Z., … Stein, M. (2014). Buprenorphine treatment for hospitalized, opioid-dependent patients: A randomized clinical trial. JAMA Internal Medicine, 174(8), 1369–1376.25090173
364 Weiss, L., Netherland, J., Egan, J. E., Flanigan, T. P., Fiellin, D. A., Finkelstein, R., & Altice, F. L. (2011). Integration of buprenorphine/naloxone treatment into HIV clinical care: Lessons from the BHIVES collaborative. Journal of Acquired Immune Deficiency Syndromes, 56(Suppl. 1), S68–S75.21317597
365 Weiss, R. D., Potter, J. S., Griffin, M. L., Provost, S. E., Fitzmaurice, G. M., McDermott, K. A., Carroll, K. M. (2015). Long-term outcomes from the National Drug Abuse Treatment Clinical Trials Network Prescription Opioid Addiction Treatment Study. Drug and Alcohol Dependence, 150, 112–119.25818060
366 Substance Abuse and Mental Health Services Administration. (2005). Substance abuse treatment for persons with cooccurring disorders. Treatment Improvement Protocol (TIP) Series 42. HHS Publication No. (SMA) 133992. Rockville, MD: Substance Abuse and Mental Health Services Administration.
367 Center for Substance Abuse Treatment. (2004). Clinical guidelines for the use of buprenorphine in the treatment of opioid addiction. Treatment Improvement Protocol (TIP) Series 40. HHS Publication No. (SMA) 04-3939. Rockville, MD: Substance Abuse and Mental Health Services Administration.
368 Drug Addiction Treatment Act of 2000, H. R. 2634 (1999-2000).
369 Vujanovic, A. A., Bonn-Miller, M. O., & Petry, N. M. (2016). Co-occurring posttraumatic stress and substance use: Emerging research on correlates, mechanisms, and treatments—Introduction to the special issue. Psychology of Addictive Behaviors, 30(7), 713–719.27786510
370 Stitzer, M. L., & Vandrey, R. (2008). Contingency management: Utility in the treatment of drug abuse disorders. Clinical Pharmacology and Therapeutics, 83(4), 644–647.18305456
371 Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3-4), 313–332.23731422
372 Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3-4), 313–332.23731422
373 McLellan, A. T., & White, W. (2012). Opioid maintenance and recovery-oriented systems of care: It is time to integrate (p. 2). London, England: National Treatment Agency for Substance Misuse.
374 American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
375 Substance Abuse and Mental Health Services Administration. (2012). Clinical drug testing in primary care. Technical Assistance Publication (TAP) Series 32. HHS Publication No. (SMA) 12-4668. Rockville, MD: Substance Abuse and Mental Health Services Administration.
376 Jarvis, M., Williams, J., Hurford, M., Lindsay, D., Lincoln, P., Giles, L., … Safarían, T. (2017). Appropriate use of drug testing in clinical addiction medicine. Journal of Addiction Medicine, 11(3), 163–173.28557958
377 Stoller, K. B., Stephens, M. A. C., & Schorr, A. (2016). Integrated service delivery models for opioid treatment programs in an era of increasing opioid addiction, health reform, and parity. Retrieved May 21, 2017, from www.aatod.org/wp-content/uploads/2016/07/2nd-Whitepaper-.pdf
378 Rich, J. D., McKenzie, M., Larney, S., Wong, J. B., Tran, L., Clarke, J., … Zaller, N. (2015, July 25). Methadone continuation versus forced withdrawal on incarceration in a combined US prison and jail: A randomised, open-label trial. Lancet, 386(9991), 350–359.26028120
379 Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
380 Genberg, B. L., Gillespie, M., Schuster, C. R., Johanson, C.-E., Astemborski, J., Kirk, G. D., … Mehta, S. H. (2013). Prevalence and correlates of street-obtained buprenorphine use among current and former injectors in Baltimore, Maryland. Addictive Behaviors, 38(12), 2868–2873.24018232
381 Genberg, B. L., Gillespie, M., Schuster, C. R., Johanson, C.-E., Astemborski, J., Kirk, G. D., … Mehta, S. H. (2013). Prevalence and correlates of street-obtained buprenorphine use among current and former injectors in Baltimore, Maryland. Addictive Behaviors, 38(12), 2868–2873.24018232
382 Cicero, T. J., Ellis, M. S., Surratt, H. L., & Kurtz, S. P. (2014). Factors contributing to the rise of buprenorphine misuse: 2008-2013. Drug and Alcohol Dependence, 142, 98–104.24984689
383 Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
384 United States National Library of Medicine. (2017, October). Buprenorphine sublingual and buccal (opioid dependence). Retrieved December 18, 2017, from https://medlineplus.gov/druginfo/meds/a605002.html
385 American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
386 Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
387 Medication Assisted Treatment for Opioid Use Disorders. HHS Final Rule, Fed. Reg. 81 44711 (July 8, 2016) (to be codified at 42 CFR pt. 8).
388 Physical security controls for practitioners, 21 CFR § 1301.75 (2016).
389 American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
390 Records for manufacturers, distributors, dispensers, researchers, importers, exporters, registrants that reverse distribute, and collectors, 21 CFR § 1304.22 (2014).
391 Lofwall, M., & Walsh, S. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world (p. 316). Journal of Addiction Medicine, 8(5), 315–326.25221984
392 American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
393 Velez, C. M., Nicolaidis, C., Korthuis, P. T., & Englander, H. (2016). “It's been an experience, a life learning experience”: A qualitative study of hospitalized patients with substance use disorders. Journal of General Internal Medicine, 32(3), 296–303.27957661
394 Liebschutz, J. M., Crooks, D., Herman, D., Anderson, B., Tsui, J., Meshesha, L. Z., … Stein, M. (2014). Buprenorphine treatment for hospitalized, opioid-dependent patients: A randomized clinical trial. JAMA Internal Medicine, 174(8), 1369–1376.25090173
395 D'Onofrio, G., O'Connor, P. G., Pantalon, M. V., Chawarski, M. C., Busch, S. H., Owens, P. H., Fiellin, D. A. (2015). Emergency department-initiated buprenorphine/naloxone treatment for opioid dependence: A randomized clinical trial. JAMA, 313(16), 1636–1644.25919527
396 Naeger, S., Ali, M. M., Mutter, R., Mark, T., & Hughey, L. (2016). Post-discharge prescription fills following an opioid hospitalization. Psychiatric Services, 67(11), 1264–1267.
397 Weiss, A. J., Elixhauser, A., Barrett, M. L., Steiner, C. A., Bailey, M. K., & O'Malley, L. (2017, January). Opioid-related inpatient stays and emergency department visits by state, 2009-2014. HCUP Statistical Brief No. 219. Rockville, MD: Agency for Healthcare Research and Quality.
398 Agency for Healthcare Research and Quality (2019). Rate of Opioid-Related Inpatient Stays per 100,000 Population. Retrieved January 11, 2020, from www.hcup-us.ahrq.gov/faststats/OpioidUseMap?setting=IP
399 Administering or dispensing of narcotic drugs, 21 CFR § 1306.07 (2005).
400 Alford, D., Compton, P., & Samet, H. (2006). Acute pain management for patients receiving maintenance methadone or buprenorphine therapy. Annals of Internal Medicine, 144(2), 127–134.16418412
401 Sen, S., Arulkumar, S., Cornett, E. M., Gayle, J. A., Flower, R. R., Fox, C. J., & Kaye, A. D. (2016). New pain management options for the surgical patient on methadone and buprenorphine. Current Pain and Headache Reports, 20(3), 16.26879874
402 Jones, H. E., Deppen, K., Hudak, M. L., Leffert, L., McClelland, C., Sahin, L., … Creanga, A. A. (2014). Clinical care for opioid-using pregnant and postpartum women: The role of obstetric providers. American Journal of Obstetrics and Gynecology, 210(4), 302–310.24120973
403 Alizadeh, S., Mahmoudi, G. A., Solhi, H., Sadeghi-Sedeh, B., Behzadi, R., & Kazemifar, A. M. (2015). Post-operative analgesia in opioid dependent patients: Comparison of intravenous morphine and sublingual buprenorphine. Addiction and Health, 7(1-2), 60–65.26322212
404 Sen, S., Arulkumar, S., Cornett, E. M., Gayle, J. A., Flower, R. R., Fox, C. J., & Kaye, A. D. (2016). New pain management options for the surgical patient on methadone and buprenorphine. Current Pain and Headache Reports, 20(3), 16.26879874
405 Administering or dispensing of narcotic drugs, 21 CFR § 1306.07 (2005).
406 Alford, D. P., Compton, P., & Samet, J. H. (2006). Acute pain management for patients receiving maintenance methadone or buprenorphine therapy. Annals of Internal Medicine, 144(2), 127–134.16418412
407 Devin, C. J., & McGirt, M. J. (2015). Best evidence in multimodal pain management in spine surgery and means of assessing postoperative pain and functional outcomes. Journal of Clinical Neuroscience, 22(6), 930–938.25766366
408 Noska, A., Mohan, A., Wakeman, S., Rich, J., & Boutwell, A. (2015). Managing opioid use disorder during and after acute hospitalization: A case-based review clarifying methadone regulation for acute care settings. Journal of Addictive Behaviors, Therapy and Rehabilitation, 4(2), 1000138.
409 Liebschutz, J. M., Crooks, D., Herman, D., Anderson, B., Tsui, J., Meshesha, L. Z., … Stein, M. (2014). Buprenorphine treatment for hospitalized, opioid-dependent patients: A randomized clinical trial. JAMA Internal Medicine, 174(8), 1369–1376.25090173
410 D'Onofrio, G., O'Connor, P. G., Pantalon, M. V., Chawarski, M. C., Busch, S. H., Owens, P. H., … Fiellin, D. A. (2015). Emergency department-initiated buprenorphine/naloxone treatment for opioid dependence: A randomized clinical trial. JAMA, 313(16), 1636–1644.25919527
411 Substance Abuse and Mental Health Services Administration. (2016, March). Special circumstances for providing buprenorphine. Retrieved December 18, 2017, from www.samhsa.gov/medication-assisted-treatment/legislation-regulations-guidelines/special-circumstances-providing-buprenorphine
412 D'Onofrio, G., O'Connor, P. G., Pantalon, M. V., Chawarski, M. C., Busch, S. H., Owens, P. H., Fiellin, D. A. (2015). Emergency department-initiated buprenorphine/naloxone treatment for opioid dependence: A randomized clinical trial. JAMA, 313(16), 1636–1644.25919527
413 Huxtable, C. A., Roberts, L. J., Somogyi, A. A., & Macintyre, P. E. (2011). Acute pain management in opioid-tolerant patients: A growing challenge. Anaesthesia and Intensive Care, 39(5), 804–823.21970125