# Chapter 3E: Medical Management Strategies for Patients Taking OUD Medications in Office-Based Settings

Chapter 3E examines key issues in medical management of patients who are prescribed buprenorphine or naltrexone in office-based opioid treatment (OBOT) settings. It covers regulatory and administrative concerns specific to buprenorphine and naltrexone that affect medical management of patients in office settings.

Management of patients taking medications for opioid use disorder (OUD) varies by setting. Whereas OBOT stabilizes patients on buprenorphine or naltrexone, providers focus on medication management and treatment of other substance use, medical comorbidities, and psychosocial needs. Treatment of comorbid conditions should be offered onsite or via referral and should be verified as having been received.

Exhibit 3E.1 addresses use of terminology in this chapter.

EXHIBIT 3E.1. Key Terms

In addition to the key terms defined in Exhibit 3.1 of this Treatment Improvement Protocol (TIP), these terms appear in Chapter 3E:

Psychosocial support: Ancillary services to enhance a patient's overall functioning and well-being, including recovery support services, case management, housing, employment, and educational services.

Psychosocial treatment: Interventions that seek to enhance patient's social and mental functioning, including addiction counseling, contingency management, and mental health services.

## Patient Selection

To assess patients' chances of success with standard office-based treatment, consider:

• Concurrent substance use disorder (SUD) involving alcohol or benzodiazepines. Benzodiazepine (illicit and prescription) and alcohol use are common in patients with OUD. This use presents clinical challenges, including increased risk of respiratory depression and unintentional overdose or death. Some patients may have taken appropriately prescribed benzodiazepines for years with limited or no evidence of misuse. For such patients, tapering benzodiazepines may be contraindicated and unrealistic. Others may require treatment for a benzodiazepine use disorder. (See Exhibit 3B.1 for strategies for assessing and managing patients in OUD treatment who have concurrent benzodiazepine use disorder.)
• Although concomitant use of buprenorphine with benzodiazepines increases the risk of an adverse reaction, including overdose death, opioid agonist treatment should not be denied to patients solely because they take benzodiazepines,^360^ because untreated OUD can pose a greater risk of morbidity and mortality. The Food and Drug Administration (FDA) advises that careful medication management by healthcare professionals can reduce risk (see www.fda.gov/Drugs/DrugSafety/ucm575307.htm for more information). Approaches to addressing concurrent benzodiazepine use include:
  - Get patients' permission to contact their benzodiazepine prescribers to confirm their histories. Speaking with close family members or friends (with patients' permission) can also help in evaluating evidence of alcohol or benzodiazepine misuse (e.g., intoxication, accidents, withdrawal seizures).
  - Make sure patients understand that combining buprenorphine with alcohol, benzodiazepines, or other central nervous system depressants risks potential respiratory depression and unintentional overdose death.^361^ Overdose death with buprenorphine is most often associated with intravenous benzodiazepine and heavy alcohol use.
  - For patients misusing benzodiazepines (e.g., taking in high doses, bingeing, using intravenously), the TIP expert panel recommends referral to higher intensity addiction treatment with medically supervised benzodiazepine withdrawal if available (e.g., intensive outpatient programs, residential treatment). Do not rule out concurrent use of buprenorphine or extended-release injectable naltrexone (XR-NTX) for treatment of OUD in more structured settings for these patients.
  - For patients who are physically dependent on illicit benzodiazepines but do not inject or binge, a gradual outpatient medically supervised withdrawal can be attempted using long-acting benzodiazepines, under certain conditions that promote safety and reduce risk. These conditions may include:
    • Requiring frequent office visits with observation of patients taking medication.
    • Having significant others monitor patients and report back to the office.
    • Offering a short-duration prescription supply.
    • Monitoring prescription drug monitoring program (PDMP) reports more frequently.
    • Conducting frequent urine tests.
    • Using written treatment agreements outlining conditions for dual buprenorphine and benzodiazepine prescriptions.
  - Review patient progress regularly; adjust treatment plans as needed. Document treatment decisions, as research showing the effectiveness and safety of these approaches is lacking.^362^
• Significant comorbid mental illness or suicidal or homicidal ideation. Patients who are actively suicidal, homicidal, severely depressed, or psychotic or who are having other significant psychiatric problems may need assessment and treatment by a mental health professional who can treat both the psychiatric comorbidity and the OUD. Depending on the severity, they may need higher levels of mental health services in a crisis center, emergency department, or inpatient setting. An addiction psychiatrist can treat such patients upon discharge.
• Significant medical comorbidity, including infections. Severe abscesses, endocarditis, or osteomyelitis from injecting drugs may require hospitalization. If hospitalization is necessary, buprenorphine can be initiated.^363^ Initiation of HIV and hepatitis C virus treatments do not contraindicate buprenorphine treatment.^364^

## Patient Management and Treatment Monitoring

Base management of OUD on a comprehensive assessment that is updated throughout treatment (see Part 2 of this TIP for more information on conducting assessments). Tailor the management approach to patients' needs and goals. Components of the management approach include:

• The length and frequency of office visits.
• The length of time between prescriptions or XR-NTX injections.
• The frequency of drug testing.
• Ancillary psychosocial and medical treatments and referrals.

### Course of Treatment

The typical course of OUD treatment is varied. There is often not a direct pathway from heavy illicit opioid use to no illicit opioid use.^365^ Some patients have only occasional returns to use and do not require reinduction on buprenorphine or naltrexone. Other patients may return to use in the context of medication nonadherence, requiring reinduction and restabilization on buprenorphine or medically supervised withdrawal from opioids and an appropriate period of abstinence before restarting naltrexone. Some patients may have sustained abstinence and choose to remain on their maintenance buprenorphine or naltrexone dose. However, others may try to taper their buprenorphine dose, discontinue naltrexone, consider a change in medication (e.g., from buprenorphine to naltrexone or naltrexone to buprenorphine), or attempt maintenance of remission of OUD without any medication.

Because OUD is often a chronic and relapsing illness, patients may have different types and durations of treatment over their lifetimes. Some may have periods of successful outpatient treatment at different times with all three available FDA-approved medications for OUD. Others may experience forced medication discontinuation (e.g., insurance lapse, time in controlled environments that disallow or discriminate against OUD medication, cases in family and drug courts, parole and probation). A relative few may remain in remission after successfully discontinuing medication voluntarily. Different treatment journeys occur in different treatment settings (e.g., intensive outpatient, residential programs) and with different pharmacotherapies and ancillary psychosocial and recovery support services.

To the extent possible, coordinate primary care, behavioral health, and wraparound services needed and desired by the patients to address their medical, social, and recovery needs. Individuals with co-occurring physical, mental, and substance use disorders may benefit from collaborative care.^366^

RESOURCE ALERT

##### Substance Abuse and Mental Health Services Administration (SAMHSA) Treatment Guidance for Individuals With Co-Occurring Disorders

TIP 42, Substance Abuse Treatment for Persons With Co-Occurring Disorders, provides treatment strategies for SUD treatment for individuals with mental disorders (https://store.samhsa.gov/product/TIP-42-Substance-Abuse-Treatment-for-Persons-With-Co-Occurring-Disorders/SMA13-3992).

General Principles for the Use of Pharmacological Agents To Treat Individuals With Co-Occurring Mental and Substance Use Disorders offers assistance for the planning, delivery, and evaluation of medication for individuals with co-occurring mental and substance use disorders (https://store.samhsa.gov/product/general-principles-use-pharmacological-agents-treat-individuals-co-occurring-mental).

Pharmacologic Guidelines for Treating Individuals With Post-Traumatic Stress Disorder and Co-Occurring Opioid Use Disorders is tailored to the provision of medication for OUD to individuals also diagnosed with posttraumatic stress disorder (https://store.samhsa.gov/product/pharmacologic-guidelines-treating-individuals-post-traumatic-stress-disorder-co-occurring).

### Role of the Treatment Plan and Treatment Agreement in Medical Management

The initial treatment plan should include:

• Treatment goals.
• Conditions for changing or stopping treatment (the Chapter 3E Appendix has a sample goal-setting form).
• Therapeutic contingencies for nonadherence and failure to meet initial goals, such as:
  - Increase in the intensity or scope of services at the office or through referral.
  - More intensive psychosocial treatment, including inpatient treatment or transfer to an opioid treatment program (OTP) for observed buprenorphine dosing if the office-based practice is unable to provide such services.
  - Reassessment to ensure psychiatric and other comorbid addictions are adequately addressed via consultation with mental health, addiction treatment, or pain management providers as available and indicated.

Some patients may need a more structured environment when there is continued opioid use or comorbid use of substances other than opioids or when mental disorders are impeding their progress toward remission and recovery. In these cases, medication for OUD should not be interrupted.

Treatment agreements can help clarify expectations for patients and healthcare professionals (see the Chapter 3C Appendix and Chapter 3D Appendix for sample treatment agreement forms for XR-NTX and buprenorphine, respectively). Review and amend treatment plans and treatment agreements periodically as patients progress (or destabilize) and new goals emerge. This will help healthcare professionals across settings deliver coordinated, effective care. Updating treatment plans and agreements helps patients recognize their progress and supports their motivation to remain engaged. Involving patients' support networks makes patients accountable to a group of caring people rather than to a single healthcare professional.

If a patient does not discontinue all illicit drugs for extended periods, it doesn't mean treatment has failed and should not result in automatic discharge. It means the treatment plan may require modification to meet the patient's needs.

Engage patients' family members and other recovery supports (with patients' written consent) by sharing their treatment goals and agreements. Identify specific ways they can support patients' goals.^367^

### Medical Management Strategies

Medical management includes:

• Providing brief supportive counseling.
• Referring to ancillary psychosocial services.
• Referring to psychiatric and medical care if not directly provided by the healthcare professional prescribing or administering OUD medication.
• Adjusting the frequency of office visits.
• Conducting drug tests.
• Monitoring patient adherence to medication with occasional observed dosing, random medication inventorying, or both.
• Addressing patient concerns about side effects.
• Discussing any concerns with the patient or their support network.
• Prescribing medication for co-occurring alcohol use disorder (e.g., disulfiram, acamprosate).

The TIP expert panel recommends medication management and brief supportive counseling at each visit. Refer for adjunctive addiction counseling and other psychosocial supports as clinically indicated.

Strategies for optimizing medical management and brief supportive counseling involve:

• Helping the patient manage stressors and identify triggers for a return to illicit opioid use.
• Providing empathic listening and nonjudgmental discussion of triggers that precede use or increased craving and how to manage them.
• Providing ongoing assessment to mark progress. Revise treatment goals via shared decision making to incorporate new insights. (See “Treatment Planning or Referral” in Part 2 of this TIP for more on shared decision making.)
• Providing medical care for comorbid health conditions.
• Referring patients as needed to:
  - Adjunctive psychiatric treatment.
  - Addiction counseling.
  - Case management.
  - Community-based recovery support groups.
• Inviting supportive family members and friends to medical visits to discuss strategies to support patients.
• Engaging and educating family members and friends who are reluctant to accept medication's role in treatment.
• Advocating for patients as needed if their treatment becomes threatened by their employer, housing provider, insurance company, the courts, or criminal justice agencies. These threats, refusal of service, or frank coercion may constitute potential violations of the Americans with Disabilities Act or other discrimination or parity violations.

#### Referral to counseling and other psychosocial supports

Prescribers of buprenorphine must be able to refer patients for appropriate adjunctive counseling and ancillary services as needed according to federal law.^368^ (However, patients can still receive buprenorphine treatment even if they do not use such services.) There's no such referral requirement for naltrexone treatment, but patients should receive medical management and be referred as needed for adjunctive addiction, mental health, or recovery services.

To achieve clinical stability and abstinence from illicit drug use, many patients need psychosocial counseling and support services beyond what their buprenorphine prescriber's practice offers. For example, patients with mental disorders (e.g., depression, posttraumatic stress disorder)^369^ should be assessed and treated with appropriate medications (as indicated) and adjunctive mental health services.

Some patients are reluctant to engage in addiction counseling or recovery support groups until they stabilize on medication. Once stabilized, they may see benefits to participating in these supports. Recommend additional addiction, mental health, and social services as appropriate if patients:

• Do not achieve full remission.
• Continue to misuse nonopioid substances.
• Do not reach their treatment goals with medication management alone.

Behavioral treatment with contingency management (e.g., rewards for illicit drug abstinence) is highly effective and is offered in some specialty treatment programs. It can motivate the patient to reduce illicit drug use, including opioids and stimulants, and increase medication adherence.^370^

Alcoholics Anonymous, Narcotics Anonymous, Self-Management and Recovery Training, and other peer recovery support groups can be helpful to patients, especially if they find groups with accepting attitudes toward OUD medication and people who take it. (See Part 5 of this TIP for resources on recovery support groups.) Some peer recovery support groups consider patients taking methadone and buprenorphine for OUD treatment as not being abstinent from opioids. Check with local groups before referring a patient. Groups not accepting of OUD medications are not appropriate for patients taking them. Patients are most likely to benefit from peer support programs if they actively participate in offered recovery activities.^371^ Monitor recovery activities to ensure that patients are accessing appropriate supports and are benefiting from them (Exhibit 3E.2).

EXHIBIT 3E.2. Monitoring Recovery Activities

At medical management visits, do not simply ask about attendance at recovery support meetings—explore the level of participation and engagement in those activities. Some activities include:

• Finding and working closely with a sponsor.
• “Working” the 12 Steps at 12-Step meetings and with a sponsor.
• Doing service at meetings (e.g., setting up chairs, making coffee, going on a “commitment” to speak at a meeting in a jail or an inpatient drug and alcohol program).
• Having and frequently attending a regular “home” group.^372^

Remember this statement from recovery experts A. Thomas McLellan and William White:

“Recovery status is best defined by factors other than medication status. Neither medication-assisted treatment of opioid addiction nor the cessation of such treatment by itself constitutes recovery. Recovery status instead hinges on broader achievements in health and social functioning—with or without medication support.”^373^

Patients may need many other psychosocial services. Case managers can help patients obtain:

• Housing support.
• Medicaid or other health insurance.
• Income support.
• Food assistance services.
• Vocational and educational services.
• Mental health and family therapy.

Refer to psychosocial services as appropriate. Get patient consent to share information and make provider introductions, just as referrals to other medical specialists would occur. Strategies include:

• Referring per program availability, affordability, and patients' needs, preferences, and treatment responses. Ensure referrals to programs that accept and support patients receiving OUD medication.
• If possible, personally introducing patients to the new behavioral health service providers or peer recovery support specialists if changing settings, to encourage a successful transition.
• Developing and maintaining a list of referral resources, including:
  - Drug and alcohol counselors.
  - Inpatient, residential, and outpatient addiction counseling programs.
  - OTPs.
  - Inpatient/outpatient behavioral health programs.
  - Primary care and mental health providers.
  - Community-based services.
  - Recovery support groups.
• Using active referral procedures (e.g., linking patients directly via phone to a specific program staff member) instead of passive ones (e.g., giving a patient a name and a phone number to call).
• Avoiding leaving patients to find their own referrals.
• Monitoring patients' follow-through via phone contact or at the next office visit.

#### Frequency of medical management visits

The TIP expert panel recommends that patients be seen approximately once a week until they demonstrate significant reductions in or abstinence from illicit substance use.^374^ This is also a time to ensure medication adherence. Nonadherence to naltrexone or buprenorphine prevents optimal treatment outcomes. In scheduling patient visits, be sensitive to treatment barriers such as:

• Work and childcare obligations.
• Cost of care and lack of insurance coverage.
• Driving time.
• Lack of public transportation to visits, which may be particularly challenging for patients in rural areas.

Goals of weekly visits include:

• Assessing patients' clinical needs and challenges.
• Assessing medication effectiveness and side effects.
• Assessing functional status (e.g., home, work, school).
• Assessing and monitoring stress coping strategies and potential triggers for return to substance use.
• Assessing adherence to the recommended frequency of attendance for XR-NTX injections or the prescribed buprenorphine dosing regimen and responsible handling of the medication (e.g., safely storing out of reach of children, taking as prescribed, not sharing or losing it).
• Monitoring use of alcohol and illicit drugs and ensuring adequate therapeutic dosing (e.g., opioid blockade if there is ongoing illicit opioid use and adherence to medication).
• Following up on any referrals made, such as adjunctive counseling, recovery support groups, or other psychosocial services (the Chapter 3E Appendix has a sample medical management visit form).

Once patients adhere to therapeutic doses of OUD medication, decrease illicit drug and alcohol use, and increase negative opioid toxicological samples, consider less frequent visits. Monthly visits (or less for carefully selected patients who have been stable on buprenorphine for extended periods with adequate support) are reasonable for patients taking naltrexone or buprenorphine who show progress toward treatment objectives. Indications that a patient is ready to come less than weekly include:

• Several weeks of illicit opioid abstinence based on self-report and negative drug tests.
• Adherence to appointments and treatment plan.
• No ongoing drug use that may risk patient safety (e.g., alcohol or benzodiazepine misuse).
• Absence of significant medication side effects.
• Stable mental health and medical conditions.
• Responsible handling of medication (e.g., safe storage, no requests for early refills).
• Absence of unexpected controlled medication prescriptions from other providers in the PDMP.

As visits become less frequent, consider random urine drug testing, medication counts (buprenorphine tablets or films), and involvement of network supports if available.

Buprenorphine implants are indicated only for stable patients already taking transmucosal buprenorphine with positive treatment response. Extended-release buprenorphine is indicated for patients treated with transmucosal buprenorphine for at least 1 week. It's expected that patients with the implants or those treated with extended-release buprenorphine will receive medication management services with visits approximately weekly at the start and then less frequently as clinically indicated based on patient treatment response. Likewise, patients treated with XR-NTX should be seen more than once per month when initiating the medication to monitor progress and assess and address any side effects.

Visit frequency should not depend only on dosing schedule for long-acting OUD medications. Also consider patients' treatment needs, preferences, and responses. To ensure continued engagement, consider adding to the treatment agreement the expected visit frequency and frequency of other ancillary treatments tailored to patients' needs, goals, and preferences.

#### Drug testing in ongoing medical management

Ongoing clinical monitoring that includes drug testing of urine or oral fluid specimens is part of good practice. Objective evidence of any ongoing illicit substance use is important to consider along with patient reports. Patients may not wish to disclose recent drug use because of shame, fear of punishment, or even fear of discharge from treatment.

Explain to patients that testing will help them meet treatment goals and is not performed to render punishments. Results help:

• Detect medication nonadherence that could cause harm (e.g., unintentional overdose).
• Monitor abstinence and response to medication treatment.
• Counsel and improve treatment plans.
• Detect a return to illicit opioid use or other substance use.

The TIP expert panel recommends periodic random testing. Drug testing frequency should be clinically determined. It should occur at least at the time of the initial evaluation and initiation of medication (naltrexone, buprenorphine) and at a frequency consistent with office visits (e.g., weekly initially).

Point-of-service tests give immediate results, allowing findings and implications to be discussed with patients during visits. However, some circumstances require confirmatory laboratory testing, such as when the patient contests the results and when testing for employment or legal monitoring. In these cases, samples may need to be collected and sent to a Department of Health and Human Services-certified laboratory under strict chain-of-custody procedure. In addition, norbuprenorphine may not be available in point-of-service tests and therefore, periodically, a specimen should be sent to a laboratory for testing. Important aspects of testing include:

• Testing technology.
• The cutoffs for positive tests.
• Any administrative requirements.
• Time windows to detect a positive result.
• Cross-reactivity, sensitivity, and specificity.
• Test interpretation. (See Part 2 for more information about how to interpret drug testing results.)
• Consideration of panels based on drugs most commonly used in the region.

Conduct point-of-service drug tests following the manufacturer's instructions. Use Clinical Laboratory Improvement Amendments-waived testing kits. A provider's office must enroll and pay a modest fee for certification. The application is available online (www.cms.gov/Medicare/CMS-Forms/CMS-Forms/downloads/cms116.pdf).

Sample collection via oral swab is straightforward; follow the manufacturer's directions. If collecting urine samples, take steps to reduce the likelihood of tampering. In settings that treat many patients or treat patients potentially facing criminal justice sanctions, consider taking these measures:

• Have patients visit the bathroom alone, without bags or jackets, to deter use of another person's urine specimen.
• Set the sink to run only cold water and use a colored toilet bowl cleaner to prevent dilution of urine specimens.
• Use specimen cups with specific gravity testing, if possible, to identify diluted samples.
• Use temperature-sensitive strips in collection cups to identify tampered specimens.

Ongoing positive opioid tests during treatment indicate the need to reassess the patient and revise the treatment plan. Repeated positives may indicate that patients:

• Are not taking some or all of their medication or may be taking the medication incorrectly.
• Need a different medication.
• Need directly observed medication administration in the office or at an OTP.
• Need a buprenorphine dose increase.
• Need more counseling or a higher level of a specialty addiction treatment program.
• Need to participate in recovery support services.

For more information on drug testing in the primary care setting, see Technical Assistance Publication 32, Clinical Drug Testing in Primary Care^375^ (https://store.samhsa.gov/product/tap-32-clinical-drug-testing-primary-care/sma12-4668) and ASAM's Consensus Statement on Appropriate Use of Drug Testing in Clinical Addiction Medicine.^376^

#### Opioids and opiates in point-of-service tests

Point-of-service and laboratory screening tests for opiates only test for opioids metabolized to morphine (e.g., codeine, heroin). Semisynthetic and synthetic opioids, such as methadone, buprenorphine, and others (e.g., fentanyl, oxycodone), are not metabolized to morphine and do not test positive on most opiate tests. Specific point-of-service tests exist for these opioids.

Some point-of-service and laboratory tests can detect methadone, buprenorphine, and other opioids. Patients taking buprenorphine should have buprenorphine specifically included in their urine test panel to assure the prescriber that the patient is indeed taking the medication. Some patients may put some of their buprenorphine in the urine to mask nonadherence. Periodically testing for a buprenorphine metabolite (e.g., norbuprenorphine, buprenorphine glucuronide) is advised.

#### Assessing buprenorphine adherence

Medication nonadherence and diversion can signal inadequately treated OUD (e.g., return to use with positive urine drug tests). Assess such behaviors clinically and develop therapeutic responses to them.

Remember that nonadherence, misuse, and diversion occur with other medications as well—those with and without abuse potential. For instance, it's clear that opioid analgesics have been overprescribed for pain, misused, and diverted; they have contributed to deaths among individuals prescribed as well as those not prescribed these medications. Antibiotics for bacterial infections are also overprescribed, and patient nonadherence (e.g., not completing the full course), misuse (e.g., saving leftover medication for a later self-diagnosed and self-treated infection), and diversion (e.g., giving leftover medication to ill family members or friends) can cause significant public health harm, given the spread of drug-resistant bacteria. Medication nonadherence has largely fueled development of longer acting medications (e.g., depot antipsychotics, long-acting contraceptives, XR-NTX, buprenorphine implants).

Strategies for addressing medication nonadherence and diversion include carefully assessing the patient to understand underlying causes of the behavior. Address these causes and monitor adherence. For instance, if a patient gives his or her medication to a relative on a waiting list for treatment, getting the relative into treatment can help that patient become adherent. Monitor adherence by:

• Asking patients to bring their unused medication into the office for counting.
• Increasing the frequency of office visits.
• Increasing urine drug testing.
• Talking with family members or significant others.
• Writing prescriptions for shorter duration.
• Observing medication administration at the office, pharmacy, or OTP.
• Checking urine for buprenorphine and its metabolites.
• Checking the PDMP.
• Avoiding doses over 24 mg (save in rare cases).

Chapter 3D Appendix includes a sample patient urine drug screen and medication count form, as well as a pharmacy tablet/film count form.

If these steps have no positive effect, patients may need referral to higher levels of care at OTPs or residential addiction treatment programs. Different formulations of medications may need to be considered.^377^ If a change in setting is required, consider patients for return to OBOT once they stabilize.

#### Discontinuing medication for OUD

Patients should decide whether to taper off or discontinue medication with the support of their healthcare professional and, if applicable, their addiction or mental health counselor, family, and peer recovery supports (e.g., peer support specialist, recovery coach). If patients' goals include stopping medication, discuss the risks and benefits of discontinuing. Work closely with patients to develop a buprenorphine dose taper plan, if needed, and a robust plan to sustain recovery and reengage in treatment before any return to substance use. Before patients begin a buprenorphine dose taper or discontinue XR-NTX, they should demonstrate:

• Medication adherence.
• Abstinence from illicit opioid use.
• A stable living environment.
• Social support.
• Sustained improvements in functioning at home and at school or work.

Consider treatment with XR-NTX following successful taper from an opioid agonist or partial agonist (after an appropriate period of abstinence). Data are limited on the effectiveness of this approach.

The TIP expert panel recommends that providers not discharge patients from treatment solely because of continued illicit opioid use if the benefits of treatment continue to outweigh the risks. If risks outweigh benefits or alternative treatments may offer more benefit, refer patients to alternative treatment (e.g., OTP). Discharging patients without attempting meaningful referral when illicit opioid use is ongoing can worsen the patient's condition and may be considered patient abandonment.

##### Forced tapers or abrupt discontinuation

Forcing a patient to taper off of medication for nonmedical reasons or because of ongoing substance misuse is generally inappropriate. Many patients are abruptly discontinued or tapered from OUD medication against their will while detained or awaiting trial. A randomized trial of continuing versus tapering off methadone for detainees found that those who kept taking medication in detention were significantly more likely to return to treatment on release.^378^ It is likely that the same holds true for forced discontinuation from buprenorphine during detention.

Do not require discontinuation of medication for OUD because of incomplete treatment response. Doing so is not a rational therapeutic response to the predicted course of a chronic condition.

As is sometimes the case in general medical practice, patients who are unable to pay their bills should not be discontinued from treatment without attempting meaningful referral. Attempt referrals to publicly funded addiction treatment services (e.g., specialty treatment programs, federally qualified health centers). If patients cannot continue treatment because of inability to pay, providers can contact the pharmaceutical company about patient assistance programs to help defer the cost of medications.

Forced dose tapers against the patient's desire may be clinically indicated when risks of treatment outweigh benefits or, in unusual cases, where the patient has been violent toward staff or other patients. In these cases, attempt to place the patient in a higher level of care and document the attempt. In some circumstances, forced tapering or abrupt discontinuation may violate the Americans with Disabilities Act. The Legal Action Center (www.lac.org) and the National Alliance for Medication Assisted Recovery (www.methadone.org) offer information on how to legally manage forced tapers.

#### Patient follow-up

Medical management should not end when patients taper off of medication. The TIP expert panel recommends regular follow-up visits (or phone checkups by clinical staff or recovery support specialists) to help patients manage their condition, address potential concerns about returning to illicit opioid use, and discuss reinitiating OUD maintenance medication if warranted. Attendance at drug counseling or mutual-help groups can be helpful, as can periodic drug testing.

## Administrative Considerations

### Patient Limits

Individual healthcare practitioners can prescribe buprenorphine in any medical setting, as long as they apply for and receive waivers of the special registration requirements defined in the Controlled Substances Act. Several laws and regulations contain information about which healthcare practitioners are eligible to apply for a waiver and how to qualify (www.samhsa.gov/medication-assisted-treatment/training-materials-resources/apply-for-practitioner-waiver). This information is summarized below.

Eligible physicians, nurse practitioners, physician assistants, and other qualifying practitioners (clinical nurse specialists, certified registered nurse anesthetists, and certified nurse midwives) can apply for a waiver.

At present, clinical nurse specialists, certified registered nurse anesthetists, and certified nurse midwives are only eligible to apply for a waiver until October 1, 2023.

For the first year of waiver use, all providers can treat up to 30 patients at one time. However, providers who satisfy additional practice and reporting requirements, and physicians who are board certified in addiction psychiatry or addiction medicine, may request to treat up to 100 patients at a time in the first year of waiver use. Additionally, practitioners who provide MAT in “qualified practice settings,” as defined in title 42, section 8.615 of the Code of Federal Regulations, may also request to treat up to 100 patients within the first year.

After the first year of waiver use, all providers may request to increase their patient limit to 100.

Physicians who are board certified in addiction psychiatry or addiction medicine or who satisfy additional practice and reporting requirements may apply to increase their patient limit to 275 after a year at the 100-patient limit.

### Diversion Control Policies for OBOT With Buprenorphine

Controlled substance diversion refers to unauthorized provision of medication to someone for whom it was not prescribed.^379^ Patients may divert buprenorphine for various reasons, such as:

• To “help” someone who needs medically supervised withdrawal or awaits treatment.^380,381^
• To provide income for the seller.
• To enable someone else to experience the euphoric effect of the medication.^382^

Address diversion of controlled substances with patients using the following strategies:

• Clarify that continuing in office-based treatment depends largely on taking medication as prescribed; nonadherence and diversion are thus problematic.
• In a nonjudgmental way, discuss to whom within their network of family, friends, and acquaintances they might be tempted to divert their medication and why they might be tempted to do so.
• Instruct patients to store medication securely (children may inadvertently ingest it and overdose, or other people may take the medication for their own use or to sell).^383^
  - Discuss patients' plans to safely store buprenorphine. Advise patients to keep the medication in the original packaging and out of the reach of children.^384^
  - Tell patients not to store their medication in common areas (e.g., kitchen, bathroom) where others may access it.
  - Educate patients that any portion of a dose taken by a child or pet can be deadly and that they should call 9-1-1 immediately if this occurs.
• Explain how diversion causes negative views of treatment, leading to discrimination against people with OUD. Therefore, healthcare professionals must proactively address diversion to help prevent it.

Possible signs that a patient is diverting buprenorphine^385^ include:

• Frequently missed appointments.
• Requests for early refills because medication was reportedly lost or stolen.
• Negative buprenorphine urine screens.
• Positive buprenorphine urine screens that are negative for buprenorphine metabolites.
• Specific requests for the buprenorphine monoproduct owing to naloxone allergy.
• Specific requests for doses of buprenorphine greater than 24 mg/6 mg.
• PDMP shows prescription fills for opioids or other medications that are not positive on his or her drug tests.
• Failed film/pill callback counts.

Establish a diversion control plan to minimize OUD medication diversion. The plan provides measures to reduce diversion and assigns specific responsibility to medical and administrative staff members for carrying out these measures.^386^ It should address medication storage, dispensing and administration (if applicable), and prescribing^387^ (see the Chapter 3E Appendix for a sample diversion control policy). For providers who store buprenorphine for administration and dispensing, plans should indicate how they will control diversion and which approaches they will use to ensure that patients take their medication. Exhibit 3E.3 summarizes key elements of a diversion control plan.

EXHIBIT 3E.3. Key Elements of an OBOT Clinic Diversion Control Plan^389^

##### New Patients

Check the state's PDMP before admission to determine whether patients are receiving opioids or benzodiazepine prescriptions from other providers.

Ask patients to sign a release of information to speak with the other prescribers. Patients who are unwilling to sign a release of information are poor candidates for outpatient treatment.

Review the clinic diversion control policy with new patients. This should include counseling patients to:

• Keep buprenorphine locked up and out of children's reach.
• Never share medication with anyone.
• Never sell medication to anyone.
• Acknowledge giving or selling medication to others as illegal.
• Take medication only as prescribed.
• Review, understand, and agree to the practice's buprenorphine treatment agreement before they start.

Prescribe buprenorphine/naloxone when possible rather than monoproduct. Exceptions include prescribing the monoproduct for pregnant women with OUD.

Prescribe an adequate but not excessive dose. Most patients respond to doses at or below 24 mg per day. Carefully evaluate requests for higher doses and confirm, document, and assess medication adherence continuously.

##### Ongoing Patients

Periodically check the state's PDMP.

Conduct random urine tests that include a wide spectrum of opioids—including morphine, oxycodone, and buprenorphine—and periodically include buprenorphine metabolites. This will help monitor response to treatment and determine whether patients are taking at least some of their prescribed buprenorphine.

Use unobserved specimen collection to preserve patient privacy and dignity:

• Do not let patients bring backpacks, jackets, or other items into the bathroom.
• Do not let others enter bathrooms with patients.
• Temperature test the urine sample.

Use observed specimen collection (obtained by a staff member of the same gender) or oral fluid testing if there is reason to suspect tampering or falsification.

Contact patients at random; ask them to bring in their medication within a reasonable period (24 to 48 hours) to count the tablets/films to ensure that all medication is accounted for.

Provide a limited number of days of medication per prescription without refills (e.g., several days or 1 week per prescription) until the patient has demonstrated stability and lowered diversion risk.

Physicians who prescribe buprenorphine to more than 100 patients need a diversion control plan. Document diversion incidents and responses to incidents in the patient record. More information about Drug Enforcement Administration (DEA) requirements for Drug Addiction Treatment Act of 2000 (DATA 2000)-waivered healthcare professionals is available online (www.deadiversion.usdoj.gov/pubs/docs/index.html).

### Storage of Buprenorphine

Practices that store buprenorphine onsite must have appropriate security, which includes storing the medication in a securely locked, substantially constructed cabinet.^388^ If a significant amount of stored buprenorphine is lost or stolen, providers must notify the local DEA office in writing within 1 business day and complete a Form DEA-106 (https://apps.deadiversion.usdoj.gov/webforms/dtlLogin.jsp).

Employees convicted of a felony related to a controlled substance or who had a DEA registration denied, revoked, or surrendered “for cause” are not permitted to have access to buprenorphine.

### Records for Dispensers

Office-based practices that dispense buprenorphine must keep records of:^390^

• The number of units and doses dispensed with the names and addresses of the patients.
• The dates the medication was dispensed.
• The names (or initials) of the staff members who dispensed or administered the medication.

The diversion control plan should include approaches to ensuring that patients take the medication and do not divert it to others.

#### Recordkeeping for ordering, storing, and dispensing buprenorphine in the office

All prescribers and staff members must follow federal and state laws for ordering, storing, administering, and dispensing buprenorphine in outpatient settings. Records of inventories of medication received, dispensed, destroyed, and lost or stolen must be maintained. For guidance on how to comply with federal requirements, see:

• DEA Recordkeeping Requirements for Buprenorphine Treatment (https://docs.clinicaltools.com/pdf/Buppractice/V5-Bup-How-To-Comply.pdf).

#### Recordkeeping for prescribing buprenorphine

Consider writing an initial prescription for only a few days. An example of a 1-day in-office induction prescription is:

Buprenorphine/naloxone 2mg /0.5 mg: Dispense #4 for in-office induction, no refills, fill on ______________ [insert date that is 1 day before the scheduled induction to make it less tempting for patients to use on their own before induction]

Keep a log for possible DEA inspection that includes:

• Patients' names (or ID numbers).
• Dates of prescriptions.
• The names, strengths, and quantities of the medications.

Although not required, such a log facilitates inspection and indicates that the provider is within the approved patient limits. Alternatively, electronic health records can be used for this purpose.

### DEA Inspections

Under DATA 2000, DEA must ensure that providers administering, dispensing, or prescribing buprenorphine are following recordkeeping, security, and other requirements. To fulfill this requirement, DEA conducts routine, unannounced onsite inspections. A description of the inspection process and how to comply with its requirements is available online (http://pcssnow.org/wp-content/uploads/2014/02/FINAL-How-to-Prepare-for-a-DEA-Inspection.pdf).

## Emergency Protocols and Patient Safety Measures

Clinics that provide buprenorphine or naltrexone do not need special emergency protocols, crash carts, or other special equipment. However, for patient safety, the TIP expert panel recommends having injectable or intranasal naloxone onsite. Clinics that administer XR-NTX or buprenorphine should have a written policy and procedure for responding to precipitated withdrawal and medication allergies.

Providers who give more than 100 patients buprenorphine must have on-call services. Such services are valuable regardless of the number of patients in treatment.

On-call services and backup during absences should be available either directly or through contracts or cooperative agreements with other local providers with waivers. Qualified medical staff can offer routine medical and psychiatric coverage even without a buprenorphine waiver.

## Recommendations for Staff Member Training

All staff members who interact with patients are part of the treatment environment. They can affect patients' treatment experiences and, ultimately, their outcomes. Staff members who interact with patients can include receptionists, billing clerks, urine specimen collection clerks, and all clinical staff members. Therefore, it is useful to educate and train all staff members in key areas, including:

• Organizational mission.
• The scientific and empirical underpinnings for the use of FDA-approved medications for OUD, how these medications work, and the evidence for their effectiveness.
• The similarity of medical management and support of patients with OUD to that of patients with other chronic illnesses.
• The importance of maintaining a nonjudgmental and welcoming attitude toward patients.
• How to hold discussions about negative perceptions and prejudices associated with OUD.
• Side effects of OUD medications and procedures to alert staff members when patients exhibit them.
• The effect of OUD and other substance use and mental disorders (including posttraumatic stress disorder) on patients' behavior and how staff members can respond appropriately.
• Procedures for seeking help from other staff members to deescalate disagreements or solve problems.
• Procedures for protecting patients' confidentiality and safety.

Treating OUD can be a challenging yet rewarding part of a clinical practice. Addressing key administrative issues keeps the focus on the rewarding aspects of developing long-term relationships with patients as they work to overcome negative effects of OUD on their lives and improve their health.

RESOURCE ALERT

#### Training and Mentorship for Prescribers

The Providers' Clinical Support System, with the American Academy of Addiction Psychiatry as the lead organization along with partners from ASAM and other professional organizations, delivers education, training, and mentorship to providers who wish to treat OUD with medications. More information about training and professional mentorship is available online (https://pcssnow.org/education-training/).

## Chapter 3E Appendix

Sample Goal-Setting Form

Sample Medical Management Visit Form

Sample Buprenorphine Diversion Control Policy