# Chapter 3D: Buprenorphine

Chapter 3D is an overview of buprenorphine pharmacology and specific dosing guidance for sublingual and buccal formulations and buprenorphine implants and injections.

Buprenorphine and buprenorphine/naloxone formulations are effective treatments for opioid use disorder (OUD). Numerous clinical studies and randomized clinical trials have demonstrated buprenorphine's efficacy in retaining patients in treatment and reducing illicit opioid use compared with treatment without medication and medically supervised withdrawal.^223,224,225^ Other research has associated it with reduction in HIV risk behavior and risk of overdose death, and its effectiveness has been shown in primary care settings.^226,227,228,229,230^ Buprenorphine is on the World Health Organization (WHO) list of essential medications.^231^

The Treatment Improvement Protocol (TIP) expert panel recommends offering the option of Food and Drug Administration (FDA)-approved buprenorphine formulations to appropriate patients with OUD, considering patient preferences for and experience with other medications or no medication. These recommendations align with Department of Veterans Affairs guidelines.^232^

## Formulations

### History of Approvals

FDA originally approved buprenorphine for analgesia. Formulations for OUD treatment were approved in:

• 2002: Sublingual buprenorphine/naloxone sublingual tablets (Suboxone); sublingual buprenorphine tablets (Subutex). The manufacturer discontinued the tablet formulations of both from the U.S. market after the film's approval, but generic tablet formulations are still available (Exhibit 3A.5, Chapter 3A).
• 2010: Buprenorphine/naloxone sublingual films.
• 2013: Buprenorphine/naloxone sublingual tablets (Zubsolv).^233^
• 2014: Buprenorphine/naloxone buccal films (Bunavail).^234^
• 2016: Buprenorphine implants (Probuphine).
• 2017: Buprenorphine extended-release injection (Sublocade).
• 2018–2019: Additional dosage strengths of buprenorphine/naloxone sublingual films.

FDA approved generic buprenorphine and buprenorphine/naloxone formulations based on evidence that they produce similar (within 90 percent confidence intervals) bioequivalence on pharmacokinetic measures, such as peak serum concentration, compared with the original sublingual buprenorphine/naloxone product.

The 2013 and 2014 branded formulations have greater bioavailability than Suboxone, meaning they deliver more buprenorphine to the bloodstream, thus achieving the same effect as the original product with lower doses. For example, 5.7 mg/1.4 mg of Zubsolv and 4.2 mg/0.7 mg of Bunavail provide the same buprenorphine exposure as 8 mg/2 mg of Suboxone.

Opioid treatment programs (OTPs) may administer or dispense buprenorphine, but only providers with Substance Abuse and Mental Health Services Administration (SAMHSA) waivers can prescribe buprenorphine for OUD. See “Resource Alert: How To Obtain a Waiver To Prescribe Buprenorphine” in Chapter 3A of this TIP.

Exhibit 3D.1 lists product strengths and recommended once-daily maintenance doses. For simplicity, dosing information here refers to sublingual Suboxone or generic equivalents. An 8 mg/2 mg dosage of sublingual Suboxone is equivalent to 5.7 mg/1.4 mg of sublingual Zubsolv and 4.2 mg/0.7 mg of buccal Bunavail.

EXHIBIT 3D.1. Buprenorphine Transmucosal Products for OUD Treatment

PRODUCT NAME/ACTIVE INGREDIENT | ROUTE OF ADMINISTRATION/FORM | AVAILABLE STRENGTHS | RECOMMENDED ONCE-DAILY MAINTENANCE DOSE
Bunavail^235^; • Buprenorphine hydrochloride; • Naloxone hydrochloride | Buccal film | 2.1 mg/0.3 mg; 4.2 mg/0.7 mg; 6.3 mg/1 mg | Target: 8.4 mg/1.4 mg; Range: 2.1 mg/0.3 mg to 12.6 mg/2.1 mg
Generic combination product^236,237^; • Buprenorphine hydrochloride; • Naloxone hydrochloride | Sublingual tablet, film | 2 mg/0.5 mg; 4 mg/1 mg; 8 mg/2 mg; 12 mg/3 mg | Target: 16 mg/4 mg; Range: 4 mg/1 mg to 24 mg/6 mg^*^
Generic monoproduct^238,239^; • Buprenorphine hydrochloride | Sublingual tablet | 2 mg; 8 mg | Target: 16 mg; Range: 4 mg to 24 mg^*^
Suboxone^240,241^; • Buprenorphine hydrochloride; • Naloxone hydrochloride | Sublingual film | 2 mg/0.5 mg; 4 mg/1 mg; 8 mg/2 mg; 12 mg/3 mg | Target: 16 mg/4 mg; Range: 4 mg/1 mg to 24 mg/6 mg^*^
Zubsolv^242,243^; • Buprenorphine hydrochloride; • Naloxone hydrochloride | Sublingual tablet | 0.7 mg/0.18 mg; 1.4 mg/0.36 mg; 2.9 mg/0.71 mg; 5.7 mg/1.4 mg; 8.6 mg/2.1 mg; 11.4 mg/2.9 mg | Target: 11.4 mg/2.9 mg; Range: 2.9 mg/0.71 mg to 17.2 mg/4.2 mg

* Dosages above 24 mg buprenorphine or 24 mg/6 mg buprenorphine/naloxone per day have shown no clinical advantage.^244,245^

Adapted from material in the public domain. ^ 246 ^

Patients who switch formulations may experience clinically significant plasma concentration changes that may require dose adjustments; bioavailability is similar, but not identical, between formulations.

### Implants

In 2016, FDA approved buprenorphine implants for OUD maintenance treatment in patients who have achieved sustained clinical stability (e.g., periods of abstinence, minimal or no desire to use illicit opioids, stable housing, social support) while taking no more than 8 mg of Suboxone or generic equivalents. The implants are a set of four rods, each 2.5 mm in diameter and 26 mm in length. Each rod contains the equivalent of 80 mg of buprenorphine hydrochloride. The implants are for subdermal insertion on the inside of the upper arm and provide 6 months of buprenorphine. The implants must be removed after 6 months.

Peak buprenorphine plasma concentrations occur 12 hours after implant insertion, slowly decrease, and reach steady-state concentrations in about 4 weeks. Steady-state concentrations are comparable to trough buprenorphine plasma levels produced by daily sublingual buprenorphine doses of 8 mg or less. Implant effectiveness lasts up to 6 months.

### Injectables

In November 2017, FDA approved extended-release (monthly) subcutaneous injectable buprenorphine for moderate-to-severe OUD treatment among patients who initiated treatment with transmucosal buprenorphine, followed by at least 7 days of dose adjustment. It is available in two doses, 300 mg/1.5 mL and 100 mg/0.5 mL. Both are stored refrigerated in prefilled syringes with safety needles and administered by subcutaneous injection in the abdomen. The first two monthly doses recommended are 300 mg each followed by a 100 mg monthly maintenance dose. Peak buprenorphine concentrations occur about 24 hours after the injection. Steady state is achieved after 4 to 6 months. After discontinuation, patients may have detectable plasma levels of buprenorphine for 12 months or longer. Duration of detection in urine is not known.^247^

## Pharmacology

Buprenorphine, an opioid receptor partial agonist, is a schedule III controlled medication derived from the opium alkaloid thebaine. Through cross-tolerance and mu-opioid receptor occupancy, at adequate doses, buprenorphine reduces opioid withdrawal and craving and blunts the effects of illicit opioids.

Buprenorphine binds tightly to the mu-opioid receptor because of its particularly high receptor affinity. This prevents other opioids with lower affinity (e.g., heroin) from binding. The net result is a blunting or blocking of the euphoria, respiratory depression, and other effects of these opioids.

Buprenorphine has less potential to cause respiratory depression, given its ceiling effect. As a partial agonist, buprenorphine's maximum effect on respiratory depression is more limited than full agonists. Once reaching a moderate dose, its effects no longer increase if the dose is increased.^248,249,250^

There is wide individual variability in buprenorphine pharmacokinetics. For example, the mean time to maximum plasma buprenorphine concentration after a single sublingual dose ranges from 40 minutes to 3.5 hours.^251^ Thus, after providing the first dose of buprenorphine, wait at least 2 hours to decide whether a second dose is necessary.

Buprenorphine has a long elimination half-life, which varies from 24 to 69 hours^252^ with a mean half-life of 24 to 42 hours.^253^ It dissociates slowly from the receptor.

Buprenorphine can be safely dosed (even at double the stabilized dose) less than daily.^254^ For example, a patient stabilized on 12 mg of buprenorphine/naloxone daily can be treated with 24 mg every other day or 24 mg on Monday/Wednesday and 36 mg on Friday. Such schedules reduce travel burden for patients who need or want supervised dosing at an OTP or a clinic. Such schedules may also be useful for patients who must spend weekends in jails that disallow buprenorphine dosing.

## Bioavailability

Buprenorphine has poor oral bioavailability compared with sublingual and buccal bioavailability. Naloxone, a short-acting mu-opioid receptor antagonist, has very poor oral, sublingual, and buccal bioavailability but is absorbed when injected or snorted. The addition of naloxone decreases buprenorphine's potential for misuse. In the Suboxone formulation of buprenorphine/naloxone, the ratio of buprenorphine to naloxone is 4:1. The ratio of buprenorphine to naloxone varies across products, as the absorption of both active ingredients is different for buccal versus sublingual films versus tablets.

Buprenorphine/naloxone transmucosal products are abuse-deterrent formulations, although they can still be misused. When a patient takes these formulations as prescribed, he or she absorbs buprenorphine but only a biologically negligible amount of naloxone. But if crushed or dissolved for intranasal or intravenous (IV) misuse, both medications are bioavailable. Naloxone then blunts the immediate opioid agonist effects of buprenorphine. It also induces opioid withdrawal in people who are physically dependent on opioids. This reduces misuse liability compared with transmucosal formulations with buprenorphine alone.^255,256^

Subdermal buprenorphine implants release buprenorphine in steady concentrations over 6 months. These concentrations are approximately equivalent to 8 mg or less of the buprenorphine sublingual formulations. Once implanted, these rods are unlikely to be diverted.

Extended-release buprenorphine for subcutaneous injection releases buprenorphine over at least a 1-month period. After injection, an initial buprenorphine plasma level peaks around 24 hours and then slowly declines to a plateau. With monthly injections, steady state is reached at 4 to 6 months.^257^

### Metabolism and Excretion

Buprenorphine:^258,259^

• Is highly plasma bound.
• Crosses the blood–brain barrier readily because of its high lipid solubility.
• Is excreted in urine and feces.
• Has only one known pharmacologically active metabolite: norbuprenorphine.

Be aware of potential CYP450 3A4 inducers,^260^ substrates, and inhibitors while monitoring for potential drug–drug interactions (see the “Drug Interactions” section below). Buprenorphine undergoes metabolism in the liver primarily by cytochrome P450 (CYP450) 3A4 enzymes. Coadministration of other medications metabolized along this pathway can affect the rate of buprenorphine metabolism.

Buprenorphine has fewer clinically relevant drug interactions than methadone in general. For detailed explanations of metabolism and excretion, see the package inserts for each buprenorphine product.

## Dosing Considerations

Buprenorphine is used for the treatment of OUD. Formulations are available as sublingual tablets and film, buccal film, implants, and extended-release injection (Exhibit 3A.5 in Chapter 3A of this TIP).

### Contraindications

Buprenorphine is contraindicated in patients who are allergic to it. Patients with true allergic reactions to naloxone should not be treated with the combination buprenorphine/naloxone product. Allergy to naloxone is infrequent. Some patients may falsely or mistakenly claim an allergy to naloxone and request buprenorphine monoproduct. Carefully assess such claims and explain the differences between an allergic reaction and symptoms of opioid withdrawal precipitated by buprenorphine or naloxone; the monoproduct has more abuse liability than buprenorphine/naloxone.^261^

### Precautions and Warnings

• Respiratory depression and overdoses are uncommon in adults, but they do happen.^262^ Most fatal overdoses involve IV buprenorphine misuse or concurrent central nervous system depressant use, including high doses of benzodiazepines, alcohol, or other sedatives.^263,264^ However, fatal overdoses have been reported in opioid-naïve patients treated with 2 mg buprenorphine for pain.^265^ Exhibit 3D.2 summarizes the management of patients with preexisting respiratory impairment.
• Unintentional pediatric exposure can be life threatening or fatal.^266^ Thus, emphasize safe storage of medication, and teach patients to remove any buprenorphine found in a child's mouth immediately (even if it was only a partial tablet or film). Call 9-1-1 so the child can go to the nearest emergency department for immediate medical attention.
• Cases of hepatitis and liver failure exist but often involve predisposing hepatic risk factors, such as preexisting liver enzyme abnormalities, hepatitis B or C infections, and use of other potentially hepatotoxic drugs or IV drugs. A multisite randomized trial of hepatic effects in patients taking methadone or buprenorphine found no evidence of liver damage in the first 6 months of treatment. The authors concluded that prescribing these medications should not cause major concern for liver injury.^267^ Exhibit 3D.2 summarizes management of patients with hepatic impairment.
• Potential for misuse and diversion exists. People can misuse buprenorphine via intranasal or IV routes or divert it for others to misuse. Do not give early or multiple refills without careful assessment and monitoring suited to the patient's level of stability.^283,284^
• Discourage misuse and diversion by:
  - Requiring frequent office visits until patients are stable.
  - Testing urine for buprenorphine and norbuprenorphine or buprenorphine glucuronide (both metabolites of buprenorphine).
  - Using other methods to ensure adequate adherence to the medication as prescribed, such as developing and adopting a diversion control plan (see Chapter 3E: Medical Management Strategies).
• Adrenal insufficiency has been reported with opioid use, most often after more than 1 month of buprenorphine maintenance.^285^
• Patients will develop physical dependence on buprenorphine. Alert patients that they'll experience opioid withdrawal if they stop buprenorphine.
• Buprenorphine may affect cognition and psychomotor performance and can have sedating effects in some people (particularly those who've lost tolerance after a period of abstinence from opioids). Concurrent use of illicit drugs, other prescribed medications, or medical or psychiatric comorbidity can affect cognition and psychomotor performance. Urge patients to exercise caution in using heavy machinery and driving until they're sure that their abilities are not compromised.^286^
• Allergic reactions have occurred in patients treated with buprenorphine, including rash, urticaria, angioedema, and anaphylaxis.
• Buprenorphine can cause precipitated opioid withdrawal. It has weaker opioid agonist effects and stronger receptor affinity than full agonists (e.g., heroin, methadone). It can displace full agonists from receptors, precipitating opioid withdrawal.^287^ Factors affecting this possibility include:
  - Current level of opioid physical dependence. The higher the level of physical dependence, the higher the likelihood of precipitating withdrawal.^288^ Ensuring that patients are in opioid withdrawal when initiating buprenorphine decreases this risk.
  - Time since the last mu-opioid receptor full agonist dose. The longer the time since the last dose, the lower the likelihood of precipitated withdrawal.^289^
  - Dose of buprenorphine administered. The smaller the dose of buprenorphine, the less likely it is to precipitate withdrawal.^290,291^
• Neonatal abstinence syndrome (NAS) may occur in newborns of pregnant women who take buprenorphine. Women receiving opioid agonist therapy while pregnant should talk with their healthcare provider about NAS and how to reduce it. Not all babies born to women treated with opioid agonists require treatment for NAS. Research has shown that the dose of opioid agonist medication is not reliably related to the severity of NAS.^292,293,294^ Thus, each woman should receive the dose of medication that best manages her illness.

EXHIBIT 3D.2. Medication Management for Patients With Respiratory or Hepatic Impairment

CONTRAINDICATION/CAUTION | MANAGEMENT
Compromised respiratory function; For example, chronic obstructive pulmonary disease, decreased respiratory reserve, hypoxia, hypercapnia (abnormally elevated blood levels of carbon dioxide), preexisting respiratory depression. | • Prescribe with caution; monitor closely.; • Warn patients about the risk of using benzodiazepines or other depressants while taking buprenorphine.^270^; • Support patients in their attempts to discontinue tobacco use.
Hepatic impairment; Buprenorphine and naloxone are extensively metabolized by the liver. Moderate-to-severe impairment results in decreased clearance, increased overall exposure to both medications, and higher risk of buprenorphine toxicity and precipitated withdrawal from naloxone. These effects have not been observed in patients with mild hepatic impairment.^268,269^ | • Mild impairment (Child-Pugh score of 5–6)^271^ No dose adjustment needed.; • Moderate impairment (Child-Pugh score of 7–9):^272^ Combination products are not recommended; they may precipitate withdrawal.; ^*^Use combination products cautiously for maintenance treatment in patients who've been inducted with a monoproduct;^273,274^ monitor for signs and symptoms of buprenorphine toxicity or overdose.^275^ Naloxone may interfere with buprenorphine's efficacy.^276,277^; • Severe impairment (Child-Pugh score of 10–15):^278^ Do not use the combination product.^279^ For monoproduct, consider halving the starting and titration doses used in patients with normal liver function; monitor for signs and symptoms of toxicity or overdose caused by increased buprenorphine levels.^280^

* Moderate-to-severe impairment results in much more reduced clearance of naloxone than of buprenorphine. Nasser et al.^281^ found that moderate impairment doubled or tripled exposure (compared with subjects with no or mild impairment) for both medications. In subjects with severe impairment, buprenorphine exposure was also two to three times higher; naloxone exposure increased more than tenfold.

Adapted from material in the public domain. ^ 282 ^

REDUCING NAS SEVERITY

Offer the following advice to pregnant women receiving treatment with an opioid agonist:

• Avoid smoking during pregnancy.
• Avoid benzodiazepines.
• Meet with the neonatologist and/or pediatrician to learn how the hospital assesses and treats NAS and what they suggest you can do as a parent to help soothe a baby with NAS.
• Request rooming-in with the child.
• Talk with the healthcare professional providing obstetric care about breastfeeding, as this may help make NAS less severe.
• In the first week after birth, keeping lights low, speaking softly, avoiding too much stimulation, and providing frequent skin-to-skin contact can help prevent or limit symptoms of NAS.

### Drug Interactions

Buprenorphine has fewer documented clinically significant drug interactions than methadone.^295^ Monitoring is still needed for patients who are starting or stopping medications that are CYP450 3A4 enzyme inhibitors or inducers or that compete with buprenorphine for this enzyme. A previously therapeutic and stable dose of either buprenorphine or the coadministered medication may be altered when one of these medications is started or stopped. In the case of buprenorphine, oversedation or withdrawal symptoms may result. In the case of altered levels of other pharmacotherapies, the patient may experience a lack of therapeutic benefit or toxic side effects of that drug. Special attention should be paid to patients using or starting depot formulations of buprenorphine. Prior to initiating a depot formulation, talk with the patient about waiting until any time-limited therapy with a potential inhibitor, inducer, or substrate of CYP450 3A4 is complete, and ensure that adherence to any such medications needed chronically is good. Make sure the patient fully understands the possible risk of fluctuations in buprenorphine serum levels resulting in sedation or withdrawal symptoms and if compliance with an inhibitor, inducer, or substrate of CYP450 3A4 is erratic. If an inhibitor, inducer, or substrate of CYP450 3A4 is to be started or stopped for a patient stable on a depot formulation of buprenorphine, the patient should be monitored closely for oversedation or signs of withdrawal. Remember, signs and symptoms may not appear until the new medication approaches a therapeutic blood level. Signs of withdrawal may be relieved, if necessary, with the short-term use of additional low doses of transmucosal buprenorphine. Patients who experience sedation may need to take safety precautions with some activities. In severe cases, removal of the depot formulation, if possible, may need to be considered. Exhibit 3D.3 partially lists these medications, including some anticonvulsants, and antibiotics, and Exhibit 3D.4 lists HIV medications. More information on drug–drug interactions is available online (www.drugs.com/drug-interactions/buprenorphine-index.html?filter=3&generic_only=).

EXHIBIT 3D.3. Partial List of Medications Metabolized by Cytochrome P450 3A4

Drugs that may DECREASE buprenorphine serum levels
Drug | Mechanism
Anticonvulsants
Phenobarbital, phenytoin, primidone, carbamazepine | Induces cytochrome P450 3A4
Antibiotics
Rifampin | Induces cytochrome P450 3A4
Immune Suppressants
Dexamethasone | Induces cytochrome P450 3A4

Drugs that may INCREASE buprenorphine serum levels
Drug | Mechanism
Antibiotics
Clarithromycin | Inhibits cytochrome P450 3A4
Clindamycin, dapsone, erythromycin | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Antidepressants
Fluoxetine, fluvoxamine, nefazodone | Inhibits cytochrome P450 3A4
Antifungals
Fluconazole, itraconazole, miconazole | Inhibits cytochrome P450 3A4
Ketoconazole | Inhibits and competes with buprenorphine for cytochrome P450 3A4
Antihypertensives
Nicardipine, verapamil | Inhibits cytochrome P450 3A4
Amlodipine, diltiazem, felodipine, nifedipine, nimodipine | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Antiarrhythmics
Amiodarone | Inhibits cytochrome P450 3A4
Disopyramide, quinidine | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Hormones
Estrogen, oral contraceptives, progestins | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Sedative/Hypnotics
Alprazolam, clonazepam, diazepam, midazolam | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Immune Suppressants
Cyclosporine, zafirlukast | Inhibits cytochrome P450 3A4
Statins
Atorvastatin, lovastatin, simvastatin | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Gastric Agents
Aprepitant, cimetidine | Inhibits cytochrome P450 3A4
Analgesics
Fentanyl | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Antihistamines
Loratadine | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Chemotherapeutics
Doxorubicin, etoposide, ifosfamide, paclitaxel, vinblastine | Competes with buprenorphine for cytochrome P450 3A4 enzyme
Blood Thinners
Warfarin | Competes with buprenorphine for cytochrome P450 3A4 enzyme

Note: Consult a point-of-service medical reference application for the most up-to-date drug–drug interactions before making medication management decisions.

Adapted from material in the public domain. ^ 296 ^

EXHIBIT 3D.4. Potential Interactions Between Buprenorphine and HIV Medications

MEDICATION | TYPE | POTENTIAL INTERACTION
Atazanavir | Protease inhibitor | Increased buprenorphine concentrations. May cause cognitive impairment^302,303^ or oversedation.^304,305^ Slower titration or dose reduction of buprenorphine may be warranted.^306,307^
Darunavir-ritonavir | Protease inhibitor | Some pharmacokinetic (PK) effect; dose adjustments unlikely to be needed, but clinical monitoring is recommended.^308^
Delavirdine | Nonnucleoside reverse transcriptase inhibitor | Increased buprenorphine concentrations, but no clinically significant effect. Dose adjustments unlikely to be needed. However, use with caution, as long-term effects (more than 7 days) are unknown.^309,310^
Efavirenz | Nonnucleoside reverse transcriptase inhibitor | Some PK effect; dose adjustments unlikely to be needed.^311^
Elvitegravir (with cobicistat) | Integrase inhibitor | Some PK effect; no dose adjustments needed.^312^
Nevirapine | Nonnucleoside reverse transcriptase inhibitor | Some PK effect; no dose adjustments needed.^313^
Ritonavir | Protease inhibitor | Some PK effect; no dose adjustments needed.^314^
Tipranavir | Protease inhibitor | Some PK effect; no dose adjustments needed.^315^

Adapted from material in the public domain. ^ 316 ^

Monitor responses to buprenorphine in patients taking nonnucleoside reverse transcriptase inhibitors. Changes in buprenorphine concentrations can be clinically significant.^297^

Combination antiretroviral therapy (atazanavir/ritonavir) increases buprenorphine and norbuprenorphine serum concentrations.^298^ Case reports have demonstrated signs of buprenorphine excess (sedation). Decreasing buprenorphine can improve this symptom.^299^ Other research has demonstrated no need to adjust the buprenorphine dose among patients taking atazanavir.^300^

For tuberculosis treatment, rifampin but not rifabutin may decrease buprenorphine concentrations. Rifampin produced opioid withdrawal in 50 percent of research volunteers with opioid dependence.^301^

FDA warns of increased serotonin syndrome risk with prescription opioids, including buprenorphine. Serotonin syndrome can include:

• Changes in mental status.
• Fever.
• Tremor.
• Sweating.
• Dilated pupils.

Serotonin syndrome can occur with simultaneous opioid and antidepressant treatment. There are only a few case reports of serotonin syndrome with buprenorphine,^317^ but be aware of this possibility given the frequent treatment of mood disorders in patients with OUD.

### Side Effects

Buprenorphine's side effects may be less intense than those of full agonists. Otherwise, they resemble those of other mu-opioid agonists. Possible side effects include the following (buprenorphine FDA labels list all potential side effects https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=8a5edcf9-828c-4f97-b671-268ab13a8ecd):

• Oral hypoesthesia (oral numbness)
• Constipation
• Glossodynia (tongue pain)
• Oral mucosal erythema
• Vomiting
• Intoxication
• Disturbance in attention
• Palpitations
• Insomnia
• Opioid withdrawal syndrome
• Excessive sweating
• Blurred vision

Serious implant-related adverse events are uncommon but possible according to the FDA label (www.accessdata.fda.gov/drugsatfda_docs/label/2016/204442Orig1s000lbl.pdf). Still, more than 10 percent of patients experience implant site pain, itching, or swelling. Migration beyond the local insertion site is rare but possible, as is nerve damage. Buprenorphine may be extruded from implants for potential misuse. Insert implants only in stable patients, for whom FDA has approved this formulation.

Implants may extrude and potentially come out (e.g., from incomplete insertion or infection). Tell patients to call the implanting physician if an implant looks like it is extruding or comes out. If the implant comes out, patients should safely store and dispose of it (following local and federal regulations) to protect others from unintended exposure.

Serious injection site adverse events for the extended-release formulation are uncommon but possible. The most common injection site adverse reactions were pain (7.2 percent), pruritus (6.6 percent), and erythema (4.7 percent) in phase three trials. Two cases of surgical removal of the monthly depot were reported in premarketing clinical studies. Surgical excision under local anesthesia within 14 days of injection is possible. It is recommended that, before treatment, baseline liver function tests be assessed with monthly monitoring during treatment, particularly with the 300 mg dose. There are limited data regarding use of the extended-release injection formulation in pregnant women with OUD. In animal reproductive studies with Sublocade's excipient, N-Methyl-2-pyrrolidone, there were reported fetal adverse reactions. Women should be advised that the use of Sublocade during pregnancy should be considered only if the benefits outweigh the risks (see FDA package insert for full details www.accessdata.fda.gov/drugsatfda_docs/label/2017/209819s000lbl.pdf).

### Assessment

No evidence clearly predicts which patients are best matched to buprenorphine versus other OUD medications. Thorough assessment helps determine whether buprenorphine treatment is appropriate for a patient. (Part 2 of this TIP covers screening and assessment in more detail.) Before prescribing buprenorphine:

• Check the state prescription drug monitoring program database.
• Assess the patient's history.
  - Conduct a medical, psychiatric, substance use, and substance use treatment history.
  - Assess recent opioid use, including frequency, quantity, type, route, and last day of use.
  - Establish OUD diagnosis.
  - Assess for other substance use disorders (SUDs), including those involving alcohol, benzodiazepines, or stimulants.
• Conduct a focused physical examination, refer for a physical exam, or get a record of a recent one.
  - Assess for signs and symptoms of intoxication. Do not give a first dose to a patient who is sedated or intoxicated. Assess and treat him or her appropriately.
  - Assess for evidence of opioid withdrawal and physiological dependence. The Clinical Opioid Withdrawal Scale (COWS) or the Clinical Institute Narcotic Assessment (CINA) Scale for Withdrawal Symptoms can be used to assess withdrawal signs (see “Resource Alert: Opioid Withdrawal Scales”). The patient should exhibit signs of opioid withdrawal before taking the first dose of buprenorphine to avoid precipitated withdrawal. For example, the Risk Evaluation and Mitigation Strategy (REMS) for buprenorphine indicates that a COWS score of 12 or higher is typically adequate for a first dose. Confirming opioid withdrawal suggests that the patient is physically dependent on opioids and can begin induction with a typical 2 mg/0.5 mg or 4 mg/1 mg buprenorphine/naloxone dose.
• Obtain laboratory tests.
  - Conduct drug and alcohol tests. Use reliable urine tests for opioids (including morphine, methadone, buprenorphine, and oxycodone), benzodiazepines, cocaine, and other drugs commonly used in the area. Use a breathalyzer to estimate the patient's blood alcohol content. Do not provide buprenorphine until the alcohol reading is considerably below the legal level of alcohol intoxication.
  - Conduct a pregnancy test. Transmucosal buprenorphine or methadone maintenance treatment is recommended for OUD in pregnancy.^318^ There are limited data regarding use in pregnant women with OUD with the buprenorphine implants and with the extended-release injection formulation. If buprenorphine is used during pregnancy, it should generally be transmucosal monoproduct.^319^ Refer pregnant patients to prenatal care.
  - Assess liver function. If possible, obtain liver function tests, but do not wait for results before starting transmucosal buprenorphine treatment. A patient with chronic hepatitis can receive OUD treatment with buprenorphine. Discuss risks and benefits if the patient's liver enzymes are at or above five times the normal level and monitor liver function during treatment. Patients with transaminase levels less than five times normal levels, including patients with hepatitis C virus, appear to tolerate buprenorphine well.^320,321^ Exhibit 3D.2 gives more information about hepatic impairment and buprenorphine. Liver function tests should be obtained and reviewed before initiating buprenorphine implants or extended-release buprenorphine because these formulations are long acting.
  - Conduct hepatitis and HIV tests. Hepatitis B and C are common among patients entering buprenorphine treatment. HIV infection is also prevalent. Everyone ages 15 to 65 should be tested at least once for HIV. Persons at higher risk, such as people who use drugs by injection, should be tested annually.^322^ Anyone who is injecting or has ever injected drugs, even once, no matter how long ago, should be tested for hepatitis C, regardless of their intention to seek treatment for SUD.^323^ The Centers for Disease Control and Prevention recommends hepatitis B vaccination for individuals seeking treatment for SUDs.^324^

RESOURCE ALERT

##### Opioid Withdrawal Scales

The COWS and other opioid withdrawal scales can be downloaded from Annex 10 of WHO's Guidelines for the Psychosocially Assisted Pharmacological Treatment of Opioid Dependence from the National Center for Biotechnology Information website (www.ncbi.nlm.nih.gov/books/NBK143183).

The CINA Scale for Withdrawal Symptoms is also available online (www.ncpoep.org/wp-content/uploads/2015/02/Appendix_7_Clinical_Institute_Narcotic_Assessment_CINA_Scale_for_Withdrawal_Symptoms.pdf).

### Patient Selection

No evidence clearly predicts which patients are best treated with buprenorphine versus other OUD medications. Inform all patients with OUD about treatment with transmucosal buprenorphine and where it's available. (See “Treatment Planning or Referral” in Part 2 of this TIP for more on shared decision making.)

Patients who responded well to buprenorphine in the past should be considered for this treatment.

Prior use of diverted buprenorphine doesn't rule out OUD treatment with buprenorphine. Diverted buprenorphine is often associated with an inability to access treatment,^325^ and it's often used to self-treat opioid withdrawal rather than to “get high.”^326,327^

Unsuccessful treatment experiences with buprenorphine in the past do not necessarily indicate that buprenorphine will be ineffective again. Motivation and circumstances change over time. Also, treatment varies by provider, clinic, and setting, as it does for other medical illnesses. Records from previous providers can contextualize the extent of past treatment.

Pregnant women should be considered for transmucosal buprenorphine treatment.

Do not taper patients to 8 mg daily solely to switch them to implants.

Stable patients are the best candidates for buprenorphine implants. Implants are indicated for patients who have already achieved illicit opioid abstinence and clinical stability while taking transmucosal buprenorphine for at least 90 days. Their current dose should be 8 mg/day or less.^328^ There is no absolute definition of clinical stability, but per the implant package insert, patients may be stable if they are:^329^

• Abstaining currently from illicit opioids.
• Having little or no craving for illicit opioids.
• Living in a stable environment.
• Participating in a structured job or activity.
• Engaging in a positive social support system.
• Lacking recent hospitalizations, emergency department visits, or crisis interventions for substance use or mental illness.
• Adhering to clinic appointments and other aspects of treatment and recovery plans.

### Informed Consent

Inform all patients of:

• Their OUD diagnosis and the nature of the disorder.
• Risks and benefits of all available medications for OUD.
• Risks and benefits of nonmedication treatments.

Educate patients about basic buprenorphine pharmacology and induction expectations (Exhibit 3D.5). They should understand the need to be in opioid withdrawal that's visible to the prescriber (or, for home induction, that meets predefined self-assessment criteria) to avoid precipitated withdrawal.

Use language and written materials appropriate to each patient's comprehension level to ensure that he or she understands the options and can make informed decisions.

EXHIBIT 3D.5. Key Points of Patient Education for Buprenorphine

Before starting OUD treatment with buprenorphine, patients should:

• Tell providers the prescribed and over-the-counter medications they take to allow drug interaction assessment.
• Understand the goal of the first week of treatment: To improve withdrawal symptoms without oversedation.
• Tell providers if they feel sedated or euphoric within 1 to 4 hours after their dose.
• Be given the appropriate buprenorphine medication guide.
• Know possible side effects, including:
  - Headache.
  - Dizziness.
  - Nausea.
  - Vomiting.
  - Sweating.
  - Constipation.
  - Sexual dysfunction.
• Agree to store medication securely and out of the reach of others.
• Alert providers if they discontinue medications, start new ones, or change their medication dose.
• Understand that discontinuing buprenorphine increases risk of overdose death upon return to illicit opioid use.
• Know that use of alcohol or benzodiazepines with buprenorphine increases the risk of overdose and death.
• Understand the importance of informing providers if they become pregnant.
• Tell providers if they are having a procedure that may require pain medication.
• Be aware of resources through which to obtain further education for:
  - Themselves: Decisions in Recovery: Treatment for Opioid Use Disorder (https://store.samhsa.gov/product/SMA16-4993)
  - Their families and friends: Medication-Assisted Treatment for Opioid Addiction: Facts for Families and Friends (https://mha.ohio.gov/Portals/0/assets/HealthProfessionals/About%20MH%20and%20Addiction%20Treatment/MAT/SMA14-4443.pdf?ver=2018-11-26-113004-157)

## Initiating Buprenorphine Treatment

It can be helpful to use a buprenorphine treatment agreement for patients treated in office-based settings (see Chapter 3D Appendix for a sample treatment agreement).

Induction can occur in the office or at home. Most clinical trials were conducted with office-based induction, and extant guidance recommends this approach.^330^ However, office-based induction can be a barrier to treatment initiation. Home induction is increasingly common.^331^

### Office-Based Induction

Providers can perform office-based induction by ordering and storing induction doses in the office or by prescribing medication and instructing patients to bring it to the office on the day of induction. Office-based induction allows providers to:

• Ensure that patients know how to take medication without swallowing or spitting it out if they have too much saliva or experience unpleasant tastes. Tell them to wait to eat or drink until the medication is totally dissolved.
• Enhance the therapeutic relationship.
• Verify the presence of opioid withdrawal and absence of precipitated opioid withdrawal.
• Ensure the lack of sedation 1 to 2 hours after the first dose in patients taking sedatives.
• Use time between doses for patient self-assessment. See the Chapter 3D Appendix for sample goal-setting forms that help patients identify treatment goals and triggers for use.

### Home Induction

Home induction can be safe and effective.^332^ Retention rates are similar to office inductions,^333^ but no comparison data from large randomized controlled studies exist. The American Society of Addiction Medicine National Practice Guideline recommends home induction only if the patient or prescriber has experience with using buprenorphine.^334,335^ Clinical experience indicates that patients suitable for home induction:

• Can describe, understand, and rate withdrawal.
• Can understand induction dosing instructions.
• Can and will contact their provider about problems.

Educate patients about how to assess their withdrawal, when to start the first dose, how to take the medication properly, and how to manage withdrawal on induction day. Instruct patients to take their first dose when they experience opioid withdrawal at least 12 hours after last use of heroin or a short-acting prescription opioid. Effectively switching from methadone to buprenorphine can be challenging. This should generally be started with office-based induction. Consult with a medical expert knowledgeable about methadone in these situations until experience is gained. Withdrawal can include:

• Goose bumps.
• Nausea.
• Abdominal cramps.
• Running nose.
• Tearing.
• Yawning.

Be available for phone consultation during the induction period and for an in-office evaluation should the need arise. See patients in the office within approximately 7 days of the start of home induction. (See the Chapter 3D Appendix for a sample buprenorphine/naloxone home dosage schedule.)

Advise patients to abstain from tobacco before dosing. Many patients with OUD use tobacco products. Nicotine causes vasoconstriction, decreasing the surface area of blood vessels that absorb buprenorphine.

### Induction

#### Patients who are currently physically dependent on opioids

Patients should begin buprenorphine when they are exhibiting clear signs of opioid withdrawal. Induction typically starts with a 2 mg to 4 mg dose of buprenorphine or a 2 mg/0.5 mg to 4 mg/1 mg dose of buprenorphine/naloxone.^336^ Depending on the formulation used and whether a given patient has a dry mouth, the dose can take between 3 and 10 minutes to dissolve fully. After approximately 2 hours, an additional 2 mg to 4 mg dose of buprenorphine/naloxone can be given if there is continued withdrawal and lack of sedation.

Always individualize dosing. The FDA label recommends a maximum buprenorphine/naloxone dose of 8 mg on Day 1 and 16 mg on Day 2.^337^ When dosing outside of FDA recommendations, document the clinical rationale, including risks and benefits. Remember that some patients stabilize on lower doses.

If patients experience sedation upon first dose, stop and reevaluate the following:

• Did they recently take other sedating medications (e.g., benzodiazepines)?
• Have they recently been in a controlled environment, such as a hospital, jail, or residential drug treatment facility?
• Was the history of recency and amount of opioid use inaccurate?
• Was the heroin used of poor quality?
• Was their use mostly of low-potency opioids (e.g., codeine)?

Consider whether a dose decrease, change in treatment plan, or both are necessary. If induction is still indicated, adjust the dose more slowly as needed to minimize sedation. The dose can be adjusted on subsequent days to address continued withdrawal or uncontrollable craving if the patient is not sedated.

#### Patients with a history of OUD who are not currently physically dependent on opioids

Buprenorphine induction can be appropriate for certain patients with a history of opioid addiction at high risk for return to use of opioids but not currently dependent on them. This includes patients who've been incarcerated or in other controlled environments.^338^ Before starting treatment, discuss risks and benefits of buprenorphine and other medications (including extended-release naltrexone [XR-NXT]). Buprenorphine doses should begin at lower-than-usual levels (e.g., 1 mg). They should be increased more slowly than in tolerant patients to avoid oversedation and possible overdose. Take particular care with patients who are being treated with other central nervous system depressant medications.^339^ At the beginning of treatment, directly administer doses in an OTP or in the office. This will allow patients to be observed for sedation after dosing and will reduce the risk that patients take more medication than prescribed.

In one study, research participants not currently physically dependent on opioids but with a history of OUD were started on 1 mg buprenorphine with weekly 1 mg dose increases to 4 mg, followed by 2 mg weekly increases to 8 mg. Most patients tolerated this dose induction, and the mean daily dose exceeded 8 mg per day by the fifth week, when the planned dose was 6 mg.^340^ As with all opioid agonist treatment, dosing should be individualized and based on careful patient assessment during treatment.

#### Patients who are currently taking methadone

Some patients who take methadone may wish to switch to buprenorphine treatment for a variety of reasons. This often requires methadone dose reduction before switching medications, which may increase the risk of return to opioid use. Exercise caution with this approach and thoroughly discuss the risks and benefits with the patients before embarking on the change in medication. Experienced prescribers should conduct this procedure in the office, not via home induction. The lower the methadone dose and the longer it's been since the last dose, the easier the transition.

Before initiating buprenorphine, carefully taper methadone to lower the risk of return to illicit opioid use during transition. Patients who take methadone for OUD should taper to 30 mg to 40 mg methadone per day and remain on that dose for at least 1 week before starting buprenorphine.^341^ With patients' permission, OTPs can confirm the time and amount of patients' last methadone dose.

Do not start buprenorphine until the patient manifests signs of opioid withdrawal. At least 24 hours should pass between the last dose of methadone and the first dose of buprenorphine. Waiting 36 hours or more reduces risk of precipitated withdrawal. Lower doses of buprenorphine/naloxone are less likely to precipitate methadone withdrawal.^342^ For example, once opioid withdrawal is verified, an initial dose of 2 mg/0.5 mg can be given. If patients continue to have unrelieved opioid withdrawal after the first 2 mg dose, administer another 2 mg/0.5 mg dose approximately every 2 hours as needed (holding for sedation). Induction should be conducted slowly; consider palliating unrelieved withdrawal with nonopioid therapies for the first few days of transition to buprenorphine. Be alert to any increase in withdrawal symptoms, as this may suggest precipitated withdrawal.

### Dose Stabilization

Stabilization occurs when there is evidence of:

• Markedly reduced or eliminated illicit opioid use.
• Reduced craving.
• Suppression of opioid withdrawal.
• Minimal side effects.
• Patient-reported blunted or blocked euphoria during illicit opioid use.

Remind patients to take their dose once daily rather than splitting it. Document reduced illicit drug use via patient self-report and urine drug testing. Consecutive negative urine test results suggest a positive prognosis.

Continue monitoring dose effectiveness during early stabilization. Dose adjustments may still be necessary (Exhibit 3D.6). Buprenorphine treatment should substantially reduce opioid cravings. See Chapter 3E: Medical Management Strategies for detailed information on the management of patients taking buprenorphine in office-based treatment settings.

EXHIBIT 3D.6. Adjusting the Buprenorphine Dose

When to increase the dose:

• Are patients taking medication correctly and as scheduled?
  - If they take at least 16 mg per day, mu-opioid receptors are approximately 80 to 95 percent occupied.^343^
  - If there are adherence problems, assess causes and intervene to promote adherence and proper administration (e.g., offer supervised dosing at the clinic, by a network support, at a pharmacy).
  - If patients are taking doses correctly, a dose increase may be indicated, if certain conditions exist.
• Are patients taking other medications that may interfere with buprenorphine metabolism?
• If patients are taking doses properly, increase the dose if they still have opioid withdrawal (document with a clinical tool like COWS), opioid craving, or “good” effects (e.g., feeling “high”) from using illicit opioids.
  - Craving can be a conditioned response. It may not decrease with dose increases if patients spend time with people who use opioids in their presence.
  - Dose increases typically occur in 2 mg to 4 mg increments.
  - It will take about 5 to 7 days to reach steady-state plasma concentrations after a dose increase.
  - Offer psychosocial referrals to help decrease and manage cravings.
• Determine whether nonpharmacological problems are contributing to the need for increase.
  - For example, do patients show signs and symptoms of untreated major depressive or generalized anxiety disorders? Are they living in a chaotic household? Do they have childcare problems or financial difficulties? Are they experiencing trauma or trauma-related mental disorders?
  - Address or refer to counseling to address these problems.

When to decrease the dose:

• Decrease the dose when there is evidence of dose toxicity (i.e., sedation or, rarely, clearly linked clinically relevant increases in liver function tests).
• Hold the dose when there is acute alcohol or benzodiazepine intoxication.

Once patients have stabilized, continue to screen and evaluate for mental disorders and psychosocial problems that may need to be addressed (e.g., having a spouse or cohabitant who is using illicit opioids). Support patients' engagement in prosocial activities and progress toward treatment goals and recovery as they decrease use of illicit substances.

Offer referrals for adjunctive counseling and recovery support services as needed. It may not be possible to eliminate opioid craving completely, regardless of the dose. Counseling can help patients reduce and manage craving. A more important measure of dose adequacy than craving is whether patients report that the feeling of euphoria associated with self-administered illicit opioids is blunted or blocked. Patients who were not interested in adjunctive addiction or mental health counseling during induction may become receptive to it when they are feeling more stable.

Be cautious when increasing doses above 24 mg/6 mg per day. Nearly all patients stabilize on daily doses of 4 mg/1 mg to 24 mg/6 mg. Very limited data show additional benefits of doses higher than the FDA label's recommended maximum of 24 mg/6 mg.^344^ Carefully document clinical justification for higher doses and always have a diversion control plan in place. Doses above 24 mg/6 mg a day may unintentionally heighten diversion risk. Patients not responding to high doses of buprenorphine at the upper limit approved by FDA should be considered for methadone treatment.

### Risk Evaluation and Mitigation Strategy

Practitioners should become familiar with the FDA-approved REMS for buprenorphine. It provides useful information and checklists for providers. REMS can be found online for:

• Buprenorphine monoproduct and buprenorphine/naloxone (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&REMS=352)
• Transmucosal buprenorphine (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=RemsDetails.page&REMS=9)
• Buprenorphine implants(www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&REMS=356)
• Buprenorphine extended-release injection (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=indvremsdetails.page&rems=376)

See also “Buprenorphine Induction and Maintenance Appropriate Use Checklists” in Chapter 3D Appendix.

### Transmucosal Buprenorphine Dosing Summary

#### Induction and stabilization

The goal is to reduce or eliminate opioid withdrawal and craving without causing sedation:

• Induction and stabilization strategies can vary based on patient variables and use of short- versus long-acting opioids. For more discussion on induction models, see the Providers' Clinical Support System's Models of Buprenorphine Induction (http://pcssmat.org/wp-content/uploads/2015/01/Models-of-Buprenorphine-Induction.pdf).
• The combination buprenorphine/naloxone product is safe to use for induction for most patients.
• The buprenorphine monoproduct (without naloxone) has been recommended for the treatment of pregnant women^345^ because of the danger to the fetus of precipitated opioid withdrawal if the combination product were to be injected. Although there are some publications with small sample sizes that indicate that the combination product appears to be safe in pregnancy,^346,347^ the safety data are insufficient at this time to recommend its use.^348^ This is an area of some uncertainty. An expert panel on the treatment of OUD in pregnancy was unable to agree whether pregnant women should be treated with the monoproduct or combination product.^349^
• Prescribers should observe the patient taking the medication to ensure proper use, especially if the patient is new to buprenorphine treatment. It can be helpful to do this periodically after induction, especially when the prescribed dose is not providing the expected benefit.
• Before the first dose, the patient should be in opioid withdrawal (to avoid precipitated withdrawal).
• The first dose is typically 4 mg/1 mg (2 mg if withdrawal is from methadone).
• Repeat dose as needed for continuing withdrawal every 2 hours up to typically 8 mg on the first day.

At the start of the next day, patients typically take the first day's total dose all at once:

• If necessary, an additional 2 mg to 4 mg can be given every 2 hours up to approximately a 16 mg total daily dose to treat continuing opioid withdrawal and craving on Day 2 or 3, barring sedation.
• The initial stabilization dose can often be achieved within the first several days of treatment.

#### Maintenance

Typical maintenance doses range from 4 mg/1 mg to 24 mg/6 mg per day. An effective maintenance dose is the lowest dose that can:

• Eliminate withdrawal.
• Reduce or eliminate opioid craving.
• Reduce or stop illicit opioid use's desirable effects.
• Be well tolerated (e.g., not produce sedation).

#### Duration of treatment

• Treatment should last for as long as patients benefit from treatment.
• Longer treatment length is associated with positive treatment outcomes.

### Initiation of Buprenorphine Implants

Prescribers and implanters of buprenorphine implants require special certification to make this formulation available to their patients. In addition, implanters must get special training in the Probuphine REMS program to obtain certification to implant and remove this formulation. After completing training, providers can order implants through a central pharmacy for delivery, along with an implant insertion kit that contains all necessary implant procedure materials except a local anesthetic. If the prescriber is not performing the procedure, the prescriber should ensure that the implanter has completed the required training. For more information, see the Probuphine REMS program webpage (https://probuphinerems.com/).

The prescriber and implanter/remover must record the number of implanted/removed rods and their serial numbers and location, the date of the implant, and who performed the procedure. The implanter should document implant and inspection procedures, as with any other standard procedure.

Instruct patients to take the last transmucosal dose of buprenorphine 12 to 24 hours before insertion. Remind them to shower and thoroughly wash the nondominant arm, which is preferred for insertion.

#### Implant procedure

Subdermal insertion of the four rods takes less than 30 minutes. Local anesthetic (lidocaine) is typically used. The implant procedure includes the following steps:

• Provide education about what to expect during the procedure.
• Obtain appropriate consent form(s).
• Provide a local anesthetic (e.g., lidocaine).
• Using sterile procedures, make a single incision in the inner upper arm between the biceps and triceps muscles, about 8 cm to 10 cm from the medial epicondyle.
• Using a cannula and an obturator, insert rods serially, pivoting the cannula slightly after each rod insertion in the subdermal space so that the rods lie next to one another, nearly parallel in a fanlike pattern.
• After implantation, apply butterfly strips and a pressure bandage.
• Review wound care with the patient, and provide a copy of the instructions.
• Advise the patient not to drive or engage in heavy physical activity for approximately 24 hours.
• Do not give the patient a prescription for transmucosal buprenorphine at this time.

#### Wound care

The patient should return within 1 week of the implant procedure for a wound care check. Check for signs of infection, trouble healing, or implant extrusion. The rods are subdermal, so they should remain palpable. Document that all four rods were palpated.

#### Stabilization

Maintain contact with patients after implant placement. Even among highly stable patients, return to illicit opioid use can occur. Explain the risk of unintentional overdose if patients return to illicit opioid or alcohol or benzodiazepine use while implants are in place. It is important to monitor the patient between implant placements.

Schedule office visits no less than once a month for continued assessment of maintenance of stability, manual palpation of the four implanted rods, and ongoing psychosocial support and counseling per the FDA label (www.accessdata.fda.gov/drugsatfda_docs/label/2016/204442Orig1s000lbl.pdf). If the patient returns to illicit opioid use, consider whether adequate psychosocial treatment has been given.

Consider transmucosal medication supplementation if a patient with implants destabilizes and reports inadequate opioid blockade. In one study,^350^ 17.9 percent of participants with buprenorphine implants needed supplemental sublingual buprenorphine/naloxone. Most required small doses, such as 2 mg/0.5 mg per day. Consider more frequent assessment and higher intensity of treatment for patients who continue using illicit opioids or other substances.

#### Removal

After 6 months, have a certified implanter remove them. Implantation of a second set of rods in the opposite arm can then occur. There is no experience with inserting additional implants into other sites or second insertion into a previously used arm. After one insertion in each arm, most patients should transition to a transmucosal buprenorphine-containing product for continued treatment. Patients should follow the same directions to prepare for implant removal as they did for insertion. The removal procedure may require stitches. Patients should visit the clinic for removal of stitches and wound assessment within 1 week of removal. Store and dispose of rods safely in accordance with local and federal regulations.

### Initiation of Buprenorphine Extended-Release Injection

Healthcare settings and pharmacies need special certification to order and dispense extended-release injectable buprenorphine to ensure long-acting preparations are dispensed directly to healthcare providers for administration and by healthcare providers to patients (see www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=indvremsdetails.page&rems=376 for more details).

Before initiating extended-release buprenorphine treatment, patients with moderate-to-severe OUD should be stabilized on transmucosal buprenorphine (8 mg to 24 mg daily) for at least 7 days. Do not use in opioid-naïve patients. Obtain liver function and pregnancy tests. Extended-release buprenorphine is not recommended for patients with severe hepatic impairment and may not be appropriate for patients with moderate hepatic impairment because of the long-acting nature of this formulation. There are insufficient data on its use in pregnancy to recommend initiating this formulation during pregnancy.

Inform patients that:

• The medication is only available in a restricted program (the Sublocade REMS Program) via specific pharmacies and healthcare providers, as intravenous self-injection by patients can cause death.
• After abdominal injection, a lump may be present at the injection site for a few weeks. It will get gradually smaller. Patients should not rub or massage it or let belts or waistbands rub against it.
• Patients should tell their healthcare providers that they are being treated with this medication.
• Using alcohol, benzodiazepines, sleeping pills, antidepressants, or some other medications with extended-release buprenorphine can lead to drowsiness or overdose.
• The most common side effects are constipation, headache, nausea, vomiting, increased liver enzymes, tiredness, and injection site itching or pain.
• Patients should inform their provider if they become pregnant during treatment with this formulation. They should have a risk/benefit discussion about continuing with this formulation given the limited safety data on its impact on the developing fetus. They should be informed that their newborn can have symptoms of opioid withdrawal at birth.

#### Storage

Follow package insert directions for medication storage under refrigeration. Keep at room temperature for at least 15 minutes before injection (discard if left at room temperature for more than 7 days).

#### Administration

Rotate the abdominal subcutaneous injection site with each injection, following the instructions in the package insert. Record the location of each injection in the medical record. Each of the first two monthly doses (with at least 26 days between doses) should be 300 mg. Subsequent monthly doses should be 100 mg. Some patients may benefit from increasing the maintenance dose to 300 mg monthly if they have tolerated the 100 mg dose but continue to use illicit opioids.

#### Medical management

Monitor patient progress and response to treatment during regular office visits and with periodic urine drug testing. Examine the injection site for reactions, infections, or evidence of attempts to remove the depot medication. If the medication is discontinued, the patient should continue to be seen and evaluated for several months for sustained progress in treatment and for signs and symptoms of opioid withdrawal, which should be treated as clinically appropriate.

## Duration of Buprenorphine Treatment

There is no known duration of therapy with buprenorphine (or methadone or XR-NTX) after which patients can stop medication and be certain not to return to illicit opioid use. Those who stay in treatment often abstain longer from illicit opioid use and show increasing clinical stability. Long-term treatment outcomes up to 8 years after buprenorphine treatment entry show lower illicit opioid use among those with more time on medication.^351^

Patients should take buprenorphine as long as they benefit from it and wish to continue.

### Successful Buprenorphine Treatment

The goal of buprenorphine treatment is full remission from OUD. Maintaining illicit opioid abstinence is ideal, but imperfect abstinence does not preclude treatment benefits. Patients should do better in treatment than before treatment. If not, seek alternatives.

Do not judge treatment progress and success on the amount of medication a patient needs or how long treatment is required. Rather, gauge treatment progress and success based on patients' achievement of specific goals that were agreed on in a shared decision-making and treatment planning process.

Given the often-chronic nature of OUD and the potentially fatal consequences of unintended opioid overdose, it is critical that you base patients' length of time in treatment on their individual needs.

Consider this analogy: A patient with poorly controlled diabetes was previously unable to work and was admitted to the hospital several times for diabetic ketoacidosis. When taking insulin regularly, the patient worked part time, had fewer hospitalizations for diabetic ketoacidosis despite a nondiabetic diet, and had lower (but still high) hemoglobin A1C. This patient's treatment with insulin is not a “failure” because perfect control and function were not restored, and the patient would not be discharged from care against his or her will.

### Dose Tapering and Buprenorphine Discontinuation

Following short-term medically supervised withdrawal, patients frequently restart illicit opioid use.^352^ In contrast to short-term medically supervised withdrawal, dose tapering refers to gradually reducing the buprenorphine dose in patients who have been stabilized on the medication for some time.

Base decisions to decrease dose or stop buprenorphine on patients' circumstances and preferences. Successful dose reductions may be more likely when patients have sustained abstinence from opioids and other drugs, psychosocial support, housing, effective coping strategies, stable mental health, employment, and involvement in mutual-help programs or other meaningful activities.^353^ However, there is no guarantee that even patients with years of abstinence, full-time employment, stable housing, and psychosocial supports can remain abstinent after discontinuing buprenorphine.

It is up to patients to decide whether to taper or eventually discontinue medication. Help them make informed choices by educating them about the process and fully including them in decision making. Invite them to reenter treatment if they believe they may return or have already returned to opioid use.

Before beginning to taper the dose of medication, explore these considerations with patients:

• How have they responded to treatment so far? Are they in full remission from OUD? Do they have adequate mental and social supports to remain in remission and maintain recovery?
• Why do they want to taper? They may be motivated by inconvenience, expense, loss of insurance coverage, side effects, feelings of shame, pressure from family, and lack of recovery supports. Many of these reasons are not predictive of a successful outcome.
• What do they expect to be different after tapering or discontinuing buprenorphine?
• Do they understand the risks and benefits of dose decrease and discontinuation of buprenorphine?
• What strategies do they have for engaging family members and recovery supports to reduce the risk of return to illicit substance use?
• Do they grasp the risk of overdose associated with a return to illicit opioid use?
• Do they have a safety plan? To reduce overdose risk after a return to use, plans should include:
  - A prescription for naloxone or a naloxone kit.
  - Instructions on recognizing and responding to an overdose.
  - Information on naloxone use for family members and others in the patient's recovery support network.
  - See the SAMHSA Opioid Overdose Prevention Toolkit (https://store.samhsa.gov/product/Opioid-Overdose-Prevention-Toolkit/SMA18-4742) for more guidance.
  - If patients return to opioid use, it may be appropriate for them to restart buprenorphine or switch to methadone or XR-NTX treatment. These options should be discussed with them.
• Have they thought about how they will feel if they attempt to taper off of medication but cannot do so? Convey to patients that the inability to taper is not a failure and that they should not be afraid or embarrassed to discuss stopping the taper.

Document the discussion, patient education, and decision in the medical record.

There is no ideal tapering protocol. Providers and patients should understand this before beginning a taper. Whether buprenorphine is ultimately discontinued, patients need additional psychosocial and recovery support during this time. Generally, taper occurs over several months to permit patients to acclimate to the lower dose and to reduce potential discomfort from opioid withdrawal and craving.

For patients who wish to discontinue buprenorphine, national and international guidelines recommend gradual dose reductions and advice to patients that they can stop the taper at any time. ^354,355,356^

Consider increased monitoring and proactive discussions about how to address and manage cravings and withdrawal symptoms. Taper protocols vary in duration and may include use of ancillary medication, such as clonidine, if needed (Exhibit 3A.2).^357^

Continue to monitor patients who successfully taper off buprenorphine completely. Establish a post-taper monitoring and support plan (see Chapter 3E for more information on medical management strategies). Continue to assess and monitor patients' progress and how they cope with stress and triggers to use. Discuss the role of XR-NTX in preventing return to opioid use after completing treatment with an opioid agonist (see Chapter 3C for more information on naltrexone).

## Chapter 3D Appendix

Buprenorphine Induction and Maintenance Appropriate Use Checklists^358^

Sample Goal Sheet and Coping Strategies Form

Sample Goal-Setting Form

Buprenorphine/Naloxone Home Dosage Schedule: Films or Tablets

Buprenorphine Treatment Agreement^359^

Patient Urine Drug Screen and Medication Count Monitoring Form

Pharmacy Tablet/Film Count Form