# Chapter 3A: Overview of Medications for Opioid Use Disorder

Chapter 3A describes general principles of OUD medication and summarizes formulations, indications, and dosing for the three FDA-approved OUD medications.

There are three FDA-approved medications used to treat OUD: the mu-opioid receptor partial agonist buprenorphine, the mu-opioid receptor full agonist methadone, and the mu-opioid receptor antagonist naltrexone.

Discussing medications that can treat OUD with patients who have this disorder is the clinical standard of care and should cover at least:

• The proven effectiveness of methadone, naltrexone, and buprenorphine compared with placebo and with outpatient counseling without medication.
• Risks and benefits of treatment with all three types of medication, treatment without medication, and no treatment.
• Safety and effectiveness of the medications when used appropriately.
• Pharmacologic properties, routes of administration, and where and how to access treatment with each medication (Exhibit 3A.1).

EXHIBIT 3A.1. OUD Medications: An Overview^9,10^

CATEGORY | BUPRENORPHINE^*^ | | METHADONE | XR-NTX^**^
| TRANSMUCOSAL | DEPOT
Appropriate patients | Typically for patients with OUD who are physiologically dependent on opioids. | Typically for patients for whom diversion or safe medication storage are concerns or for patients who must travel large distances to the prescriber. | Typically for patients with OUD who are physiologically dependent on opioids and who meet federal criteria for OTP admission. | Typically for patients with OUD who have abstained from short-acting opioids for at least 7–10 days and long-acting opioids for at least 10–14 days.
Pharmacology | Opioid receptor partial agonist; Reduces opioid withdrawal and craving; blunts or blocks euphoric effects of self-administered illicit opioids through cross-tolerance and opioid receptor occupancy. | Opioid receptor partial agonist; Reduces opioid withdrawal and craving; blunts or blocks euphoric effects of self-administered illicit opioids through cross-tolerance and opioid receptor occupancy.; Note: Patients receiving a depot formulation of buprenorphine must be inducted onto buprenorphine using a transmucosal product. | Opioid receptor agonist; Reduces opioid withdrawal and craving; blunts or blocks euphoric effects of self-administered illicit opioids through cross-tolerance and opioid receptor occupancy. | Opioid receptor antagonist; Blocks euphoric effects of self-administered illicit opioids through opioid receptor occupancy. Causes no opioid effects. Reduces opioid craving.
Patient education | Tell patients:; • That they will need to be in opioid withdrawal to receive their first dose to avoid buprenorphine-precipitated opioid withdrawal.; • About the risk of overdose with concurrent benzodiazepine or alcohol use, with injecting buprenorphine, and after stopping the medication. | Tell patients:; • For implantable rods (Probuphine^®^), they will need to be stable on no more than 8 mg of transmucosal Suboxone or generic equivalents.; • For subcutaneous injection (Sublocade^®^), they must first be on a transmucosal form of buprenorphine for at least 7 days at a dose equivalent to 8 to 24 mg of buprenorphine. | Tell patients:; • That their dose will start low and build up slowly to avoid oversedation; it takes several days for a given dose to have its full effect.; • About overdose risk in the first 2 weeks of treatment, especially with concurrent benzodiazepine or alcohol use, and after stopping the medication. | Tell patients:; • That they will need to be opioid free for at least 7–10 days for short-acting opioids and at least 10–14 days for long-acting opioids before their first dose of extended-release naltrexone (XR-NTX) to avoid precipitated withdrawal (which may require hospitalization).; • About the risk of overdose after stopping the medication.
Administration | Daily (or off-label less-than-daily dosing regimens) administration of sublingual or buccal tablet or film. Subdermal implants every 6 months, for up to 1 year, for stable patients. Monthly subcutaneous injection of extended-release formulation in abdominal region for patients treated with transmucosal buprenorphine for at least 1 week. | Subdermal implants every 6 months, for up to 1 year, for stable patients.; Monthly subcutaneous injection of extended-release formulation in abdominal region for patients treated with transmucosal buprenorphine for at least 1 week. | Daily oral administration as liquid concentrate, tablet, or oral solution from dispersible tablet or powder (unless patients can take some home). | Every 4 weeks or once-per-month intramuscular injection.
Prescribing | Physicians, nurse practitioners (NPs), and physician assistants (PAs) need a waiver to prescribe. Until October 1, 2023, qualified clinical nurse specialists, certified registered nurse anesthetists, and certified nurse midwives also can obtain a waiver to prescribe. Any pharmacy can fill a prescription for sublingual or buccal formulations. OTPs can administer/dispense by OTP physician order without a waiver. | Prescribers must have a waiver (as for transmucosal buprenorphine) and complete the product's REMS program.; Providers of the implantable rods must complete additional training in their insertion and removal.; Both the implantable rods and subdermal injections are available via restricted distribution programs and are not available in retail pharmacies.; OTPs can be providers of depot formulations of buprenorphine, provided the above criteria are satisfied. | SAMHSA-certified OTPs can provide methadone for daily onsite administration or at-home self-administration for stable patients. | Physicians, NPs, PAs, and, until October 1, 2023, clinical nurse specialists, certified registered nurse anesthetists, and certified nurse midwives can prescribe or order administration by qualified healthcare professionals.

* Long-acting buprenorphine implants (every 6 months) for patients on a stable dose of buprenorphine are also available through implanters and prescribers with additional training and certification through the Probuphine Risk Evaluation and Mitigation Strategy (REMS) Program. Extended-release buprenorphine monthly subcutaneous injections are available only through prescribers and pharmacies registered with the Sublocade REMS Program.

** Naltrexone hydrochloride tablets (50 mg each) are also available for daily oral dosing but have not been shown to be more effective than treatment without medication or placebo because of poor patient adherence.

## Introduction to Medications That Address OUD

### Methadone

Methadone is the most used and most studied OUD medication in the world.^11,12^ The World Health Organization (WHO) considers it an essential medication.^13^ Many clinical trials and meta-analyses have shown that it effectively reduces illicit opioid use, treats OUD, and retains patients in treatment better than placebo or no medication.^14,15,16^ (Part 1 of this Treatment Improvement Protocol [TIP] further covers methadone's efficacy.)

In the United States, roughly 1,500 federally certified opioid treatment programs (OTPs) offer methadone for OUD. Increasingly, they also offer buprenorphine, and some provide XR-NTX. Core OTP services include medical oversight of treatment, direct observation of dose administration, take-home dose dispensing under certain conditions, counseling, and drug testing.

Some OTPs provide other services, including mental health and primary care, HIV and hepatitis C virus care, and recovery support. Even so, significant demand remains for better integration and coordination of care among OTPs, primary care services, and mental health services to treat the range of needs common in people with OUD.^17^ Coordination is especially important for people with co-occurring medical, mental, and substance use disorders, who need multiple services and face challenges in treatment access and adherence.

### Naltrexone

XR-NTX has demonstrated efficacy in reducing return to illicit opioid use, increasing treatment retention, and reducing opioid craving compared with placebo or no medication in randomized controlled trials.^18,19,20^ (See Part 1 for more information on XR-NTX's efficacy in OUD treatment.) Because the injectable form was approved more recently by FDA than methadone and buprenorphine, XR-NTX has been less studied than those medications. Physicians, NPs, and, PAs, and, until October 1, 2023, clinical nurse specialists, certified registered nurse anesthetists, and certified nurse midwives may prescribe or order XR-NTX for administration by qualified staff members without additional waiver requirements.

Although only OTPs can administer or dispense methadone for OUD, all healthcare professionals and addiction and mental health counselors should be familiar with methadone. Their patients may be enrolled in or need referral to OTPs.

RESOURCE ALERT

##### Substance Abuse and Mental Health Services Administration (SAMHSA) Federal Guidelines for OTPs

Federal Guidelines for Opioid Treatment Programs offers guidance on how to satisfy federal OTP regulations (https://store.samhsa.gov/product/Federal-Guidelines-for-Opioid-Treatment-Programs/PEP15-FEDGUIDEOTP).

XR-NTX initiated prior to release from controlled environments (e.g., jails, prisons, residential rehabilitation programs) may be useful in preventing return to opioid use after release.^21^ These settings are typically associated with extended periods of opioid abstinence, so maintaining abstinence for sufficient time to start naltrexone is less challenging than initiating it among outpatients in the community. Short-term pilot studies show that offering XR-NTX under these circumstances can increase treatment engagement after release.^22,23^

The oral formulation of naltrexone is not widely used to treat OUD because of low rates of patient acceptance and high rates of non-adherence leading to a lack of efficacy.^24^ However, consideration should be given to its use in situations where adherence can be ensured, such as with observed daily dosing. Naltrexone is also FDA approved for the treatment of alcohol use disorder and therefore may be useful for patients with both OUD and alcohol use disorder.

RESOURCE ALERT

##### SAMHSA Brief Guide on the Use of XR-NTX

SAMHSA's Clinical Use of Extended-Release Injectable Naltrexone in the Treatment of Opioid Use Disorder: A Brief Guide offers guidance on the use of XR-NTX and is available online (https://store.samhsa.gov/product/Clinical-Use-of-Extended-Release-Injectable-Naltrexone-in-the-Treatment-of-Opioid-Use-Disorder-A-Brief-Guide/SMA14-4892R).

### Buprenorphine

Buprenorphine is effective in retaining patients in treatment and reducing illicit opioid use, as demonstrated by many clinical trials comparing buprenorphine with placebo or no medication.^25^ Buprenorphine treatment is available throughout the world. WHO includes it in its list of essential medicines.^26^ (See Part 1 for more information on buprenorphine's efficacy in OUD treatment.)

Buprenorphine is a partial agonist with a ceiling effect on opioid activity. Hence, it is less likely than methadone and other full agonists to cause respiratory depression in an accidental overdose. This property contributed to the decision permitting buprenorphine to be prescribed to treat opioid dependence outside OTPs.^27^ That being said, lethal overdose with buprenorphine is possible in opioid-naïve individuals or when it is taken in combination with central nervous system depressants such as benzodiazepines or alcohol.

Transmucosal buprenorphine is available by prescription through pharmacies, because the Drug Addiction Treatment Act of 2000 (DATA 2000) created an exception to the Controlled Substances Act to permit FDA schedule III, IV, and V medications approved to treat opioid dependence to be prescribed for that purpose outside OTPs. Buprenorphine, in various formulations, is the only medication to which DATA 2000 currently applies.

Qualifying physicians, NPs, and PAs can prescribe buprenorphine if they receive special training, obtain a SAMHSA waiver under DATA 2000, and get a unique Drug Enforcement Administration registration number. Until October 1, 2023, clinical nurse specialists, certified registered nurse anesthetists, and certified nurse midwives also are waiver-eligible to prescribe buprenorphine.

Additionally, providers who are state licensed and possess a valid Drug Enforcement Agency registration may be exempted from training requirements and the required attestation (about providing patients access to or referrals for psychosocial services) that are normally needed to obtain the X waiver.^28^ These providers are limited to treating no more than 30 patients. This has greatly increased the number and type of settings where medication for OUD is available and the number of patients in treatment. New settings include non-OTP outpatient addiction treatment programs, as well as general medical and mental health practices or clinics (office-based opioid treatment). OTPs can also provide buprenorphine.

In 2016, FDA approved buprenorphine implants (Probuphine) that last about 6 months for patients stabilized on sublingual or buccal formulations. Implants have been found to be more effective than placebo in reducing illicit opioid use among opioid-dependent patients receiving counseling.^29^ Implants are available in the same settings as other buprenorphine formulations but require waivered providers to receive specific training from the manufacturer on insertion and removal per the FDA-approved REMS (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&REMS=356).

In 2017, FDA approved a monthly extended-release buprenorphine injectable formulation (Sublocade) for patients with moderate-to-severe OUD who had been initiated and treated with transmucosal buprenorphine for at least 7 days. The medication is for subcutaneous abdominal injection by a healthcare provider and is intended to be available for ordering and dispensing (not by prescription to patients) in healthcare settings that receive special certification, pursuant to the FDA-approved REMS (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&REMS=376).

DATA 2000 restrictions currently apply only to buprenorphine used to treat OUD. They do not apply to pain treatment using buprenorphine formulations approved to treat pain.

RESOURCE ALERT

##### How To Obtain a Waiver To Prescribe Buprenorphine

• Learn how to qualify for a DATA 2000 physician waiver: www.samhsa.gov/medication-assisted-treatment/training-materials-resources/apply-for-practitioner-waiver
• Learn how to qualify for an NP, PA, clinical nurse specialist, certified registered nurse anesthetist, or certified nurse midwife waiver: www.samhsa.gov/medication-assisted-treatment/training-materials-resources/apply-for-practitioner-waiver
• Learn how providers may be exempted from training and psychosocial service attestation requirements usually needed for obtaining the X waiver: www.federalregister.gov/documents/2021/04/28/2021-08961/practice-guidelines-for-the-administration-of-buprenorphine-for-treating-opioid-use-disorder. Also review SAMHSA's “FAQs About the New Buprenorphine Practice Guidelines” at www.samhsa.gov/medication-assisted-treatment/practitioner-resources/faqs
• Learn how waivered practitioners can increase their patient limit from 30 to 100, and then to 275 patients: www.samhsa.gov/medication-assisted-treatment/training-materials-resources/apply-for-practitioner-waiver

### Choosing an OUD Medication

Currently, no empirical data indicate which patients will respond better to which OUD medications. All patients considering treatment should be educated about the effectiveness, risks, and benefits of each of the three OUD medications, treatment without medication, and no treatment. Emphasize that OUD medications are safe and effective when used appropriately, and point out that these medications can help patients reduce or stop illicit opioid use and improve their health and functioning.

Tailor decisions to patients' medical, psychiatric, and substance use histories; to their preferences; and to treatment availability when deciding which medication and treatment to provide. Consider:

• Patients' prior response to a medication.
• The medication's side effect profile.
• The strength of the published data on safety and effectiveness.
• Patients' use of other substances (e.g., naltrexone is also approved for the treatment of alcohol dependence).
• Patients' occupation. For patients in safety-sensitive occupations, consider XR-NTX.
• Patients' pregnancy status.^*^
• Patients' physical dependence on opioids. Patients not currently physically dependent on opioids who are returning to the community from a residential treatment program or incarceration should have the option of XR-NTX,^30^ methadone, or buprenorphine based on which best suits their needs and circumstances (see below for special safety dosing considerations for methadone and buprenorphine in nontolerant patients).^31,32,33,34^
• Patients' preferences. Respect patients' preferences for agonist versus antagonist medication. (See Part 2 of this TIP for an indepth discussion of treatment planning.)

* Methadone or buprenorphine maintenance is recommended for OUD treatment during pregnancy,^35^ as these medications have better maternal and infant outcomes than no treatment or medically supervised withdrawal.^36,37,38^ Methadone and buprenorphine are not associated with birth defects and have minimal long-term neurodevelopmental impact on infants.^39^ However, neonatal abstinence syndrome can occur, which requires hospitalization.^40^ The American College of Obstetricians and Gynecologists notes that limited data exist on the safety and effectiveness of naltrexone in pregnancy.^41^ Starting naltrexone rather than opioid agonist treatment in pregnancy is not recommended, given the risk of precipitated withdrawal. An expert panel did not agree on whether women already receiving treatment with naltrexone at the onset of pregnancy should remain on that medication during pregnancy.^42^ Patients who were taking naltrexone before their pregnancy should weigh with their providers the risks regarding unknown potential harm to the developing fetus versus the potential benefits of continuing this medication during pregnancy.^43^ Pregnant patients who discontinue naltrexone and return to opioid use should be considered for methadone or buprenorphine treatment.^44^

### Comparative Effectiveness

A Cochrane review of 5 randomized clinical trials with 788 participants found that, when provided at flexible doses on an outpatient basis, methadone retained patients in treatment longer than buprenorphine.^45^ That same review found that methadone and buprenorphine equally reduced illicit opioid use based on 8 studies with urine drug testing data from 1,027 participants and 4 studies with self-reported drug use from 501 participants.

There is not yet a Cochrane review on the comparative effectiveness of XR-NTX and buprenorphine. However, in 2017, two randomized trials comparing buprenorphine to XR-NTX were published. A multisite study with 570 participants in the United States compared initiating buprenorphine versus XR-NTX at 8 inpatient treatment programs.^46^ That study found that patients randomly assigned to start buprenorphine had significantly lower return-to-use rates during 24 weeks of outpatient treatment compared with those patients assigned to start XR-NTX. This finding was because of the known difficulty in successfully completing induction in the XR-NTX group. However, comparing only the subgroups of those participants who did start their assigned medication, there were no significant between-group differences in return-to-use rates. In a 12-week trial in Norway with 159 participants who were opioid abstinent at the time of random assignment, XR-NTX was found to be noninferior to buprenorphine in terms of treatment retention and illicit opioid use.^47^ There is no extant literature evaluating the comparative effectiveness of methadone, XR-NTX, buprenorphine implant, or extended-release buprenorphine injection to one another.

### Duration of Medication

Continued treatment with buprenorphine or methadone is associated with better outcomes than medically supervised withdrawal.^48,49,50^ Continued treatment with XR-NTX is associated with better outcomes than discontinuing XR-NTX.^51^ Patients should be informed of the risks and benefits of discontinuing medication. Buprenorphine or methadone can be used for medically supervised withdrawal over a period of days to weeks (Exhibit 3A.2) for patients who prefer it to ongoing opioid agonist treatment. When opioid agonist medications are unavailable, the alpha_2_-adrenergic agonist clonidine can relieve some withdrawal symptoms, although clinical trials found it less effective.^52^ Pair medically supervised withdrawal with the chance to begin XR-NTX. Discontinuing medication increases risk of return to substance use and overdose death.^53^ Stable patients can continue on their selected OUD medication indefinitely as long as it is beneficial.^54,55,56,57^

The TIP expert panel recommends offering maintenance therapy with medication, not short-term medically supervised withdrawal. The TIP expert panel also supports maintaining patients on OUD medication for years, decades, and even a lifetime if patients are benefiting.

EXHIBIT 3A.2. Medically Supervised Withdrawal Using Buprenorphine or Methadone

Medically supervised withdrawal using buprenorphine or methadone is appropriate when patients:

• Prefer it to treatment without medications, after they have been told the risks and benefits of this approach compared with treatment with medications.
• Wish to start XR-NTX, which is also FDA approved for the treatment of alcohol dependence.
• Are entering a controlled environment or workplace that disallows opioid agonists.

Data conflict on the ideal duration of medically supervised withdrawal.^60,61,62^ Even so, shorter term dose reductions alone (formerly, “detoxification”) are rarely effective.^63,64,65^

The TIP expert panel does not recommend short-term medically supervised withdrawal alone because of its high rates of return to illicit opioid use.^66,67,68^ If patients prefer this approach, it should be provided with psychosocial treatment.^69^ XR-NTX treatment should always be considered to reduce the likelihood of return to use after medically supervised withdrawal is completed and an adequate period of abstinence achieved,^70^ as well as to reduce the likelihood of overdose death upon a return to opioid use.

If withdrawal is appropriate for the patient, the TIP expert panel recommends the following strategies:

• Individualize supervised withdrawal duration per patient preference and response to lower medication doses.
• Note that patients may benefit from nonopioid medication (e.g., clonidine, ondansetron, loperamide) or nonsteroidal anti-inflammatory medications to manage withdrawal symptoms near the end of the taper.
• Consider discontinuing dose reduction and increasing the dose if the patient begins to use illicit opioids.
• Encourage patients to continue receiving counseling, monitoring, and other psychosocial support after medication discontinuation.
• Urge patients to reenter treatment promptly if they return or think they may return to illicit opioid use.

During medically supervised withdrawal, ancillary medications can treat some of the withdrawal symptoms (Exhibit 3A.3).

EXHIBIT 3A.3. Medications for Management of Opioid Withdrawal Symptoms

SYMPTOM | MEDICATION
Nausea | Ondansetron, metoclopramide (avoid promethazine; it potentiates opioids)
Diarrhea | Loperamide
Anxiety, irritability, sweating | Clonidine
Insomnia | Diphenhydramine, trazodone
Pain | Nonsteroidal anti-inflammatory drugs

## Principles of OUD Medications

### Basic Function

Several factors underlie the development of addiction involving opioids and the difficulty people have in achieving and maintaining abstinence from them. These factors include:^58,59^

• Short-term direct and indirect mu-opioid receptor agonist effects.
• Neuroplastic changes in the brain.
• Genetic, developmental, and environmental factors (e.g., exposure to high-risk environments, effect of stress on the hypothalamic–pituitary–adrenal axis).

Methadone, buprenorphine, and naltrexone bind to the mu-opioid receptors in the central and peripheral nervous systems, gastrointestinal tract, and vascular system. In the brain, these receptors mediate opioids' analgesic and other effects (e.g., euphoria, respiratory depression, meiosis).^71,72,73^ Through modulation of mu-opioid receptor activity in the brain, these medications exert therapeutic efficacy in treating OUD.

### Intrinsic Activity

Intrinsic activity at the mu-opioid receptor varies based on whether the medication is a full agonist, partial agonist, or antagonist (Exhibit 3A.4). The amount of intrinsic activity corresponds to the amount of opioid receptor agonist effects. A full agonist exerts maximal effects at increasing doses. A partial agonist has a ceiling effect. Its opioid effects increase as the dose increases, but only up to a certain point. An antagonist binds to the opioid receptor but does not stimulate the receptor at all. Thus, it has no intrinsic activity regardless of its dose.

Exhibit 3A.4. Intrinsic Activity of OUD Medications^74^

## Overview of Medication Indications and Dosing

Healthcare professionals should consider medication for all patients with OUD. Prescribers must read FDA labels (i.e., package inserts) for the medications they prescribe. They must also evaluate patients clinically to determine the safety and effectiveness of the medication and dose.

Exhibit 3A.5 summarizes OUD medication formulations, indications, and dosing.

EXHIBIT 3A.5. OUD Medications: Formulations^75,76^

GENERIC/TRADE NAME | FORMULATIONS | ACTION AT THE RECEPTOR | FDA INDICATIONS | DOSING REGIMEN
Methadone (Methadose, Dolophine) | Orally as liquid concentrate, tablet, or oral solution of powder or dispersible tablet | Mu-opioid receptor full agonist | Medically supervised withdrawal and maintenance treatment of opioid dependence; additional formulations FDA approved for pain are not a focus of this TIP | Once daily (also off-label dosing regimens if appropriate, such as split dose twice daily)
Generic buprenorphine monoproduct | Sublingual tablet | Mu-opioid receptor partial agonist | Treatment of opioid dependence; additional formulations FDA approved for pain are not a focus of this TIP | Once daily (also alternative off-label regimens)
Generic buprenorphine/naloxone combination product | Sublingual tablet, film | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine/naloxone (Zubsolv) | Sublingual tablet | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine/naloxone (Bunavail) | Buccal film | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine/naloxone (Suboxone) | Sublingual film; may also be administered buccally | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine (Probuphine) | Implants | Mu-opioid receptor partial agonist | Maintenance treatment of opioid dependence in clinically stable patients taking 8 mg/day or less of Suboxone equivalents | Implants last for 6 months and are then removed, after which a second set can be inserted
Extended-release injection buprenorphine (Sublocade) | Subcutaneous injection in the abdominal region | Mu-opioid receptor partial agonist | Treatment of moderate-to-severe OUD among patients initiated and taking transmucosal buprenorphine for at least 7 days | Monthly
Oral naltrexone (Naltrexone hydrochloride) | Oral tablet | Mu-opioid receptor antagonist | Block the effects of administered opioid agonists | Once daily (also alternative off-label regimens)
XR-NTX (Vivitrol) | Intramuscular injection | Mu-opioid receptor antagonist | Prevent return to opioid dependence after medically supervised opioid withdrawal | Once monthly by injection

The dosing guidance in subsequent chapters for methadone (Chapter 3B), naltrexone (Chapter 3C), and buprenorphine (Chapter 3D) is for healthcare professionals in general medical and addiction treatment settings. This guidance is based on:

• A review of the literature.
• A review of national and international organizations' guidelines.
• FDA-approved medication labels.
• The TIP expert panel's recommendations.