# Part 5 Resources Related to Medications for Opioid Use Disorder

For Healthcare and Addiction Professionals, Policymakers, Patients, and Families

Part 5 of this Treatment Improvement Protocol (TIP) provides a collection of resources by audience and a glossary of key terms to help readers better understand how Food and Drug Administration (FDA)-approved medications can be used to treat opioid use disorder (OUD).

KEY MESSAGES

• Practice guidelines and decision-making tools can help healthcare professionals with OUD screening, assessment, diagnosis, treatment planning, and referral.
• Patient- and family-oriented resources provide information about opioid addiction in general; the role of medication, behavioral and supportive services, and mutual-help groups in the treatment of OUD; how-tos for identifying recovery support services; and how-tos for locating medical and behavioral health service providers who specialize in treating OUD or other substance use disorders (SUDs).

There are numerous resources to help healthcare professionals and behavioral health service providers better understand the use of FDA-approved medications for OUD. Many other resources are available to help patients, their families and friends, and the general public better understand OUD and the medications available to treat it and support recovery from it. Part 5 of this TIP provides an audience-segmented collection of resources and a glossary of key terms related to OUD. It is of use to all interested readers.

## General Resources

### Facts and Figures

American Association for the Treatment of Opioid Dependence (AATOD), Frequently Asked Questions (www.aatod.org/resources/frequently-asked-questions).

Centers for Disease Control and Prevention (CDC), Smoking & Tobacco Use (www.cdc.gov/tobacco/index.htm).

Legal Action Center (LAC), Medication-Assisted Treatment for Opioid Addiction: Myths and Facts (http://lac.org/wp-content/uploads/2016/02/Myth-Fact-for-MAT.pdf).

Missouri Department of Mental Health, Methadone Maintenance Myths and Resources (https://dmh.mo.gov/docs/ada/methadonemyths.pdf).

National Institute on Drug Abuse (NIDA) (www.drugabuse.gov):

• Addiction Science (www.drugabuse.gov/related-topics/addiction-science). Provides two short videos that explain the nature of addiction. These are useful in educating people in primary care who suffer from addiction. This site has links to publications for professionals that explain the nature of addiction.
• NIDAMED, Medical and Health Professionals (www.drugabuse.gov/nidamed-medical-health-professionals). Disseminates science-based resources to healthcare professionals on the causes and consequences of drug use and addiction and advances in pain management.

Opioid overdose caused 42,249 DEATHS nationwide in 2016—this exceeded the # caused by motor vehicle crashes.^1,2^

Image of two cars crashing. Text reads: Opioid overdose caused 42,249 deaths nationwide in 2016—this exceeded the number caused by motor vehicle crashes.1,2

Office of National Drug Control Policy, Medication-Assisted Treatment for Opioid Addiction (https://online.ndbh.com/docs/providers/SubstanceUseCenter/Medication-Assisted-Treatment-Edited.pdf): Offers a factsheet with a useful summary of pharmacotherapy for OUD and its effectiveness.

Partnership for Drug-Free Kids, Commentary: Countering the Myths About Methadone (www.drugfree.org/news-service/commentary-countering-the-myths-about-methadone).

Substance Abuse and Mental Health Services Administration (SAMHSA):

• Addiction Technology Transfer Center (ATTC) (http://attcnetwork.org/home). Network with 10 regional centers across the country that provide training and information on evidence-based practices to practitioners. The ATTC website's section on OUD medication has many resources for clinicians, patients, and family members (www.attcnetwork.org/explore/priorityareas/wfd/mat/mat.pubs.asp).
• State Opioid Treatment Authorities (SOTAs) (https://dpt2.samhsa.gov/regulations/smalist.aspx).

United States Surgeon General's Report, Facing Addiction in America: The Surgeon General's Report on Alcohol, Drugs, and Health (https://addiction.surgeongeneral.gov).

### Groups and Organizations

AATOD (www.aatod.org): Works with federal and state agencies on opioid treatment policy throughout the United States. Convenes conferences every 18 months on evidence-based clinical practice, current research, and organizational developments related to OUD treatment. AATOD develops publications that serve as resources for addiction counselors and peer support providers.

American Academy of Addiction Psychiatry (AAAP) (www.aaap.org): Offers education and training materials on addiction psychiatry (e.g., webinars, continuing medical education courses).

American Society of Addiction Medicine (ASAM) (www.asam.org): Provides medical education and resources on the treatment of SUDs, including OUD.

LAC (https://lac.org): Offers information about the rights of people with criminal records, HIV/AIDS, and SUDs.

Medical Assisted Treatment of America (www.medicalassistedtreatment.org): Raises awareness and understanding of substance misuse, the problems it creates, and ways to address these problems.

National Alliance for Medication Assisted Recovery (NAMA Recovery) (www.methadone.org): Supports quality opioid agonist treatment through its many U.S. chapters and its international network of affiliate chapters. Thousands of methadone clients and healthcare professionals belong to the organization.

National Alliance of Advocates for Buprenorphine Treatment (www.naabt.org): Aims to educate the public about opioid addiction and buprenorphine as a treatment option, to reduce prejudice and discrimination against clients who have SUDs, and to connect clients in need to qualified treatment providers.

SAMHSA (www.samhsa.gov):

• Buprenorphine Practitioner Verification for Pharmacists (www.samhsa.gov/bupe/lookup-form)
• National Recovery Month (https://recoverymonth.gov)
• Opioid Treatment Program (OTP) Directory (https://dpt2.samhsa.gov/treatment)
• SOTAs (https://dpt2.samhsa.gov/regulations/smalist.aspx)

### SAMHSA Publications

All publications listed in this section are available for free from SAMHSA's publications ordering webpage (https://store.samhsa.gov) or by calling 1-877-SAMHSA-7 (1-877-726-4727):

• TIP 42: Substance Abuse Treatment for Persons With Co-Occurring Disorders (https://store.samhsa.gov/product/TIP-42-Substance-Abuse-Treatment-for-Persons-With-Co-Occurring-Disorders/SMA13-3992)
• TIP 54: Managing Chronic Pain in Adults With or in Recovery From Substance Use Disorders (https://store.samhsa.gov/product/TIP-54-Managing-Chronic-Pain-in-Adults-With-or-in-Recovery-From-Substance-Use-Disorders/SMA13-4671)
• TIP 57: Trauma-Informed Care in Behavioral Health Services (https://store.samhsa.gov/product/TIP-57-Trauma-Informed-Care-in-Behavioral-Health-Services/SMA14-4816)
• TIP 62: Relapse Prevention and Recovery Promotion in Behavioral Health Services (Once published, this TIP will be available on SAMHSA's publications ordering webpage, https://store.samhsa.gov)
• Advisory: An Introduction to Extended-Release Injectable Naltrexone for the Treatment of People With Opioid Dependence (https://store.samhsa.gov/product/An-Introduction-to-Extended-Release-Injectable-Naltrexone-for-the-Treatment-of-People-with-Opioid-Dependence/SMA12-4682)
• Advisory: Sublingual and Transmucosal Buprenorphine for Opioid Use Disorder: Review and Update (https://store.samhsa.gov/product/Advisory-Sublingual-and-Transmucosal-Buprenorphine-for-Opioid-Use-Disorder-Review-and-Update/SMA16-4938)
• Clinical Guidance for Treating Pregnant and Parenting Women With Opioid Use Disorder and Their Infants (https://store.samhsa.gov/product/Clinical-Guidance-for-Treating-Pregnant-and-Parenting-Women-With-Opioid-Use-Disorder-and-Their-Infants/All-New-Products/SMA18-5054)
• Clinical Use of Extended-Release Injectable Naltrexone in the Treatment of Opioid Use Disorders: A Brief Guide (https://store.samhsa.gov/shin/content//SMA14-4892/SMA14-4892.pdf)
• A Collaborative Approach to the Treatment of Pregnant Women With Opioid Use Disorders (https://store.samhsa.gov/product/A-Collaborative-Approach-to-the-Treatment-of-Pregnant-Women-with-Opioid-Use-Disorders/SMA16-4978)
• Decisions in Recovery: Treatment for Opioid Use Disorders, Handbook (https://store.samhsa.gov/product/SMA16-4993)
• Integrated Treatment for Co-Occurring Disorders Evidence-Based Practices (EBP) Kit (https://store.samhsa.gov/product/Integrated-Treatment-for-Co-Occurring-Disorders-Evidence-Based-Practices-EBP-KIT/SMA08-4367)
• Technical Assistance Publication 32: Clinical Drug Testing in Primary Care (https://store.samhsa.gov/shin/content//SMA12-4668/SMA12-4668.pdf)
• What Are Peer Recovery Support Services? (https://store.samhsa.gov/shin/content/SMA09-4454/SMA09-4454.pdf)

### General Information

Agency for Healthcare Research and Quality:

• Medication-Assisted Treatment Models of Care for Opioid Use Disorder in Primary Care Settings (www.ncbi.nlm.nih.gov/books/NBK402352)
• Academy for Integrating Behavioral Health and Primary Care (https://integrationacademy.ahrq.gov)

American Academy of Family Physicians:

• Chronic Pain Management and Opioid Misuse: A Public Health Concern (Position Paper) (www.aafp.org/about/policies/all/pain-management-opioid.html)
• Pain Management and Opioid Use Resources (www.aafp.org/patient-care/public-health/pain-opioids/resources.html)

ATTC Network (http://attcnetwork.org/home): This nationwide network of SAMHSA-sponsored regional centers is a multidisciplinary resource for professionals in the addiction treatment and recovery services fields. The network has many valuable resources and projects of interest to people involved in treating SUDs. Of particular interest to readers of this TIP are the training programs produced as part of the NIDA/SAMHSA-ATTC Blending Initiative:

• Buprenorphine Treatment: Training for Multidisciplinary Addiction Professionals (www.attcnetwork.org/projects/buptx.aspx)
• Buprenorphine Treatment for Young Adults (www.attcnetwork.org/projects/bupyoung.aspx)
• Prescription Opioid Addiction Treatment Study (POATS) (www.attcnetwork.org/projects/poats.aspx)

BupPractice.com Federal Recordkeeping Requirements for Buprenorphine Treatment (www.buppractice.com/node/12246): Provides information about federal recordkeeping requirements.

CDC Smoking & Tobacco Use (www.cdc.gov/tobacco/index.htm): Includes resource links for clinicians on smoking and the treatment of tobacco use.

Centers for Medicare & Medicaid Services (www.cms.gov/Medicare/Medicare-General-Information/Telehealth/index.html): Gives guidance on the delivery of telehealth.

Department of Health and Human Services (HHS):

• Centers for Medicare & Medicaid Services Clinical Laboratory Improvement Amendments Application for Certification (www.cms.gov/Medicare/CMS-Forms/CMS-Forms/downloads/cms116.pdf)
• Medication Assisted Treatment for Opioid Use Disorders: Final Rule (www.federalregister.gov/documents/2016/07/08/2016-16120/medication-assisted-treatment-for-opioid-use-disorders)

Drug Enforcement Administration (DEA):

• DEA Requirements for DATA Waived Physicians (www.deadiversion.usdoj.gov/pubs/docs/dwp_buprenorphine.htm). Lists DEA requirements for Drug Addiction Treatment Act of 2000 (DATA 2000)-waivered healthcare professionals.
• Form DEA-106, Report of Theft or Loss of Controlled Substances (https://apps.deadiversion.usdoj.gov/webforms/dtlLogin.jsp). Provides instructions for completing form DEA-106, which must be filed when stored buprenorphine is lost or stolen.
• Practitioner's Manual (www.deadiversion.usdoj.gov/pubs/manuals/pract). Provides guidance on how to comply with federal requirements on recordkeeping for ordering, storing, and dispensing buprenorphine in the office. This manual is from the DEA's Office of Diversion Control.

Drugs.com:

• Buprenorphine Drug Interactions (www.drugs.com/drug-interactions/buprenorphine-index.html?filter=3&generic_only= (http://www.drugs.com/drug-interactions/buprenorphine-index.html?filter=3&amp;generic_only=))
• Drug Interactions Checker (www.drugs.com/drug_interactions.php)

FDA:

• Approved Risk Evaluation and Mitigation Strategy (REMS): Buprenorphine Transmucosal Products for Opioid Dependence (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=RemsDetails.page&REMS=9 (http://www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=RemsDetails.page&amp;REMS=9))
• REMS: Probuphine (buprenorphine hydrochloride) (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&REMS=356 (http://www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&amp;REMS=356))
• REMS: Sublocade (extended-release injectable buprenorphine) (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&REMS=376 (http://www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&amp;REMS=376))
• REMS: Suboxone/Subutex (buprenorphine and naloxone/buprenorphine) (www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&REMS=352 (http://www.accessdata.fda.gov/scripts/cder/rems/index.cfm?event=IndvRemsDetails.page&amp;REMS=352))
• REMS: Vivitrol (extended-release naltrexone [XR-NTX]) (www.vivitrolrems.com)

LAC (https://lac.org): LAC attorneys provide legal advice by phone to service providers and government agencies. They assist dozens of agencies annually with questions about confidentiality of treatment records, discrimination, and other issues. LAC's confidentiality hotline provides information about the federal law protecting the confidentiality of drug and alcohol treatment and prevention records (42 CFR Part 2). The hotline is free to New York treatment providers and government agencies. Outside New York, the hotline is accessible if the state alcohol/drug oversight agency subscribes to LAC's Actionline service (http://lac.org/wp-content/uploads/2014/12/New_Actionline_Flyer.pdf). To speak with a hotline attorney, call LAC Monday through Friday 1−5 p.m. (Eastern Time Zone) at 1-212-243-1313, or toll-free at 1-800-223-4044.

National Alliance of Advocates for Buprenorphine Treatment 30–100 Patient Limit (www.naabt.org/30_patient_limit.cfm): Summarizes the DATA 2000 law.

National Association of State Controlled Substances Authorities State Profiles (www.nascsa.org/stateprofiles.htm): Contains a directory of each state's prescription drug monitoring program (PDMP).

National Conference of State Legislatures Drug Overdose Immunity and Good Samaritan Laws (www.ncsl.org/research/civil-and-criminal-justice/drug-overdose-immunity-good-samaritan-laws.aspx): Provides information about naloxone and Good Samaritan immunity.

National Institute on Alcohol Abuse and Alcoholism (NIAAA) Professional Education Materials (www.niaaa.nih.gov/publications/clinical-guides-and-manuals): Provides professional education materials; offers links to screening, treatment planning, and general information for clinicians in outpatient programs.

National Library of Medicine's DailyMed:

• FDA label information for methadone (https://dailymed.nlm.nih.gov/dailymed/search.cfm?labeltype=all&query=METHADONE (https://dailymed.nlm.nih.gov/dailymed/search.cfm?labeltype=all&amp;query=METHADONE))
• FDA label information for naltrexone (https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=cd11c435-b0f0-4bb9-ae78-60f101f3703f)

NIDA:

• Available Treatments for Marijuana Use Disorders (www.drugabuse.gov/publications/research-reports/marijuana/available-treatments-marijuana-use-disorders). Provides information about treatment options for individuals with marijuana use disorder.
• Opioid Overdose Reversal With Naloxone (Narcan, Evzio) (www.drugabuse.gov/related-topics/opioid-overdose-reversal-naloxone-narcan-evzio). Contains naloxone information for providers.
• NIDAMED, Medical and Health Professionals (www.drugabuse.gov/nidamed-medical-health-professionals). Provides practice-related and professional education-related resources.
• Medications To Treat Opioid Addiction (www.drugabuse.gov/publications/research-reports/medications-to-treat-opioid-addiction/overview). Provides an overview of the need for and efficacy of OUD medications and discusses common misconceptions, impacts on outcome, and use of OUD medications with certain specific populations.
• Effective Treatments for Opioid Addiction (https://www.drugabuse.gov/publications/effective-treatments-opioid-addiction/effective-treatments-opioid-addiction).
• Therapeutic Communities (www.drugabuse.gov/publications/research-reports/therapeutic-communities/what-are-therapeutic-communities). Gives a brief overview of OUD medications and links to additional information.
• Principles of Drug Addiction Treatment: A Research-Based Guide (www.drugabuse.gov/publications/principles-drug-addiction-treatment-research-based-guide-third-edition/preface). Discusses how OUD affects the brain and covers the state of addiction treatment in the United States, principles of effective treatment, frequently asked questions about OUD medication, evidence-based approaches to treatment, and additional resources.
• Principles of Adolescent Substance Use Disorder Treatment: A Research-Based Guide (www.drugabuse.gov/publications/principles-adolescent-substance-use-disorder-treatment-research-based-guide/introduction). Discusses principles of SUDs in adolescents, addresses frequently asked questions, summarizes treatment settings and evidence-based treatment approaches, and provides treatment referral resources.
• Treating Opioid Use Disorder During Pregnancy (www.drugabuse.gov/publications/treating-opioid-use-disorder-during-pregnancy/treating-opioid-use-disorder-during-pregnancy). Addresses the risks of OUD to the pregnant woman and the fetus, briefly summarizes OUD pharmacotherapies for use during pregnancy, and provides links to additional information.

North American Syringe Exchange Program (https://nasen.org/directory): Provides a national directory of syringe exchange programs in the United States.

Prescription Drug Abuse Policy System's Naloxone Overdose Prevention Laws (http://pdaps.org/datasets/laws-regulating-administration-of-naloxone-1501695139): Provides a map with a link to each state's naloxone overdose prevention laws, including policies on prescribing, dispensing, and civil and criminal immunity.

Project Lazarus's Naloxone: The Overdose Antidote (www.projectlazarus.org/naloxone): Provides guidance on administering naloxone.

Providers’ Clinical Support System's (PCSS's) How To Prepare for a Visit From the Drug Enforcement Agency Regarding Buprenorphine Prescribing (http://pcssmat.org/wp-content/uploads/2014/02/FINAL-How-to-Prepare-for-a-DEA-Inspection.pdf): Provides a description of the DEA inspection process and how to comply with its requirements.

SAMHSA:

• Dear Colleague Letters for Medication-Assisted Treatment Providers (www.samhsa.gov/medication-assisted-treatment/legislation-regulations-guidelines/dear-colleague-letters). Offers regular communications to the opioid treatment community regarding clinical and regulatory issues related to opioid treatment. Regulations, policies, and best practices for OTPs and office-based opioid treatment (OBOT) clinics can change, and Dear Colleague Letters help providers stay up to date.
• Understanding the Final Rule for a Patient Limit of 275 (www.samhsa.gov/sites/default/files/programs_campaigns/medication_assisted/understanding-patient-limit275.pdf). Provides information about the final rule and how to use it to increase patient access to medication for OUD and associated reporting requirements.
• Buprenorphine Waiver Management (www.samhsa.gov/medication-assisted-treatment/buprenorphine-waiver-management). Provides information on the buprenorphine waiver, including links to the buprenorphine waiver application and an explanation of the processes, requirements, and recordkeeping strategies associated with prescribing buprenorphine.
• Qualify for Nurse Practitioners (NPs) and Physician Assistants (PAs) Waiver (www.samhsa.gov/medication-assisted-treatment/qualify-nps-pas-waivers). Provides information for NPs and PAs about the buprenorphine waiver training, with links to trainings and the application process.
• Buprenorphine Training for Physicians (www.samhsa.gov/medication-assisted-treatment/training-resources/buprenorphine-physician-training). Offers links to organizations that provide buprenorphine training for physicians.
• SAMHSA Opioid Overdose Prevention Toolkit (https://store.samhsa.gov/product/SAMHSA-Opioid-Overdose-Prevention-Toolkit/SMA16-4742). Prepares healthcare professionals, communities, and local governments with material to develop practices and policies to help prevent opioid-related overdoses and deaths. It addresses issues for healthcare professionals, first responders, treatment providers, and those recovering from opioid overdose.
• Federal Guidelines for Opioid Treatment Programs (https://store.samhsa.gov/product/Federal-Guidelines-for-Opioid-Treatment-Programs/PEP15-FEDGUIDEOTP). Provides updated guidelines for how OTPs can satisfy the federal regulations.
• Form SMA-168 Opioid Treatment Exception Request (www.samhsa.gov/medication-assisted-treatment/opioid-treatment-programs/submit-exception-request). Provides instructions for physicians on how to request exceptions to federal standards for opioid treatment.
• Laws and Regulations (www.samhsa.gov/about-us/who-we-are/laws-regulations). Provides an overview and summary of the most frequent questions about disclosure and patient records pertaining to substance use treatment that federal programs maintain.
• Substance Abuse in Brief Fact Sheet: Introduction to Mutual-Support Groups for Alcohol and Drug Abuse (https://store.samhsa.gov/shin/content/SMA08-4336/SMA08-4336.pdf). Provides information to help medical and behavioral health service providers understand mutual-help groups and how to make referrals to such groups.
• SAMHSA has developed several resources to guide healthcare professionals in their use of telehealth and telemedicine approaches for OUD:
  - In Brief: Rural Behavioral Health: Telehealth Challenges and Opportunities (https://store.samhsa.gov/shin/content/SMA16-4989/SMA16-4989.pdf)
  - Certified Community Behavioral Health Clinics (CCBHCs) Using Telehealth or Telemedicine (www.samhsa.gov/section-223/care-coordination/telehealth-telemedicine)

### Practice Guidelines and Decision-Support Tools

ASAM:

• Appropriate Use of Drug Testing in Clinical Addiction Medicine (http://download.lww.com/wolterskluwer_vitalstream_com/PermaLink/JAM/A/JAM_11_3_2017_06_02_SAFARIAN_JAM-D-17-00020_SDC1.pdf). Details the ASAM consensus statement on drug testing in addiction treatment.
• The ASAM Criteria (www.asam.org/quality-practice/guidelines-and-consensus-documents/the-asam-criteria). Provides criteria and a comprehensive set of guidelines for placement, continued stay, and transfer/discharge of patients with addiction and co-occurring conditions.
• The ASAM National Practice Guidelines: For the Use of Medication in the Treatment of Addiction Involving Opioid Use (www.asam.org/docs/default-source/practice-support/guidelines-and-consensus-docs/asam-national-practice-guideline-supplement.pdf). Provides information on prescribing methadone, buprenorphine, naltrexone, and naloxone. The document also discusses the needs of special populations, including women during pregnancy, patients with chronic pain, adolescents, individuals in the criminal justice system, and patients with co-occurring psychiatric conditions.

CDC:

• CDC Guideline for Prescribing Opioids for Chronic Pain (www.cdc.gov/drugoverdose/prescribing/guideline.html).
• Guideline Resources: Clinical Tools (www.cdc.gov/drugoverdose/prescribing/clinical-tools.html). Provides links and tools to help clinicians prevent opioid overdose deaths.

Credible Meds (www.crediblemeds.org): Maintains a list of medications that may increase QTc intervals. Free registration is required to access the most up-to-date list.

HHS:

• BeTobaccoFree.gov News and Resources (https://betobaccofree.hhs.gov/quit-now/index.html#professionals). Offers links for clinicians that provide guidance on the care for patients with nicotine addiction. The Resources section is at the bottom of the page linked here.
• BeTobaccoFree.gov Nicotine Addiction and Your Health (https://betobaccofree.hhs.gov/health-effects/nicotine-health). Provides information on nicotine addiction and its health effects.

Institute for Research, Evaluation, and Training in Addictions’ Management of Benzodiazepines in Medication-Assisted Treatment (http://ireta.org/wp-content/uploads/2014/12/BP_Guidelines_for_Benzodiazepines.pdf): Provides information on managing benzodiazepine use in patients taking medications for OUD.

PCSS for Medication Assisted Treatment (https://pcssmat.org): Provides buprenorphine waiver training for clinicians (physicians, NPs, and PAs).

PCSS Mentoring Program (https://pcssmat.org/mentoring): Gives providers guidance on prescribing OUD medications. This national network of experienced providers is available at no cost. Mentors provide support by telephone, email, or in person if possible.

PCSS Models of Buprenorphine Induction (http://pcssmat.org/wp-content/uploads/2015/02/Buprenorphine-Induction-Online-Module.pdf): Provides information about various buprenorphine induction approaches including in-office, non-OTP, and at-home dosing.

Prescribe To Prevent (http://prescribetoprevent.org): Provides information about naloxone prescribing for overdose prevention, including educational patient handouts and videos.

SAMHSA:

• MATx Mobile App To Support Medication-Assisted Treatment of Opioid Use Disorder (https://store.samhsa.gov/apps/mat). Provides information on FDA-approved treatment approaches and medications used to treat OUD. It includes a buprenorphine prescribing guide with information on the DATA 2000 waiver process and patient limits. Clinical support tools (e.g., treatment guidelines; International Classification of Diseases, 10th Edition, coding; guidance on working with special populations), help lines, and SAMHSA's treatment locators are also included.
• Pocket Guide: Medication-Assisted Treatment of Opioid Use Disorder (https://store.samhsa.gov/shin/content/SMA16-4892PG/SMA16-4892PG.pdf).
• Buprenorphine (www.samhsa.gov/medication-assisted-treatment/treatment/buprenorphine).
• Naltrexone (www.samhsa.gov/medication-assisted-treatment/treatment/naltrexone).
• Decisions in Recovery: Treatment for Opioid Use Disorder (https://media.samhsa.gov/MAT-Decisions-in-Recovery). Provides information on shared decision making in pharmacotherapy for OUD.
• Decisions in Recovery: Treatment for Opioid Use Disorder, Planning for Success (https://media.samhsa.gov/MAT-Decisions-in-Recovery/section/how/planning_for_success.aspx). Provides assistance in developing a recovery plan.
• Bringing Recovery Supports to Scale Technical Assistance Center Strategy (www.samhsa.gov/brss-tacs) and Shared Decision-Making Tools (www.samhsa.gov/brss-tacs/recovery-support-tools/shared-decision-making). Offers training and technical assistance on many topics related to medication for OUD, including recovery-oriented systems of care, mutual-support groups, capacity building, leadership by people in recovery and family members, certification requirements for peer specialists and mutual-support group coaches, and core competencies for recovery-oriented behavioral health workers.
• Pharmacologic Guidelines for Treating Individuals With Post-Traumatic Stress Disorder and Co-Occurring Opioid Use Disorders (https://store.samhsa.gov/shin/content/SMA12-4688/SMA12-4688.pdf).
• General Principles for the Use of Pharmacological Agents To Treat Individuals With Co-Occurring Mental and Substance Use Disorders (https://store.samhsa.gov/shin/content/SMA12-4689/SMA12-4689.pdf).

Veterans Administration (VA)/Department of Defense (DoD) Clinical Practice Guideline for the Management of Substance Use Disorders (www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf): Provides information on screening, assessment, and treatment of OUD as well as other SUDs. It is primarily for VA and DoD healthcare providers and others involved in the care of service members or veterans with an SUD.

### Assessment Scales and Screening Tools

AAAP, Education & Training (www.aaap.org/education-training/cme-opportunities): Provides Performance-in-Practice Clinical Modules for alcohol use disorder and tobacco use disorder.

American Psychiatric Nurses Association, Tobacco & Nicotine Use Screening Tools & Assessments (www.apna.org/i4a/pages/index.cfm?pageID=6150): Provides the Fagerström screening tools for nicotine dependence and smokeless tobacco and a screening checklist for adolescent tobacco use.

ASAM Appropriate Use of Drug Testing in Clinical Addiction Medicine (www.asam.org/quality-practice/guidelines-and-consensus-documents/drug-testing): Gives information on the appropriate use of drug testing in identifying, diagnosing, and treating people with or at risk for SUDs.

Clinical Institute Narcotic Assessment Scale for Withdrawal Symptoms (www.ncpoep.org/wp-content/uploads/2015/02/Appendix_7_Clinical_Institute_Narcotic_Assessment_CINA_Scale_for_Withdrawal_Symptoms.pdf).

NIDA, Screening, Assessment, and Drug Testing Resources (www.drugabuse.gov/nidamed-medical-health-professionals/tool-resources-your-practice/additional-screening-resources): Gives resources such as an evidence-based screening tool chart for adolescents and adults and drug use screening tool supports; also has a clinician resource and quick reference guide for drug screening in general medical settings.

World Health Organization Guidelines for the Psychosocially Assisted Pharmacological Treatment of Opioid Dependence (www.ncbi.nlm.nih.gov/books/NBK143183): Includes links to the Clinical Opiate Withdrawal Scale (www.drugabuse.gov/sites/default/files/files/ClinicalOpiateWithdrawalScale.pdf) and other opioid withdrawal scales from Annex 10 of the guidelines.

## Resources for Counselors and Peer Providers

### Organizations

Community Care Behavioral Health Organization (www.ccbh.com): A provider network focused on recovery that has published Supporting Recovery From Opioid Addiction: Community Care Best Practice Guidelines for Recovery-Oriented Methadone Maintenance (www.ccbh.com/pdfs/providers/healthchoices/bestpractice/MethadoneBestPracticeGuideline.pdf), a set of recovery-oriented practice implementation guidelines for methadone programs.

Faces & Voices of Recovery (https://facesandvoicesofrecovery.org): Dedicated to organizing and mobilizing the millions of Americans in recovery from addiction to alcohol and drugs, their families and friends, and other allies into recovery community organizations and networks. Faces & Voices of Recovery promotes the right resources to recover through advocacy, education, and demonstration of the power and proof of long-term recovery.

International Association of Peer Supporters (https://inaops.org): An organization for mental health and addiction peer recovery support specialists, recovery coaches, recovery educators and trainers, administrators of consumer-operated or peer-run organizations, and others.

Medication-Assisted Recovery Services (MARS) Project (www.marsproject.org): A peer-initiated, peer-based recovery support project sponsored by NAMA Recovery that offers, among other resources, an educational video about the MARS peer support program and an online network for MARS peer support personnel:

• MARS Project Video (www.marsproject.org).
• New York State Peer Recovery Network, Peers Organizing for Results Through Advocacy and Leadership (PORTAL) (http://advocacy.marsproject.org). Created to help peers in recovery more effectively organize their communities, communicate with each other, and create a stronger voice for advocacy efforts.

Pillars of Peer Support Services (www.pillarsofpeersupport.org): Develops and fosters the use of Medicaid funding to support peer recovery services in state mental health systems of care.

Recovery Community Services Program—Statewide Network (www.samhsa.gov/grants/grant-announcements/ti-14-001): A SAMHSA grant program for peer-to-peer recovery support services that help people initiate and sustain recovery from SUDs.

### Publications and Other Resources

ATTC's Recovery-Oriented Methadone Maintenance (www.attcnetwork.org/userfiles/file/GreatLakes/5th%20Monograph_RM_Methadone.pdf): This guide is the most thorough document on this topic currently available and is applicable to clients receiving other medications for OUD.

Community Care Behavioral Health Organization: These publications outline phase-specific tasks and accompanying strategies for programs that serve clients who take methadone or buprenorphine:

• Supporting Recovery From Opioid Addiction: Community Care Best Practice Guidelines for Recovery-Oriented Methadone Maintenance (www.williamwhitepapers.com/pr/Recovery-oriented%20Methadone%20Maintenance%20Best%20Practice%20Guidelines%202014%20-%20CCBHO.pdf)
• Supporting Recovery From Opioid Addiction: Community Care Best Practice Guidelines for Buprenorphine and Suboxone (www.ccbh.com/pdfs/providers/healthchoices/bestpractice/Community_Care_BP_Guidelines_for_Buprenorphine_and_Suboxone.pdf)

Narcotics Anonymous (NA) (www.na.org): The organization's most recent statement on medications for treating OUD—Narcotics Anonymous and Persons Receiving Medication-Assisted Treatment—is available online (www.na.org/admin/include/spaw2/uploads/pdf/pr/2306_NA_PRMAT_1021.pdf).

SAMHSA (https://store.samhsa.gov): This agency oversees medications to treat opioid addiction, including methadone, buprenorphine, and naltrexone; sets regulations; guides policy; and offers information and resources for the field. SAMHSA has many recovery-oriented publications for providers:

• Dear Colleague Letters for Medication-Assisted Treatment Providers (www.samhsa.gov/medication-assisted-treatment/legislation-regulations-guidelines/dear-colleague-letters). Regulations, policies, and best practices for OTPs can change; these regular communications help providers stay up to date on clinical and regulatory issues related to opioid treatment.
• Medication-Assisted Recovery: Medication Assisted Peer Recovery Support Services Meeting Report (www.samhsa.gov/sites/default/files/programs_campaigns/medication_assisted/dear_colleague_letters/2015-prss-summary-report.pdf).
• Financing Recovery Support Services: Review and Analysis of Funding Recovery Support Services and Policy Recommendations (www.samhsa.gov/sites/default/files/partnersforrecovery/docs/RSS_financing_report.pdf).
• SAMHSA's Working Definition of Recovery (https://store.samhsa.gov/shin/content/PEP12-RECDEF/PEP12-RECDEF.pdf).
• Access to Recovery Approaches to Recovery-Oriented Systems of Care (https://store.samhsa.gov/product/Access-to-Recovery-ATR-Approaches-to-Recovery-Oriented-Systems-of-Care/SMA09-4440).
• Building Bridges—Co-Occurring Mental Illness and Addiction: Consumers and Service Providers, Policymakers, and Researchers in Dialogue (https://store.samhsa.gov/shin/content//SMA04-3892/SMA04-3892.pdf).

Selected Papers of William L. White (www.williamwhitepapers.com): Contains papers, monographs, and presentations on recovery, including recovery-oriented methadone maintenance, methadone and anti-medication bias, discrimination and methadone, NA and the pharmacotherapeutic treatment of OUD, and co-participation in 12-Step mutual-support groups and methadone maintenance.

## Resources for Clients and Families

### Organizations

AAOTD (www.aatod.org): Offers a variety of resources, news releases about medication for the treatment of OUD, and information about its national conferences.

Al-Anon Family Groups (www.al-anon.org): Describes group meetings where friends and family members of people with substance use issues share their experiences and learn how to apply the principles of the Al-Anon program to their individual situations. Sponsorship gives members the chance to get personal support from more experienced individuals in the program.

Alcoholics Anonymous (AA) (www.aa.org): Offers group meetings for people who have problems relating to drinking and wish to stop. AA sponsors provide members with more personal support from experienced individuals. Many people who are taking medication to treat OUD find AA increasingly receptive to their decisions about medication, and AA meetings are more widely available to these individuals.

ASAM: Provides patient and family education tools about addiction in general and OUD specifically:

• Patient Resources (www.asam.org/resources/patientresources)
• Opioid Addiction Treatment: A Guide for Patients, Families, and Friends (http://eguideline.guidelinecentral.com/i/706017-asam-opioid-patient-piece/0?)

Double Trouble in Recovery (www.hazelden.org/HAZ_MEDIA/3818_doubletroubleinrecovery.pdf): Describes a fellowship of people who support each other in recovering from substance use and mental disorders.

Dual Recovery Anonymous (www.draonline.org): Presents information on mutual-help organization that follows 12-Step principles in supporting people recovering from addiction and emotional or mental illness. Focuses on preventing relapse and actively improving members’ quality of life through a community of mutual support.

Faces & Voices of Recovery (https://facesandvoicesofrecovery.org): Offers recovery stories, news, events information, publications, and webinars.

Heroin Anonymous (http://heroinanonymous.org): Describes a nonprofit fellowship of individuals in recovery from heroin addiction committed to helping each other stay sober. This organization holds local support meetings, a directory of which can be found on its website.

LAC (https://lac.org): Offers information about the rights of people with criminal records, HIV/AIDS, and SUDs.

Learn to Cope (www.learn2cope.org): Describes a secular mutual-help group that offers education, resources, and peer support for the families of people with SUDs (although the focus is primarily on OUD). The organization maintains an online forum, but groups are only available in a few states.

NA (www.na.org): Provides a global, community-based organization with a multilingual, multicultural membership that supports addiction recovery via a 12-Step program, including regular group meeting attendance. Members hold nearly 67,000 meetings weekly in 139 countries. NA is an ongoing support network for maintaining a drug-free lifestyle. NA doesn't focus on a particular addictive substance.

NAMA Recovery (www.methadone.org): Offers an education series, provides training and certification for Certified MAT Advocates, and has local chapters and international affiliates that act to advocate for methadone patients. It has a helpful webpage titled FAQs About Advocate Training and Certification (www.methadone.org/certification/faq.html).

Nar-Anon Family Groups (www.nar-anon.org): Provides group meetings where friends and family of people with drug use problems can share their experiences and learn to apply the 12-Step Nar-Anon program to their lives. Nar-Anon groups also offer more individualized support from experienced individuals in the program who act as sponsors.

National Alliance on Mental Illness (NAMI) (www.nami.org): Describes the largest grassroots educational, peer support, and mental health advocacy organization in the United States. Founded in 1979 by a group of family members of people with mental disorders, NAMI has developed into an association of hundreds of local affiliates, state organizations, and volunteers.

Parents of Addicted Loved Ones (https://palgroup.org): Presents a secular support group for parents who have a child with an SUD. The organization has meetings in only some states but also hosts telephone meetings.

Pills Anonymous (www.pillsanonymous.org): Offers a 12-Step mutual-support group that holds regular meetings in which individuals in recovery from addiction to pills share their experiences, build their strengths, and offer hope for recovery to one another.

Secular Organizations for Sobriety (www.sossobriety.org): Describes a nonprofit, nonreligious network of autonomous, nonprofessional local groups that support people in achieving and maintaining abstinence from alcohol and drug addiction.

Self-Management for Addiction Recovery (SMART Recovery) (www.smartrecovery.org): Is a self-empowering addiction recovery support group; participants learn science-based tools for addiction recovery and have access to an international recovery community of mutual-help groups.

Stop Stigma Now (www.stopstigmanow.org): Describes an advocacy organization that works to eradicate prejudice associated with taking medication to treat OUD and offers resources and a media library.

Women for Sobriety (https://womenforsobriety.org/beta2): Offers an abstinence-based mutual-help group that helps women find their individual paths to recovery by acknowledging the unique needs women have in recovery. This organization is not affiliated with any other recovery organization. It offers recovery tools to help women in recovery develop coping skills focused on emotional growth, spiritual growth, self-esteem, and a healthy lifestyle.

### Publications and Other Resources

AAAP Patient Resources (www.aaap.org/patient-resources/helpful-links): Offers resources and publications for patients and their families.

Addiction Treatment Forum, Narcotics Anonymous and the Pharmacotherapeutic Treatment of Opioid Addiction in the United States (http://atforum.com/documents/2011NAandMedication-assistedTreatment.pdf): Presents William White's publication for people receiving medication for OUD that gives information on the pros and cons of 12-Step groups and how to prepare for meetings.

ASAM, Opioid Addiction Treatment: A Guide for Patients, Families, and Friends (http://eguideline.guidelinecentral.com/i/706017-asam-opioid-patient-piece): Provides a guide about the treatment of OUD for patients, families, and friends.

HHS:

• Smokefree.gov (https://smokefree.gov). Provides useful information that helps individuals in planning and maintaining tobacco cessation.
• BeTobaccoFree.gov (https://betobaccofree.hhs.gov/health-effects/nicotine-health). Provides information for individuals struggling with nicotine addiction and links for clinicians that provide guidance on the care for patients with nicotine addiction.

LAC (https://lac.org/resources/substance-use-resources/medication-assisted-treatment-resources). Maintains a library of documents related to medication for the treatment of OUD and other resources, including an advocacy toolkit, sample support letter form, training materials, and webinars:

• Driving on Methadone or Buprenorphine (Suboxone): DUI? (http://lac.org/wp-content/uploads/2014/07/Driving-on-Methadone-or-Suboxone-DUI.pdf) factsheet.
• Know Your Rights: Employment Discrimination Against People With Alcohol/Drug Histories (https://lac.org/resources/substance-use-resources/employment-education-housing-resources/webinar-know-rights-employment-discrimination-people-alcoholdrug-histories) webinar.
• Know Your Rights: Rights for Individuals on Medication-Assisted Treatment (https://lac.org/wp-content/uploads/2014/12/Know_Your_Rts_-_MAT_final_9.28.10.pdf) publication.
• Medication-Assisted Treatment for Opioid Addiction: Myths and Facts (http://lac.org/wp-content/uploads/2016/02/Myth-Fact-for-MAT.pdf) factsheet.

NAMA Recovery (www.methadone.org): Offers many resources and training opportunities to become a certified advocate for pharmacotherapy for OUD and provides links to resources related to medication for the treatment of OUD.

National Council on Alcoholism and Drug Dependence's Consumer Guide to Medication-Assisted Recovery (www.ncadd.org/images/stories/PDF/Consumer-Guide-Medication-Assisted-Recovery.pdf).

NIAAA's Rethinking Drinking (www.rethinkingdrinking.niaaa.nih.gov/help-links): Provides links to patient and family education, help lines, and other recovery resources.

SAMHSA (https://store.samhsa.gov): Provides patient and family educational tools about OUD and medication treatment for OUD treatment. The resources below are available in several languages, including Spanish and Russian:

• Decisions in Recovery: Treatment for Opioid Use Disorders (https://store.samhsa.gov/product/Decisions-in-Recovery-Treatment-for-Opioid-Use-Disorders/SMA16-4993). Helps clients identify an appropriate path of recovery from OUD.
• The Facts About Buprenorphine for Treatment of Opioid Addiction (https://store.samhsa.gov/shin/content//SMA14-4442/SMA14-4442.pdf (https://store.samhsa.gov/shin/content/SMA14-4442/SMA14-4442.pdf)).
• The Facts About Naltrexone for Treatment of Opioid Addiction (https://store.samhsa.gov/shin/content/SMA09-4444/SMA09-4444.pdf).
• Know Your Rights: Rights for Individuals on Medication-Assisted Treatment (https://store.samhsa.gov/product/Rights-for-Individuals-on-Medication-Assisted-Treatment/SMA09-4449).
• Medication-Assisted Treatment for Opioid Addiction: Facts for Families and Friends (www.ct.gov/dmhas/lib/dmhas/publications/MAT-InfoFamilyFriends.pdf).
• What Every Individual Needs To Know About Methadone Maintenance (https://store.samhsa.gov/product/What-Every-Individual-Needs-to-Know-About-Methadone-Maintenance/SMA06-4123).
• What Is Substance Abuse Treatment? A Booklet for Families (https://store.samhsa.gov/shin/content/SMA14-4126/SMA14-4126.pdf).

### Treatment Locators

Faces & Voices of Recovery Guide to Mutual Aid Resources (http://facesandvoicesofrecovery.org/resources/mutual-aid-resources): Offers a comprehensive list of 12-Step and non-12-Step recovery support groups throughout the United States and online.

National Alliance of Advocates for Buprenorphine Treatment (www.treatmentmatch.org/TM_index.php): Offers a free, 24/7 anonymous treatment-matching service for patients and providers.

Probuphine Healthcare Provider Locator (https://probuphinerems.com/probuphine-locator): Offers a list of healthcare professionals who prescribe, insert, and/or remove buprenorphine implants.

SAMHSA:

• Behavioral Health Treatment Services Locator is a directory of inpatient treatment providers (https://findtreatment.samhsa.gov).
• Behavioral Health Treatment Services Locator: Self-Help, Peer Support, and Consumer Groups (Addiction) provides a directory for consumers (https://findtreatment.samhsa.gov/locator/link-focSelfGP).
• Buprenorphine Treatment Practitioner Locator provides an interactive treatment locator of providers who prescribe buprenorphine (www.samhsa.gov/medication-assisted-treatment/physician-program-data/treatment-physician-locator).
• Opioid Treatment Program Directory provides an interactive SAMHSA OTP treatment locator (https://dpt2.samhsa.gov/treatment/directory.aspx).

VA Substance Use Disorder Program Locator (www.va.gov/directory/guide/SUD.asp): Provides an interactive treatment locator for VA SUD treatment programs.

### Patient Success Stories

Patients’ success stories highlight the powerful ways in which medication for the treatment of OUD can help people achieve remission and recovery. Examples of patient success stories include the following:

• Carol (https://vimeo.com/105287902)
• Brandon (https://vimeo.com/105078010)
• Archie (www.youtube/iHJ6K4VQvrw?list=PLGV_2NAg58zkUOZRupfKc6_Z7jaBf7h-V (https://youtu.be/iHJ6K4VQvrw?list=PLGV_2NAg58zkUOZRupfKc6_Z7jaBf7h-V))
• MARS Project Video (www.marsproject.org)

### Online Boards and Chat Rooms

12-Step Forums: A variety of NA and AA meetings are available online, each with its own perspective on medication:

• The AA online intergroup directory lists numerous online AA meetings, which occur at specific times (https://aa-intergroup.org/directory_venue.php?code=CH).
• The NA chatroom asks that participants not talk about medication (www.nachatroom.net).

Facebook Forums and Groups: Many medication-assisted recovery organizations maintain a presence on Facebook because of the ease of creating online mutual-support and chat groups:

• A.T. Watchdog: A Pro Methadone Maintenance Support Group (www.facebook.com/groups/1599996730222196)
• Clean & Sober Today (www.facebook.com/groups/1822841161286327)
• Heroin Anonymous (www.facebook.com/HeroinAnonymous)
• Medication-Assisted Treatment Miracles (www.facebook.com/groups/MATMiracles)
• Methadone Discussion (www.facebook.com/groups/MethadoneSupport)
• NAMA Recovery:
  - NAMA-R (www.facebook.com/groups/NAMARecoveryTN)
  - Boston Methadone & Bupe Patient Discussion (www.facebook.com/groups/833560336673414)
  - NAMA Recovery of Washington (www.facebook.com/groups/398175280306632)
• Secular Organizations for Sobriety (www.facebook.com/groups/251215211975)
• Social Media 4Recovery (www.facebook.com/groups/748016625286020)
• Stop Stigma Now (www.facebook.com/Stop-Stigma-Now-1482990085299885)
• Suboxone/Buprenorphine Treatment and Support—Detox/Maintenance (www.facebook.com/groups/Fightingthestigmaofaddiction)

Heroin Addiction & Recovery Forum (http://killtheheroinepidemicnationwide.org/forum): An online discussion forum for both people who are addicted to heroin and their friends and families.

Moms on Methadone (www.circleofmoms.com/moms-on-methadone): An online support group for pregnant women or women with children who are taking medication to treat OUD.

SMART Recovery Online Forum (www.smartrecovery.org/community/forum.php): An online group that welcomes new members.

We Speak Methadone (and Buprenorphine) (www.methadone.org/wespeakmethadone): A discussion forum for medication-assisted treatment patients, their families, and advocates.

## Provider Tools and Sample Forms

### Provider Screening and Assessment Tools and Aids

Alcohol Use Disorders Identification Test (AUDIT)

Stable Resource Toolkit

AUDIT-C Questionnaire

Drug Abuse Screening Test (DAST-10)

DSM-5 Opioid Use Disorder Checklist^7^

### Heaviness of Smoking Index

Ask these two questions of current or recent smokers:

1. How soon after waking do you smoke your first cigarette?
  • Within 5 minutes (3 points)
  • 5–30 minutes (2 points)
  • 31–60 minutes (1 point)
  • 61 or more minutes (no points)
2. How many cigarettes a day do you smoke?
  • 10 or less (no points)
  • 11–20 (1 point)
  • 21–30 (2 points)
  • 31 or more (3 points)

Total score: 1 to 2 points = very low dependence; 3 points = low to moderate dependence; 4 points = moderate dependence; 5 or more points = high dependence

Adapted with permission. ^ 8 ^

### NIAAA Single-Item Screener

How many times in the past year have you had five or more drinks in a day (four drinks for women and all adults older than age 65)?

A response of one or more times is considered a positive screen. Patients who screen positive should have an assessment for alcohol use disorder.

Adapted with permission. ^ 9 ^

### Opioid Overdose: Risk, Prevention, Identification, and Response

#### Overdose Risk

• Using heroin (possibly mixed with illicitly manufactured fentanyl or fentanyl analogs)
• Using prescription opioids that were not prescribed
• Using prescription opioids more frequently or at higher doses than prescribed
• Using opioids after a period of abstinence or reduced use (e.g., after medically supervised withdrawal or incarceration)
• Using opioids with alcohol, benzodiazepines, or both

#### Overdose Prevention

• Don't use opioids that were not prescribed.
• Take medications only as prescribed.
• Don't use drugs when you are alone.
• Don't use multiple substances at once.
• Have naloxone available and make sure others know where it is and how to use it.
• Use a small “test dose” if returning to opioid use after a period of abstinence, if the substance appears altered or has been acquired from an unfamiliar source. Beware: This doesn't guarantee safety; illicitly manufactured fentanyl or other substances may be present in the drug, and any use may be fatal.

#### Overdose Identification

• Fingernails or lips are blue or purple.
• Breathing or heartbeat is slow or stopped.
• The person is vomiting or making gurgling noises.
• The person can't be awakened or is unable to speak.

#### Overdose Response

• Call 9-1-1.
• Administer naloxone (more than one dose may be needed to restore adequate spontaneous breathing).
• Perform rescue breathing. If certified to provide cardiopulmonary resuscitation, perform chest compressions if there is no pulse.
• Put the person in the “recovery position,” on his or her side and with the mouth facing to the side to prevent aspiration of vomit, if he or she is breathing independently.
• Stay with the person until emergency services arrive. Naloxone's duration of action is 30–90 minutes. The person should be observed after this time for a return of opioid overdose symptoms.

Adapted from material in the public domain. ^ 10 ^

### Physical Signs of Opioid Withdrawal and Time to Onset

STAGE | GRADE | PHYSICALSIGNS/SYMPTOMS
Early Withdrawal; Short-acting opioids: 8–24 hours after last use; Long-acting opioids: Up to 36 hours after last use | Grade 1 | Lacrimation, rhinorrhea, or both; Diaphoresis; Yawning; Restlessness; Insomnia
Early Withdrawal; Short-acting opioids: 8–24 hours after last use; Long-acting opioids: Up to 36 hours after last use | Grade 2 | Dilated pupils; Piloerection; Muscle twitching; Myalgia; Arthralgia; Abdominal pain
Fully Developed Withdrawal; Short-acting opioids: 1–3 days after last use; Long-acting opioids: 72–96 hours after last use | Grade 3 | Tachycardia; Hypertension; Tachypnea; Fever; Anorexia or nausea; Extreme restlessness
Fully Developed Withdrawal; Short-acting opioids: 1–3 days after last use; Long-acting opioids: 72–96 hours after last use | Grade 4 | Diarrhea, vomiting, or both; Dehydration; Hyperglycemia; Hypotension; Curled-up position

Total duration of withdrawal:

• Short-acting opioids: 7–10 days.

• Long-acting opioids: 14 days or more.

### Signs of Opioid Intoxication

Physical Findings

Drowsy but arousable

Sleeping intermittently (“nodding off”)

Constricted pupils

Mental Status Findings

Slurred speech

Impaired memory or concentration

Normal to euphoric mood

### Single-Item Drug Screener

How many times in the past year have you used an illegal drug or used a prescription medication for nonmedical reasons?

(A positive screen is 1 or more days.)

Reprinted with permission. ^ 11 ^

### Substance Misuse and SUD Screening

A flowchart of steps to follow when screening and assessing for substance misuse. Substance Misuse and SUD Screening This image is a decision tree with substance misuse screening as the start point with two options: negative or positive. If negative is selected, the next step is to “reinforce healthy behavior.” If positive is selected, the next step is to “assess substance use and comorbidities” followed by two more options. One path flows to “substance misuse,” “brief counseling,” “monitoring/follow-up,” and ends with, “if misuse continues, negotiate a plan and refer to treatment.” The other path begins with “substance use disorder,” “brief counseling and treatment referral,” “consider pharmacotherapy,” and ends with “ongoing assessment and support.” Adapted with permission (pending).12

Adapted with permission.^12^

TAPS Tool Part 1

TAPS Tool Part 2

### Two-Item Drug Use Disorder Screener for Primary Care Clinics Serving U.S. Veterans

Question 1: How many days in the past 12 months have you used drugs other than alcohol? (A positive screen is 7 or more days.) If <7, proceed with Question 2.

Question 2: How many days in the past 12 months have you used drugs more than you meant to? (A positive screen is 2 or more days.)

Adapted with permission.^14^

### Urine Drug Testing Window of Detection^15,16^

DRUG | POSITIVE TEST | WINDOW OF DETECTION^*^ | COMMENTS
Amphetamine; methamphetamine; 3,4-methylenedioxymethamphetamine | Amphetamine | 1–2 days | False positives w/ bupropion, chlorpromazine, desipramine, fluoxetine, labetalol, promethazine, ranitidine, pseudoephedrine, trazadone, and other common medications. Confirm unexpected positive results with the laboratory.
Barbiturates | Barbiturates | Up to 6 weeks | N/A
Benzodiazepines | Benzodiazepines | 1–3 days; up to 6 weeks with heavy use of long-acting benzodiazepines | Immunoassays may not be sensitive to therapeutic doses, and most immunoassays have low sensitivity to clonazepam and lorazepam. Check with your laboratory regarding sensitivity and cutoffs. False positives with sertraline or oxaprozin.
Buprenorphine | Buprenorphine | 3–4 days | Will screen negative on opiate screen. Tramadol can cause false positives. Can be tested for specifically.
Cocaine | Cocaine, benzoylecgonine | 2–4 days; 10–22 days with heavy use | N/A
Codeine | Morphine, codeine, high-dose hydrocodone | 1–2 days | Will screen positive on opiate immunoassay.
Fentanyl | Fentanyl | 1–2 days | Will screen negative on opiate screen. Can be tested for specifically. May not detect all fentanyl-like substances.^17^
Heroin | Morphine, codeine | 1–2 days | Will screen positive on opiate immunoassay. 6-monoacetylmorphine, a unique metabolite of heroin, is present in urine for about 6 hours. Can be tested for specifically to distinguish morphine from heroin, but this is rarely clinically useful.
Hydrocodone | Hydrocodone, hydromorphone | 2 days | May screen negative on opiate immunoassay. Can be tested for specifically.
Hydromorphone | May not be detected | 1–2 days | May screen negative on opiate immunoassay. Can be tested for specifically.
Marijuana | Tetrahydrocannabinol | Infrequent use of 1–3 days; chronic use of up to 30 days | False positives possible with efavirenz, ibuprofen, and pantoprazole.
Methadone | Methadone | 2–11 days | Will screen negative on opiate screen. Can be tested for specifically.
Morphine | Morphine, hydromorphone | 1–2 days | Will screen positive on opiate immunoassay. Ingestion of poppy plant/seed may screen positive.
Oxycodone | Oxymorphone | 1–1.5 days | Typically screens negative on opiate immunoassay. Can be tested for specifically.

* Detection time may vary depending on the cutoff.

### Using Signs and Symptoms To Determine Optimal Methadone Level

Using Signs and Symptoms To Determine Optimal Methadone Level This chart depicts signs and symptoms that occur over time and at various serum levels of methadone. At the lowest serum levels, opioid withdrawal and severe opioid withdrawal may be present and can be identified through objective signs (e.g., dilated pupils, illicit opioid use) and subjective symptoms (e.g., drug craving, anxious feelings or depression). At a higher serum level with peak and trough, the “methadone comfort zone” occurs, with no illicit opioid use and no withdrawal or overmedication. At the highest level, opioid overmedication may occur and can be identified through signs such as pinpoint pupils, drowsiness, and so forth. Adapted with permission.18

Adapted with permission.^18^

### Provider Informational, Educational, and Decision-Making Tools

Key Elements of an OBOT Clinic Diversion Control Plan^19^

##### New Patients

Check the state's PDMP before admission to determine whether patients are receiving opioids or benzodiazepine prescriptions from other providers.

Ask patients to sign a release of information to speak with the other prescribers. Patients who are unwilling to sign a release of information are poor candidates for outpatient treatment.

Review the clinic diversion control policy with new patients. This should include counseling patients to:

• Keep buprenorphine locked up and out of children's reach.
• Never share medication with anyone.
• Never sell medication to anyone.
• Acknowledge giving or selling medication to others as illegal.
• Take medication only as prescribed.
• Review, understand, and agree to the practice's buprenorphine treatment agreement before they start.

Prescribe buprenorphine/naloxone when possible, rather than monoproduct. Exceptions would include prescribing the monoproduct for pregnant women with OUD.

Prescribe an adequate but not excessive dose. Most patients respond to doses at or below 24 mg per day. Carefully evaluate requests for higher doses and confirm, document, and assess medication adherence continuously.

##### Ongoing Patients

Periodically check the state's PDMP.

Conduct random urine tests that include a wide spectrum of opioids—including morphine, oxycodone, and buprenorphine—and periodically include buprenorphine metabolites. This will help monitor response to treatment and determine whether patients are taking at least some of their prescribed buprenorphine.

Use unobserved specimen collection to preserve patient privacy and dignity:

• Do not let patients bring backpacks, jackets, or other items into the bathroom.
• Do not let others enter bathrooms with patients.
• Temperature test the urine sample.

Use observed specimen collection (obtained by a staff member of the same gender) or oral fluid testing if there is reason to suspect tampering or falsification.

Contact patients at random; ask them to bring in their medication within a reasonable period (24 to 48 hours) to count the tablets/films to ensure that all medication is accounted for.

Provide a limited number of days of medication per prescription without refills (e.g., several days or 1 week per prescription) until the patient has demonstrated stability and lowered diversion risk.

### Key Points of Patient Education for Buprenorphine

Before starting OUD treatment with buprenorphine, patients should:

• Tell providers the prescribed and over-the-counter medications they take, to allow drug interaction assessment.
• Understand the goal of the first week of treatment: To improve withdrawal symptoms without oversedation.
• Tell providers if they feel sedated or euphoric within 1 to 4 hours after their dose.
• Be given the appropriate buprenorphine medication guide.
• Know possible side effects, including:
  - Headache.
  - Dizziness.
  - Nausea.
  - Vomiting.
  - Sweating.
  - Constipation.
  - Sexual dysfunction.
• Agree to store medication securely and out of the reach of others.
• Alert providers if they discontinue medications, start new ones, or change their medication dose.
• Understand that discontinuing buprenorphine increases risk of overdose death upon return to illicit opioid use.
• Know that use of alcohol or benzodiazepines with buprenorphine increases the risk of overdose and death.
• Understand the importance of informing providers if they become pregnant.
• Tell providers if they are having a procedure that may require pain medication.
• Be aware of resources through which to obtain further education for:
  - Themselves (https://store.samhsa.gov/product/SMA16-4993).
  - Their families and friends (http://www.ct.gov/dmhas/lib/dmhas/publications/MAT-InfoFamilyFriends.pdf).

### Key Points of Patient Education for Methadone

Before starting OUD treatment with methadone, patients should:

• Be told that the methadone dose is started low and increased slowly over days and weeks with monitoring, because it takes 4 or more days for the body to adjust to a dose change. This is necessary to avoid the risk of overdose.
• Understand that the goal of the first weeks of treatment is to improve withdrawal symptoms without oversedation. Patients should tell providers if they feel sedated or high within the first 4 hours after their dose.
• Learn the symptoms of methadone intoxication and how to seek emergency care. The first 2 weeks of treatment have the highest risk of overdose.
• Be aware that rescue naloxone does not last very long, so they should remain in emergency care for observation if they are treated for opioid overdose.
• Know that concurrent alcohol, benzodiazepine, or other sedative use with methadone increases the risk of overdose and death.
• Inform OTP nursing/medical staff about prescribed and over-the-counter medications and herbs (e.g., St. John's wort) they are taking, stopping, or changing doses of to allow assessment of potential drug–drug interactions.
• Inform other treating healthcare professionals that they are receiving methadone treatment.
• Plan to avoid driving or operating heavy machinery until their dose is stabilized.
• Learn about other possible side effects of methadone, including dizziness, nausea, vomiting, sweating, constipation, edema, and sexual dysfunction.
• Agree to keep take-home doses locked up and out of the reach of others. Understand that giving methadone, even small amounts, to others may be fatal.
• Inform providers if they become pregnant.
• Understand that stopping methadone increases their risk of overdose death if they return to illicit opioid use.

### Key Points of Patient Education for Naltrexone

• Do not use any opioids in the 7 to 10 days (for short acting) or 10 to 14 days (for long acting) before starting XR-NTX, to avoid potentially serious opioid withdrawal symptoms. Opioids include:
  - Heroin.
  - Prescription opioid analgesics (including tramadol).
  - Cough, diarrhea, or other medications that contain codeine or other opioids.
  - Methadone.
  - Buprenorphine.
• Seek immediate medical help if symptoms of allergic reaction or anaphylaxis occur, such as:
  - Itching.
  - Swelling.
  - Hives.
  - Shortness of breath.
  - Throat tightness.
• Do not try to override the opioid blockade with large amounts of opioids, which could result in overdose.
• Understand the risk of overdose from using opioids near the time of the next injection, after missing a dose, or after stopping medications.
• Report injection site reactions including:
  - Pain.
  - Hardening.
  - Lumps.
  - Blisters.
  - Blackening.
  - Scabs.
  - An open wound.
    Some of these reactions could require surgery to repair (rarely).
• Report signs and symptoms of hepatitis.
• Report depression or suicidal thoughts. Seek immediate medical attention if these symptoms appear.
• Seek medical help if symptoms of pneumonia appear (e.g., shortness of breath, fever).
• Tell providers of naltrexone treatment, as treatment differs for various types of pneumonia.
• Inform all healthcare professionals of XR-NTX treatment.
• Report pregnancy.
• Inform providers of any upcoming medical procedures that may require pain medication.
• Understand that taking naltrexone may result in difficulty achieving adequate pain control if acute medical illness or trauma causes severe acute pain.
• Wear medical alert jewelry and carry a medical alert card indicating you are taking XR-NTX. A patient wallet card or medical alert bracelet can be ordered at 1-800-848-4876.

### Medication Management for Patients With Respiratory or Hepatic Impairment Who Take Buprenorphine

CONTRAINDICATION/CAUTION | MANAGEMENT
Compromised respiratory function (e.g., chronic obstructive pulmonary disease, decreased respiratory reserve, hypoxia, hypercapnia [abnormally elevated blood levels of carbon dioxide], preexisting respiratory depression). | • Prescribe with caution; monitor closely.; • Warn patients about the risk of using benzodiazepines or other depressants while taking buprenorphine.^20^; • Support patients in their attempts to discontinue tobacco use.
Hepatic impairment Buprenorphine and naloxone are extensively metabolized by the liver. Moderate to severe impairment results in decreased clearance, increased overall exposure to both medications, and higher risk of buprenorphine toxicity and precipitated withdrawal from naloxone. These effects have not been observed in patients with mild hepatic impairment.^21,22^ | • Mild impairment (Child-Pugh score of 5–6):^23^ No dose adjustment needed.; • Moderate impairment (Child-Pugh score of 7–9):^24^ Combination products are not recommended; they may precipitate withdrawal.; ^*^Use combination products cautiously for maintenance treatment in patients who've been inducted with a monoproduct;^25,26^ monitor for signs and symptoms of buprenorphine toxicity or overdose.^27^ Naloxone may interfere with buprenorphine's efficacy.^28,29^; • Severe impairment (Child-Pugh score of 10–15):^30^Do not use the combination product.^31^ For monoproduct, consider halving the starting and titration doses used in patients with normal liver function; monitor for signs and symptoms of toxicity or overdose caused by increased buprenorphine levels.^32^

* Moderate to severe impairment results in much more reduced clearance of naloxone than of buprenorphine. Nasser et al.^33^ found that moderate impairment doubled or tripled exposure (compared with subjects with no or mild impairment) for both medications. In subjects with severe impairment, buprenorphine exposure was two to three times higher; naloxone exposure increased more than tenfold.

Adapted from material in the public domain.^34^

### Monitoring Recovery Activities

At medical management visits, do not simply ask about attendance at recovery support meetings; explore the level of participation and engagement in those activities. Some activities include:

• Finding and working closely with a sponsor.
• “Working” the 12 Steps at 12-Step meetings and with a sponsor.
• Doing service at meetings (e.g., setting up chairs, making coffee, going on a “commitment” to speak at a meeting in a jail or an inpatient drug and alcohol program).

Having and frequently attending a regular “home” group.^35^

Remember this statement from recovery experts A. Thomas McLellan and William White: “Recovery status is best defined by factors other than medication status. Neither medication-assisted treatment of opioid addiction nor the cessation of such treatment by itself constitutes recovery. Recovery status instead hinges on broader achievements in health and social functioning—with or without medication support.”^36^

### OUD Medications: An Overview^37,38^

CATEGORY | BUPRENORPHINE^*^ | METHADONE | XR-NTX^**^
Appropriate patients | Typically for patients with OUD who are physiologically dependent on opioids | Typically for patients with OUD who are physiologically dependent on opioids and who meet federal criteria for OTP admission | Typically for patients with OUD who have abstained from short-acting opioids for at least 7–10 days and long-acting opioids for at least 10–14 days
Pharmacology | Opioid receptor partial agonist; Reduces opioid withdrawal and craving; blunts or blocks euphoric effects of self-administered illicit opioids through cross-tolerance and opioid receptor occupancy. | Opioid receptor agonist; Reduces opioid withdrawal and craving; blunts or blocks euphoric effects of self-administered illicit opioids through cross-tolerance and opioid receptor occupancy. | Opioid receptor antagonist; Blocks euphoric effects of self-administered illicit opioids through opioid receptor occupancy. Causes no opioid effects.
Patient Education | Tell patients:; • That they will need to be in opioid withdrawal to receive their first dose to avoid buprenorphine-precipitated opioid withdrawal.; • About the risk of overdose with concurrent benzodiazepine or alcohol use, with injecting buprenorphine, and after stopping the medication. | Tell patients:; • That their dose will start low and build up slowly to avoid oversedation; it takes several days for a given dose to have its full effect.; • About overdose risk in the first 2 weeks of treatment, especially with concurrent benzodiazepine or alcohol use, and after stopping the medication. | Tell patients:; • That they will need to be opioid free for at least 7–10 days for short-acting and at least 10–14 days for long-acting opioids before their first dose to avoid XR-NTX-precipitated opioid withdrawal (which may require hospitalization).; • About the risk of overdose after stopping the medication.
Administration | Daily (or off-label less-than-daily dosing regimens) administration of sublingual or buccal tablet or film. Subdermal implants every 6 months, for up to 1 year, for stable patients. Monthly subcutaneous injection of extended-release formulation in abdominal region for patients treated with transmucosal buprenorphine for at least 1 week. | Daily oral administration as liquid concentrate, tablet, or oral solution from dispersible tablet or powder (unless patients can take some home). | Every 4 weeks or once-per-month intramuscular injection.
Prescribing | Physicians, NPs, and PAs need a waiver to prescribe. Any pharmacy can fill a prescription for sublingual or buccal formulations. OTPs can administer/dispense by OTP physician order without a waiver. | SAMHSA-certified OTPs can provide methadone for daily onsite administration or at-home self-administration for stable patients. | Physicians, NPs, or PAs prescribe or order administration by qualified healthcare professionals.

* Long-acting buprenorphine implants (every 6 months) for patients on a stable dose of buprenorphine are also available through implanters and prescribers with additional training and certification through the Probuphine REMS Program. Extended-release buprenorphine monthly subcutaneous injections are available only through prescribers and pharmacies registered with the Sublocade REMS Program.

** Naltrexone hydrochloride tablets (50 mg each) are also available for daily oral dosing but have not been shown to be more effective than treatment without medication or placebo because of poor patient adherence.

### OUD Medications: Comparison To Guide Shared Decision Making

CATEGORY | BUPRENORPHINE | METHADONE | NALTREXONE
Appropriate patients | Typically for patients with OUD who are physiologically dependent on opioids | Typically for patients with OUD who are physiologically dependent on opioids and who meet federal criteria for OTP admission | Typically for patients with OUD who are abstinent from short-acting opioids for 7 days and long-acting opioids for 10–14 days
Outcome: Retention in treatment | Higher than treatment without medication and treatment with placebo^39^ | Higher than treatment without OUD medication and treatment with placebo^40^ | Treatment retention with oral naltrexone is no better than with placebo or no medication;^41^ for XR-NTX, treatment retention is higher than for treatment without OUD medication and treatment with placebo;^42,43^ treatment retention is lower than with opioid receptor agonist treatment
Outcome: Suppression of illicit opioid use | Effective | Effective | Effective
Outcome: Overdose mortality | Lower for people in treatment than for those not in it | Lower for people in treatment than for those not in it | Unknown
Location/frequency of office visits | Office/clinic: Begins daily to weekly, then tailored to patient's needs; OTP: Can treat with buprenorphine 6–7 days/week initially; take-homes are allowed without the time-in-treatment requirements of methadone | OTP only: 6–7 days/week initially; take-homes are allowed based on time in treatment and patient progress | Office/clinic: Varies from weekly to monthly
Who can prescribe/order? | Physicians, NPs,^*^ and PAs^*^ possessing federal waiver can prescribe and dispense; can be dispensed by a community pharmacy or an OTP | OTP physicians order the medication; nurses and pharmacists administer and dispense it | Physicians, NPs,^*^ and PAs^*^
Administration | Sublingual/buccal; implant by specially trained provider, and only for stabilized patients | Oral | Oral or intramuscular (Note: Oral naltrexone is less effective than the other OUD medications.)
Misuse/diversion potential | Low in OTPs or other settings with observed dose administration; moderate for take-home doses; risk can be mitigated by providing take-homes to stable patients and a diversion control plan | Low in OTPs with directly observed therapy; moderate for take-home doses; risk can be mitigated by a diversion control plan | None
Sedation | Low unless concurrent substances are present (e.g., alcohol, benzodiazepines) | Low unless dose titration is too quick or dose is not adjusted for the presence of concurrent substances (e.g., alcohol, benzodiazepines) | None
Risk of medication-induced respiratory depression | Very rare; lower than methadone | Rare, although higher than buprenorphine; may be elevated during the first 2 weeks of treatment or in combination with other sedating substances | None
Risk of precipitated withdrawal when starting medication | Can occur if started too prematurely after recent use of other opioids | None | Severe withdrawal is possible if period of abstinence is inadequate before starting medication
Withdrawal symptoms on discontinuation | Present; lower than methadone if abruptly discontinued | Present; higher than buprenorphine if abruptly discontinued | None
Most common side effects | Constipation, vomiting, headache, sweating, insomnia, blurred vision | Constipation, vomiting, sweating, dizziness, sedation | Difficulty sleeping, anxiety, nausea, vomiting, low energy, joint and muscle pain, headache, liver enzyme elevation; XR-NTX: Injection site pain, nasopharyngitis, insomnia, toothache

* NPs and PAs should check with their state to determine whether prescribing buprenorphine, naltrexone, or both is within their allowable scope of practice.

D. Coffa, December 2017 (personal communication). Adapted with permission.

### OUD Medications: Formulations^44,45^

GENERIC/TRADE NAME | FORMULATIONS | ACTION AT THE RECEPTOR | FDA INDICATIONS | DOSING REGIMEN
Methadone (Methadose, Dolophine) | Orally as liquid concentrate, tablet, or oral solution of powder or dispersible tablet | Mu-opioid receptor full agonist | Medically supervised withdrawal and maintenance treatment of opioid dependence; additional formulations FDA-approved for pain are not a focus of this TIP | Once daily (also off-label dosing regimens if appropriate, such as split dose twice daily)
Generic buprenorphine monoproduct | Sublingual tablet | Mu-opioid receptor partial agonist | Treatment of opioid dependence; additional formulations FDA-approved for pain are not a focus of this TIP | Once daily (also alternative off-label regimens)
Generic combination product (buprenorphine/naloxone) | Sublingual tablet | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine/naloxone (Zubsolv) | Sublingual tablet | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine/naloxone (Bunavail) | Buccal film | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine/naloxone (Suboxone) | Sublingual film; may also be administered buccally | Mu-opioid receptor partial agonist combined with mu-opioid receptor antagonist; the latter is not absorbed sublingually | Treatment of opioid dependence | Once daily (also alternative off-label regimens)
Buprenorphine (Probuphine) | Implants | Mu-opioid receptor partial agonist | Maintenance treatment of opioid dependence in clinically stable patients taking 8 mg/day or less of Suboxone equivalents | Implants last for 6 months and are then removed, after which a second set can be inserted
Extended-release injection buprenorphine (Sublocade) | Subcutaneous injection in the abdominal region | Mu-opioid receptor partial agonist | Treatment of moderate-to-severe OUD among patients initiated and taking transmucosal buprenorphine for at least 7 days | Monthly
Oral naltrexone (Revia) | Oral tablet | Mu-opioid receptor antagonist | Block the effects of administered opioid agonists | Once daily (also alternative off-label regimens)
XR-NTX (Vivitrol) | Intramuscular injection | Mu-opioid receptor antagonist | Prevent return to opioid dependence after medically supervised opioid withdrawal | Once monthly by injection

### Referring Patients Who Receive OUD Pharmacotherapy to Behavioral Health Therapies

This four-level decision tree helps healthcare providers appropriately refer patients who take OUD medication to behavioral health services. Referring Patients Who Receive OUD Pharmacotherapy to Behavioral Health Therapies A decision tree begins a series of yes/no questions. The first, “Is the patient willing to engage in additional behavior health therapies?” With a yes answer, the next question is “Is the patient entering an OTP for methadone or intensive treatment? With a no answer, the next step is to “offer medical management and ongoing motivational interviewing; revisit offer for behavioral health therapies.” The discussion tree ends. The next set of questions from the “entering an OTP,” with a yes answer, the next step is “Counseling, peer support, and case management will likely be provided through the OTP. The discussion tree ends. However, if the response from the “entering an OTP”, is a no answer, the next step is “Identify specific needs, and refer appropriately to one or more of the following:” Counseling: individual, family and/or group; Peer support groups: Alcoholics Anonymous, Narcotics Anonymous, SMART Recovery, buprenorphine groups; Case management; Vocational training; Housing transportation, food, legal and other support programs.

### Strategies for Managing Benzodiazepine Use by Patients in OUD Treatment

• Carefully assess the patient's benzodiazepine use, including:
  - Intent of use.
  - Source (check the state's PDMP).
  - Amount and route of use.
  - Binge use.
  - Prior overdoses.
  - Harms (e.g., car crashes, criminal acts, sleep trouble).
  - Co-use with other substances that further increase risk for respiratory depression and overdose.
  - Withdrawal history (e.g., seizures, delirium).
• Also assess the following:
  - Psychiatric and medical comorbidity
  - Motivation for change
  - Psychosocial support system (obtain history from a significant other if the patient permits)
• Gauge level of care and setting needed (e.g., residential, outpatient). Inpatient treatment may be best for patients with poor motivation, limited psychosocial support, serious or complicated comorbidity, or injection or binge use.
• Coordinate with other prescribers. Some patients may have taken appropriately prescribed benzodiazepines for years with limited or no evidence of misuse. For such patients, tapering benzodiazepines may be contraindicated and unrealistic.
• Address comorbid mental disorders (e.g., anxiety, depression) with other medications or psychosocial treatments, when feasible.
• Provide medically supervised withdrawal from benzodiazepines or refer to specialty care for same.
• Create a treatment plan with built-in conditions (e.g., urine testing, more frequent visits, short medication supply).
• Frequently review patient progress and objective outcomes, such as:
  - Urine drug testing.
  - PDMP reports.
  - Psychosocial functioning.
  - Reports from significant others.
• Revise treatment plans as needed, and document the rationale for treatment decisions.

Adapted with permission.^46^

## Sample Provider Forms

### General forms

Goal-Setting Form

Goal Sheet and Coping Strategies Form

Medical Management Visit Form

Patient Urine Drug Screen and Medication Count Monitoring Form

Pharmacy Tablet/Film Count Form

Standard Consent to Opioid Maintenance Treatment Form for OTPs

### Buprenorphine Forms

Buprenorphine Diversion Control Policy

Buprenorphine Induction and Maintenance Appropriate Use Checklists

Buprenorphine Treatment Agreement

### Naltrexone forms

Key Techniques for Reducing Injection Site Reactions^52^

Patient Counseling Tool for XR-NTX

Sample XR-NTX Treatment Agreement

## Glossary of TIP Terminology

Abuse liability: The likelihood that a medication with central nervous system activity will cause desirable psychological effects, such as euphoria or mood changes, that promote the medication's misuse.

Addiction: As defined by ASAM,^55^ “a primary, chronic disease of brain reward, motivation, memory, and related circuitry.” It is characterized by inability to consistently abstain, impairment in behavioral control, craving, diminished recognition of significant problems with one's behaviors and interpersonal relationships, and a dysfunctional emotional response. Like other chronic diseases, addiction often involves cycles of relapse and remission. The Diagnostic and Statistical Manual of Mental Disorders, Fifth Edition^56^ (DSM-5), does not use the term for diagnostic purposes, but it commonly describes the more severe forms of opioid use disorder.

Bioavailability: Proportion of medication administered that reaches the bloodstream.

Care provider: Encompasses both healthcare professionals and other professionals who do not provide medical services, such as counselors or providers of supportive services. Often shortened to “provider.”

Cross-tolerance: Potential for people tolerant to one opioid (e.g., heroin) to be tolerant to another (e.g., methadone).

Dissociation: Rate at which a drug uncouples from the receptor. A drug with a longer dissociation rate will have a longer duration of action than a drug with a shorter dissociation rate.

Half-life: Rate of removal of a drug from the body. One half-life removes 50 percent from the plasma. After a drug is stopped, it takes five half-lives to remove about 95 percent from the plasma. If a drug is continued at the same dose, its plasma level will continue to rise until it reaches steady state concentrations after about five half-lives.

Healthcare professionals: Physicians, nurse practitioners, physician assistants, and other medical service professionals who are eligible to prescribe medications for and treat patients with OUD. The term “prescribers” also refers to these healthcare professionals.

Induction: Process of initial dosing with medication for OUD treatment until the patient reaches a state of stability; also called initiation.

Intrinsic activity: The degree of receptor activation attributable to drug binding. Full agonist, partial agonist, and antagonist are terms that describe the intrinsic activity of a drug.

Maintenance treatment: Providing medications to achieve and sustain clinical remission of signs and symptoms of OUD and support the individual process of recovery without a specific endpoint (as with the typical standard of care in medical and psychiatric treatment of other chronic illnesses).

Medically supervised withdrawal (formerly called detoxification): Using an opioid agonist (or an alpha-2 adrenergic agonist if opioid agonist is not available) in tapering doses or other medications to help a patient discontinue illicit or prescription opioids.

Medical management: Process whereby healthcare professionals provide medication, basic brief supportive counseling, monitoring of drug use and medication adherence, and referrals, when necessary, to addiction counseling and other services to address the patient's medical, mental health, comorbid addiction, and psychosocial needs.

Mutual-help groups: Groups of people who work together on obtaining and maintaining recovery. Unlike peer support (e.g., the use of recovery coaches), mutual-help groups consist entirely of people who volunteer their time and typically have no official connection to treatment programs. Most are self-supporting. Although 12-Step groups such as AA and NA are the most widespread and well-researched type of mutual-help groups, other groups may be available in some areas. They range from groups affiliated with a religion or church (e.g., Celebrate Recovery, Millati Islami) to purely secular groups (e.g., SMART Recovery, Women for Sobriety).

Office-based opioid treatment (OBOT): Providing medication for OUD in settings other than certified OTPs.

Opiates: A subclass of opioids derived from opium (e.g., morphine, codeine, thebaine).

Opioid misuse: The use of prescription opioids in any way other than as directed by a prescriber; the use of any opioid in a manner, situation, amount, or frequency that can cause harm to self or others.^57^

Opioid receptor agonist: A substance that has an affinity for and stimulates physiological activity at cell receptors in the central nervous system that are normally stimulated by opioids. Mu-opioid receptor full agonists (e.g., methadone) bind to the mu-opioid receptor and produce actions similar to those produced by the endogenous opioid beta-endorphin. Increasing the dose increases the effect. Mu-opioid receptor partial agonists (e.g., buprenorphine) bind to the mu-opioid receptor. Unlike with full agonists, increasing their dose may not produce additional effects once they have reached their maximal effect. At low doses, partial agonists may produce effects similar to those of full agonists.

Opioid receptor antagonist: A substance that has an affinity for opioid receptors in the central nervous system without producing the physiological effects of opioid agonists. Mu-opioid receptor antagonists (e.g., naltrexone) can block the effects of exogenously administered opioids.

Opioid receptor blockade: Blunting or blocking of the euphoric effects of an opioid through opioid receptor occupancy by an opioid agonist (e.g., methadone, buprenorphine) or antagonist (e.g., naltrexone).

Opioids: All natural, synthetic, and semisynthetic substances that have effects similar to morphine. They can be used as medications having such effects (e.g., methadone, buprenorphine, oxycodone).

Opioid treatment program (OTP): An accredited treatment program with SAMHSA certification and DEA registration to administer and dispense opioid agonist medications that are approved by FDA to treat opioid addiction. Currently, these include methadone and buprenorphine products. Other pharmacotherapies, such as naltrexone, may be provided but are not subject to these regulations. OTPs must provide adequate medical, counseling, vocational, educational, and other assessment and treatment services either onsite or by referral to an outside agency or practitioner through a formal agreement.^58^

Opioid use disorder (OUD): Per DSM-5,^59^ a disorder characterized by loss of control of opioid use, risky opioid use, impaired social functioning, tolerance, and withdrawal. Tolerance and withdrawal do not count toward the diagnosis in people experiencing these symptoms when using opioids under appropriate medical supervision. OUD covers a range of severity and replaces what the DSM-IV termed “opioid abuse” and “opioid dependence.” An OUD diagnosis is applicable to a person who uses opioids and experiences at least 2 of the 11 symptoms in a 12-month period. (See Exhibit 2.11 in Part 2 for full DSM-5 diagnostic criteria for OUD.)

Peer support: The use of peer support specialists in recovery to provide nonclinical (i.e., not requiring training in diagnosis or treatment) recovery support services to individuals in recovery from addiction and to their families.

Peer support specialist: Someone in recovery who has lived experience in addiction plus skills learned in formal training. Peer support specialists may be paid professionals or volunteers. They are distinguished from members of mutual-help groups because they maintain contact with treatment staff. They offer experiential knowledge that treatment staff often lack.

Prescribers: Healthcare professionals who are eligible to prescribe medications for OUD.

Psychosocial support: Ancillary services to enhance a patient's overall functioning and well-being, including recovery support services, case management, housing, employment, and educational services.

Psychosocial treatment: Interventions that seek to enhance a patient's social and mental functioning, including addiction counseling, contingency management, and mental health services.

Receptor affinity: Strength of the bond between a medication and its receptor. A medication with high mu-opioid receptor affinity requires lower concentrations to occupy the same number of mu-opioid receptors as a drug with lower mu-opioid receptor affinity. Drugs with high mu-opioid receptor affinity may displace drugs with lower affinity.

Recovery: A process of change through which individuals improve their health and wellness, live a self-directed life, and strive to reach their full potential. Even individuals with severe and chronic SUDs can, with help, overcome their SUDs and regain health and social function. Although abstinence from all substance misuse is a cardinal feature of a recovery lifestyle, it is not the only healthy, prosocial feature. Patients taking FDA-approved medication to treat OUD can be considered in recovery.

Recovery capital: The sum of the internal (e.g., motivation, self-efficacy, spirituality) and external (e.g., access to health care, employment, family support) resources that an individual can draw on to begin and sustain recovery from SUDs.

Recovery-oriented care: A service orientation that supports individuals with behavioral health conditions in a process of change through which they can improve their health and wellness, live self-directed lives, and strive to reach their full potential.

Relapse: A process in which a person with OUD who has been in remission experiences a return of symptoms or loss of remission. A relapse is different from a return to opioid use in that it involves more than a single incident of use. Relapses occur over a period of time and can be interrupted. Relapse need not be long lasting. The TIP uses relapse to describe relapse prevention, a common treatment modality.

Remission: A medical term meaning a disappearance of signs and symptoms of the disease.^60^ DSM-5 defines remission as present in people who previously met OUD criteria but no longer meet any OUD criteria (with the possible exception of craving).^61^ Remission is an essential element of recovery.

Return to opioid use: One or more instances of opioid misuse without a return of symptoms of OUD. A return to opioid use may lead to relapse.

Tolerance: Alteration of the body's responsiveness to alcohol or other drugs (including opioids) such that higher doses are required to produce the same effect achieved during initial use. See also medically supervised withdrawal.

## Notes

1. Centers for Disease Control and Prevention. (2017). Drug overdose death data. Retrieved January 9, 2018, from www.cdc.gov/drugoverdose/data/statedeaths.html
2. National Safety Council. (2017). NSC motor vehicle fatality estimates. Retrieved October 31, 2017, from www.nsc.org/NewsDocuments/2017/12-month-estimates.pdf
3. Babor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). The Alcohol Use Disorders Identification Test. Guidelines for use in primary care (2nd ed.). Geneva, Switzerland: The World Health Organization.
4. Bush, K., Kivlahan, D. R., McDonell, M. B., Fihn, S. D., & Bradley, K. A. (1998). The AUDIT alcohol consumption questions (AUDIT-C): An effective brief screening test for problem drinking. Ambulatory Care Quality Improvement Project (ACQUIP). Alcohol Use Disorders Identification Test. Archives of Internal Medicine, 158(16), 1789–1795.9738608
5. Skinner, H. A. (1982). The Drug Abuse Screening Test. Addictive Behavior, 7(4), 363–371.
6. Yudko, E., Lozhkina, O., & Fouts, A. (2007). A comprehensive review of the psychometric properties of the Drug Abuse Screening Test. Journal of Substance Abuse Treatment, 32, 189–198.17306727
7. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed., p. 541). Arlington, VA: American Psychiatric Publishing.
8. Heatherton, T. F., Kozlowski, L. T., Frecker, R. C., Rickert, W., & Robinson, J. (1989). Measuring the heaviness of smoking: Using self-reported time to the first cigarette of the day and number of cigarettes smoked per day. British Journal of Addiction, 84(7), 791–799.2758152
9. Smith, P. C., Schmidt, S. M., Allensworth-Davies, D., & Saitz, R. (2009). Primary care validation of a single-question alcohol screening test. Journal of General Internal Medicine, 24(7), 783–788. doi:10.1007/s11606-009-0928-619247718
10. Substance Abuse and Mental Health Services Administration. (2016). SAMHSA opioid overdose prevention toolkit. HHS Publication No. (SMA) 16-4742. Rockville, MD: Substance Abuse and Mental Health Services Administration.
11. Smith, P. C., Schmidt, S. M., Allensworth-Davies, D., & Saitz, R. (2010). A single-question screening test for drug use in primary care. Archives of Internal Medicine, 170(13), 1155–1160.20625025
12. Shapiro, B., Coffa, D., & McCance-Katz, E. F. (2013). A primary care approach to substance misuse. American Family Physician, 88(2), 113–121.23939642
13. McNeely, J., Wu, L. T., Subramaniam, G., Sharma, G., Cathers, L. A., Svikis, D., … Schwartz, R. P. (2016). Performance of the Tobacco, Alcohol, Prescription Medication, and Other Substance Use (TAPS) Tool for substance use screening in primary care patients. Annals of Internal Medicine, 165(10), 690–699.27595276
14. Tiet, Q. Q., Leyva, Y. E., Moos, R. H., Frayne, S. M., Osterberg, L., & Smith, B. (2015). Screen of drug use: Diagnostic accuracy of a new brief tool for primary care. JAMA Internal Medicine, 175(8), 1371–1377.26075352
15. Lynch, K. (2014). San Francisco General Hospital laboratory protocol. San Francisco, CA: San Francisco General Hospital.
16. Warner, E., & Lorch, E. (2014). Laboratory diagnosis. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), Principles of addiction medicine (5th ed., pp. 332–343). Philadelphia, PA: Wolters Kluwer.
17. Milone, M. C. (2012). Laboratory testing for prescription opioids. Journal of Medical Toxicology, 8(4), 408–416. doi:10.1007/s13181-012-0274-723180358
18. Leavitt, S. B., Shinderman, M., Maxwell, S., Eap, C. B., & Paris, P. (2000). When “enough” is not enough: New perspectives on optimal methadone maintenance dose. Mount Sinai Journal of Medicine, 67(5–6), 404–411.11064491
19. American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
20. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
21. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
22. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
23. Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
24. Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
25. Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
26. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
27. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
28. Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
29. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
30. Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
31. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
32. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
33. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetic, 54(8), 837–849.
34. Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
35. Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3–4), 313–332.23731422
36. McLellan, A. T., & White, W. (2012). Opioid maintenance and recovery-oriented systems of care: It is time to integrate (p. 2). London, England: National Treatment Agency for Substance Misuse.
37. Substance Abuse and Mental Health Services Administration. (2016). Pocket guide: Medication-assisted treatment of opioid use disorder. HHS Publication No. (SMA) 16-4892PG. Rockville, MD: Substance Abuse and Mental Health Services Administration.
38. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
39. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
40. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
41. Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database Systems Review, 4, CD001333.
42. Krupitsky, E., Zvartau, E., Blokhina, E., Verbitskaya, E., Wahlgren, V., Tsoy-Podosenin, M., … Woody, G. E. (2012) Randomized trial of long-acting sustained-release naltrexone implant vs oral naltrexone or placebo for preventing relapse to opioid dependence. Archives of General Psychiatry, 69(9), 973–981.22945623
43. Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. A., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.27028913
44. Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 2, CD001333.
45. Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
46. Lintzeris, N., & Nielsen, S. (2010). Benzodiazepines, methadone and buprenorphine: Interactions and clinical management. American Journal on Addictions, 19(1), 59–72.20132123
47. Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
48. Lofwall, M. & Walsh, S. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world (p. 316). Journal of Addiction Medicine, 8(5), 315–326.25221984
49. American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
50. Food and Drug Administration (2017, May). Appropriate use checklist: Buprenorphine-containing transmucosal products for opioid dependence. Silver Spring, MD: Food and Drug Administration.
51. American Society of Addiction Medicine. (2017). Sample treatment agreement. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-treatment-agreement30fa159472bc604ca5b7ff000030b21a.pdf?sfvrsn=0
52. Alkermes. (2015). Key techniques to reduce severe injection site reactions: VIVITROL (naltrexone for extended release injectable suspension) intramuscular injection. Retrieved January 9, 2018, from www.vivitrolrems.com/content/pdf/patinfo-injection-poster.pdf
53. Alkermes. (2013). Patient counseling tool: VIVITROL (naltrexone for extended-release injectable suspension). Retrieved January 9, 2018, from www.vivitrolrems.com/content/pdf/patinfo-counseling-tool.pdf
54. American Society of Addiction Medicine. (2017). Sample treatment agreement. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-treatment-agreement30fa159472bc604ca5b7ff000030b21a.pdf?sfvrsn=0
55. American Society of Addiction Medicine. (2011). Definition of addiction. Retrieved October 30, 2017, from www.asam.org/resources/definition-of-addiction
56. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
57. Department of Health and Human Services, Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: Department of Health and Human Services.
58. Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
59. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
60. National Cancer Institute. (n.d.). NCI dictionary of cancer terms: Remission. Retrieved November 22, 2017, from www.cancer.gov/publications/dictionaries/cancer-terms?cdrid=45867
61. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.