# Chapter 3F: Medical Management of Patients Taking OUD Medications in Hospital Settings

Chapter 3F guides the management of patients taking OUD medications in hospital settings. The audience is healthcare professionals in emergency, general medical, surgical, psychiatric, and obstetric units.

Patients with opioid use disorder (OUD) who present to emergency departments (EDs) or are admitted to hospitals for acute medical or psychiatric care can benefit from medication to treat OUD in the hospital setting. During acute medical illness, patients experiencing consequences of opioid use may be motivated to change.^379^ Hospital-based providers can take this opportunity to initiate long-term medication maintenance.^380,381^

Unfortunately, less than one-quarter of patients with an opioid-related hospitalization are offered Food and Drug Administration-approved medication for OUD within 30 days of discharge.^382^ Patients who already take OUD medication may also present to the hospital. Thus, a broad understanding of how to manage their OUD medication during hospitalization is necessary.

The keys to effective patient management in general hospital settings are:

• Balancing pharmacotherapy for OUD with other medical concerns (e.g., surgery, pain management) during hospitalization.
• Careful management after discharge.
• Seamless transfer to opioid treatment via an opioid treatment program (OTP) or office-based opioid treatment (OBOT) provider after discharge.

OPIOID-RELATED inpatient hospital stays INCREASED 64% nationally from 2005–2014.^383^

Image of a hospital. Text reads: Opioid-related inpatient hospital stays increased 64% nationally from 2005 to 2014.383

## Hospitalized or ED Patients Taking Medication for OUD

Buprenorphine, methadone, and naltrexone may be ordered in EDs or inpatient hospital units. It's essential for the patient to continue receiving OUD medication while hospitalized.

### Pain Management

Pain management for hospitalized patients who take OUD medication is a key element of medical management. Discuss pain management and engage in a shared decision-making process with patients being treated for OUD with buprenorphine, methadone, or naltrexone. Patients may have strong preferences and opinions about pain and use of opioid analgesics for pain treatment. Some patients may want to avoid opioid analgesics. For others, inadequately treated pain may be a trigger for illicit drug use. Involve primary care pain specialists and addiction treatment providers in discussing options for managing OUD medication and pain during patient hospitalization.

### Buprenorphine

The hospital team will need to manage buprenorphine for patients who present to the ED or are hospitalized on buprenorphine maintenance. Physicians in inpatient settings can legally order buprenorphine without a waiver if a patient is admitted primarily for other medical reasons.^384^ Key medication management strategies include:

• Obtaining written consent to contact the patient's providers, including:
  - Primary care provider.
  - Buprenorphine prescriber.
  - Pharmacy.
• Confirming the patient's outpatient buprenorphine dose by:
  - Checking prescribing records.
  - Contacting the prescriber or pharmacy.
  - Examining recent prescription bottles.
  - Checking the prescription drug monitoring program database before administering buprenorphine.
• Providing the usual daily dose to the patient, once that dose is confirmed.
• Ensuring the patient's outpatient prescriber understands the reason for any missed visits.
• Informing the patient's outpatient prescriber that the patient may test positive for opioids if treated with opioid analgesics while in the hospital.
• Maintaining contact with the patient's prescriber, especially when a buprenorphine dose change is considered and in discharge planning.

Patients with pain may continue their buprenorphine while in the hospital. For mild-to-moderate pain, dividing the patient's usual buprenorphine dose three times per day (TID) may provide sufficient pain relief.^385^ In some cases, increased buprenorphine dose may be appropriate. For moderate-to-severe pain, additional analgesia will be necessary. Two approaches to consider:

1. Continue buprenorphine treatment and use full agonist opioids for added pain relief. Because of the partial blockade caused by buprenorphine, higher-than-usual doses of opioids will probably be required for pain relief. Fentanyl, hydromorphone, and morphine have relatively high binding affinities for the mu-opioid receptor and are most likely to displace buprenorphine from receptors and provide improved analgesia. Once the painful condition has improved, if mild-to-moderate pain persists, buprenorphine can be divided TID to manage residual pain. This approach is usually successful and allows the patient to remain stable on buprenorphine.
2. Discontinue buprenorphine upon hospitalization and use full agonist opioids to treat pain and prevent withdrawal. This approach avoids the blockade effect of buprenorphine on the mu-opioid receptors but leaves the patient vulnerable to a return to illicit opioid use. It may be useful if the first approach does not achieve adequate pain control.^386^ Consider a consult by an addiction medicine, psychiatric, or pain management provider if appropriate and available.

Pregnant women on buprenorphine can continue buprenorphine through their labor. Labor pain for pregnant patients on buprenorphine can be managed effectively with epidural analgesia or intravenous opioids. Spinal anesthesia is effective in patients on buprenorphine; patients can receive general anesthesia if needed.^387^

Perioperative pain management of patients on buprenorphine requires further study, but multiple approaches have been found effective. Most patients can continue buprenorphine through the operative period. Treat postoperative pain with regional anesthesia, nonopioid pain management, or full agonist opioids. Remember that higher doses are likely to be necessary. Some data suggest that buprenorphine divided TID may even be as effective as morphine for postoperative pain control.^388^ Alternatively, buprenorphine can be discontinued 72 hours before a planned surgery and restarted after resolution of acute postoperative pain. The risk of this approach is that it leaves the patient vulnerable to a return to use of illicit opioids.^389^

### Methadone

The hospital team will need to manage methadone for patients who present to the ED or are hospitalized on methadone maintenance treatment. This includes pregnant women. Generally, only physicians in OTPs can order methadone to treat OUD. However, physicians in an inpatient setting can legally order methadone administration to patients admitted primarily for other reasons.^390^

Contact the patient's OTP directly to confirm the outpatient methadone dose, the last day of dose administration, and whether the patient was dispensed take-home doses (and how many doses) after the last dose administration at the OTP. This is to avoid double dosing and to avoid providing a full dose to a patient who hasn't been to the OTP for several days. Notify the OTP of the patient's admission and discharge so that OTP staff is aware of:

• The patient's upcoming missed visits.
• Medications received during hospitalization.
• Medications prescribed at discharge.

Patients in pain should receive their full usual daily dose of methadone, barring contraindications. This is their baseline dose and should not be considered a dose for pain management. They'll need pain medication in addition to their usual methadone dose. If their condition is painful enough to require opioids, prescribe short-acting opioids as scheduled, not as-needed, treatment. Because these patients are already opioid tolerant, they'll likely require higher doses of opioids than patients without tolerance.^391^ However, as with any patient, use nonopioid multimodal pain management when possible to minimize reliance on opioids and maximize pain control.^392^

The expert panel for this Treatment Improvement Protocol (TIP) recommends restarting buprenorphine before discharge when possible, with a proper handoff between inpatient and outpatient providers.

CLINICAL CAUTION

##### Do Not Rely Solely on Patient Self-Report of Methadone Dosage

Do not administer the methadone dose based on patient self-report of OTP enrollment and methadone dose; get OTP confirmation. This is important because doses above 30 mg can be lethal if the patient is not currently receiving methadone treatment and has relatively low tolerance to opioids. If it's not possible to confirm the patient's methadone dose because the OTP is closed on nights or weekends and has no emergency contact, up to 20 mg per day can be administered to treat opioid withdrawal symptoms, but monitor for signs of opioid intoxication. If the patient shows no signs of sedation or opioid intoxication 3 to 4 hours after the initial dose and continues to display symptoms of withdrawal, an additional 5 mg to 10 mg may be safe to administer.

It is important to tell patients who receive take-home doses that they should not take their own medication while in the hospital. They will receive methadone from the treatment team. Patients can be asked to lock their take-home medications with their other valuables. It is also important to monitor these patients closely after the initial and subsequent methadone administration in the hospital. Some patients who receive take-home doses do not take their entire dose every day, so they may display signs of intoxication or frank overdose if the hospital staff gives them the full dose.

### Naltrexone

Patients taking oral naltrexone for OUD treatment may continue naltrexone when admitted to the hospital if they do not have and are not at risk for developing a painful condition requiring opioid analgesia. Oral naltrexone provides full blockade of opioid receptors for up to 72 hours. Extended-release injectable naltrexone (XR-NTX) provides measurable naltrexone levels for 1 month or longer. Thus, managing acute pain in patients taking XR-NTX is complicated.

In patients who have taken naltrexone, manage severe pain intensively via nonopioid approaches, such as regional anesthesia or injected nonsteroidal anti-inflammatory drugs.

Naltrexone blockade can be overcome with very high doses of opioids, but patients must be closely monitored for respiratory depression in a setting with anesthesia services. This is especially true upon discontinuation of oral naltrexone, which dissociates from opioid receptors.

## Hospitalized or ED Patients Not Taking Medication for OUD

Patients with OUD who present to the ED or are admitted to the hospital for an acute medical problem may benefit from initiating medications for OUD during their hospitalization. A thoughtful and respectful discussion of treatment options and patient-centered provision of medication can be a critical entry point into care. Research supports the efficacy of initiating either buprenorphine or methadone during acute hospital stays^393,394^ and starting patients on buprenorphine in the ED.^395^

## Buprenorphine Induction in the Hospital Setting

Patients admitted to the hospital for medical conditions incident to OUD can undergo medically supervised withdrawal or receive buprenorphine maintenance treatment during their inpatient stay.^396^ It is important to adequately address opioid withdrawal because hospital patients may otherwise sign out against medical advice or use illicit opioids in the hospital. Buprenorphine can also be initiated for maintenance treatment if there is a system in place that allows smooth and reliable discharge to an outpatient buprenorphine prescriber. Unlike methadone, a several-day delay between discharge and the first visit to the outpatient provider is acceptable for stable patients, as long as sufficient medication is provided until the patient begins outpatient treatment. The prescription for medication to be taken outside the hospital must be written by a prescriber with a buprenorphine waiver. If there is no prescriber with a waiver, it is possible to have a patient return to the hospital ED or a clinic within the hospital to have the buprenorphine dose administered by a physician (who does not need to be waivered) for up to 3 days.

To provide continuity of care at discharge, use these strategies:

• Develop and maintain a network of local buprenorphine prescribers and other drug treatment providers.
• Discharge patients directly to a specific outpatient prescriber for stabilization and maintenance after inpatient buprenorphine induction.
• Send discharge information directly to the outpatient prescriber, including treatment course, medications administered, and medications prescribed.

To initiate buprenorphine during hospitalization:

• Confirm that there are no contraindications to buprenorphine before initiation.
• Discontinue opioids for pain management only when no longer needed and the patient is stable enough to tolerate withdrawal.
• Wait for patients to develop opioid withdrawal symptoms.
• Initiate buprenorphine treatment.
• Individualize buprenorphine dosing.
• Follow the dosing guidance found in Chapter 3D of this TIP.

A clinical trial found that starting buprenorphine in the ED to treat OUD was more effective in linking patients to buprenorphine treatment in the community than were two other approaches without medication.^397^ When patients presented in opioid withdrawal, they received 8 mg of buprenorphine in the ED. Patients who were not in withdrawal received a detailed self-medication guide and were provided buprenorphine for an unobserved home induction. In both cases, patients were given sufficient buprenorphine to take 16 mg per day at home until they could see an outpatient prescriber within 72 hours. Close follow-up with an outpatient buprenorphine prescriber was critical for dose stabilization and ongoing medication management.

### Methadone Induction in the Hospital Setting

Offer to treat hospitalized patients in opioid withdrawal with methadone (or buprenorphine) maintenance if they can continue the medication in an OTP seamlessly after discharge. Do not start patients on methadone maintenance in the hospital without a clear follow-up plan. Form relationships with local OTPs that allow discharging of patients directly into methadone maintenance treatment.

RESOURCE ALERT

##### Telehealth Tools for the Treatment of OUD

The Substance Abuse and Mental Health Services Administration and other federal agencies have developed numerous resources to guide healthcare professionals in their use of telehealth and telemedicine approaches for OUD. These resources include information on:

• Guidance on the use of telemedicine in OTPs (https://store.samhsa.gov/shin/content/PEP15-FEDGUIDEOTP/PEP15-FEDGUIDEOTP.pdf).
• The policies that must be put in place (to comply with the Controlled Substances Act) by physicians who wish to use telehealth in treating patients with buprenorphine for OUD under the Drug Addiction Treatment Act of 2000. Federal (and sometimes state) restrictions apply, which can be reviewed by accessing 21 USC § 802 (www.gpo.gov/fdsys/pkg/USCODE-2011-title21/pdf/USCODE-2011-title21-chap13-subchapI-partA-sec802.pdf).
• Centers for Medicare and Medicaid guidance on telehealth (www.cms.gov/Medicare/Medicare-General-Information/Telehealth/index.html).
• Challenges and opportunities in using telehealth for rural populations (https://store.samhsa.gov/shin/content/SMA16-4989/SMA16-4989.pdf).
• How certified community behavioral health clinics can use telehealth approaches to expand their services (www.samhsa.gov/section-223/care-coordination/telehealth-telemedicine).

The TIP expert panel urges providers not to force patients to withdraw from opioid agonist treatment in the hospital, especially if they have acute illness, pain, or a mental illness.

Inpatient methadone inductions should follow the same “start low, go slow” principles that outpatient inductions do (see Chapter 3B of this TIP). The initial dose should be from 10 mg to 20 mg per day. Increase slowly by 5 mg every few days in response to symptoms of opioid withdrawal and level of sedation at the peak plasma level 2 to 4 hours after dosing.

### Naltrexone Induction in the Hospital Setting

Consider XR-NTX initiation for patients who complete withdrawal in the hospital and are opioid free for 7 days (short acting) and up to 14 days (long acting). Only do so if:

• There are no contraindications (such as the need for opioid analgesia).
• The patient prefers it after a risk/benefit discussion that covers alternative treatments.
• There are available follow-up opportunities for ongoing medication maintenance upon discharge.

No published data indicate this approach's effectiveness.

If a patient desires and gives informed consent for medically supervised withdrawal and naltrexone initiation while in the hospital, a first dose of naltrexone can be given before discharge. As with other medications for OUD, discharge coordination is critical. Hospitals that develop naltrexone induction protocols need to have a clear discharge plan in place for patients who will then need to continue naltrexone in the outpatient setting. Patients should be advised about the risk of overdose if return to opioid use occurs after discontinuing naltrexone.

## Medical Management Plan

The key to effective treatment is to involve patients and all treating healthcare professionals in developing a comprehensive plan for managing treatment with OUD medication during and after hospitalization. This plan should include:

• Strategies for pain management (if required).
• In-hospital dosing procedures.
• Postdischarge coordination of care with outpatient programs and outpatient providers.

This plan ensures effective pain relief as well as continuity of ongoing care for patients taking medication for OUD.^398^

## Notes

1. Department of Health and Human Services. (2016). The opioid epidemic: By the numbers. Washington, DC: Author.
2. Center for Behavioral Health Statistics and Quality. (2017). Key substance use and mental health indicators in the United States: Results from the 2016 National Survey on Drug Use and Health. Rockville, MD: Substance Abuse and Mental Health Services Administration.
3. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
4. Weiss, A. J., Elixhauser, A., Barrett, M. L., Steiner, C. A., Bailey, M. K., & O'Malley, L. (2017, January). Opioid-related inpatient stays and emergency department visits by state, 2009–2014. HCUP Statistical Brief No. 219. Rockville, MD: Agency for Healthcare Research and Quality.
5. American Society of Addiction Medicine. (2011). Definition of addiction. Chevy Chase, MD: American Society of Addiction Medicine. Retrieved January 5, 2018, from www.asam.org/resources/definition-of-addiction
6. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
7. Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
8. Substance Abuse and Mental Health Services Administration. (2016). Pocket guide: Medication-assisted treatment of opioid use disorder. HHS Publication No. (SMA) 16-4892PG. Rockville, MD: Substance Abuse and Mental Health Services Administration.
9. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
10. Kreek, M. J., Borg, L., Ducat, E., & Ray, B. (2010). Pharmacotherapy in the treatment of addiction: Methadone. Journal of Addictive Diseases, 29(2), 200–216.20407977
11. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
12. World Health Organization. (2015). 19th WHO model list of essential medicines. Geneva, Switzerland: Author.
13. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
14. Sees, K. L., Delucchi, K. L., Masson, C., Rosen, A., Clark, H. W., Robillard, H., … Hall, S. M. (2000). Methadone maintenance vs 180-day psychosocially enriched detoxification for treatment of opioid dependence: A randomized controlled trial. JAMA, 283(10), 1303–1310.10714729
15. Nielsen, S., Larance, B., Degenhardt, L., Gowing, L., Kehler, C., & Lintzeris, N. (2016). Opioid agonist treatment for pharmaceutical opioid dependent people. Cochrane Database of Systematic Reviews, 2016(5), 1–61.
16. Stoller, K. B., Stephens, M. A. C., & Schorr, A. (2016). Integrated service delivery models for opioid treatment programs in an era of increasing opioid addiction, health reform, and parity. Retrieved October 16, 2017, from www.aatod.org/wp-content/uploads/2016/07/2nd-Whitepaper-.pdf
17. Comer, S. D., Sullivan, M. A., Yu, E., Rothenberg, J. L., Kleber, H. D., Kampman, K., … O'Brien, C. P. (2006). Injectable, sustained-release naltrexone for the treatment of opioid dependence: A randomized, placebo-controlled trial. Archives of General Psychiatry, 63(2), 210–218.16461865
18. Krupitsky, E., Nunes, E. V., Ling, W., Illeperuma, A., Gastfriend, D. R., & Silverman, B. L. (2011). Injectable extended-release naltrexone for opioid dependence: A double-blind, placebo-controlled, multicentre randomised trial. Lancet, 377(9776), 1506–1513.21529928
19. Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. A., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.27028913
20. American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
21. Lee, J. D., McDonald, R., Grossman, E., McNeely, J., Laska, E., Rotrosen, J., & Gourevitch, M. N. (2015). Opioid treatment at release from jail using extended-release naltrexone: A pilot proof-of-concept randomized effectiveness trial. Addiction, 110(6), 1008–1014.25703440
22. Leslie, D. L., Milchak, W., Gastfriend, D. R., Herschman, P. L., Bixler, E. O., Velott, D. L., & Meyer, R. E. (2015). Effects of injectable extended-release naltrexone (XR-NTX) for opioid dependence on residential rehabilitation outcomes and early follow-up. American Journal on Addictions, 24(3), 265–270.25655226
23. Sullivan, M. A., Garawi, F., Bisaga, A., Comer, S. D., Carpenter, K., Raby, W. N., … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 91(2–3), 289–292.17681716
24. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
25. World Health Organization. (2015). 19th WHO model list of essential medicines. Geneva, Switzerland: Author.
26. Jaffe, J. H., & O'Keeffe, C. (2003). From morphine clinics to buprenorphine: Regulating opioid agonist treatment of addiction in the United States. Drug and Alcohol Dependence, 70(2 Suppl.), S3–S11.12738346
27. Ling, W., Casadonte, P., Bigelow, G., Kampman, K. M., Patkar, A., Bailey, G. L., … Beebe, K. L. (2010). Buprenorphine implants for treatment of opioid dependence: A randomized controlled trial. JAMA, 304(14), 1576–1583.20940383
28. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
29. Kinlock, T. W., Gordon, M. S., Schwartz, R. P., Fitzgerald, T. T., & O'Grady, K. E. (2009). A randomized clinical trial of methadone maintenance for prisoners: Results at twelve-months post-release. Journal of Substance Abuse Treatment, 37(3), 277–285.19339140
30. McKenzie, M., Zaller, N., Dickman, S. L., Green, T. C., Parihk, A., Friedmann, P. D., & Rich, J. D. (2012). A randomized trial of methadone initiation prior to release from incarceration. Substance Abuse, 33(1), 19–29.22263710
31. Gordon, M. S., Kinlock, T. W., Schwartz, R. P., O'Grady, K. E., Fitzgerald, T. T., & Vocci, F. J. (2017). A randomized trial of buprenorphine for prisoners: Findings at 12-months post-release. Drug and Alcohol Dependence, 172, 34–42.28107680
32. Vocci, F. J., Schwartz, R. P., Wilson, M. E., Gordon, M. S., Kinlock, T. W., Fitzgerald, T. T., O'Grady, K. E., & Jaffe, J. H. (2015). Buprenorphine dose induction in non-opioid-tolerant pre-release prisoners. Drug and Alcohol Dependence, 156, 133–138.26409751
33. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
34. Binder, T., & Vavrinková, B. (2008). Prospective randomised comparative study of the effect of buprenorphine, methadone and heroin on the course of pregnancy, birthweight of newborns, early postpartum adaptation and course of the neonatal abstinence syndrome (NAS) in women followed up in the outpatient department. Neuro Endocrinology Letters, 29(1), 80–86.18283247
35. Fajemirokun-Odudeyi, O., Sinha, C., Tutty, S., Pairaudeau, P., Armstrong, D., Phillips, T., & Lindow, S. W. (2006). Pregnancy outcome in women who use opiates. European Journal of Obstetrics & Gynecology and Reproductive Biology, 126(2), 170–175.16202501
36. Stimmel, B., & Adamsons, K. (1976). Narcotic dependency in pregnancy. Methadone maintenance compared to use of street drugs. JAMA, 235, 1121–1124.946208
37. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
38. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
39. American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711. Retrieved October 30, 2017, from www.acog.org/Resources-And-Publications/Committee-Opinions/Committee-on-Obstetric-Practice/Opioid-Use-and-Opioid-Use-Disorder-in-Pregnancy
40. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
41. American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711. Retrieved October 30, 2017, from www.acog.org/Resources-And-Publications/Committee-Opinions/Committee-on-Obstetric-Practice/Opioid-Use-and-Opioid-Use-Disorder-in-Pregnancy
42. American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
43. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2). CD002207.
44. Lee, J. D., Nunes, E. V., Jr., Novo, P., Bachrach, K., Bailey, G. L., Bhatt, S., … Rotrosen, J. (2018). Comparative effectiveness of extended-release naltrexone versus buprenorphine-naloxone for opioid relapse prevention (X:BOT): A multicentre, open-label, randomised controlled trial. Lancet, 391(10118), 309–318.29150198
45. Tanum, L., Solli, K. K., Latif, Z. E., Benth, J. Š., Opheim, A., Sharma-Haase, K., … Kun⊘e, N. (2017). The effectiveness of injectable extended-release naltrexone vs daily buprenorphine-naloxone for opioid dependence: A randomized clinical noninferiority trial. JAMA Psychiatry, 74(12), 1197–1205.29049469
46. Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
47. Sees, K. L., Delucchi, K. L., Masson, C., Rosen, A., Clark, H. W., Robillard, H., … Hall, S. M. (2000). Methadone maintenance vs 180-day psychosocially enriched detoxification for treatment of opioid dependence: A randomized controlled trial. JAMA, 283(10), 1303–1310.10714729
48. Weiss, R. D., Potter, J. S., Fiellin, D. A., Byrne, M., Connery, H. S., Dickinson, W., … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
49. Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. A., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.27028913
50. Gowing, L., Ali, R., White, J. M., & Mbewe, D. (2017). Buprenorphine for managing opioid withdrawal. Cochrane Database of Systematic Reviews, 2017(2). CD002025.
51. Degenhardt, L., Randall, D., Hall, W., Law, M., Butler, T., & Burns, L. (2009). Mortality among clients of a state-wide opioid pharmacotherapy program over 20 years: Risk factors and lives saved. Drug and Alcohol Dependence, 105(1–2), 9–15.19608355
52. Hser, Y. I., Huang, D., Saxon, A. J., Woody, G., Moskowitz, A. L., Matthews, A. G., & Ling, W. (2017). Distinctive trajectories of opioid use over an extended follow-up of patients in a multisite trial on buprenorphine + naloxone and methadone. Journal of Addiction Medicine, 11(1), 63–69.27898496
53. Novick, D. M., Salsitz, E. A., Joseph, H., & Kreek, M. J. (2015). Methadone medical maintenance: An early 21st-century perspective. Journal of Addictive Diseases, 34(2–3), 226–237.26110221
54. Fiellin, D. A., Moore, B. A., Sullivan, L. E., Becker, W. C., Pantalon, M. V., Chawarski, M. C., … Schottenfeld, R. S. (2008). Long-term treatment with buprenorphine/naloxone in primary care: Results at 2-5 years. American Journal on Addictions, 17(2), 116–120.18393054
55. Krupitsky, E., Nunes, E. V., Ling, W., Gastfriend, D. R., Memisoglu, A., & Silverman, B. L. (2013). Injectable extended-release naltrexone (XR-NTX) for opioid dependence: long-term safety and effectiveness. Addiction, 108(9), 162–1637.
56. Kreek, M. J., Levran, O., Reed, B., Schlussman, S. D., Zhou, Y., & Butelman, E. R. (2012). Opiate addiction and cocaine addiction: Underlying molecular neurobiology and genetics. Journal of Clinical Investigation, 122(10), 3387–3393.23023708
57. Volkow, N. D., Koob, G. F., & McLellan, A. T. (2016). Neurobiologic advances from the brain disease model of addiction. New England Journal of Medicine, 374(4), 363–371.26816013
58. Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., … Bilangi, R. (2009). Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
59. Senay, E. C., Dorus, W., & Thornton, W. (1977). Withdrawal from methadone maintenance: Rate of withdrawal and expectation. Archives of General Psychiatry, 34(3), 361–367.843188
60. Sigmon, S. C., Dunn, K. E., Saulsgiver, K., Patrick, M. E., Badger, G. J., Heil, S. H., … Higgins, S. T. (2013). A randomized, double-blind evaluation of buprenorphine taper duration in primary prescription opioid abusers. JAMA Psychiatry, 70(12), 1347–1354.24153411
61. Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
62. Fullerton, C. A., Kim, M., Thomas, C. P., Lyman, D. R., Montejano, L. B., Dougherty, R. H., … Delphin-Rittmon, M. E. (2014). Medication-assisted treatment with methadone: Assessing the evidence. Psychiatric Services, 65(2), 146–157.24248468
63. Weiss, R. D., Potter, J. S., Fiellin, D. A., Byrne, M., Connery, H. S., Dickinson, W., … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
64. Amato, L., Davoli, M., Minozzi, S., Ferroni, E., Ali, R., & Ferri M. (2013). Methadone at tapered doses for the management of opioid withdrawal. Cochrane Database of Systematic Reviews, 2013(2). CD003409.
65. Weiss, R. D., Potter, J. S., Fiellin, D. A., Byrne, M., Connery, H. S., Dickinson, W., … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
66. Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., & Bilangi, R. (2009) Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
67. Amato, L., Minozzi, S., Davoli, M., & Vecchi, S. (2011). Psychosocial and pharmacological treatments versus pharmacological treatments for opioid detoxification. Cochrane Database of Systematic Reviews, 2011(9). CD005031.
68. Nunes, E. V., Gordon, M., Friedmann, P. D., Fishman, M. J., Lee, J. D., Chen, D. T., … O'Brien, C. P. (2018). Relapse to opioid use disorder after inpatient treatment: Protective effect of injection naltrexone. Journal of Substance Abuse Treatment, 85, 49–55.28473233
69. Satoh, M., & Minami, M. (1995). Molecular pharmacology of the opioid receptors. Pharmacology & Therapeutics, 68(3), 343–364.8788562
70. Akbarali, H. I., Inkisar, A., & Dewey, W. L. (2014). Site and mechanism of morphine tolerance in the gastrointestinal tract. Neurogastroenterology and Motility, 26(10), 1361–1367.25257923
71. Bodnar, R. J. (2017). Endogenous opiates and behavior, 2015. Peptides, 88, 126–188.28012859
72. Johnson, R. E., Strain, E. C., & Amass, L. (2003). Buprenorphine: How to use it right. Drug and Alcohol Dependence, 70(Suppl.), S59–S77.12738351
73. Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 2011(2). CD001333.
74. Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
75. Kreek, M. J., Borg, L., Ducat, E., & Ray, B. (2010). Pharmacotherapy in the treatment of addiction: Methadone. Journal of Addictive Diseases, 29(2), 200–216.20407977
76. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
77. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
78. Degenhardt, L., Randall, D., Hall, W., Law, M., Butler, T., & Burns, L. (2009). Mortality among clients of a state-wide opioid pharmacotherapy program over 20 years: Risk factors and lives saved. Drug and Alcohol Dependence, 105(1–2), 9–15.19608355
79. Metzger, D. S., Woody, G. E., McLellan, A. T., O'Brien, C. P., Druley, P., Navaline, H., … Abrutyn, E. J. (1993). Human immunodeficiency virus seroconversion among intravenous drug users in- and out-of-treatment: An 18-month prospective follow-up. Journal of Acquired Immune Deficiency Syndromes, 6(9), 1049–1056.8340896
80. Ball, J. C., & Ross, A. (1991). The effectiveness of methadone maintenance treatment. New York, NY: Springer Verlag.
81. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2). CD002207.
82. Walsh, S. L., & Strain, E. C. (2006). Pharmacology of methadone. In E. C. Strain & M. L. Stitzer (Eds.), The treatment of opioid dependence (pp. 59–76). Baltimore, MD: John Hopkins University Press.
83. Mallinckrodt Pharmaceuticals. (2017). Label: Methadose - methadone hydrochloride concentrate; Methadose sugar-free- methadone hydrochloride concentrate. Retrieved on January 9, 2018, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=808a9d0b-720b-4034-a862-5122ff514608
84. Walsh, S. L., & Strain, E. C. (2006). Pharmacology of methadone. In E. C. Strain & M. L. Stitzer (Eds.), The treatment of opioid dependence (pp. 59–76). Baltimore, MD: John Hopkins University Press.
85. Payte, J. T., & Zweben, J. E. (1998). Opioid maintenance therapies. In A. W. Graham, T. K. Schultz, & B. B. Wilford (Eds.), Principles of addiction medicine (pp. 557–570). Chevy Chase, MD: American Society of Addiction Medicine.
86. Eap, C. B., Buclin, T., & Baumann, P. (2002). Interindividual variability of the clinical pharmacokinetics of methadone: Implications for the treatment of opioid dependence. Clinical Pharmacokinetics, 41(14), 1153–1193.12405865
87. Mallinckrodt Pharmaceuticals. (2017). Label: Methadose - methadone hydrochloride concentrate; Methadose sugar-free- methadone hydrochloride concentrate. Retrieved on January 9, 2018, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=808a9d0b-720b-4034-a862-5122ff514608
88. Oda, Y., & Kharasch, E. D. (2001). Metabolism of methadone and levo-alpha-acetylmethadol (LAAM) by human intestinal cytochrome P450 3A4 (CYP3A4): Potential contribution of intestinal metabolism to presystemic clearance and bioactivation. Journal of Pharmacology and Experimental Therapeutics, 298(3), 1021–1032.11504799
89. Eap, C. B., Buclin, T., & Baumann, P. (2002). Interindividual variability of the clinical pharmacokinetics of methadone: Implications for the treatment of opioid dependence. Clinical Pharmacokinetics, 41(14), 1153–1193.12405865
90. Eap, C. B., Buclin, T., & Baumann, P. (2002). Interindividual variability of the clinical pharmacokinetics of methadone: Implications for the treatment of opioid dependence. Clinical Pharmacokinetics, 41(14), 1153–1193.12405865
91. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
92. Federal opioid treatment standards, 42 CFR § 8.12 (2015).
93. Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.24685458
94. Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
95. Food and Drug Administration. (2016, March). FDA Drug Safety Communications, FDA urges caution about withholding opioid addiction medications from patients taking benzodiazepines or CNS depressant: Careful medication management can reduce risks. Retrieved January 3, 2018, from www.fda.gov/downloads/Drugs/DrugSafety/UCM576377.pdf
96. Lintzeris, N., & Nielsen, S. (2010). Benzodiazepines, methadone and buprenorphine: Interactions and clinical management. American Journal on Addictions, 19(1), 59–72.20132123
97. Bart, G., Wyman, Z., Wang, Q., Hodges, J. S., Karim, R., & Bart, B. A. (2017). Methadone and the QTc interval: Paucity of clinically significant factors in a retrospective cohort. Journal of Addiction Medicine, 11(6), 489–493.28863009
98. Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.24685458
99. Bednar, M. M., Harrigan, E. P., & Ruskin, J. N. (2002). Torsades de pointes associated with nonantiarrhythmic drugs and observations on gender and QTc. American Journal of Cardiology, 89(11), 1316–1319.12031739
100. Al-Khatib, S. M., LaPointe, N. M. A., Kramer, J. M., & Califf, R. M. (2003). What clinicians should know about the QT interval. JAMA, 289(16), 2120–2127.12709470
101. Martin, J. A., Campbell, A., Killip, T., Kotz, M., Krantz, M. J., Kreek, M. J., … Wilford, B. B. (2011). QT interval screening in methadone maintenance treatment: Report of a SAMHSA expert panel. Journal of Addictive Diseases, 30(4), 283–306.22026519
102. Bazett, H. C. (1997). An analysis of the time-relations of electrocardiograms. Annals of Noninvasive Electrocardiology, 2(2), 177–194.
103. Martin, J. A., Campbell, A., Killip, T., Kotz, M., Krantz, M. J., Kreek, M. J., … Wilford, B. B. (2011). QT interval screening in methadone maintenance treatment: Report of a SAMHSA expert panel. Journal of Addictive Diseases, 30(4), 283–306.22026519
104. Mallinckrodt Pharmaceuticals. (2015). Methadose™ dispersible tablets, 40 mg (Methadone hydrochloride tablets for oral suspension USP), CII - Generic products. Retrieved October 16, 2017, from https://dailymed.nlm.nih.gov/dailymed/archives/fdaDrugInfo.cfm?archiveid=8731
105. Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.24685458
106. Krantz, M. J., Martin, J., Stimmel, B., Mehta, D., & Haigney, M. C. (2009). QTc interval screening in methadone treatment. Annals of Internal Medicine, 150(6), 387–395.19153406
107. Bart, G., Wyman, Z., Wang, Q., Hodges, J. S., Karim, R., & Bart, B. A. (2017). Methadone and the QTc interval: Paucity of clinically significant factors in a retrospective cohort. Journal of Addiction Medicine, 11(6), 489–493.28863009
108. Pani, P. P., Trogu, E., Maremmani, I., & Pacini, M. (2013). QTc interval screening for cardiac risk in methadone treatment of opioid dependence. Cochrane Database of Systematic Reviews, 2013(6). CD008939.
109. Martin, J. A., Campbell, A., Killip, T., Kotz, M., Krantz, M. J., Kreek, M. J., … Wilford, B. B. (2011). QT interval screening in methadone maintenance treatment: Report of a SAMHSA expert panel. Journal of Addictive Diseases, 30(4), 283–306.22026519
110. Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.24685458
111. Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.24685458
112. Jones, H. E., Dengler, E., Garrison, A., O'Grady, K. E., Seashore, C., Horton, E., … Thorp, J. (2014). Neonatal outcomes and their relationship to maternal buprenorphine dose during pregnancy. Drug and Alcohol Dependence, 134, 414–417.24290979
113. Cleary, B. J., Reynolds, K., Eogan, M., O'Connell, M. P., Fahey, T., Gallagher, P. J., … Murphy, D. J. (2014). Methadone dosing and prescribed medication use in a prospective cohort of opioid-dependent pregnant women. Addiction, 108(4), 762–770.
114. Kaltenbach, K., Holbrook, A. M., Coyle, M. G., Heil, S. H., Salisbury, A. L., Stine, S. M., … Jones, H. E. (2012). Predicting treatment for neonatal abstinence syndrome in infants born to women maintained on opioid agonist medication. Addiction, 107(Suppl. 1), 45–52.
115. Food and Drug Administration. (2016, March). FDA Drug Safety Communication: FDA warns about several safety issues with opioid pain medicines; requires label changes. Retrieved December 18, 2017, from www.fda.gov/downloads/Drugs/DrugSafety/UCM491302.pdf
116. McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.20132117
117. Martin, J., Zweben, J. E., & Payte, J. T. (2014). Opioid maintenance treatment. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), The ASAM principles of addiction medicine (5th ed., pp. 759–777). Philadelphia, PA: Wolters Kluwer Health.
118. Saxon, A. J., & Miotto, K. (2011). Methadone maintenance. In P. Ruiz & E. Strain (Eds.), Lowinson and Ruiz's substance abuse: A comprehensive textbook (5th ed., pp. 419–436). Philadelphia, PA: Wolters Kluwer Health.
119. McCance-Katz, E. F., Rainey, P. M., Jatlow, P., & Friedland, G. (1998). Methadone effects on zidovudine disposition (AIDS Clinical Trials Group 262). Journal of Acquired Immune Deficiency Syndromes and Human Retrovirology, 18(5), 435–443.9715839
120. World Health Organization. (2009). Guidelines for the psychosocially assisted pharmacological treatment of opioid dependence. Geneva, Switzerland: WHO Press.
121. American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711. Retrieved October 30, 2017, from www.acog.org/Resources-And-Publications/Committee-Opinions/Committee-on-Obstetric-Practice/Opioid-Use-and-Opioid-Use-Disorder-in-Pregnancy
122. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
123. Centers for Disease Control and Prevention. (2016). Viral hepatitis. Retrieved December 1, 2017, from www.cdc.gov/hepatitis/hbv/bfaq.htm
124. Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
125. McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.20132117
126. Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
127. Jones, H. E. (2004). Practical considerations for the clinical use of buprenorphine. Science and Practice Perspectives, 2(2), 4–20.18552728
128. Vocci, F. J., Schwartz, R. P., Wilson, M. E., Gordon, M. S., Kinlock, T. W., Fitzgerald, T. T., … Jaffe, J. H. (2015). Buprenorphine dose induction in non-opioid-tolerant pre-release prisoners. Drug and Alcohol Dependence, 156, 133–138.26409751
129. Kinlock, T. W., Gordon, M. S., Schwartz, R. P., & O'Grady, K. E. (2008). A study of methadone maintenance for male prisoners: 3-month postrelease outcomes. Criminal Justice and Behavior, 35(1), 34–47.18612373
130. Martin, J., Zweben, J. E., & Payte, J. T. (2014). Opioid maintenance treatment. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), The ASAM principles of addiction medicine (5th ed., pp. 759–777). Philadelphia, PA: Wolters Kluwer.
131. Baxter, L. E., Sr., Campbell, A., Deshields, M., Levounis, P., Martin, J. A., McNicholas, L., … Wilford, B. B. (2013). Safe methadone induction and stabilization: Report of an expert panel. Journal of Addiction Medicine, 7(6), 377–386.24189172
132. Center for Substance Abuse Treatment. (1993). State methadone treatment guidelines. HHS Publication No. (SMA) 93-1991. Rockville, MD: Substance Abuse and Mental Health Services Administration.
133. Chou, R., Cruciani, R. A., Fiellin, D. A., Compton, P., Farrar, J. T., Haigney, M. C., … Zeltzer, L. (2014). Methadone safety: A clinical practice guideline from the American Pain Society and College on Problems of Drug Dependence, in collaboration with the Heart Rhythm Society. Journal of Pain, 15(4), 321–337.24685458
134. Gowing, L., Ali, R., Dunlop, A., Farrell, M., & Lintzeris, N. (2014). National guidelines for medication-assisted treatment of opioid dependence. Retrieved January 4, 2018, from www.nationaldrugstrategy.gov.au/internet/drugstrategy/Publishing.nsf/content/AD14DA97D8EE00E8CA257CD1001E0E5D/$File/National_Guidelines_2014.pdf
135. Leavitt, S. B., Shinderman, M., Maxwell, S., Eap, C. B., & Paris, P. (2000). When “enough” is not enough: New perspectives on optimal methadone maintenance dose. Mount Sinai Journal of Medicine, 67(5–6), 404–411.11064491
136. Payte, J. T. (2002). Opioid agonist treatment of addiction. Slide presentation at ASAM Review Course in Addiction Medicine.
137. Leavitt, S. B. (2003). The methadone dose debate continues. Addiction Treatment Forum, 12(1), 1,3.
138. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
139. Benmebarek, M., Devaud, C., Gex-Fabry, M., Powell Golay, K., Brogli, C., Baumann, P., … Eap, C. B. (2004). Effects of grapefruit juice on the pharmacokinetics of the enantiomers of methadone. Clinical Pharmacology and Therapeutics, 76(1), 55–63.15229464
140. Drozdick, J., III, Berghella, V., Hill, M., & Kaltenbach, K. (2002). Methadone trough levels in pregnancy. American Journal of Obstetrics and Gynecology, 187(5), 1184–1188.12439500
141. Leavitt, S. B., Shinderman, M., Maxwell, S., Eap, C. B., & Paris, P. (2000). When “enough” is not enough: New perspectives on optimal methadone maintenance dose. Mount Sinai Journal of Medicine, 67(5–6), 404–411.11064491
142. Hallinan, R., Ray, J., Byrne, A., Agho, K., & Attia, J. (2006). Therapeutic thresholds in methadone maintenance treatment: A receiver operating characteristic analysis. Drug and Alcohol Dependence, 81, 129–136.16026938
143. Stine, S. M., & Kosten, T. R. (2014). Pharmacologic interventions for opioid dependence. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), The ASAM principles of addiction medicine (5th ed., pp. 745–758). Philadelphia, PA: Wolters Kluwer.
144. Drozdick, J., III, Berghella, V., Hill, M., & Kaltenbach, K. (2002). Methadone trough levels in pregnancy. American Journal of Obstetrics and Gynecology, 187(5), 1184–1188.12439500
145. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
146. Food and Drug Administration. (2008). Methadose™ oral concentrate. Retrieved October 16, 2017, from www.accessdata.fda.gov/drugsatfda_docs/label/2008/017116s021lbl.pdf
147. Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
148. Stitzer, M. L., Iguchi, M. Y., & Felch, L. J. (1992). Contingent take-home incentive: Effects on drug use of methadone maintenance patients. Journal of Consulting and Clinical Psychology, 60(6), 927–934.1460154
149. Gwin Mitchell, S., Kelly, S. M., Brown, B. S., Schacht Reisinger, H., Peterson, J. A., Ruhf, A., … Schwartz, R. P. (2009). Uses of diverted methadone and buprenorphine by opioid-addicted individuals in Baltimore, Maryland. American Journal on Addictions, 18(5), 346–355.19874152
150. Vlahov, D., O'Driscoll, P., Mehta, S. H., Ompad, D. C., Gern, R., Galai, N., & Kirk, G. D. (2007). Risk factors for methadone outside treatment programs: Implications for HIV treatment among injection drug users. Addiction, 102(5), 771–777.17506154
151. Timko, C., Schultz, N. R., Cucciare, M. A., Vittorio, L., & Garrison-Diehn, C. (2016). Retention in medication-assisted treatment for opiate dependence: A systematic review. Journal of Addictive Diseases, 35(1), 22–35.26467975
152. Woody, G. E., Kane, V., Lewis, K., & Thompson, R. (2007). Premature deaths after discharge from methadone maintenance: A replication. Journal of Addiction Medicine, 1(4), 180–185.21768955
153. Sordo, L., Barrio, G., Bravo, M. J., Indave, I., Degenhardt, L., Wiessing, L., Ferri, M., & Pastor-Barriuso, R. (2017). Mortality risk during and after opioid substitution treatment: Systematic review and meta-analysis of cohort studies. BMJ, 357, j1550.28446428
154. Gibson, A., Degenhardt, L., Mattick, R. P., Ali, R., White, J., & O'Brien, S. (2008). Exposure to opioid maintenance treatment reduces long-term mortality. Addiction, 103(3), 462–468.18190664
155. Schwartz, R. P., Highfield, D. A., Jaffe, J. H., Brady, J. V., Butler, C. B., Rouse, C. O., … Battjes, R. J. (2006). A randomized controlled trial of interim methadone maintenance. Archives of General Psychiatry, 63(1), 102–109.16389204
156. Yancovitz, S. R., Des Jarlais, D. C., Peyser, N. P., Drew, E., Friedmann, P., Trigg, H. L., & Robinson, J. W. (1991). A randomized trial of an interim methadone maintenance clinic. American Journal of Public Health, 81(9), 1185–1191.1659236
157. Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
158. Martin, W. R., Jasinski, D. R., & Mansky, P. A. (1973). Naltrexone, an antagonist for the treatment of heroin dependence: Effects in man. Archives of General Psychiatry, 28(6), 784–791.4707988
159. Sullivan, M. A., Garawi, F., Bisaga, A., Comer, S. D., Carpenter, K., Raby, W. N., … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 91(2–3), 289–292.17681716
160. American Society of Addiction Medicine. (2015). National practice guideline for the use of medications in the treatment of addiction involving opioid use. Retrieved December 1, 2017, from www.asam.org/docs/default-source/practice-support/guidelines-and-consensus-docs/asam-national-practice-guideline-supplement.pdf?sfvrsn=24
161. Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 2011(2), 1–45. doi:10.1002/14651858.CD001333.pub3
162. Alkermes. (2015). Vivitrol. Retrieved May 21, 2017, from http://medlibrary.org/lib/rx/meds/vivitrol/page/6
163. Krupitsky, E., Nunes, E. V., Ling, W., Illeperuma, A., Gastfriend, D. R., & Silverman, B. L. (2011). Injectable extended-release naltrexone for opioid dependence: A double-blind, placebo-controlled, multicentre randomised trial. Lancet, 377(9776), 1506–1513.21529928
164. Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. A., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.27028913
165. Krupitsky, E., Nunes, E. V., Ling, W., Illeperuma, A., Gastfriend, D. R., & Silverman, B. L. (2011, April 30). Injectable extended-release naltrexone for opioid dependence: A double-blind, placebo-controlled, multicentre randomised trial. Lancet, 377(9776), 1506–1513.21529928
166. Lee, J. D., Nunes, E. V., Jr., Novo, P., Bachrach, K., Bailey, G. L., Bhatt, S., … Rotrosen J. (2018). Comparative effectiveness of extended-release naltrexone versus buprenorphine-naloxone for opioid relapse prevention (X:BOT): A multicentre, open-label, randomised controlled trial. Lancet, 391(10118), 309–318.29150198
167. Tanum, L., Solli, K. K., Latif, Z. E., Benth, J. Š., Opheim, A., Sharma-Haase, K., … Kun⊘e, N. (2017). The effectiveness of injectable extended-release naltrexone vs daily buprenorphine-naloxone for opioid dependence: A randomized clinical noninferiority trial. JAMA Psychiatry, 74(12), 1197–1205.29049469
168. Meyer, M. C., Straughn, A. B., Lo, M. W., Schary, W. L., & Whitney, C. C. (1984). Bioequivalence, dose-proportionality, and pharmacokinetics of naltrexone after oral administration. Journal of Clinical Psychiatry, 45(9 Pt 2), 15–19.6469932
169. Alkermes. (2015). Vivitrol (naltrexone for extended release injectable suspension) 380 mg/vial. Retrieved on January 9, 2018, from www.vivitrol.com/content/pdfs/prescribing-information.pdf
170. Alkermes. (2015). Vivitrol (naltrexone for extended release injectable suspension) 380 mg/vial. Retrieved on January 9, 2018, from www.vivitrol.com/content/pdfs/prescribing-information.pdf
171. Meyer, M. C., Straughn, A. B., Lo, M. W., Schary, W. L., & Whitney, C. C. (1984). Bioequivalence, dose-proportionality, and pharmacokinetics of naltrexone after oral administration. Journal of Clinical Psychiatry, 45(9, Pt. 2), 15–19.6469932
172. Bigelow, G. E., Preston, K. L., Schmittner, J., Dong, Q., & Gastfriend, D. R. (2012). Opioid challenge evaluation of blockade by extended-release naltrexone in opioid-abusing adults: Dose-effects and time-course. Drug and Alcohol Dependence, 123(1–3), 57–65.22079773
173. Tetrault, J. M., Tate, J. P., McGinnis, K. A., Goulet, J. L., Sullivan, L. E., Bryant, K., … Fiellin, D. A. (2012). Hepatic safety and antiretroviral effectiveness in HIV-infected patients receiving naltrexone. Alcoholism: Clinical and Experimental Research, 36(2), 318–324.
174. Jones, H. E., Kaltenbach, K., Heil, S. H., Stine, S. M., Coyle, M. G., Arria, A. M., … Fischer, G. (2010). Neonatal abstinence syndrome after methadone or buprenorphine exposure. New England Journal of Medicine, 363(24), 2320–2331.21142534
175. Mozurkewich, E. L., & Rayburn, W. F. (2014). Buprenorphine and methadone for opioid addiction during pregnancy. Obstetrics and Gynecology Clinics of North America, 41(2), 241–253.24845488
176. Alkermes. (2015). Vivitrol. Retrieved October 16, 2017, from http://medlibrary.org/lib/rx/meds/vivitrol/page/6
177. Sullivan, M., Bisaga, A., Pavlicova, M., Choi, C. J., Mishlen, K., Carpenter, K. M., … Nunes, E. V. (2017). Long-acting injectable naltrexone induction: A randomized trial of outpatient opioid detoxification with naltrexone versus buprenorphine. American Journal of Psychiatry, 174(5), 459–467.28068780
178. Tetrault, J. M., Tate, J. P., McGinnis, K. A., Goulet, J. L., Sullivan, L. E., Bryant, K., … Fiellin, D. A. (2012). Hepatic safety and antiretroviral effectiveness in HIV-infected patients receiving naltrexone. Alcoholism: Clinical and Experimental Research, 36(2), 318–324.
179. Crowley, T. J., Wagner, J. E., Zerbe, G., & Macdonald, M. (1985). Naltrexone-induced dysphoria in former opioid addicts. American Journal of Psychiatry, 142(9), 1081–1084.2992300
180. Miotto, K., McCann, M., Basch, J., Rawson, R., & Ling, W. (2002). Naltrexone and dysphoria: Fact or myth? American Journal on Addictions, 11(2), 151–160.12028745
181. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
182. National Library of Medicine. (2014). NALTREXONE HYDROCHLORIDE - naltrexone hydrochloride tablet, film coated DAILY MED. Retrieved October 16, 2017, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=06ff2d5a-e62b-4fa4-bbdb-01938535bc65
183. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
184. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
185. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
186. Centers for Disease Control and Prevention. (2016). Viral hepatitis. Retrieved October 16, 2017, from www.cdc.gov/hepatitis/hbv/bfaq.htm
187. Nunes, E. V., Krupitsky, E., Ling, W., Zummo, J., Memisoglu, A., Silverman, B. L., & Gastfriend, D. R. (2015). Treating opioid dependence with injectable extended-release naltrexone (XR-NTX): Who will respond? Journal of Addiction Medicine, 9(3), 238–243.25901451
188. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
189. Sigmon, S. C., Bisaga, A., Nunes, E. V., O'Connor, P. G., Kosten, T., & Woody, G. (2012). Opioid detoxification and naltrexone induction strategies: Recommendations for clinical practice. American Journal of Drug and Alcohol Abuse, 38(3), 187–199.22404717
190. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
191. Sullivan, M. A., Bisaga, A., Mariani, J. J., Glass, A., Levin, F. R., Comer, S. D., & Nunes, E. V. (2013). Naltrexone treatment for opioid dependence: Does its effectiveness depend on testing the blockade? Drug and Alcohol Dependence, 133(1), 80–85.23827259
192. Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892R. Rockville, MD: Substance Abuse and Mental Health Services Administration.
193. Kosten, T. R., Morgan, C., & Kleber, H. D. (1992). Phase II clinical trials of buprenorphine: Detoxification and induction onto naltrexone. NIDA Research Monograph, 121, 101–119.1406906
194. Bisaga, A., Sullivan, M. A., Glass, A., Mishlen, K., Pavlicova, M., Haney, M., … Nunes, E. V. (2015). The effects of dronabinol during detoxification and the initiation of treatment with extended release naltrexone. Drug and Alcohol Dependence, 154, 38–45.26187456
195. Sigmon, S. C., Bisaga, A., Nunes, E. V., O'Connor, P. G., Kosten, T., & Woody, G. (2012). Opioid detoxification and naltrexone induction strategies: Recommendations for clinical practice. American Journal of Drug and Alcohol Abuse, 38(3), 187–199.22404717
196. Sullivan, M., Bisaga, A., Pavlicova, M., Choi, C. J., Mishlen, K., Carpenter, K. M., … Nunes, E. V. (2017). Long-acting injectable naltrexone induction: A randomized trial of outpatient opioid detoxification with naltrexone versus buprenorphine. American Journal of Psychiatry, 174(5), 459–467.28068780
197. Sullivan, M., Bisaga, A., Pavlicova, M., Choi, C. J., Mishlen, K., Carpenter, K. M., … Nunes, E. V. (2017). Long-acting injectable naltrexone induction: A randomized trial of outpatient opioid detoxification with naltrexone versus buprenorphine. American Journal of Psychiatry, 174(5), 459–467.28068780
198. Bisaga, A. (2015). Implementing antagonist-based relapse prevention treatment for buprenorphine-treated individuals. Providence, RI: Providers’ Clinical Support System for Medication-Assisted Treatment.
199. Shearer, J., Wodak, A. D., & Dolan, K. A. (2007). Evaluation of a prison-based naltrexone program. International Journal of Prisoner Health, 3(3), 214–224.
200. Adi, Y., Juarez-Garcia, A., Wang, D., Jowett, S., Frew, E., Day, E., … Burls, A. (2007). Oral naltrexone as a treatment for relapse prevention in formerly opioid-dependent drug users: A systematic review and economic evaluation. Health Technology Assessment, 11(6), iii–iv, 1–85.
201. Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
202. Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 2011(2), 1–45.
203. Ling, W., & Wesson, D. R. (1984). Naltrexone treatment for addicted health-care professionals: A collaborative private practice experience. Journal of Clinical Psychiatry, 45(9 Pt. 2), 46–48.
204. Washton, A. M., Gold, M. S., & Pottash, A. C. (1984). Successful use of naltrexone in addicted physicians and business executives. Advances in Alcohol and Substance Abuse, 4(2), 89–96.6524509
205. Sullivan, M. A., Rothenberg, J. L., Vosburg, S. K., Church, S. H., Feldman, S. J., Epstein, E. M., … Nunes, E. V. (2006). Predictors of retention in naltrexone maintenance for opioid dependence: Analysis of a Stage I trial. American Journal on Addictions, 15(2), 150–159.16595353
206. Sullivan, M. A., Garawi, F., Bisaga, A., Comer, S. D., Carpenter, K., Raby, W. N., … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 91(2–3), 289–292.17681716
207. Sullivan, M. A., Garawi, F., Bisaga, A., Comer, S. D., Carpenter, K., Raby, W. N., … Nunes, E. V. (2007). Management of relapse in naltrexone maintenance for heroin dependence. Drug and Alcohol Dependence, 91(2–3), 289–292.17681716
208. American Society of Addiction Medicine. (2017). Sample treatment agreement. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-treatment-agreement30fa159472bc604ca5b7ff000030b21a.pdf?sfvrsn=0
209. Alkermes. (2013). Patient counseling tool: VIVITROL (naltrexone for extended-release injectable suspension. Retrieved January 9, 2018, from www.vivitrolrems.com/content/pdf/patinfo-counseling-tool.pdf
210. Alkermes. (2015). Key techniques to reduce severe injection site reactions: VIVITROL (naltrexone for extended release injectable suspension) intramuscular injection. Retrieved January 9, 2018, from www.vivitrolrems.com/content/pdf/patinfo-injection-poster.pdf
211. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
212. Caldiero, R. M., Parran, T. J., Adelman, C. L., & Piche, B. (2006). Inpatient initiation of buprenorphine maintenance vs. detoxification: Can retention of opioid-dependent patients in outpatient counseling be improved? American Journal on Addictions, 15(1), 1–7.
213. Weiss, R. D., Potter, J. S., Fiellin, D. A., Byrne, M., Connery, H. S., Dickinson, W., … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
214. Fiellin, D. A., Moore, B. A., Sullivan, L. E., Becker, W. C., Pantalon, M. V., Chawarski, M. C., … Schottenfeld, R. S. (2008). Long-term treatment with buprenorphine/naloxone in primary care: Results at 2–5 years. American Journal on Addictions, 17(2), 116–120.18393054
215. Edelman, E. J., Chantarat, T., Caffrey, S., Chaudhry, A., O'Connor, P. G., Weiss, L., … Fiellin, L. E. (2014). The impact of buprenorphine/naloxone treatment on HIV risk behaviors among HIV-infected, opioid-dependent patients. Drug and Alcohol Dependence, 139, 79–85.24726429
216. Sullivan, L. E., Moore, B. A., Chawarski, M. C., Pantalon, M. V., Barry, D., O'Connor, P. G., … Fiellin, D. A. (2008). Buprenorphine/naloxone treatment in primary care is associated with decreased human immunodeficiency virus risk behaviors. Journal of Substance Abuse Treatment, 35(1), 87–92.17933486
217. Auriacombe, M., Fatséas, M., Dubernet, J., Daulouède, J. P., & Tignol, J. (2004). French field experience with buprenorphine. American Journal on Addictions, 13(Suppl. 1), S17–S28.15204673
218. Degenhardt, L., Randall, D., Hall, W., Law, M., Butler, T., & Burns, L. (2009). Mortality among clients of a state-wide opioid pharmacotherapy program over 20 years: Risk factors and lives saved. Drug and Alcohol Dependence, 105(1–2), 9–15.19608355
219. Herget, G. (2005). Methadone and buprenorphine added to the WHO list of essential medicines. HIV/AIDS Policy and Law Review, 10(3), 23–24.
220. Department of Veterans Affairs & Department of Defense. (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Retrieved October 16, 2017, from substance use disorders. Retrieved October 16, 2017, from www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
221. Orexo US. (2016). Zubsolv (buprenorphine and naloxone) sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from www.zubsolv.com/wp-content/uploads/2015/01/ZubsolvFullPrescribingInformation.pdf
222. BioDelivery Sciences International. (2015). Bunavail (buprenorphine and naloxone) buccal film: Full prescribing information. Retrieved from https://bunavail.com/hcp/assets/pdfs/BUNAVAIL_Full_Prescribing_Information.pdf
223. BioDelivery Sciences International. (2015). Bunavail (buprenorphine and naloxone) buccal film: Full prescribing information. Retrieved October 16, 2017, from https://bunavail.com/hcp/assets/pdfs/BUNAVAIL_Full_Prescribing_Information.pdf
224. Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, through www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
225. Roxane Laboratories. (2015). Buprenorphine and naloxone sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=713db2c6-0544-4633-b874-cfbeaf93db89
226. Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, through www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
227. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
228. Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, from www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
229. Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
230. Orexo US. (2015). Zubsolv (buprenorphine and naloxone) sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from www.zubsolv.com/wp-content/uploads/2015/01/ZubsolvFullPrescribingInformation.pdf
231. Food and Drug Administration. (n.d.). Drugs@FDA: FDA approved drug products. Retrieved October 16, 2017, from www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm
232. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
233. Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
234. Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
235. Indivor. (2017). Label: Sublocade (buprenorphine extended-release injection, for subcutaneous use. Retrieved January 9, 2018, from www.accessdata.fda.gov/drugsatfda_docs/label/2017/209819s000lbl.pdf
236. Amass, L., Kamien, J. B., & Mikulich, S. K. (2001). Thrice-weekly supervised dosing with the combination buprenorphine-naloxone tablet is preferred to daily supervised dosing by opioid-dependent humans. Drug and Alcohol Dependence, 61(2), 173–181.11137282
237. Schottenfeld, R. S., Pakes, J., O'Connor, P., Chawarski, M., Oliveto, A., & Kosten, T. R. (2000). Thrice-weekly versus daily buprenorphine maintenance. Biological Psychiatry, 47(12), 1072–1079.10862807
238. Walsh, S. L., Preston, K. L., Stitzer, M. L., Cone, E. J., & Bigelow, G. E. (1994). Clinical pharmacology of buprenorphine: Ceiling effects at high doses. Clinical Pharmacology and Therapeutics, 55(5), 569–580.8181201
239. Elkader, A., & Sproule, B. (2005). Buprenorphine: Clinical pharmacokinetics in the treatment of opioid dependence. Clinical Pharmacokinetics, 44(7), 661–680.15966752
240. Kuhlman, J. J., Jr., Levine, B., Johnson, R. E., Fudala, P. J., & Cone, E. J. (1998). Relationship of plasma buprenorphine and norbuprenorphine to withdrawal symptoms during dose induction, maintenance and withdrawal from sublingual buprenorphine. Addiction, 93(4), 549–559.9684393
241. Indivor. (2016). Label: Suboxone – buprenorphine hydrochloride, naloxone hydrochloride film, soluble. Retrieved January 9, 2018, from https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=8a5edcf9-828c-4f97-b671-268ab13a8ecd
242. Marsch, L. A., Bickel, W. K., Badger, G. J., & Jacobs, E. A. (2005). Buprenorphine treatment for opioid dependence: The relative efficacy of daily, twice and thrice weekly dosing. Drug & Alcohol Dependence, 77(2), 195–204.15664721
243. Jones, J. D., Sullivan, M. A., Vosburg, S. K., Manubay, J. M., Mogali, S., Metz, V., & Comer, S. D. (2015). Abuse potential of intranasal buprenorphine versus buprenorphine/naloxone in buprenorphine-maintained heroin users. Addiction Biology, 20(4), 784–798.25060839
244. Walsh, S. L., Nuzzo, P. A., Babalonis, S., Casselton, V., & Lofwall, M. R. (2016). Intranasal buprenorphine alone and in combination with naloxone: Abuse liability and reinforcing efficacy in physically dependent opioid abusers. Drug and Alcohol Dependence, 162, 190–198.27012435
245. Indivior. (2017). Sublocade (buprenorphine extended-release) injection: Full prescribing information. Retrieved December 18, 2017, from www.accessdata.fda.gov/drugsatfda_docs/label/2017/209819s000lbl.pdf
246. Elkader, A., & Sproule, B. (2005). Buprenorphine: Clinical pharmacokinetics in the treatment of opioid dependence. Clinical Pharmacokinetics, 44(7), 661–680.15966752
247. Zhang, W., Ramamoorthy, Y., Tyndale, R. F., & Sellers, E. M. (2003). Interaction of buprenorphine and its metabolite norbuprenorphine with cytochromes p450 in vitro. Drug Metabolism and Disposition: The Biological Fate of Chemicals, 31(6), 768–772.12756210
248. McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.20132117
249. Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
250. Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
251. Selden, T., Ahlner, J., Druid, H., & Kronstrand, R. (2012). Toxicological and pathological findings in a series of buprenorphine related deaths. Possible risk factors for fatal outcome. Forensic Science International, 220(1–3), 284–290.22565115
252. Hakkinen, M., Launiainen, T., Vuori, E., & Ojanpera, I. (2012). Benzodiazepines and alcohol are associated with cases of fatal buprenorphine poisoning. European Journal of Clinical Pharmacology, 68(3), 301–309.21927835
253. Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
254. Toce, M. S., Burns, M. M., & O'Donnell, K. A. (2017). Clinical effects of unintentional pediatric buprenorphine exposures: Experience at a single tertiary care center. Clinical Toxicology (Philadelphia, Pa.), 55(1), 12–17.
255. Saxon, A. J., Ling, W., Hillhouse, M., Thomas, C., Hasson, A., Ang, A., … Jacobs, P. (2013). Buprenorphine/naloxone and methadone effects on laboratory indices of liver health: A randomized trial. Drug and Alcohol Dependence, 128(1–2), 71–76.22921476
256. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
257. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
258. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
259. Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
260. Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
261. Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
262. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
263. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
264. Indivior. (2015). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
265. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
266. Durand, F., & Valla, D. (2008). Assessment of prognosis of cirrhosis. Seminars in Liver Disease, 28(1), 110–122.18293281
267. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetics, 54(8), 837–849.25603822
268. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
269. Nasser, A. F., Heidbreder, C., Liu, Y., & Fudala, P. J. (2015). Pharmacokinetics of sublingual buprenorphine and naloxone in subjects with mild to severe hepatic impairment (Child-Pugh classes A, B, and C), in hepatitis C virus-seropositive subjects, and in healthy volunteers. Clinical Pharmacokinetic, 54(8), 837–849.
270. Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
271. Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
272. Lofwall, M. R., Martin, J., Tierney, M., Fatseas, M., Auriacombe, M., & Lintzeris, N. (2014). Buprenorphine diversion and misuse in outpatient practice. Journal of Addiction Medicine, 8(5), 327–332.25221985
273. Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
274. Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
275. Strain, E. C., & Lofwall, M. R. (Eds.). (2008). Buprenorphine. The American Psychiatric Publishing textbook of substance abuse treatment (4th ed.). Arlington, VA: American Psychiatric Publishing.
276. Walsh, S. L., June, H. L., Schuh, K. J., Preston, K. L., Bigelow, G. E., & Stitzer, M. L. (1995). Effects of buprenorphine and methadone in methadone-maintained subjects. Psychopharmacology, 119(3), 268–276.7675960
277. Strain, E. C., Preston, K. L., Liebson, I. A., & Bigelow, G. E. (1995). Buprenorphine effects in methadone-maintained volunteers: Effects at two hours after methadone. Journal of Pharmacology and Experimental Therapeutics, 272(2), 628–638.7853176
278. Rosado, J., Walsh, S. L., Bigelow, G. E., & Strain, E. C. (2007). Sublingual buprenorphine/naloxone precipitated withdrawal in subjects maintained on 100mg of daily methadone. Drug and Alcohol Dependence, 90(2–3), 261–269.17517480
279. Walsh, S. L., June, H. L., Schuh, K. J., Preston, K. L., Bigelow, G. E., & Stitzer, M. L. (1995). Effects of buprenorphine and methadone in methadone-maintained subjects. Psychopharmacology, 119(3), 268–276.7675960
280. Jones, H. E., Dengler, E., Garrison, A., O'Grady, K. E., Seashore, C., Horton, E., … Thorp, J. (2014). Neonatal outcomes and their relationship to maternal buprenorphine dose during pregnancy. Drug and Alcohol Dependence, 134, 414–417.24290979
281. Cleary, B. J., Reynolds, K., Eogan, M., O'Connell, M. P., Fahey, T., Gallagher, P. J., … Murphy, D. J. (2014). Methadone dosing and prescribed medication use in a prospective cohort of opioid-dependent pregnant women. Addiction, 108(4), 762–770.
282. Kaltenbach, K., Holbrook, A. M., Coyle, M. G., Heil, S. H., Salisbury, A. L. Stine, S. M., … Jones, H. E. (2012). Predicting treatment for neonatal abstinence syndrome in infants born to women maintained on opioid agonist medication. Addiction, 107(Suppl. 1), 45–52.
283. McCance-Katz, E. F., Sullivan, L. E., & Nallani, S. (2010). Drug interactions of clinical importance among the opioids, methadone and buprenorphine, and other frequently prescribed medications: A review. American Journal on Addictions, 19(1), 4–16.20132117
284. Center for Substance Abuse Treatment. (2004). Clinical guidelines for the use of buprenorphine in the treatment of opioid addiction. Treatment Improvement Protocol (TIP) Series 40. HHS Publication No. (SMA) 04-3939. Rockville, MD: Substance Abuse and Mental Health Services Administration.
285. Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
286. McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., DiFrancesco, R., Friedland, G., … Rainey, P. M. (2007). Interaction between buprenorphine and atazanavir or atazanavir/ritonavir. Drug and Alcohol Dependence, 91(2–3), 269–278.17643869
287. Bruce, R. D., & Altice, F. L. (2006). Three case reports of a clinical pharmacokinetic interaction with buprenorphine and atazanavir plus ritonavir. AIDS, 20(5), 783–784.16514314
288. Vergara-Rodriguez, P., Tozzi, M. J., Botsko, M., Nandi, V., Altice, F., Egan, J. E., … Fiellin, D. A. (2011). Hepatic safety and lack of antiretroviral interactions with buprenorphine/naloxone in HIV-infected opioid-dependent patients. Journal of Acquired Immune Deficiency Syndromes, 56(Suppl. 1), S62–S67.21317596
289. McCance-Katz, E. F., Moody, D. E., Prathikanti, S., Friedland, G., & Rainey, P. M. (2011). Rifampin, but not rifabutin, may produce opiate withdrawal in buprenorphine-maintained patients. Drug and Alcohol Dependence, 118(2–3), 326–334.21596492
290. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
291. McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., DiFrancesco, R., Friedland, G., … Rainey, P. M. (2007). Interaction between buprenorphine and atazanavir or atazanavir/ritonavir. Drug and Alcohol Dependence, 91(2–3), 269–278.17643869
292. McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., DiFrancesco, R., Friedland, G., … Rainey, P. M. (2007). Interaction between buprenorphine and atazanavir or atazanavir/ritonavir. Drug and Alcohol Dependence, 91(2–3), 269–278.17643869
293. Bruce, R. D., Moody, D. E., Altice, F. L., Gourevitch, M. N., & Friedland, G. H. (2013). A review of pharmacological interactions between HIV or hepatitis C virus medications and opioid agonist therapy: Implications and management for clinical practice. Expert Review of Clinical Pharmacology, 6(3), 249–269.23656339
294. Roxane Laboratories. (2015). Buprenorphine HCl sublingual tablets: Full prescribing information. Retrieved October 16, 2017, from http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1bf8b35a-b769-465c-a2f8-099868dfcd2f
295. Bruce, R. D., Moody, D. E., Altice, F. L., Gourevitch, M. N., & Friedland, G. H. (2013). A review of pharmacological interactions between HIV or hepatitis C virus medications and opioid agonist therapy: Implications and management for clinical practice. Expert Review of Clinical Pharmacology, 6(3), 249–269.23656339
296. Gruber, V. A., Rainey, P. M., Moody, D. E., Morse, G. D., Ma, Q., Prathikanti, S., … McCance-Katz, E. F. (2012). Interactions between buprenorphine and the protease inhibitors darunavir-ritonavir and fosamprenavir-ritonavir. Clinical Infectious Diseases, 54(3), 414–423.22100576
297. Bruce, R. D., Moody, D. E., Altice, F. L., Gourevitch, M. N., & Friedland, G. H. (2013). A review of pharmacological interactions between HIV or hepatitis C virus medications and opioid agonist therapy: Implications and management for clinical practice. Expert Review of Clinical Pharmacology, 6(3), 249–269.23656339
298. McCance-Katz, E. F., Moody, D. E., Morse, G. D., Friedland, G., Pade, P., Baker, J., … Rainey, P. M. (2006). Interactions between buprenorphine and antiretrovirals. I. The nonnucleoside reverse-transcriptase inhibitors efavirenz and delavirdine. Clinical Infectious Diseases, 43(Suppl. 4), S224–S234.17109309
299. McCance-Katz, E. F., Moody, D. E., Morse, G. D., Friedland, G., Pade, P., Baker, J., … Rainey, P. M. (2006). Interactions between buprenorphine and antiretrovirals. I. The nonnucleoside reverse-transcriptase inhibitors efavirenz and delavirdine. Clinical Infectious Diseases, 43(Suppl. 4), S224–S234.17109309
300. Bruce, R. D., Winkle, P., Custodio, J., Yin, X., Rhee, M., Andrews, J., … Ramanathan, S. (2012, September). Pharmacokinetics of cobicistat-boosted elvitegravir administered in combination with methadone or buprenorphine/naloxone. Paper presented at the 52nd Interscience Conference on Antimicrobial Agents and Chemotherapy, San Francisco, CA.
301. McCance-Katz, E. F., Moody, D. E., Morse, G. D., Ma, Q., & Rainey, P. M. (2010). Lack of clinically significant drug interactions between nevirapine and buprenorphine. American Journal on Addictions, 19(1), 30–37.20132119
302. McCance-Katz, E. F., Moody, D. E., Smith, P. F., Morse, G. D., Friedland, G., Pade, P., … Rainey, P. (2006). Interactions between buprenorphine and antiretrovirals. II. The protease inhibitors nelfinavir, lopinavir/ritonavir, and ritonavir. Clinical Infectious Diseases, 43(Suppl. 4), S235–S246.17109310
303. Bruce, R. D., Altice, F. L., Moody, D. E., Lin, S. N., Fang, W. B., Sabo, J. P., … Friedland, G. H. (2009). Pharmacokinetic interactions between buprenorphine/naloxone and tipranavir/ritonavir in HIV-negative subjects chronically receiving buprenorphine/naloxone. Drug and Alcohol Dependence, 105(3), 234–239.19726139
304. Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
305. Isenberg, D., Wong, S. C., & Curtis, J. A. (2008). Serotonin syndrome triggered by a single dose of Suboxone. American Journal of Emergency Medicine, 26(7), 840.e3–840.e5.
306. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
307. Soyka, M. (2013). Buprenorphine use in pregnant opioid users: A critical review. CNS Drugs, 27(8), 653–662.23775478
308. Saxon, A. J., Ling, W., Hillhouse, M., Thomas, C., Hasson, A., Ang, A., … Jacobs, P. (2013). Buprenorphine/naloxone and methadone effects on laboratory indices of liver health: A randomized trial. Drug and Alcohol Dependence, 128(1–2), 71–76.22921476
309. Vergara-Rodriguez, P., Tozzi, M. J., Botsko, M., Nandi, V., Altice, F., Egan, J. E., … Fiellin, D. A. (2011). Hepatic safety and lack of antiretroviral interactions with buprenorphine/naloxone in HIV-infected opioid-dependent patients. Journal of Acquired Immune Deficiency Syndromes, 56(Suppl. 1), S62–S67.21317596
310. Centers for Disease Control and Prevention. (2016). Viral hepatitis. Retrieved October 16, 2017, from www.cdc.gov/hepatitis/hbv/bfaq.htm
311. Lofwall, M. R., & Havens, J. R. (2012). Inability to access buprenorphine treatment as a risk factor for using diverted buprenorphine. Drug and Alcohol Dependence, 126(3), 379–383.22704124
312. Bazazi, A. R., Yokell, M., Fu, J. J., Rich, J. D., & Zaller, N. D. (2011). Illicit use of buprenorphine/naloxone among injecting and noninjecting opioid users. Journal of Addiction Medicine, 5(3), 175–180.21844833
313. Moratti, E., Kashanpour, H., Lombardelli, T., & Maisto, M. (2010). Intravenous misuse of buprenorphine: Characteristics and extent among patients undergoing drug maintenance therapy. Clinical Drug Investigation, 30(Suppl. 1), 3–11.
314. Braeburn Pharmaceuticals. (2016). Probuphine (buprenorphine) implant: Full prescribing information. Retrieved October 16, 2017, from www.accessdata.fda.gov/drugsatfda_docs/label/2016/204442Orig1s000lbl.pdf
315. Braeburn Pharmaceuticals. (2016). Probuphine (buprenorphine) implant: Full prescribing information. Retrieved October 16, 2017, from www.accessdata.fda.gov/drugsatfda_docs/label/2016/204442Orig1s000lbl.pdf
316. Center for Substance Abuse Treatment. (2004). Clinical guidelines for the use of buprenorphine in the treatment of opioid addiction. Treatment Improvement Protocol (TIP) Series 40. HHS Publication No. (SMA) 04-3939. Rockville, MD: Substance Abuse and Mental Health Services Administration.
317. Walley, A. Y., Alperen, J. K., Cheng, D. M., Botticelli, M., Castro-Donlan, C., Samet, J. H., & Alford, D. P. (2008). Office-based management of opioid dependence with buprenorphine: Clinical practices and barriers. Journal of General Internal Medicine, 23(9), 1393–1398.18592319
318. Gunderson, E. W., Wang, X. Q., Fiellin, D. A., Bryan, B., & Levin, F. R. (2010). Unobserved versus observed office buprenorphine/naloxone induction: A pilot randomized clinical trial. Addictive Behaviors, 35(5), 537–540.20106601
319. Lee, J. D., Vocci, F., & Fiellin, D. A. (2014). Unobserved “home” induction onto buprenorphine. Journal of Addiction Medicine, 8(5), 299–308.25254667
320. American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
321. Providers Clinical Support System for Medication Assisted Treatment. (2013, November). PCSS Guidance. Retrieved December 18, 2017, from http://pcssmat.org/wp-content/uploads/2014/02/PCSS-MATGuidanceBuprenorphineInduction.Casadonte.pdf
322. Tompkins, D. A., & Strain, E. C. (2011). Buprenorphine in the treatment of opioid dependence. In P. Ruiz & E. C. Strain (Eds.), Substance abuse. A comprehensive textbook (5th ed., pp. 437–446). Philadelphia, PA: Wolters Kluwer.
323. Indivior. (2016). Suboxone (buprenorphine and naloxone) sublingual film: Full prescribing information. Retrieved October 16, 2017, from www.suboxone.com/content/pdfs/prescribing-information.pdf
324. Strain, E. C. (2006). Clinical use of buprenorphine. In E. C. Strain & M. L. Stitzer (Eds.) The treatment of opioid dependence (pp. 230–252). Baltimore, MD: Johns Hopkins University Press.
325. Rich, J. D., McKenzie, M., Dickman, S., Bratberg, J., Lee, J. D., & Schwartz, R. P. (2011). An adverse reaction to buprenorphine/naloxone induction in prison: A case report. Addictive Disorders and Their Treatment, 10(4), 199–200.22121339
326. Vocci, F. J., Schwartz, R. P., Wilson, M. E., Gordon, M. S., Kinlock, T. W., Fitzgerald, T. T., … Jaffe, J. H. (2015). Buprenorphine dose induction in non-opioid-tolerant pre-release prisoners. Drug and Alcohol Dependence, 156, 133–138.26409751
327. Tompkins, D. A., & Strain, E. C. (2011). Buprenorphine in the treatment of opioid dependence. In P. Ruiz & E. C. Strain (Eds.), Substance abuse: A comprehensive textbook (5th ed., pp. 437–446). Philadelphia, PA: Wolters Kluwer.
328. Rosado, J., Walsh, S. L., Bigelow, G. E., & Strain, E. C. (2007). Sublingual buprenorphine/naloxone precipitated withdrawal in subjects maintained on 100mg of daily methadone. Drug and Alcohol Dependence, 90(2–3), 261–269.17517480
329. Zubieta, J., Greenwald, M. K., Lombardi, U., Woods, J. H., Kilbourn, M. R., Jewett, D. M., … Johanson, C. E. (2000). Buprenorphine-induced changes in mu-opioid receptor availability in male heroin-dependent volunteers: A preliminary study. Neuropsychopharmacology, 23(3), 326–334.10942856
330. Hser, Y., Saxon, A. J., Huang, D., Hasson, A., Thomas, C., Hillhouse, M. … Ling, W. (2014). Treatment retention among patients randomized to buprenorphine/naloxone compared to methadone in a multi-site trial. Addiction, 109(1), 79–87.23961726
331. American College of Obstetricians and Gynecologists Committee Opinion. (2017, August). Opioid use and opioid use disorder in pregnancy. Number 711. Retrieved October 30, 2017, from www.acog.org/Resources-And-Publications/Committee-Opinions/Committee-on-Obstetric-Practice/Opioid-Use-and-Opioid-Use-Disorder-in-Pregnancy
332. Debelak, K., Morrone, W. R., O'Grady, K. E., & Jones, H. E. (2013). Buprenorphine + naloxone in the treatment of opioid dependence during pregnancy-initial patient care and outcome data. American Journal on Addictions, 22, 252–254.23617867
333. Wiegand, S. L., Stringer, E. M., Stuebe, A. M., Jones, H., Seashore, C., & Thorp, J. (2015). Buprenorphine and naloxone compared with methadone treatment in pregnancy. Obstetrics & Gynecology, 125, 363–368.25569005
334. American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
335. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
336. Chavoustie, S., Frost, M., Snyder, O., Owen, J., Darwish, M., Dammerman, R., & Sanjurjo, V. (2017). Buprenorphine implants in medical treatment of opioid addiction. Expert Review of Clinical Pharmacology, 10(8), 799–807.28571505
337. Hser, Y. I., Huang, D., Saxon, A. J., Woody, G., Moskowitz, A. L., Matthews, A. G., & Ling, W. (2017). Distinctive trajectories of opioid use over an extended follow-up of patients in a multisite trial on buprenorphine + naloxone and methadone. Journal of Addiction Medicine, 11(1), 63–69.27898496
338. Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., … Bilangi, R. (2009). Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
339. Substance Abuse and Mental Health Services Administration. (2016). Sublingual and transmucosal buprenorphine for opioid use disorder: Review and update. Advisory, Vol. 15, Issue 1. Rockville, MD: Substance Abuse and Mental Health Services Administration.
340. American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
341. Henry-Edwards, S., Gowing, L., White, J., Ali, R., Bell, J., Brough, R., … Quigley, A. (2003). Clinical guidelines and procedures for the use of methadone in the maintenance treatment of opioid dependence. Publication approval number: 3263 (JN 7616).
342. World Health Organization. (2009). Guidelines for the psychosocially assisted pharmacological treatment of opioid dependence. Geneva, Switzerland: WHO Press.
343. Ling, W., Hillhouse, M., Domier, C., Doraimani, G., Hunter, J., Thomas, C., … Bilangi, R. (2009). Buprenorphine tapering schedule and illicit opioid use. Addiction, 104(2), 256–265.19149822
344. Food and Drug Administration. (2017, May). Appropriate use checklist: Buprenorphine-containing transmucosal products for opioid dependence. Silver Spring, MD: Author.
345. American Society of Addiction Medicine. (2017). Sample treatment agreement. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-treatment-agreement30fa159472bc604ca5b7ff000030b21a.pdf?sfvrsn=0
346. Food and Drug Administration. (2017). FDA Drug Safety Communication: FDA urges caution about withholding opioid addiction medications from patients taking benzodiazepines or CNS depressants: Careful medication management can reduce risks. Retrieved December 18, 2017, from www.fda.gov/Drugs/DrugSafety/ucm575307.htm
347. Lintzeris, N., & Nielsen, S. (2010). Benzodiazepines, methadone and buprenorphine: Interactions and clinical management. American Journal on Addictions, 19(1), 59–72.20132123
348. Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
349. Liebschutz, J. M., Crooks, D., Herman, D., Anderson, B., Tsui, J., Meshesha, L. Z., … Stein, M. (2014). Buprenorphine treatment for hospitalized, opioid-dependent patients: A randomized clinical trial. JAMA Internal Medicine, 174(8), 1369–1376.25090173
350. Weiss, L., Netherland, J., Egan, J. E., Flanigan, T. P., Fiellin, D. A., Finkelstein, R., & Altice, F. L. (2011). Integration of buprenorphine/naloxone treatment into HIV clinical care: Lessons from the BHIVES collaborative. Journal of Acquired Immune Deficiency Syndromes, 56(Suppl. 1), S68–S75.21317597
351. Weiss, R. D., Potter, J. S., Griffin, M. L., Provost, S. E., Fitzmaurice, G. M., McDermott, K. A., … Carroll, K. M. (2015). Long-term outcomes from the National Drug Abuse Treatment Clinical Trials Network Prescription Opioid Addiction Treatment Study. Drug and Alcohol Dependence, 150, 112–119.25818060
352. Substance Abuse and Mental Health Services Administration. (2005). Substance abuse treatment for persons with cooccurring disorders. Treatment Improvement Protocol (TIP) Series 42. HHS Publication No. (SMA) 133992. Rockville, MD: Substance Abuse and Mental Health Services Administration.
353. Center for Substance Abuse Treatment. (2004). Clinical guidelines for the use of buprenorphine in the treatment of opioid addiction. Treatment Improvement Protocol (TIP) Series 40. HHS Publication No. (SMA) 04-3939. Rockville, MD: Substance Abuse and Mental Health Services Administration.
354. Drug Addiction Treatment Act of 2000, H. R. 2634 (1999–2000).
355. Vujanovic, A. A., Bonn-Miller, M. O., & Petry, N. M. (2016). Co-occurring posttraumatic stress and substance use: Emerging research on correlates, mechanisms, and treatments—Introduction to the special issue. Psychology of Addictive Behaviors, 30(7), 713–719.27786510
356. Stitzer, M. L., & Vandrey, R. (2008). Contingency management: Utility in the treatment of drug abuse disorders. Clinical Pharmacology and Therapeutics, 83(4), 644–647.18305456
357. Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3–4), 313–332.23731422
358. Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3–4), 313–332.23731422
359. McLellan, A. T., & White, W. (2012). Opioid maintenance and recovery-oriented systems of care: It is time to integrate (p. 2). London, England: National Treatment Agency for Substance Misuse.
360. American Society of Addiction Medicine. (2015). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use. Chevy Chase, MD: Author.
361. Substance Abuse and Mental Health Services Administration. (2012). Clinical drug testing in primary care. Technical Assistance Publication (TAP) Series 32. HHS Publication No. (SMA) 12-4668. Rockville, MD: Substance Abuse and Mental Health Services Administration.
362. Jarvis, M., Williams, J., Hurford, M., Lindsay, D., Lincoln, P., Giles, L., … Safarian, T. (2017) Appropriate use of drug testing in clinical addiction medicine. Journal of Addiction Medicine, 11(3), 163–173.28557958
363. Stoller, K. B., Stephens, M. A. C., & Schorr, A. (2016). Integrated service delivery models for opioid treatment programs in an era of increasing opioid addiction, health reform, and parity. Retrieved May 21, 2017, from www.aatod.org/wp-content/uploads/2016/07/2nd-Whitepaper-.pdf
364. Rich, J. D., McKenzie, M., Larney, S., Wong, J. B., Tran, L., Clarke, J., … Zaller, N. (2015, July 25). Methadone continuation versus forced withdrawal on incarceration in a combined US prison and jail: A randomised, open-label trial. Lancet, 386(9991), 350–359.26028120
365. Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
366. Genberg, B. L., Gillespie, M., Schuster, C. R., Johanson, C.-E., Astemborski, J., Kirk, G. D., … Mehta, S. H. (2013). Prevalence and correlates of street-obtained buprenorphine use among current and former injectors in Baltimore, Maryland. Addictive Behaviors, 38(12), 2868–2873.24018232
367. Schuman-Olivier, Z., Albanese, M., Nelson, S. E., Roland, L., Puopolo, F., Klinker, L., & Shaffer, H. J. (2010). Self-treatment: Illicit buprenorphine use by opioid-dependent treatment seekers. Journal of Substance Abuse Treatment, 39(1), 41–50.20434868
368. Cicero, T. J., Ellis, M. S., Surratt, H. L., & Kurtz, S. P. (2014). Factors contributing to the rise of buprenorphine misuse: 2008-2013. Drug and Alcohol Dependence, 142, 98–104.24984689
369. Lofwall, M. R., & Walsh, S. L. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world. Journal of Addiction Medicine, 8(5), 315–326.25221984
370. United States National Library of Medicine. (2017, October). Buprenorphine sublingual and buccal (opioid dependence). Retrieved December 18, 2017, from https://medlineplus.gov/druginfo/meds/a605002.html
371. American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
372. Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
373. Medication Assisted Treatment for Opioid Use Disorders. HHS Final Rule, Fed. Reg. 81 44711 (July 8, 2016) (to be codified at 42 CFR pt. 8).
374. Physical security controls for practitioners, 21 CFR § 1301.75 (2016).
375. American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
376. Records for manufacturers, distributors, dispensers, researchers, importers, exporters, registrants that reverse distribute, and collectors, 21 CFR § 1304.22 (2014).
377. Lofwall, M., & Walsh, S. (2014). A review of buprenorphine diversion and misuse: The current evidence base and experiences from around the world (p. 316). Journal of Addiction Medicine, 8(5), 315–326.25221984
378. American Society of Addiction Medicine. (2016). Sample office-based opioid use disorder policy and procedure manual. Retrieved October 19, 2017, from www.asam.org/docs/default-source/advocacy/sample-diversion-policy.pdf?sfvrsn=0
379. Velez, C. M., Nicolaidis, C., Korthuis, P. T., & Englander, H. (2016). “It's been an experience, a life learning experience”: A qualitative study of hospitalized patients with substance use disorders. Journal of General Internal Medicine, 32(3), 296–303.27957661
380. Liebschutz, J. M., Crooks, D., Herman, D., Anderson, B., Tsui, J., Meshesha, L. Z., … Stein, M. (2014). Buprenorphine treatment for hospitalized, opioid-dependent patients: A randomized clinical trial. JAMA Internal Medicine, 174(8), 1369–1376.25090173
381. D'Onofrio, G., O'Connor, P. G., Pantalon, M. V., Chawarski, M. C., Busch, S. H., Owens, P. H., … Fiellin, D. A. (2015). Emergency department-initiated buprenorphine/naloxone treatment for opioid dependence: A randomized clinical trial. JAMA, 313(16), 1636–1644.25919527
382. Naeger, S., Ali, M. M., Mutter, R., Mark, T., & Hughey, L. (2016). Post-discharge prescription fills following an opioid hospitalization. Psychiatric Services, 67(11), 1264–1267.
383. Weiss, A. J., Elixhauser, A., Barrett, M. L., Steiner, C. A., Bailey, M. K., & O'Malley, L. (2017, January). Opioid-related inpatient stays and emergency department visits by state, 2009–2014. HCUP Statistical Brief No. 219. Rockville, MD: Agency for Healthcare Research and Quality.
384. Administering or dispensing of narcotic drugs, 21 CFR § 1306.07 (2005).
385. Alford, D., Compton, P., & Samet, H. (2006). Acute pain management for patients receiving maintenance methadone or buprenorphine therapy. Annals of Internal Medicine, 144(2), 127–134.16418412
386. Sen, S., Arulkumar, S., Cornett, E. M., Gayle, J. A., Flower, R. R., Fox, C. J., & Kaye, A. D. (2016). New pain management options for the surgical patient on methadone and buprenorphine. Current Pain and Headache Reports, 20(3), 16.26879874
387. Jones, H. E., Deppen, K., Hudak, M. L., Leffert, L., McClelland, C., Sahin, L., … Creanga, A. A. (2014). Clinical care for opioid-using pregnant and postpartum women: The role of obstetric providers. American Journal of Obstetrics and Gynecology, 210(4), 302–310.24120973
388. Alizadeh, S., Mahmoudi, G. A., Solhi, H., Sadeghi-Sedeh, B., Behzadi, R., & Kazemifar, A. M. (2015). Post-operative analgesia in opioid dependent patients: Comparison of intravenous morphine and sublingual buprenorphine. Addiction and Health, 7(1–2), 60–65.26322212
389. Sen, S., Arulkumar, S., Cornett, E. M., Gayle, J. A., Flower, R. R., Fox, C. J., & Kaye, A. D. (2016). New pain management options for the surgical patient on methadone and buprenorphine. Current Pain and Headache Reports, 20(3),16.26879874
390. Administering or dispensing of narcotic drugs, 21 CFR § 1306.07 (2005).
391. Alford, D. P., Compton, P., & Samet, J. H. (2006). Acute pain management for patients receiving maintenance methadone or buprenorphine therapy. Annals of Internal Medicine, 144(2), 127–134.16418412
392. Devin, C. J., & McGirt, M. J. (2015). Best evidence in multimodal pain management in spine surgery and means of assessing postoperative pain and functional outcomes. Journal of Clinical Neuroscience, 22(6), 930–938.25766366
393. Noska, A., Mohan, A., Wakeman, S., Rich, J., & Boutwell, A. (2015). Managing opioid use disorder during and after acute hospitalization: A case-based review clarifying methadone regulation for acute care settings. Journal of Addictive Behaviors, Therapy and Rehabilitation, 4(2), 1000138.
394. Liebschutz, J. M., Crooks, D., Herman, D., Anderson, B., Tsui, J., Meshesha, L. Z., … Stein, M. (2014). Buprenorphine treatment for hospitalized, opioid-dependent patients: A randomized clinical trial. JAMA Internal Medicine, 174(8), 1369–1376.25090173
395. D'Onofrio, G., O'Connor, P. G., Pantalon, M. V., Chawarski, M. C., Busch, S. H., Owens, P. H., … Fiellin, D. A. (2015). Emergency department-initiated buprenorphine/naloxone treatment for opioid dependence: A randomized clinical trial. JAMA, 313(16), 1636–1644.25919527
396. Substance Abuse and Mental Health Services Administration. (2016, March). Special circumstances for providing buprenorphine. Retrieved December 18, 2017, from www.samhsa.gov/medication-assisted-treatment/legislation-regulations-guidelines/special-circumstances-providing-buprenorphine
397. D'Onofrio, G., O'Connor, P. G., Pantalon, M. V., Chawarski, M. C., Busch, S. H., Owens, P. H., … Fiellin, D. A. (2015). Emergency department-initiated buprenorphine/naloxone treatment for opioid dependence: A randomized clinical trial. JAMA, 313(16), 1636–1644.25919527
398. Huxtable, C. A., Roberts, L. J., Somogyi, A. A., & Macintyre, P. E. (2011). Acute pain management in opioid-tolerant patients: A growing challenge. Anaesthesia and Intensive Care, 39(5), 804–823.21970125