# Chapter 3C: Naltrexone

Chapter 3C gives an overview of naltrexone pharmacology and specific guidance on dosing for oral and injectable naltrexone.

The opioid receptor antagonist naltrexone was synthesized in the 1960s to block the euphoric effects of morphine.^158^ Oral naltrexone was approved by the Food and Drug Administration (FDA) in 1984 for the blockade of the effects of exogenously administered opioids. Long-acting, sustained-release opioid agonist preparations have been investigated since the 1970s to improve adherence over oral medications. In 2010, FDA approved injectable extended-release naltrexone (XR-NTX) for preventing return to opioid dependence after medically supervised withdrawal.

Despite its potential advantages (e.g., no abuse liability, no special regulatory requirements), oral naltrexone is not widely used to treat opioid use disorder (OUD) because of low rates of patient acceptance, difficulty in achieving abstinence for the necessary time before initiation of treatment, and high rates of medication nonadherence.^159^

Before initiating either formulation of naltrexone, patients must be opioid abstinent for an adequate period of time after completing opioid withdrawal. Medically supervised opioid withdrawal can be conducted on an outpatient or inpatient basis. The latter is often reserved for patients with co-occurring substance use disorders (SUDs) or medical or psychiatric illness.

There are several pharmacological approaches to medically supervised withdrawal. Methadone can be used for this purpose in opioid treatment programs (OTPs) and hospital settings. Patients in opioid withdrawal typically receive an individualized dose between 20 mg and 30 mg per day, gradually reduced over 6 days or more. Buprenorphine can be used in an adequate dose to lessen withdrawal symptoms and then reduced gradually over several days or more. If an opioid agonist is used for medically supervised withdrawal, an adequate interval of time following the last dose must occur before naltrexone induction. When it is not possible to use opioid agonists, alpha-2 adrenergic agonists such as clonidine can be used off label at doses from 0.1 mg to 0.3 mg every 6 to 8 hours to treat symptoms.^160^

## Formulations

Oral: Oral naltrexone is a 50 mg tablet of naltrexone hydrochloride. It was approved by FDA in 1984 for blockade of the effects of exogenously administered opioids and in 1994 for alcohol dependence treatment. A Cochrane review examined 13 randomized trials among 1,158 patients who were opioid dependent and provided counseling. They were treated with or without oral naltrexone. The review concluded that oral naltrexone was not superior to placebo or to no medication in treatment retention or illicit opioid use reduction.^161^

XR-NTX: In 2006, FDA approved XR-NTX as an intramuscular (IM) injection every 4 weeks or once a month for the treatment of alcohol dependence. In 2010, FDA approved XR-NTX for the prevention of return to opioid dependence following medically supervised withdrawal. XR-NTX is a suspension of 380 mg naltrexone embedded in microspheres made from a biodegradable copolymer that undergoes hydrolysis as it absorbs water. XR-NTX requires refrigeration and is supplied as a vial of dry powder along with a separate vial of an aqueous diluent, which providers combine just before use.^162^

XR-NTX is more effective than placebo^163^ or no medication^164^ in reducing risk of return to opioid use.^165^ A multisite randomized trial in the United States started in residential treatment programs found that buprenorphine treatment was associated with lower rates of return to use during 24 weeks of postdischarge outpatient treatment compared with XR-NTX,^166^ given the significant proportion of patients who did not actually receive XR-NTX because of challenges related to XR-NTX induction. The same study found no significant between-group differences in rates of return to use when data were analyzed based solely on patients who did begin assigned medications. Study findings may not generalize to outpatient settings, where naltrexone induction may be more difficult than in residential treatment settings.

One additional study merits mention. A 12-week trial was conducted in Norway with 159 participants who, at the time of random assignment to XR-NTX or buprenorphine, had completed medically supervised withdrawal or were already opioid abstinent. XR-NTX was found to be noninferior to buprenorphine in terms of treatment retention or reduction in illicit opioid use.^167^

## Pharmacology

Naltrexone is a competitive mu-opioid receptor antagonist with strong receptor affinity. Naltrexone does not activate the mu-opioid receptor and exerts no opioid effects. Unlike opioid agonists, naltrexone will not alleviate withdrawal symptoms, will not cause withdrawal when stopped, and cannot be diverted.

If patients maintained on naltrexone use opioid agonists, naltrexone can block their effects—a key feature of its therapeutic efficacy. However, because the interaction at the receptor is competitive, the blockade can potentially be overridden with high doses of opioids.

Taking naltrexone after recent use of opioids can precipitate opioid withdrawal. Given its strong affinity, naltrexone can displace other opioids from the receptor. Patients must typically wait 7 to 10 days after their last use of short-acting opioids and 10 to 14 days after their last use of long-acting opioids before taking their first dose of naltrexone.

### Bioavailability

Oral: The gastrointestinal tract readily absorbs oral naltrexone. Peak concentrations occur in 1 to 2 hours.^168^

XR-NTX: IM injection causes a transient peak blood concentration 2 hours after injection and another at 2 to 3 days after injection.^169^ About 14 days after injection, concentrations gradually diminish, with measurable blood levels for more than 1 month.

Both formulations are extensively metabolized by the kidneys and liver, but without CYP450 enzyme system involvement. Unlike methadone and buprenorphine, naltrexone has limited potential drug–drug interactions. Its major metabolite, 6-beta naltrexol, is also a mu-opioid receptor antagonist. It is eliminated primarily by the kidneys in the urine.^170^

Orally administered naltrexone has a half-life of approximately 4 hours. Its primary metabolite, 6-beta-naltrexol, is a weak mu-opioid receptor antagonist with a half-life of approximately 12 hours.^171^

XR-NTX, or “depot naltrexone,” is encapsulated in biodegradable polymer microspheres. It provides opioid blockade by delivering steady naltrexone concentrations for about 1 month.^172^ Elimination half-life is 5 to 10 days. Repeated administration causes no accumulation of naltrexone or its metabolites.

## Dosing Considerations

### XR-NTX

XR-NTX is indicated for the prevention of return to opioid dependence following medically supervised opioid withdrawal. Appropriate patients should have an adequate period of abstinence with no signs of opioid withdrawal before XR-NTX administration. Patients must be willing to receive monthly IM injections. Become acquainted with the FDA label for XR-NTX, which is available online (https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=cd11c435-b0f0-4bb9-ae78-60f101f3703f).

#### Contraindications

Contraindications to receiving XR-NTX (as well as to receiving oral naltrexone, with the exception of hypersensitivity to the XR-NTX suspension and diluent) include:^173^

• Current pain treatment with opioid analgesics.
• Current physiological opioid dependence.
• Current acute opioid withdrawal.
• Severe hepatic impairment.
• Naloxone challenge (Exhibit 3C.1) or oral naltrexone dose causing opioid withdrawal symptoms.
• Positive urine opioid screen for morphine, methadone, buprenorphine, oxycodone, fentanyl, or other opioids.
• History of hypersensitivity to naltrexone, polylactide-co-glycolide, carboxymethylcellulose, or any other components of the diluent.

EXHIBIT 3C.1. Naloxone Challenge

Use the naloxone challenge to assess lack of physical opioid dependence. Naloxone can be administered via intravenous, subcutaneous, or IM routes to patients who report an adequate period of opioid abstinence and have a negative opioid urine test (including morphine, methadone, buprenorphine, and oxycodone). A negative naloxone challenge does not guarantee that the patient will not experience precipitated opioid withdrawal upon naltrexone administration.^181^

###### Intravenous Administration

1. Draw 0.8 mg naloxone into a sterile syringe.
2. Inject 0.2 mg naloxone intravenously.
3. Wait 30 seconds for signs and symptoms of withdrawal. If withdrawal signs/symptoms are present, stop the naloxone challenge and treat symptomatically.
4. If no withdrawal signs and symptoms are present and vital signs are stable, inject remaining naloxone (0.6 mg) and observe for 20 minutes. Check the patient's vital signs and monitor for withdrawal.
5. If withdrawal signs and symptoms are present, stop the naloxone challenge and treat symptomatically. The test can be repeated in 24 hours or the patient can be considered for opioid agonist treatment.
6. If no withdrawal signs and symptoms are present^*^ and oral naltrexone is the desired treatment course, give the patient two tablets of 25 mg naltrexone (take one tablet on each of the next 2 days) and a sufficient number of 50 mg naltrexone tablets (take one 50 mg tablet daily starting on the third day) until they are able to fill their prescription for oral naltrexone. Skip to Step 8.
7. If no withdrawal signs and symptoms are present^**^ and XR-NTX is the desired treatment course, administer XR-NTX in the upper outer quadrant of the buttock, following package insert directions (summarized below).
8. Instruct the patient about the risk of overdose and death if they use opioids to override the blockade.

###### Subcutaneous Administration

1. Inject 0.8 mg naloxone subcutaneously.
2. Wait 20 minutes while checking vital signs and observing for signs and symptoms of opioid withdrawal.
3. If withdrawal signs and symptom are present, stop the naloxone challenge and treat symptomatically. The test can be repeated in 24 hours or the patient can be considered for opioid agonist treatment.
4. If no withdrawal signs and symptoms are present, follow Step 6 (for oral naltrexone treatment) or Step 7 (for XR-NTX treatment) above.

* Optional: If withdrawal signs and symptoms are absent, administer 25 mg oral naltrexone and observe for 2 hours. If the patient develops opioid withdrawal, treat symptomatically. If no withdrawal signs or symptoms are present following the 25 mg naltrexone dose and oral naltrexone is the desired treatment course, give the patient one tablet of 25 mg naltrexone to take the next day and 50 mg naltrexone tablets to take daily starting the day after.

** Optional: If withdrawal signs and symptoms are absent, administer 25 mg oral naltrexone and observe for 2 hours. If the patient develops opioid withdrawal, treat symptomatically and do not administer XR-NTX. This step is recommended to minimize the likelihood of longer lasting precipitated withdrawal in patients given XR-NTX who took buprenorphine recently (naloxone may not displace it from opioid receptors). This step can help identify a naltrexone allergy before providing XR-NTX. If no withdrawal symptoms are present following the 25 mg naltrexone dose and XR-NTX is the desired course, administer XR-NTX as described above.

Adapted from material in the public domain. ^ 182 ^

#### Precautions and warnings

• Discuss the risks and benefits of continuing naltrexone with patients who become pregnant while receiving naltrexone treatment and whose OUD is in remission. Unlike methadone and buprenorphine, naltrexone has been little researched in pregnant populations.^174,175^
• Patients are vulnerable to opioid overdose death after completing the every-4-weeks or once-monthly dosing period, missing a dose, or stopping treatment. Trying to override opioid blockade with high opioid doses may cause overdose.
• Patients may experience injection site reactions including pain, tenderness, induration, swelling, erythema, bruising, or pruritus. Severe injection site reactions may occur (e.g., cellulitis, hematoma, abscess, sterile abscess, necrosis). Some cases may require surgical intervention and may result in significant scarring. (See the Chapter 3C Appendix for techniques to reduce injection site reactions). As with any IM injection, use caution in patients with thrombocytopenia or a coagulation disorder.
• Precipitated opioid withdrawal can occur in patients who used illicit opioids recently or switched from an opioid agonist medication. Symptoms may be severe enough for hospitalization. To avoid precipitated withdrawal from either formulation, patients should typically stop use of short-acting opioid agonists for 7 to 10 days and long-acting agonists for 10 to 14 days.^176^ There is active research on approaches to initiate XR-NTX more quickly for patients physically dependent on opioid agonists.^177^
• Hepatitis has been associated with XR-NTX, often in the presence of other potential causes of hepatic toxicity (e.g., alcohol liver disease, viral hepatitis). Monitor liver function tests during treatment. Stop naltrexone in the presence of acute hepatitis and severe liver disease.^178^ Initiate or refer patients to treatment for hepatitis.
• Use cautiously in patients with moderate-to-severe renal impairment, because the medication is eliminated primarily through the kidneys.
• Hypersensitivity reactions can occur, including rash, urticaria, angioedema, and anaphylaxis.
• Monitor patients with OUD for depression and suicidal ideation. Naltrexone use has been occasionally associated with dysphoria,^179^ although it's unclear whether this is a side effect of the medication or a manifestation of underlying depression or depressed mood related to OUD.^180^ Monitor patients for depression, which is common with OUD.
• If a patient needs emergency pain treatment, regional anesthesia or nonopioid analgesics are alternatives to opioid analgesics. A patient who must have opioids for pain treatment or anesthesia requires continuous monitoring in an anesthesia care setting.

#### Side effects

Possible side effects of XR-NTX include (see the FDA label for a complete list https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=cd11c435-b0f0-4bb9-ae78-60f101f3703f):^183^

• Insomnia.
• Injection site pain.
• Hepatic enzyme abnormalities.
• Nasopharyngitis.

#### Assessment

Thorough assessment helps determine whether naltrexone treatment is appropriate for a patient. (Part 2 of this Treatment Improvement Protocol [TIP] covers screening and assessment in more detail.)

Patients who have been abstinent from short-acting opioids (including tramadol) for 7 to 10 days or long-acting opioids (e.g., methadone, buprenorphine) for 10 to 14 days can initiate naltrexone following assessment that includes:

• Checking the state prescription drug monitoring program database.
• Taking the patient's history.
  - Conduct a medical, psychiatric, substance use, and substance use treatment history.
  - Assess recent opioid use, including frequency, quantity, type, route, and last day of use. Confirm an adequate opioid abstinence period.
  - Establish OUD diagnosis.
  - Assess for other SUDs, including those that involve alcohol, benzodiazepines, or stimulants.
• Conducting a physical exam.
  - Assess for signs and symptoms of intoxication. Do not give a first dose to a patient who is sedated or intoxicated. Assess and treat him or her appropriately.
  - Assess for evidence of opioid withdrawal and physiological dependence. The Clinical Opioid Withdrawal Scale (COWS) or the Clinical Institute Narcotic Assessment (CINA) Scale for Withdrawal Symptoms can be used to assess withdrawal signs (see “Resource Alert: Opioid Withdrawal Scales”). The patient should not exhibit any signs of opioid withdrawal before taking the first dose of naltrexone, to avoid precipitated withdrawal.
• Obtaining laboratory tests.
  - Conduct drug and alcohol tests. Use reliable urine tests for opioids (including morphine, methadone, buprenorphine, and oxycodone), benzodiazepines, cocaine, and other drugs commonly used in the area. Use a breathalyzer to estimate the patient's blood alcohol content.
  - Conduct a pregnancy test. Naltrexone is not recommended for OUD treatment in pregnancy. Refer pregnant patients to prenatal care.^184^
  - Assess liver function. Obtain liver function tests followed by periodic monitoring at 6- or 12-month intervals during treatment.^185^
  - Obtain kidney function tests (e.g., creatinine) for people who inject drugs.
  - Conduct hepatitis and HIV tests. Hepatitis B and C are common among patients entering naltrexone treatment. HIV infection is also prevalent. If possible, test the patient for these infections and refer to treatment as appropriate. The Centers for Disease Control and Prevention recommends hepatitis B vaccine for individuals seeking treatment for SUDs.^186^

RESOURCE ALERT

###### Opioid Withdrawal Scales

The COWS and other opioid withdrawal scales from Annex 10 of the World Health Organization's Guidelines for the Psychosocially Assisted Pharmacological Treatment of Opioid Dependence can be downloaded from the National Center for Biotechnology Information website (www.ncbi.nlm.nih.gov/books/NBK143183).

The CINA Scale for Withdrawal Symptoms is also available online (www.ncpoep.org/wp-content/uploads/2015/02/Appendix_7_Clinical_Institute_Narcotic_Assessment_CINA_Scale_for_Withdrawal_Symptoms.pdf).

During assessment, discuss with patients the risks and benefits of naltrexone and alternative treatment approaches. Explore patients’ motivation to initiate medication treatment and to adhere to the dosing regimen. Start naltrexone if the patient:

• Meets Diagnostic and Statistical Manual of Mental Disorders, Fifth Edition, criteria for OUD.
• Understands risks and benefits.
• Reports opioid abstinence for 7 to 10 days (short acting) or 10 to 14 days (long acting).
• Reports no allergies to naltrexone or the components of the XR-NTX preparation.
• Does not have a coagulation disorder.
• Will not soon require opioid analgesia.
• Has a negative pregnancy test.
• Has a negative urine opioid screen for morphine, methadone, buprenorphine, oxycodone, and other opioids.
• Is free of current opioid withdrawal signs and symptoms (Exhibit 3C.2).
• Has liver function test results that do not indicate acute hepatitis or liver failure.
• Has a negative naloxone challenge result (Exhibit 3C.1).

EXHIBIT 3C.2. Signs and Symptoms of Opioid Withdrawal

Signs | Symptoms
Runny nose | Skin crawling
Tearing | Abdominal cramps
Yawning | Temperature changes
Sweating | Nausea
Tremor | Vomiting
Vomiting | Diarrhea
Piloerection | Bone or muscle pain
Pupillary dilation | Dysphoria
| Craving for opioids

#### Patient selection

No evidence clearly predicts which patients are best treated with XR-NTX versus other OUD medications. A secondary analysis of the data from a randomized trial of XR-NTX versus placebo conducted in Russia found no significant baseline predictors of successes among the 25 variables examined, including demographics, clinical severity, level of functioning, craving, and HIV serostatus.^187^

Inform patients of all their treatment options and the settings in which they are available. OTPs may be best for patients needing more structure. Tailor decisions about which medication to use to patients’ medical and substance use histories, patient preferences, and treatment availability.

Pregnant women are not appropriate candidates for XR-NTX treatment.

Consider for XR-NTX treatment patients who: ^ 188 ^

• Do not wish to take opioid agonists.
• Have been opioid abstinent for at least 1 week, have recently been or will soon be released from controlled environments (e.g., incarceration, residential addiction treatment), and do not wish to initiate (or are not able to access) opioid agonist treatment. For patients requesting opioid agonist treatment, methadone or buprenorphine must be started at much lower doses and increased much more slowly than for opioid-tolerant patients (see sections on methadone and buprenorphine dosing).
• Have not responded well to prior adequate treatment with opioid agonist therapy.^189^
• Are part of an overall program with external monitoring and significant, immediate external consequences for lack of adherence. These patients (e.g., healthcare professionals, pilots, probationers, parolees) may show higher rates of retention with XR-NTX because of required external monitoring.^190^
• Have home locations or work schedules making daily or almost-daily OTP visits impossible or risky (e.g., job loss).

#### Informed consent

Inform all patients of the following basic information:

• Their OUD diagnosis and the nature of the disorder
• Risks and benefits of XR-NTX and other OUD medications
• Risks and benefits of nonmedication treatments

Consider asking patients to sign a treatment agreement form before starting treatment. (See Appendix 3C for a sample treatment agreement.) Document informed consent discussions in the medical record.

Educate patients and their families about what to expect from naltrexone treatment (Exhibit 3C.3). A naltrexone medication guide should be dispensed to patients with each injection. Caution them about increased risk of overdose if they stop treatment and return to illicit opioid use or attempt to override the receptor blockade of XR-NTX. Document education in the medical record. Chapter 3C Appendix has a patient education counseling tool for XR-NTX.

EXHIBIT 3C.3. Key Points of Patient Education for Naltrexone

• Do not use any opioids in the 7 to 10 days (for short acting) or 10 to 14 days (for long acting) before starting XR-NTX, to avoid potentially serious opioid withdrawal symptoms. Opioids include:
  - Heroin.
  - Prescription opioid analgesics (including tramadol).
  - Cough, diarrhea, or other medications that contain codeine or other opioids.
  - Methadone.
  - Buprenorphine.
• Seek immediate medical help if symptoms of allergic reaction or anaphylaxis occur, such as:
  - Itching.
  - Swelling.
  - Hives.
  - Shortness of breath.
  - Throat tightness.
• Do not try to override the opioid blockade with large amounts of opioids, which could result in overdose.
• Understand the risk of overdose from using opioids near the time of the next injection, after missing a dose, or after stopping medications.
• Report injection site reactions including:
  - Pain.
  - Hardening.
  - Lumps.
  - Blisters.
  - Blackening.
  - Scabs.
  - An open wound.
  Some of these reactions could require surgery to repair (rarely).
• Report signs and symptoms of hepatitis (e.g., fatigue, abdominal pain, yellowing skin or eyes, dark urine).
• Report depression or suicidal thoughts. Seek immediate medical attention if these symptoms appear.
• Seek medical help if symptoms of pneumonia appear (e.g., shortness of breath, fever).
• Inform providers of naltrexone treatment, as treatment differs for various types of pneumonia.
• Inform all healthcare professionals of XR-NTX treatment.
• Report pregnancy.
• Inform providers of any upcoming medical procedures that may require pain medication.
• Understand that taking naltrexone may result in difficulty achieving adequate pain control if acute medical illness or trauma causes severe acute pain.
• Wear medical alert jewelry and carry a medical alert card indicating you are taking XR-NTX. A patient wallet card or medical alert bracelet can be ordered at 1-800-848-4876.

Use language and written materials appropriate to each patient's comprehension level to ensure that he or she understands the options and can make informed decisions.

#### Initiating XR-NTX treatment

##### Storage and preparation

A pharmacy will send XR-NTX and its diluent in a refrigerated package with two sets of administration needles (1.5 and 2 inches), a 1-inch preparation needle, and a needle protection device.

The XR-NTX microspheres are temperature sensitive. When the carton arrives from the pharmacy, store it in a refrigerator at 36 to 46 degrees Fahrenheit (2 to 8 degrees Celsius). The refrigerator should have a working thermometer; check the temperature regularly.

Do not freeze the carton or expose it to temperatures above 77 degrees Fahrenheit (25 degrees Celsius). XR-NTX can be stored unrefrigerated for up to 7 days before administration.

Before preparing XR-NTX for administration, keep it at room temperature for about 45 minutes. Examine the microspheres and diluent to ensure that no particulate matter or discoloration are present. Mix following FDA-approved package insert directions, using the 1-inch preparation needle. Resulting suspension should be milky white, without clumps, and able to move freely down the wall of the vial.

Two sets of needles of two different lengths are shipped with the medication in case the first needle clogs before injection. Use the 1.5-inch needle for lean patients and the 2-inch needle for patients with more subcutaneous tissue overlying the gluteal muscle. The longer needle helps ensure that the injection reaches the muscle. Inject patients with average body habitus with either needle.

##### Administration

Administer XR-NTX every 4 weeks or once a month as a 380 mg IM gluteal injection. Alternate buttocks for each 4-week injection. Given the risk of severe injection site reactions, FDA requires a risk evaluation and mitigation strategy (www.vivitrolrems.com) for XR-NTX including a patient counseling tool, a patient medication guide, and a visual aid to reinforce proper XR-NTX injection technique.

##### Follow-up care after first dose

Examine patients within a week of administering their first XR-NTX dose. It can be clinically beneficial to maintain weekly contact in the first month to:

• Provide supportive counseling.
• Assess ongoing drug or alcohol use.
• Monitor side effects.
• Obtain drug testing.
• Follow up on status of referrals to counseling or other services.

Patients who test the opioid blockade of XR-NTX may discontinue use because of the blocking of the euphoric effects of illicit opioids.^191^ Patients who miss a dose can restart medication (use procedures outlined earlier in this section) after an adequate period of opioid abstinence (7 to 14 days).

The TIP expert panel cautions that, based on current data, arbitrary time limits on XR-NTX are inappropriate.

See Chapter 3E for information on the management of patients taking naltrexone in office-based treatment settings.

#### Duration of treatment

Barring contraindications, patients should continue taking XR-NTX as long as they benefit from it and want to continue. Data are limited on the long-term effectiveness of XR-NTX compared with methadone or buprenorphine.

##### Treatment discontinuation

When patients wish to discontinue naltrexone, engage in shared decision making and explore:

• Their reasons for wanting to discontinue.
• The risks and benefits of discontinuing.
• Problem-solving strategies that can help them make an informed choice.
• Their appropriateness for buprenorphine or methadone treatment.

Discourage patients who are not yet stable from discontinuing treatment, because of the high rate of return to illicit opioid use and the increased chance of overdose death.

Signs that a patient may be ready to discontinue medication include:^192^

• Sustaining illicit drug abstinence over time.
• Having stable housing and income.
• Having no legal problems.
• Having substantially reduced craving.
• Attending counseling or mutual-help groups.

RESOURCE ALERT

###### Patient and Family Educational Resources

Decisions in Recovery: Treatment for Opioid Use Disorder offers information for patients on the use of medications for OUD (https://store.samhsa.gov/product/SMA16-4993)

Medication-Assisted Treatment for Opioid Addiction: Facts for Families and Friends offers information for family and friends (www.ct.gov/dmhas/lib/dmhas/publications/MAT-InfoFamilyFriends.pdf)

Patients who discontinue should have a recovery plan that may include monitoring as well as adjunctive counseling and recovery support. If they return to opioid use, encourage them to return for assessment and reentry into treatment.

Given the high risk of return to illicit opioid use, offer patients information about opioid overdose prevention and a naloxone prescription they can use in case of overdose. When patients stop using naltrexone, they will have no tolerance for opioids. Their risk of overdose is very high if they use again. For more information, see the SAMHSA Opioid Overdose Prevention Toolkit (https://store.samhsa.gov/shin/content//SMA16-4742/SMA16-4742.pdf).

##### Rapid naltrexone induction

Patients with OUD need to discontinue opioids and wait 7 to 14 days after last opioid use (including any given for withdrawal treatment) before receiving XR-NTX. As described above, they can do so through medically supervised withdrawal in a controlled environment, such as an inpatient unit, residential addiction treatment program, correctional facility, or hospital, or on an outpatient basis.

Financial issues and managed care constraints may influence patients’ access to controlled treatment environments. The alternative—abstaining long enough after outpatient medically supervised withdrawal—is challenging. Thus, various approaches to rapid naltrexone induction have been developed^193^ and more recently refined in research settings.^194,195,196^

Consider rapid induction in specialty addiction treatment programs, not general medical settings. It may be hard for providers in general medical settings to start XR-NTX successfully with patients who need medically supervised opioid withdrawal. Rapid induction approaches are likely beyond the scope of general outpatient settings. However, patients can successfully initiate XR-NTX in a general outpatient medical setting if they:

• Have been abstinent for sufficient time and pass the naloxone challenge.
• Started taking XR-NTX elsewhere and are due for the next injection.

One randomized trial compared two approaches to starting XR-NTX on an outpatient basis. This study assigned adults dependent on opioids to either a standard 14-day buprenorphine-assisted opioid withdrawal or more rapid 7-day oral naltrexone-assisted opioid withdrawal.^197^ Naltrexone-assisted withdrawal was conducted over 7 days. It included 1 day of buprenorphine administration; 1 day with ancillary medications including clonidine and clonazepam but no buprenorphine; followed by 4 days of ancillary medications and increasing daily doses of oral naltrexone (starting with 1 mg, 3 mg, 12 mg, and 25 mg); and concluding on day 7 with XR-NTX administration. Buprenorphine-assisted withdrawal consisted of a 7-day buprenorphine taper followed by the recommended 7 days without opioids. The naltrexone-assisted withdrawal group was significantly more likely to begin XR-NTX compared with the buprenorphine-assisted withdrawal group (56.1 percent versus 32.7 percent, respectively). This type of approach, which must be conducted with careful daily monitoring, is used in some residential programs and may prove to be a useful approach to outpatient XR-NTX induction in specialty programs. More discussion on rapid induction approaches is available in Implementing Antagonist-Based Relapse Prevention Treatment for Buprenorphine-Treated Individuals,^198^ available online (http://pcssmat.org/wp-content/uploads/2015/02/PCSSMAT-Implementing-Antagonist-with-Case.Bisaga.CME_.pdf).

### Oral Naltrexone

The effectiveness of oral naltrexone is limited, given poor adherence and the requirement of 7 to 14 days of opioid abstinence before initiation. During this waiting period, patients may drop out of care. One study found significantly lower patient retention in treatment after incarceration for patients treated with oral naltrexone compared with methadone.^199^

Oral naltrexone blocks opioid-induced euphoria for only a day or two. When patients stop taking it, risks of return to opioid use and overdose increase.

The TIP expert panel doesn't recommend using oral naltrexone except in the limited circumstances described in the following sections. This view is in keeping with expert reviews for the United Kingdom's National Health Service,^200^ a clinical practice guideline published by the Department of Veterans Affairs and Department of Defense,^201^ and a Cochrane review.^202^

#### Indications and contraindications, precautions and warnings, side effects, and assessment.

All are similar to those for XR-NTX, save issues specific to suspension/diluent contents and the injection itself.

### Patient Selection

In limited circumstances, oral naltrexone may be considered after the risks and benefits, as well as alternative treatments, are discussed with the patient. Examples include:

• Patients who cannot afford XR-NTX but wish to take an opioid receptor antagonist.
• Patients with high levels of monitoring and negative consequences for nonadherence, such as healthcare professionals who may not be permitted to have opioid agonist treatment.^203,204^
• Patients leaving controlled environments (e.g., prisons, hospitals, inpatient addiction rehabilitation) who may benefit from medication to prevent return to illicit drug use but cannot or will not take XR-NTX and do not wish to be treated with (or do not have access to) opioid agonists.

The TIP expert panel does not recommend that payers require patients to fail oral naltrexone before providing access to XR-NTX, given the risk of unintentional overdose death if the patient returns to illicit opioid use.

Patients who have taken methadone or extensively used heroin are especially poor oral naltrexone candidates.^205^

#### Dosing

Following a negative naloxone challenge, the first oral dose of naltrexone can be 25 mg (half of the usual daily naltrexone maintenance dose). This reduces risk of a more severe precipitated opioid withdrawal than could occur with a full 50 mg dose. This lower dose may also reduce nausea associated with the first naltrexone dose. The dose can be increased to 50 mg daily on the second day.

To increase adherence, arrange for directly observed administration of oral naltrexone. This is more feasible if patients who tolerate a daily dose of 50 mg are switched to a 3-days-per-week regimen for a total weekly dose of 350 mg (e.g., administer 100 mg on Monday and Wednesday and 150 mg on Friday). A member of the patient's social network (e.g., spouse) may also directly observe therapy.

#### Duration of treatment

The optimal length of treatment with oral naltrexone is not known. In general, the longer patients take an effective medication, the better their outcomes.

Use of illicit opioids during treatment with oral naltrexone is a cause of concern and may be a precursor to treatment discontinuation.^206^ Some patients will initially test the opioid blockade with illicit opioids and then discontinue opioid use. However, others will continue using illicit opioids.^207^

If patients continue to test the blockade, immediately discuss alternative treatment plans that include:

• Increased counseling.
• Switching to XR-NTX.
• Closer monitoring.
• Directly observed oral naltrexone therapy.
• Residential treatment.
• Assessment for the appropriateness of buprenorphine or methadone.

## Naltrexone Dosing Summary

### XR-NTX

• Before administering XR-NTX, keep it at room temperature for about 45 minutes.
• Use the correct needle length to ensure the injection is in the gluteal muscle.
  - Use the 2-inch needle for patients with more subcutaneous tissue and the 1.5-inch needle for patients with less adipose tissue.
  - Use either length in patients with normal body habitus.
• Use proper aseptic technique.
• Use proper gluteal IM injection technique.
• Never inject intravenously or subcutaneously.
• Repeat the injection every 4 weeks or once per month.

### Oral Naltrexone

• Use in limited circumstances after discussing risks and benefits, as well as alternative treatment options, with the patient.
• Do the naloxone challenge.
• The first oral naltrexone dose should be 25 mg.
• The dose can be increased on the second day to 50 mg daily if necessary.
• If desired, switch patients who tolerate a daily dose of 50 mg to a 3-days-per-week regimen for a total weekly dose of 350 mg.

## Chapter 3C Appendix

Sample XR-NTX Treatment Agreement

Patient Counseling Tool for XR-NTX

### Key Techniques for Reducing Injection Site Reactions^210^

To reduce severe injection site reactions when administering XR-NTX via intramuscular injection, use the following techniques:

• Use one of the administration needles provided with the XR-NTX kit to ensure that the injection reaches the gluteal muscle. Use the 2-inch needle for patients who have more subcutaneous adipose tissue. Use the 1.5-inch needle for patients with less subcutaneous adipose tissue. Either needle is appropriate for use with patients who have average amounts of subcutaneous adipose tissue.
• Use aseptic technique when administering intramuscularly. Using a circular motion, clean the injection site with an alcohol swab. Let the area dry before administering the injection. Do not touch this area again before administration.
• Use proper deep intramuscular injection technique into the gluteal muscle. XR-NTX must not be injected intravenously, subcutaneously, or into adipose tissue. Accidental subcutaneous injection may increase the risk of severe injection site reactions.
  - Administer the suspension by deep intramuscular injection into the upper outer quadrant of gluteal muscle, alternating buttocks per monthly injection.
  - Remember to aspirate for blood before injection. If blood aspirates or the needle clogs, do not inject. Change to the spare needle provided in the package and administer into an adjacent site in the same gluteal region, again aspirating for blood before injection.
  - Inject the suspension in a smooth, continuous motion.

A patient counseling tool is available to help you counsel your patients before administration about the serious risks associated with XR-NTX.

The above information is a selection of key safety information about the XR-NTX injection. For complete safety information, refer to the directions for use and the prescribing information provided in the medication kit. You can also obtain this information online (www.vivitrolrems.com) or by calling 1-800-VIVITROL.

Available online (www.vivitrolrems.com/content/pdf/patinfo-injection-poster.pdf).