# Part 3 Pharmacotherapy for Opioid Use Disorder

For Healthcare Professionals

Part 3 of this Treatment Improvement Protocol (TIP) describes general principles of opioid use disorder (OUD) pharmacotherapy and discusses medication formulations, indications, and dosing for the three medications used to treat OUD—methadone, naltrexone, and buprenorphine.

KEY MESSAGES

• OUD medications are safe and effective when used appropriately.
• OUD medications can help patients reduce or stop illicit opioid use and improve their health and functioning.
• Pharmacotherapy should be considered for all patients with OUD. Reserve opioid pharmacotherapies for those with moderate-to-severe OUD with physical dependence.
• Patients with OUD should be informed of the risks and benefits of pharmacotherapy, treatment without medication, and no treatment.
• Patients should be advised on where and how to get treatment with OUD medication.
• Doses and schedules of pharmacotherapy must be individualized.

Part 3 of this TIP describes general principles of OUD pharmacotherapy and discusses medication formulations, indications, and dosing for the three Food and Drug Administration (FDA)-approved medications used to treat OUD—methadone, naltrexone, and buprenorphine. Part 3 also discusses patient management and monitoring in outpatient settings other than opioid treatment programs (OTPs) as well as medical management of patients with OUD in hospital settings.

## Scope of the Problem

The United States is experiencing an opioid addiction epidemic.^1^ In 2016, an estimated 2.1 million Americans had OUD.^2^ Illicit opioid use contributes to the development of OUD, the spread of HIV and hepatitis infections, and increasing numbers of overdose deaths.

OUD is a set of cognitive, behavioral, and physiological symptoms marked by an inability to stop opioid use despite negative consequences.^3^ When severe, it can present as a chronic, recurring condition with compulsive opioid use that is often termed “addiction.” It can cause serious physical and mental health, employment, legal, and family problems.

Each FDA-approved medication used to treat OUD can help patients achieve remission and begin or maintain recovery. Pharmacotherapy for OUD should be accompanied by individually tailored medical management and psychosocial and recovery support services as needed and wanted by patients to support their remission and recovery.

OPIOID-RELATED EMERGENCY DEPARTMENT visits nearly doubled from 2005–2014.^4^

Image of a hospital gurney. Text reads: Opioid-related emergency department visits nearly doubled from 2005 to 2014.4

Medication supports the efforts of the individual to achieve lasting recovery.

Exhibit 3.1 defines key terms in Part 3. For more definitions, see the glossary in Part 5 of this TIP.

NOTE TO HEALTHCARE PROFESSIONALS

This TIP cannot replace sound clinical judgment and shared decision making based on careful patient assessment. Providers should familiarize themselves with FDA labeling of all OUD medications and current practices standards described here and in other resources such as the Providers' Clinical Support System (https://pcssmat.org).

EXHIBIT 3.1. Key Terms

Addiction: As defined by the American Society of Addiction Medicine,^5^ “a primary, chronic disease of brain reward, motivation, memory, and related circuitry.” It is characterized by inability to consistently abstain, impairment in behavioral control, craving, diminished recognition of significant problems with one's behaviors and interpersonal relationships, and a dysfunctional emotional response. Like other chronic diseases, addiction often involves cycles of relapse and remission. The Diagnostic and Statistical Manual of Mental Disorders, Fifth Edition,^6^ does not use the term for diagnostic purposes, but it commonly describes the more severe forms of OUD.

Induction: Process of initial dosing with medication for OUD treatment until the patient reaches a state of stability; also called initiation.

Maintenance treatment: Providing medications to achieve and sustain clinical remission of signs and symptoms of OUD and support the individual process of recovery without a specific endpoint (as is the typical standard of care in medical and psychiatric treatment of other chronic illnesses).

Medically supervised withdrawal (formerly called detoxification): Using an opioid agonist (or an alpha-2 adrenergic agonist if opioid agonist is not available) in tapering doses or other medications to help a patient discontinue illicit or prescription opioids.

Medical management: Process whereby healthcare professionals provide medication, basic brief supportive counseling, monitoring of drug use and medication adherence, and referrals, when necessary, to addiction counseling and other services to address the patient's medical, mental health, comorbid addiction, and psychosocial needs.

Office-based opioid treatment: Providing medication for OUD in outpatient settings other than certified OTPs.

Opioid treatment program (OTP): An accredited treatment program with Substance Abuse and Mental Health Services Administration certification and Drug Enforcement Administration registration to administer and dispense opioid agonist medications that are approved by FDA to treat opioid addiction. Currently, these include methadone and buprenorphine products. Other pharmacotherapies, such as naltrexone, may be provided but are not subject to these regulations. OTPs must provide adequate medical, counseling, vocational, educational, and other assessment and treatment services either onsite or by referral to an outside agency or practitioner through a formal agreement.^7^

Key Terms Related to OUD Medication Pharmacology

Abuse liability: The likelihood that a medication with central nervous system activity will cause desirable psychological effects, such as euphoria or mood changes, that promote the medication's misuse.

Bioavailability: Proportion of medication administered that reaches the bloodstream.

Cross-tolerance: Potential for people tolerant to one opioid (e.g., heroin) to be tolerant to another (e.g., methadone).

Dissociation: Rate at which a drug uncouples from the receptor. A drug with a longer dissociation rate will have a longer duration of action than a drug with a shorter dissociation rate.

Half-life: Rate of removal of a drug from the body. One half-life removes 50 percent from the plasma. After a drug is stopped, it takes five half-lives to remove about 95 percent from the plasma. If a drug is continued at the same dose, its plasma level will continue to rise until it reaches steady-state concentrations after about five half-lives.

Intrinsic activity: The degree of receptor activation attributable to drug binding. Full agonist, partial agonist, and antagonist are terms that describe the intrinsic activity of a drug.

Opiates: A subclass of opioids derived from opium (e.g., morphine, codeine, thebaine).

Opioid blockade: Blunting or blocking of the euphoric effects of an opioid through opioid receptor occupancy by an opioid agonist (e.g., methadone, buprenorphine) or antagonist (e.g., naltrexone).

Opioid receptor agonist: A substance that has an affinity for and stimulates physiological activity at cell receptors in the nervous system that are normally stimulated by opioids. Mu-opioid receptor full agonists (e.g., methadone) bind to the mu-opioid receptor and produce actions similar to those produced by the endogenous opioid beta-endorphin. Increasing the dose increases the effect. Mu-opioid receptor partial agonists (e.g., buprenorphine) bind to the mu-opioid receptor. Unlike with full agonists, increasing their dose in an opioid-tolerant individual may not produce additional effects once they have reached their maximal effect. At low doses, partial agonists may produce effects similar to those of full agonists. Methadone and buprenorphine can blunt or block the effects of exogenously administered opioids.

Opioid receptor antagonist: A substance that has an affinity for opioid receptors in the central nervous system without producing the physiological effects of opioid agonists. Mu-opioid receptor antagonists (e.g., naltrexone) can block the effects of exogenously administered opioids.

Opioids: All natural, synthetic, and semisynthetic substances that have effects similar to morphine. They can be used as medications having such effects (e.g., methadone, buprenorphine, oxycodone).

Receptor affinity: Strength of the bond between a medication and its receptor. A medication with high mu-opioid receptor affinity requires lower concentrations to occupy the same number of mu-opioid receptors as a drug with lower mu-opioid receptor affinity. Drugs with high mu-opioid receptor affinity may displace drugs with lower affinity.