# Part 2 Addressing Opioid Use Disorder in General Medical Settings

For Healthcare Professionals

Part 2 of this Treatment Improvement Protocol (TIP) will guide practitioners’ efforts to identify, assess, and treat or refer patients with opioid use disorder (OUD) in general medical settings.

KEY MESSAGES

• All healthcare practices should screen for alcohol, tobacco, and other substance misuse (including opioid misuse).
• Validated screening tools, symptom surveys, and other resources are readily available; this part lists many of them.
• When patients screen positive for risk of harm from substance use, practitioners should assess them using tools that determine whether substance use meets diagnostic criteria for a substance use disorder (SUD).
• Thorough assessment should address patients’ medical, social, SUD, and family histories.
• Laboratory tests can inform treatment planning.
• Practitioners should develop treatment plans or referral strategies (if onsite SUD treatment is unavailable) for patients who need SUD treatment.

Part 2 of this TIP is for healthcare professionals who work in general medical settings^*^ and care for patients who misuse opioids or have OUD. Healthcare professionals in such settings address most personal healthcare needs, develop sustained partnerships with patients, and practice in the context of family and community. Thus, they have a good basis from which to understand patients’ needs related to OUD screening, assessment, and treatment (or referral to specialty treatment.

* In this TIP, the term “general medical setting” includes medical clinics, community health centers, and private practices.

## Scope of the Problem

The number of patients presenting with OUD in medical clinics, community health centers, and private practices is increasing. Healthcare professionals in these general settings are in an important position to identify, assess, and treat OUD or to refer patients for treatment. Moreover, patients who are medically and mentally stable can benefit from receiving OUD medications in integrated care settings, where they often have already established therapeutic relationships with their healthcare providers.

Exhibit 2.1 defines key terms in Part 2. For more definitions, see the glossary in Part 5 of this TIP.

EXHIBIT 2.1. Key Terms

Addiction: As defined by the American Society of Addiction Medicine (ASAM),^3^ “a primary, chronic disease of brain reward, motivation, memory, and related circuitry.” It is characterized by inability to consistently abstain, impairment in behavioral control, craving, diminished recognition of significant problems with one's behaviors and interpersonal relationships, and a dysfunctional emotional response. Like other chronic diseases, addiction often involves cycles of relapse and remission. The Diagnostic and Statistical Manual of Mental Disorders, Fifth Edition^4^ (DSM-5), does not use the term for diagnostic purposes, but it commonly describes the more severe forms of OUD.

Healthcare professionals: Physicians, nurse practitioners (NPs), physician assistants (PAs), and other medical service professionals who are eligible to prescribe medications for and treat patients with OUD. The term “prescribers” also refers to these healthcare professionals.

Maintenance treatment: Providing medications to achieve and sustain clinical remission of signs and symptoms of OUD and support the individual process of recovery without a specific endpoint (as with the typical standard of care in medical and psychiatric treatment of other chronic illnesses).

Medically supervised withdrawal (formerly called detoxification): Using an opioid agonist (or an alpha-2 adrenergic agonist if an opioid agonist is not available) in tapering doses or other medications to help a patient discontinue illicit or prescription opioids.

Medical management: Process whereby healthcare professionals provide medication, basic brief supportive counseling, monitoring of drug use and medication adherence, and referrals, when necessary, to addiction counseling and other services to address the patient's medical, mental health, comorbid addiction, and psychosocial needs.

Office-based opioid treatment (OBOT): Providing medication for OUD in outpatient settings other than certified opioid treatment programs (OTPs).

Opioid misuse: The use of prescription opioids in any way other than as directed by a prescriber; the use of any opioid in a manner, situation, amount, or frequency that can cause harm to self or others.^5^

Opioid receptor agonist: A substance that has an affinity for and stimulates physiological activity at cell receptors in the central nervous system that are normally stimulated by opioids. Mu-opioid receptor full agonists (e.g., methadone) bind to the mu-opioid receptor and produce actions similar to those produced by the endogenous opioid beta-endorphin. Increasing the dose increases the effect. Mu-opioid receptor partial agonists (e.g., buprenorphine) bind to the mu-opioid receptor. Unlike with full agonists, increasing their dose may not produce additional effects once they have reached their maximal effect. At low doses, partial agonists may produce effects similar to those of full agonists.

Opioid receptor antagonist: A substance that has an affinity for opioid receptors in the central nervous system without producing the physiological effects of opioid agonists. Mu-opioid receptor antagonists (e.g., naltrexone) can block the effects of exogenously administered opioids.

Opioid treatment program (OTP): An accredited treatment program with Substance Abuse and Mental Health Services Administration (SAMHSA) certification and Drug Enforcement Administration (DEA) registration to administer and dispense opioid agonist medications that are approved by the Food and Drug Administration (FDA) to treat opioid addiction. Currently, these include methadone and buprenorphine products. Other pharmacotherapies, such as naltrexone, may be provided but are not subject to these regulations. OTPs must provide adequate medical, counseling, vocational, educational, and other assessment and treatment services either onsite or by referral to an outside agency or practitioner through a formal agreement.^6^

Opioid use disorder (OUD): Per DSM-5,^7^ a disorder characterized by loss of control of opioid use, risky opioid use, impaired social functioning, tolerance, and withdrawal. Tolerance and withdrawal do not count toward the diagnosis in people experiencing these symptoms when using opioids under appropriate medical supervision. OUD covers a range of severity and replaces what the Diagnostic and Statistical Manual of Mental Disorders, Fourth Edition, termed “opioid abuse” and “opioid dependence.” An OUD diagnosis is applicable to a person who uses opioids and experiences at least 2 of the 11 symptoms in a 12-month period. (See Exhibit 2.13 and the Appendix in Part 2 for full DSM-5 diagnostic criteria for OUD.)

Recovery: A process of change through which individuals improve their health and wellness, live a self-directed life, and strive to reach their full potential. Even individuals with severe and chronic SUDs can, with help, overcome their SUDs and regain health and social function. Although abstinence from all substance misuse is a cardinal feature of a recovery lifestyle, it is not the only healthy, prosocial feature. Patients taking FDA-approved medication to treat OUD can be considered in recovery.

Relapse: A process in which a person with OUD who has been in remission experiences a return of symptoms or loss of remission. A relapse is different from a return to opioid use in that it involves more than a single incident of use. Relapses occur over a period of time and can be interrupted. Relapse need not be long lasting. The TIP uses relapse to describe relapse prevention, a common treatment modality.

Remission: A medical term meaning a disappearance of signs and symptoms of the disease.^8^ DSM-5 defines remission as present in people who previously met OUD criteria but no longer meet any OUD criteria (with the possible exception of craving).^9^ Remission is an essential element of recovery.

Return to opioid use: One or more instances of opioid misuse without a return of symptoms of OUD. A return to opioid use may lead to relapse.

Tolerance: Alteration of the body's responsiveness to alcohol or other drugs (including opioids) such that higher doses are required to produce the same effect achieved during initial use. See also medically supervised withdrawal.

EXHIBIT 2.13. DSM-5 Criteria for OUD^72^

A problematic pattern of opioid use leading to clinically significant impairment or distress, as manifested by at least two of the following, occurring within a 12-month period:

1. Opioids are often taken in larger amounts or over a longer period of time than was intended.
2. There is a persistent desire or unsuccessful efforts to cut down or control opioid use.
3. A great deal of time is spent in activities to obtain the opioid, use the opioid, or recover from its effects.
4. Craving, or a strong desire or urge to use opioids.
5. Recurrent opioid use resulting in a failure to fulfill major role obligations at work, school, or home.
6. Continued opioid use despite having persistent or recurrent social or interpersonal problems caused by or exacerbated by the effects of opioids.
7. Important social, occupational, or recreational activities are given up or reduced because of opioid use.
8. Recurrent opioid use in situations in which it is physically hazardous.
9. Continued opioid use despite knowledge of having a persistent or recurrent physical or psychological problem that's likely to have been caused or exacerbated by the substance.
10. Tolerance,^*^ as defined by either of the following:
  a. A need for markedly increased amounts of opioids to achieve intoxication or desired effect
  b. A markedly diminished effect with continued use of the same amount of an opioid
11. Withdrawal,^*^ as manifested by either of the following:
  a. The characteristic opioid withdrawal syndrome
  b. The same—or a closely related—substance is taken to relieve or avoid withdrawal symptoms

* This criterion is not met for individuals taking opioids solely under appropriate medical supervision.

Severity: mild = 2–3 symptoms; moderate = 4–5 symptoms; severe = 6 or more symptoms

## Screening

Screening can identify patients who may have diseases or conditions related to their substance use. Health care in general medical settings routinely includes screening for common, treatable conditions such as cancer that are associated with significant morbidity and mortality. Screening for SUDs is important, as misuse of alcohol, tobacco, and other substances is common among patients in medical settings (Exhibit 2.2).^1^

EXHIBIT 2.2. Substance Misuse and SUD Screening

Exhibit 2.2. Substance Misuse and SUD Screening This exhibit shows a decision tree with “Substance misuse screening” as the start point. The two options are negative or positive. If negative is selected, the next step is to “Reinforce healthy behavior.” If positive is selected, the next step is to “Assess substance use and comorbidities” followed by two options. One path flows from “Substance misuse,” to “Brief counseling,” to “Monitoring/follow-up,” and ends with, “If misuse continues, negotiate a plan and refer to treatment.” The other path begins with “Substance use disorder,” to “Brief counseling and treatment referral,” to “Consider pharmacotherapy,” and ends with “Ongoing assessment and support.” Adapted with permission.15

Adapted with permission.^15^

An estimated 1.9M AMERICANS have OUD related to opioid painkillers; 589k, related to heroin.^2^

Image of pills falling out of an open medicine bottle. Text reads: An estimated 1.9 million Americans have OUD related to opioid painkillers; 589K, related to heroin.2

Screening can identify substance misuse in patients who wouldn't otherwise discuss it or connect it with the negative consequences they're experiencing. Some patients may spontaneously reveal their substance use and ask for help. This is more likely when they're experiencing harmful consequences of substance use. However, screening may identify unhealthy substance use (e.g., binge drinking) and SUDs before patients connect their substance use with their presenting complaint. Screening is also helpful when patients feel ashamed or afraid to reveal their concerns spontaneously.

The TIP expert panel recommends that healthcare professionals screen patients for alcohol, tobacco, prescription drug, and illicit drug use at least annually.

Every medical practice should determine which screening tools to use and when, how, and by whom they will be administered. Each practice should also identify steps to take when a patient screens positive. One efficient workflow strategy is to have clinical assistants or nurses administer the screening instrument in an interview or provide patients with a paper or computer tablet version for self-administration. (Self-administration is generally as reliable as interviewer administration.)^10^ Providers should be nonjudgmental and rely on established rapport when discussing screening results with patients. The following sections summarize reliable screening tools. (See Part 5 for more resources.)

### Alcohol Screening

Screening for alcohol misuse can identify patients at increased risk for opioid use. When screening patients for opioid misuse, providers should also screen for alcohol misuse and alcohol use disorder (AUD), which cause considerable morbidity and mortality.^11^ Providers should warn patients who use opioids that alcohol may increase opioid overdose risk.^12^ The U.S. Preventive Services Task Force (USPSTF) recommends screening adults for alcohol misuse, including risky drinking and AUD. USPSTF also recommends brief counseling for patients with risky drinking.^13,14^

USPSTF recommends the following alcohol screeners:
• The single-item National Institute on Alcohol Abuse and Alcoholism (NIAAA) Screener is the briefest tool available (Exhibit 2.3). It can help distinguish at-risk patients who require further screening from those not at risk for AUD. Encourage patients in the latter category to maintain healthy behavior.
• The Alcohol Use Disorders Identification Test (AUDIT)^16^ or its briefer version, the AUDIT-Consumption,^17^ can elicit more information from patients who screen positive on the single-item screener. The full AUDIT tool (Exhibit 2.4) and its briefer version have demonstrated acceptable reliability in AUD screening.^18^ Assess patients with positive screens for AUD.

EXHIBIT 2.3. NIAAA Single-Item Screener

How many times in the past year have you had five or more drinks in a day (four drinks for women and all adults older than age 65)?

One or more times constitutes a positive screen. Patients who screen positive should have an assessment for AUD.

Adapted with permission.^20^

EXHIBIT 2.4. AUDIT Screener

Skip to Questions 9 and 10 if total score for Questions 2 and 3 = 0

1.

How often do you have a drink containing alcohol?

0

Never [Skip to Questions 9–10]

1

Monthly or less

2

2 to 4 times a month

3

2 to 3 times a week

4

4 or more times a week

2.

How many drinks containing alcohol do you have on a typical day when you are drinking?

0

1 or 2

1

3 or 4

2

5 or 6

3

7, 8, or 9

4

10 or more

3.

How often do you have six or more drinks on one occasion?

0

Never

1

Less than monthly

2

Monthly

3

Weekly

4

Daily or almost daily

4.

How often during the last year have you found that you were not able to stop drinking once you had started?

0

Never

1

Less than monthly

2

Monthly

3

Weekly

4

Daily or almost daily

5.

How often during the last year have you failed to do what was normally expected from you because of drinking?

0

Never

1

Less than monthly

2

Monthly

3

Weekly

4

Daily or almost daily

6.

How often during the last year have you needed an alcoholic drink first thing in the morning to get yourself going after a night of heavy drinking?

0

Never

1

Less than monthly

2

Monthly

3

Weekly

4

Daily or almost daily

7.

How often during the last year have you had a feeling of guilt or remorse after drinking?

0

Never

1

Less than monthly

2

Monthly

3

Weekly

4

Daily or almost daily

8.

How often during the last year have you been unable to remember what happened the night before because you had been drinking?

0

Never

1

Less than monthly

2

Monthly

3

Weekly

4

Daily or almost daily

9.

Have you or someone else been injured as a result of your drinking?

(0)

No

(2)

Yes, but not in the last year

(4)

Yes, during the last year

10.

Has a relative, friend, doctor, or another health professional expressed concern about your drinking or suggested you cut down?

(0)

No

(2)

Yes, but not in the last year

(4)

Yes, during the last year

Note: Add up the points associated with answers. A score of 8 or more is considered a positive test for unhealthy drinking.

Adapted from material in the public domain.^35^ Available online (http://auditscreen.org).

Practitioners should consider pharmacotherapy and referral for counseling for people with AUD. The three FDA-approved medications to treat AUD—acamprosate, disulfiram, and naltrexone (oral and extended-release injectable naltrexone [XR-NTX])—can be prescribed in general medical and specialty SUD treatment settings. (For more information on AUD treatment, see the SAMHSA/NIAAA publication Medication for the Treatment of Alcohol Use Disorder: A Brief Guide.)^19^

### Tobacco Screening

More than 80 percent of patients who are opioid dependent smoke cigarettes.^21^ Understanding of the major health consequences and risks associated with tobacco use has grown significantly over the past 50 years. Among preventable causes of premature death, smoking remains most prevalent, with more than 480,000 deaths per year in the United States.^22^ In addition, more than 40 percent of all people who smoke are mentally ill or have SUDs.^23,24^

USPSTF recommends that primary care providers screen for tobacco use, advise patients to quit, and provide counseling and FDA-approved medications for tobacco cessation.^25^ The six-item Fagerström Test for Nicotine Dependence^26^ assesses cigarette use and nicotine dependence. The maximum score is 10; the higher the total score, the more severe the patient's nicotine dependence. The two-item Heaviness of Smoking Index (Exhibit 2.5) is also useful.^27^

EXHIBIT 2.5. Heaviness of Smoking Index

Ask these two questions of current or recent smokers:

1. How soon after waking do you smoke your first cigarette?
  • Within 5 minutes (3 points)
  • 5–30 minutes (2 points)
  • 31–60 minutes (1 point)
  • 61 or more minutes (no points)
2. How many cigarettes a day do you smoke?
  • 10 or less (no points)
  • 11–20 (1 point)
  • 21–30 (2 points)
  • 31 or more (3 points)

Total score:

1–2 points = very low dependence

3 points = low to moderate dependence

4 points = moderate dependence

5 or more points = high dependence

Adapted with permission.^36^

### Drug Screening

Screening for illicit drug use and prescription medication misuse is clinically advantageous. USPSTF's position as of this writing is that insufficient evidence exists to recommend for or against routine screening for illicit drug use in primary care.^28^ However, there are clinical reasons to screen for prescription medication misuse and use of illicit substances. Identifying misuse of prescription or illegal drugs can prevent harmful drug interactions, lead to adjustments in prescribing practices, improve medical care adherence, and increase the odds of patients getting needed interventions or treatment.^29^

Brief screening instruments for drug use can determine which patients need further assessment. Providers should reinforce healthy behaviors among patients who report “no use” and direct those who report “some use” for further screening and assessment to obtain a diagnosis.

Several brief screening instruments for drug use can help primary care practitioners identify patients who use drugs.^30,31^ For example, a single-item screen is available for the general public (Exhibit 2.6).^32^ A two-item valid screener is available for use with U.S. veterans (Exhibit 2.7).^33^

EXHIBIT 2.6. Single-Item Drug Screener

How many times in the past year have you used an illegal drug or a prescription medication for nonmedical reasons?

(A positive screen is 1 or more days.)

Reprinted with permission.^39^

EXHIBIT 2.7. Two-Item Drug Use Disorder Screener for Primary Care Clinics Serving U.S. Veterans

Question 1: How many days in the past 12 months have you used drugs other than alcohol? (A positive screen is 7 or more days.) If fewer than 7, proceed with Question 2.

Question 2: How many days in the past 12 months have you used drugs more than you meant to? (A positive screen is 2 or more days.)

Adapted with permission.^40^

Brief drug screens don't indicate specific types of drugs used (nor does the longer Drug Abuse Screening Test; see the Part 2 Appendix).^34^ If providers use nonspecific screens, they need to assess further which substances patients use and to what degree.

The TIP expert panel recommends universal OUD screening. Given the high prevalence of SUDs in patients visiting primary care settings and the effectiveness of medications to treat OUD specifically, the TIP expert panel recommends screening all patients for opioid misuse.

The Alcohol, Smoking, and Substance Involvement Screening Test (ASSIST) screens patients for all categories of substance misuse, including alcohol and tobacco. This World Health Organization (WHO) screener also assesses substance-specific risk. The ASSIST's length and rather complex scoring system have hindered its adoption, but a computerized version and a briefer hard copy version (ASSIST-lite) make its use more efficient.^37,38^ (See the “Screening, Assessment, and Drug Testing Resources” section for a link to a modified version of the ASSIST.)

The TIP expert panel does not recommend routine universal drug testing with urine, blood, or oral fluids in primary care. Still, drug testing can confirm recent drug use in patients receiving diagnostic workups for changes in mental status, seizures, or other disorders. Conduct drug testing before patients start OUD medication and during treatment for monitoring.

Follow up any positive one-question screen with a brief assessment. An example of a two-step screening and brief assessment is the Tobacco, Alcohol, Prescription Medications, and Other Substance Use (TAPS Tool; see Part 2 Appendix), developed and tested in primary care settings.^41^ This tool is based on the National Institute on Drug Abuse (NIDA) Quick Screen V1.0^42,43^ and a modified WHO ASSIST-lite.^44^

The TAPS Tool screens for clinically relevant heroin and prescription opioid misuse (meeting one or more DSM-5 SUD criteria) and misuse of an array of other substances in primary care patients. However, it may also detect SUDs only for the most often-used substances (i.e., alcohol, tobacco, and marijuana). Patients with positive screens for heroin or prescription opioid misuse need more indepth assessment.^45^

## Assessment

### Determine the Need for and Extent of Assessment

Assess patients for OUD if:

• They screen positive for opioid misuse.
• They disclose opioid misuse.
• Signs or symptoms of opioid misuse are present.

The extent of assessment depends on a provider's ability to treat patients directly.

If a provider does not offer pharmacotherapy, the focus should be on medical assessment, making a diagnosis of OUD, and patient safety. This allows the provider to refer patients to the appropriate level of treatment. The provider can also conduct:

• Assessment and treatment for co-occurring medical conditions or mental disorders.
• Motivational brief interventions to promote safer behavior and foster effective treatment engagement.
• Overdose prevention education and provide a naloxone prescription.
• Education for patients who inject drugs on how to access sterile injecting equipment.
• An in-person follow-up, regardless of referral to specialty treatment.

If the provider offers pharmacotherapy, the patient needs more comprehensive assessment, including:

• A review of the prescription drug monitoring program (PDMP).
• A history, including a review of systems.
• A targeted physical exam for signs of opioid withdrawal, intoxication, injection, and other medical consequences of misuse.
• Determination of OUD diagnosis and severity.
• Appropriate laboratory tests (e.g., urine or oral fluid drug tests, liver function tests, hepatitis B and C tests, HIV tests).^46^

OPIOID ADDICTION is linked with significant MORBIDITY and MORTALITY related to HIV and hepatitis C.^47^

Image of spores of HIV and hepatitis C. Text reads: Opioid addiction is linked with significant morbidity and mortality related to HIV and hepatitis C.47

A comprehensive assessment is intended to:

• Establish the diagnosis of OUD.
• Determine the severity of OUD.
• Identify contraindicated medications.
• Indicate other medical conditions to address during treatment.
• Identify mental and social issues to address.

### Set the Stage for Successful Assessment

The medical setting should create a welcoming environment that is nonjudgmental, respectful, and empathetic. Many patients with OUD are reluctant to discuss their opioid use in medical settings.^48^ A welcoming environment can help patients feel safe disclosing facts they may find embarrassing.^49^ Motivational interviewing strategies, such as asking open-ended questions, foster successful assessment.^50^ (Refer to TIP 34, Brief Interventions and Brief Therapies for Substance Abuse, for more specific examples of interview questions and responses.)^51^

Staff should explore patients’ ambivalence and highlight problem areas to help them find motivations for change. Almost all patients have some ambivalence about their opioid use. They will find some aspects pleasant and beneficial, but others problematic, painful, or destructive. By exploring that ambivalence and highlighting problem areas, providers can help patients discover their own motivations for change. Motivational Interviewing: Helping People Change^52^ discusses specific applications of motivational interviewing in health care.

Open-ended, thought-provoking questions encourage patients to explore their own experiences. Ask questions like “In what ways has oxycodone affected your life?” or “What could you do to prevent infections like this in the future?” Closed-ended questions with yes/no answers—like “Has oxycodone caused your family trouble?”—can seem judgmental to patients who already feel ashamed and defensive. Closed-ended questions don't help patients become aware of and express their own circumstances and motivations, nor do they encourage patients to identify what they see as the consequences of their substance use.

### Take a Complete History

Staff should prioritize medical, mental health, substance use, and SUD treatment histories. When obtaining patient histories, staff should address these domains before starting treatment. As providers and staff build trust over future visits, they can get into more detailed elements of the assessment.

#### Medical history

Taking a complete medical history of patients with OUD is critical, as it is for patients with any other medical condition treatable with pharmacotherapy. Asking about patients’ medical/surgical history can:

• Reveal medical effects of substance use (e.g., endocarditis, soft tissue infection, hepatitis B or C, HIV infection) that may need treatment.
• Highlight consequences that motivate change.
• Identify medical issues (e.g., severe liver disease) that contraindicate or alter dosing approaches for OUD pharmacotherapies.
• Reveal chronic pain issues.
• Help providers consider interactions among various medications and other substances.

Exhibit 2.8 lists medical problems associated with opioid misuse.

EXHIBIT 2.8. Medical Problems Associated With Opioid Misuse^56^

CATEGORY | POSSIBLE COMPLICATIONS
Cancer | Injection drug use: Hepatocellular carcinoma related to hepatitis C
Cardiovascular | Injection drug use: Endocarditis, septic thrombophlebitis
Endocrine/metabolic | Opioids: Osteopenia, hypogonadism, erectile dysfunction, decreased sperm motility, menstrual irregularity including amenorrhea, infertility
Hematologic | Injection drug use/sharing intranasal use equipment: Hematologic consequences of liver disease from hepatitis C, hepatitis C-related cryoglobulinemia and purpura
Hepatic | Injection drug use/sharing intranasal use equipment: Hepatitis B, C, D; infectious and toxic hepatitis
Infectious | Opioids: Aspiration pneumonia, sexually transmitted infections; Injection drug use: Endocarditis, cellulitis, necrotizing fasciitis, pneumonia, septic thrombophlebitis, mycotic aneurysm, septic arthritis (unusual joints, such as sternoclavicular), osteomyelitis (including vertebral), epidural and brain abscess, abscesses and soft tissue infections, mediastinitis, malaria, tetanus, hepatitis B, hepatitis C, hepatitis D, HIV, botulism
Neurologic | Opioids: Seizure (overdose and hypoxia), compression neuropathy (following overdose), sleep disturbances
Nutritional | Opioids: Protein malnutrition
Other gastrointestinal | Opioids: Constipation, ileus, intestinal pseudo-obstruction, sphincter of Oddi spasm, nausea
Pulmonary | Opioids: Respiratory depression/failure, bronchospasm, exacerbation of sleep apnea, noncardiogenic pulmonary edema, bullae; Injection drug use: Pulmonary hypertension, talc granulomatosis, septic pulmonary embolism, pneumothorax, emphysema, needle embolization
Renal | Opioids: Rhabdomyolysis, acute renal failure (not direct toxic effect of opioids but secondary to central nervous system depression and resulting complications), factitious hematuria; Injection drug use: Focal glomerular sclerosis (HIV, heroin), glomerulonephritis from hepatitis or endocarditis, chronic renal failure, amyloidosis, nephrotic syndrome (hepatitis C)

#### Mental health history

Assessing for comorbid mental illness is critical. Mental illness is prevalent among people with SUDs; it can complicate their treatment and worsen their prognosis. In one study, nearly 20 percent of primary care patients with OUD had major depression.^53^ SUDs can also mimic or induce depression and anxiety disorders. Although substance-induced depression and anxiety disorders may improve with abstinence, they may still require treatment in their own right after a period of careful observation.^54^ Take a history of the relationship between a patient's psychiatric symptoms and periods of substance use and abstinence. Treatment for mental disorders and SUDs can occur concurrently.

#### Substance use history

Substance use histories can help gauge OUD severity, inform treatment planning, clarify potential drug interactions, and highlight the negative consequences of patients’ opioid use.

To help determine the severity of patients’ substance use, explore historical features of their use, like:

• Age at first use.
• Routes of ingestion (e.g., injection).
• History of tolerance, withdrawal, drug mixing, and overdose.

Histories should also explore current patterns of use,^55^ which inform treatment planning and include:

• Which drugs patients use.
• Comorbid alcohol and tobacco use.
• Frequency, recency, and intensity of use.

To diagnose an SUD, assess patients’ negative consequences of use, which can affect:

• Physical health.
• Mental health.
• Family relationships.
• Work/career status.
• Legal involvement.
• Housing status.

Buprenorphine and methadone can cause complications for patients who misuse or have SUDs involving alcohol or benzodiazepines. Providers should take specific histories on the use of these substances.

#### SUD treatment history

Information about a patient's past efforts to get treatment or quit independently can inform treatment planning. The same is true for details about the events and behaviors that led to a patient's return to substance use after periods of abstinence and remission of SUD. Similarly, identifying the features of successful quit attempts can help guide treatment plan decisions. Such features may involve:

• Specific treatment settings.
• Use of support groups.
• Previous responses to OUD medications.

#### Social history

Information about a patient's social environments and relationships can aid treatment planning. Social factors that may influence treatment engagement and retention, guide treatment planning, and affect prognosis include:

• Transportation and child care needs.
• Adequacy and stability of housing.
• Criminal justice involvement.
• Employment status and quality of work environment.
• Close/ongoing relationships with people with SUDs.
• Details about drug use from people the patient lives or spends time with (obtained with patient's consent).
• Sexual orientation, identity, and history, including risk factors for HIV/sexually transmitted infections.
• Safety of the home environment. Substance misuse substantially increases the risk of intimate partner violence; screen all women presenting for treatment for domestic violence.^57^

#### Family history

Learn the substance use histories of patients’ parents, siblings, partners, and children. One of the strongest risk factors for developing SUDs is having a parent with an SUD. Genetic factors, exposure to substance use in the household during childhood, or both can contribute to the development of SUDs.^58^

Understanding patients’ motivations for change can be more useful than assessing “readiness” for change. Patients coerced into treatment—such as through parole and probation or drug courts—are as likely to succeed in treatment as patients engaging voluntarily. Readiness fluctuates and depends on context. Helping patients explore why they want to change their drug use can motivate them and prepare their providers to support them during assessment and treatment.

### Conduct a Physical Examination

Perform a physical exam as soon as possible if recent exam records aren't accessible. Assess for:

• Opioid intoxication or withdrawal.
• Physical signs of opioid use.
• Medical consequences of opioid use.

Exhibit 2.9 provides an overview of physical and mental status findings for opioid intoxication.

EXHIBIT 2.9. Signs of Opioid Intoxication

##### Physical findings

Drowsy but arousable

Sleeping intermittently (“nodding off”)

Constricted pupils

##### Mental status findings

Slurred speech

Impaired memory or concentration

Normal to euphoric mood

PATIENT TESTIMONY

Opioid Withdrawal

“Severe opioid withdrawal isn't something I'd wish on my worst enemy. The last time I went cold turkey, I was determined to come off all the way. The physical symptoms were just the tip of the iceberg. My mind was a nightmare that I thought I would never wake up from. There were times when I was almost convinced that dying would be better than what I was feeling. I did not experience a moment of ease for the first 3 months, and it was 6 months until I started to feel normal.”

#### Opioid withdrawal

Opioid withdrawal can be extremely uncomfortable. Symptoms are similar to experiencing gastroenteritis, severe influenza, anxiety, and dysphoria concurrently.

Severity of withdrawal can indicate a patient's level of physical dependence and can inform medication choices and dosing decisions. The duration of withdrawal depends on the specific opioid from which the patient is withdrawing and can last 1 to 4 weeks. After the initial withdrawal phase is complete, many patients experience a prolonged phase of dysphoria, craving, insomnia, and hyperalgesia that can last for weeks or months.

Assess opioid withdrawal in the physical exam by noting physical signs and symptoms (Exhibit 2.10). Structured measures (e.g., Clinical Opiate Withdrawal Scale [COWS]; Clinical Institute Narcotic Assessment Scale for Withdrawal Symptoms) can help standardize documentation of signs and symptoms to support diagnosis, initial management, and treatment planning. See the “Resources” section for links to standardized scales. Part 3 of this TIP covers withdrawal symptom documentation for pharmacotherapy initiation.

EXHIBIT 2.10. Physical Signs of Opioid Withdrawal and Time to Onset

STAGE | GRADE | PHYSICAL SIGNS/SYMPTOMS
Early withdrawal; Short-acting opioids:; 8–24 hours after last use; Long-acting opioids:; Up to 36 hours after last use | Grade 1 | Lacrimation, rhinorrhea, or both; Diaphoresis; Yawning; Restlessness; Insomnia
Early withdrawal; Short-acting opioids:; 8–24 hours after last use; Long-acting opioids:; Up to 36 hours after last use | Grade 2 | Dilated pupils; Piloerection; Muscle twitching; Myalgia; Arthralgia; Abdominal pain
Fully developed withdrawal; Short-acting opioids:; 1–3 days after last use; Long-acting opioids:; 72–96 hours after last use | Grade 3 | Tachycardia; Hypertension; Tachypnea; Fever; Anorexia or nausea; Extreme restlessness
Fully developed withdrawal; Short-acting opioids:; 1–3 days after last use; Long-acting opioids:; 72–96 hours after last use | Grade 4 | Diarrhea, vomiting, or both; Dehydration; Hyperglycemia; Hypotension; Curled-up position

Total duration of withdrawal:

• Short-acting opioids: 7–10 days
• Long-acting opioids: 14 days or more

The physical signs of opioid misuse vary depending on the route of ingestion:

• Patients who primarily smoke or sniff (“snort”) opioids or take them orally often have few physical signs of use other than signs of intoxication and withdrawal. However, snorting can cause congestion and damage nasal mucosa.
• Patients who inject opioids may develop:
  • Sclerosis or scarring of the veins and needle marks, or “track marks,” in the arms, legs, hands, neck, or feet (intravenous use).
  • Edema in the foot, hand, or both (common in injection use, but may occur in oral use).
  • Abscesses or cellulitis.
  • Jaundice, caput medusa, palmar erythema, spider angiomata, or an enlarged or hardened liver secondary to liver disease.
  • Heart murmur secondary to endocarditis.

### Obtain Appropriate Laboratory Tests

#### Urine or oral fluid drug testing

Urine or oral fluid drug testing is useful before initiating OUD pharmacotherapy. Testing establishes a baseline of substances the patient has used so that the provider can monitor the patient's response to treatment over time. Testing for a range of commonly used substances helps confirm patient histories, facilitates discussion of recent drug use and symptoms, and aids in diagnosing and determining severity of SUDs. Drug testing is an important tool in the diagnosis and treatment of addiction. A national guideline on the use of drug testing is available from ASAM.^59^ Exhibit 2.11 provides guidance on talking with patients about drug testing.

EXHIBIT 2.11. Patient–Provider Dialog: Talking About Drug Testing

Frame drug testing in a clinical, nonpunitive way. For example, before obtaining a drug test, ask the patient, “What do you think we'll find on this test?” The patient's response is often quite informative and may make the patient less defensive than confrontation with a positive test result.

SCENARIO: | A provider discusses urine drug testing with a patient being assessed for OUD treatment with medication.
Provider: | When we assess patients for medication for opioid addiction, we always check urine samples for drugs.
Patient: | I'll tell you if I used. You don't need to test me.
Provider: | Thank you, I really appreciate that. The more we can talk about what's going on with you, the more I can help. I'm not checking the urine to catch you or because I don't trust you. I trust you. I can see how motivated you are. But I don't trust the addiction because I know how powerful addiction can be, too. To monitor your safety on medication and help determine what other services you may need, it's important for us to test you periodically and discuss the results. Does that sound okay?
Patient: | Yeah, that makes sense.

During ongoing pharmacotherapy with buprenorphine or methadone, drug testing can confirm medication adherence.

To assess and manage patients with OUD properly, providers must know which tests to order and how to interpret results. There are many drug testing panels; cutoffs for positive results vary by laboratory. One widely used panel, the NIDA-5, tests for cannabinoids, cocaine, amphetamines, opiates, and phencyclidine. Additional testing for benzodiazepines, the broader category of opioids, and specific drugs commonly used in the patient's locality may be warranted. The typical opioid immunoassay will only detect morphine, which is a metabolite of heroin, codeine, and some other opioids. The typical screen will not detect methadone, buprenorphine, or fentanyl and may not detect hydrocodone, hydromorphone, or oxycodone. Specific testing is needed to identify these substances.

Co-occurring SUDs require separate, specific treatment plans.

Testing for substances that can complicate OUD pharmacotherapy is essential. Testing for cocaine, benzodiazepines, and methamphetamine is clinically important because these and other substances (and related SUDs, which may require treatment in their own right), especially benzodiazepines, can complicate pharmacotherapy for OUD. Benzodiazepine and other sedative misuse can increase the risk of overdose among patients treated with opioid agonists. When assessing benzodiazepine use, note that typical benzodiazepine urine immunoassays will detect diazepam but perhaps not lorazepam or clonazepam. Providers must specifically request testing for these two benzodiazepines. Exhibit 2.12 shows urine drug testing windows of detection.

EXHIBIT 2.12. Urine Drug Testing Window of Detection^60,61^

DRUG | POSITIVE TEST | WINDOW OF DETECTION^*^ | COMMENTS
Amphetamine; methamphetamine; 3,4-methylenedioxymethamphetamine | Amphetamine | 1–2 days | False positives with bupropion, chlorpromazine, desipramine, fluoxetine, labetalol, promethazine, ranitidine, pseudoephedrine, trazadone, and other common medications. Confirm unexpected positive results with the laboratory.
Barbiturates | Barbiturates | Up to 6 weeks | N/A
Benzodiazepines | Benzodiazepines | 1–3 days; up to 6 weeks with heavy use of long-acting benzodiazepines | Immunoassays may not be sensitive to therapeutic doses, and most immunoassays have low sensitivity to clonazepam and lorazepam. Check with your laboratory regarding sensitivity and cutoffs. False positives with sertraline or oxaprozin.
Buprenorphine | Buprenorphine | 3–4 days | Will screen negative on opiate screen. Tramadol can cause false positives. Can be tested for specifically.
Cocaine | Cocaine, benzoylecgonine | 2–4 days; 10–22 days with heavy use | N/A
Codeine | Morphine, codeine, high-dose hydrocodone | 1–2 days | Will screen positive on opiate immunoassay.
Fentanyl | Fentanyl | 1–2 days | Will screen negative on opiate screen. Can be tested for specifically. May not detect all fentanyl-like substances.^62^
Heroin | Morphine, codeine | 1–2 days | Will screen positive on opiate immunoassay. 6-monoacetylmorphine, a unique metabolite of heroin, is present in urine for about 6 hours. Can be tested for specifically to distinguish morphine from heroin, but this is rarely clinically useful.
Hydrocodone | Hydrocodone, hydromorphone | 2 days | May screen negative on opiate immunoassay. Can be tested for specifically.
Hydromorphone | May not be detected | 1–2 days | May screen negative on opiate immunoassay. Can be tested for specifically.
Marijuana | Tetrahydrocannabinol | Infrequent use of 1–3 days; chronic use of up to 30 days | False positives possible with efavirenz, ibuprofen, and pantoprazole.
Methadone | Methadone | 2–11 days | Will screen negative on opiate screen. Can be tested for specifically.
Morphine | Morphine, hydromorphone | 1–2 days | Will screen positive on opiate immunoassay. Ingestion of poppy plant/seed may screen positive.
Oxycodone | Oxymorphone | 1–1.5 days | Typically screens negative on opiate immunoassay. Can be tested for specifically.

* Detection time may vary depending on the cutoff.

Positive opioid tests can confirm recent use. Document recent use before starting patients on buprenorphine or methadone. Positive methadone or buprenorphine tests are expected for patients receiving these treatments. Positive opioid tests contraindicate starting naltrexone.

Negative opioid test results require careful interpretation. A patient may test negative for opioids despite presenting with opioid withdrawal symptoms if he or she hasn't used opioids for several days. A negative opioid test in the absence of symptoms of opioid withdrawal likely indicates that the patient has little or no opioid tolerance, which is important information for assessment and treatment planning. Consider that the opioid the patient reports using may not be detected on the particular immunoassay.

Screening tests are not definitive; false positive and false negative test results are possible. Confirmatory testing should follow all unexpected positive screens. Urine drug testing will detect metabolites from many prescription opioids but miss others, so it is easy to misinterpret results in patients taking these medications.^63^ False positives are also common in amphetamine testing.^64^

Point-of-service testing provides the opportunity to discuss results with patients immediately. However, cutoffs for positive screens are not standardized across point-of-service tests. Know the specifications of the screens used.^65^

#### Other laboratory tests

Patients with OUD, particularly those who inject drugs, are at risk for liver disease and blood-borne viral infections. Pregnancy is another important consideration in determining treatment course. Recommended laboratory tests for patients with OUD include:

Pregnancy testing, which is important because:

• It is not advisable for patients to start naltrexone during pregnancy.
• Pregnant women treated for active OUD typically receive buprenorphine or methadone.
• The American College of Obstetricians and Gynecologists and a recent SAMHSA-convened expert panel on the treatment of OUD in pregnancy^66^ recommend that pregnant women with OUD receive opioid receptor agonist pharmacotherapy.^67^
• Providers should refer pregnant women to prenatal care or, if qualified, provide it themselves.

Liver function tests (e.g., aspartate aminotransferase, alanine aminotransferase, bilirubin), which can:

• Guide medication selection and dosing.
• Rule out severe liver disease, which may contraindicate OUD medication (see Part 3 of this TIP).

Hepatitis B and C serology, which can indicate:

• Patients with positive tests (evaluate for hepatitis treatment).
• The need to administer hepatitis A and B and tetanus vaccines, if appropriate.

HIV serology, which can help identify:

• Patients who are HIV positive (evaluate for antiretroviral treatment).
• Patients who are HIV negative (evaluate for preexposure prophylaxis and targeted education).

### Review the PDMP

Before initiating OUD medication, providers should check their states’ PDMPs to determine whether their patients receive prescriptions for controlled substances from other healthcare professionals. Using the PDMP improves the ability to manage the risks of controlled substances and to identify potentially harmful drug interactions.^68^ Although OTPs are not permitted to report methadone treatment to PDMPs, pharmacies that dispense buprenorphine and other controlled substances do report to PDMPs. Medications that need monitoring and required frequency of updates vary by state (for more information about state PDMPs, visit www.pdmpassist.org/content/state-profiles).

### Determine Diagnosis and Severity of OUD

Use DSM-5 criteria to make an OUD diagnosis (Exhibit 2.13).^69^ Patients who meet two or three criteria have mild OUD. Those meeting four or five criteria have moderate OUD, and those meeting six or more criteria have severe OUD.^70^ A printable checklist of DSM-5^71^ criteria is available in the Part 2 Appendix.

## Treatment Planning or Referral

### Making Decisions About Treatment

Start by sharing the diagnosis with patients and hearing their feedback. Patients with OUD need to make several important treatment decisions:

• Whether to begin medication to treat OUD.
• What type of OUD medication to take.
• Where and how to access desired treatment.
• Whether to access potentially beneficial mental health, recovery support, and other ancillary services, whether or not they choose pharmacotherapy.

RESOURCE ALERT

##### Shared Decision-Making Tool for Patients and Family Members

SAMHSA's online shared decision-making tool for patients is a good information source for patients to review before their visit or in the office (http://brsstacs.com/Default.aspx). In addition, providers can suggest that family, friends, and other potential recovery supports (e.g., 12-Step program sponsors, employers, clergy) read educational material tailored for them. See Medication-Assisted Treatment for Opioid Addiction: Facts for Families and Friends (http://mha.ohio.gov/Portals/0/assets/Initiatives/GCOAT/SMA14-4443.pdf).

Offer information to patients about the various treatments for OUD and collaborate with them to make decisions about treatment plans or referrals (Exhibit 2.14). Consider discussing:

• Indications, risks, and benefits of medications and alternatives to pharmacotherapy.
• Types of settings that deliver medications (including healthcare professionals’ own practice locations, if applicable).
• Availability of and accessibility to treatment (i.e., transportation).
• Alternative treatments without medication (e.g., residential treatment, which often offers medically supervised opioid withdrawal).
• Costs of treatment with OUD medication, including insurance coverage and affordability.

EXHIBIT 2.14. Comparison of OUD Medications To Guide Shared Decision Making

CATEGORY | BUPRENORPHINE | METHADONE | NALTREXONE
Appropriate patients | Typically for patients with OUD who are physiologically dependent on opioids | Typically for patients with OUD who are physiologically dependent on opioids and who meet federal criteria for OTP admission | Typically for patients with OUD who are abstinent from short-acting opioids for 7 days and long-acting opioids for 10–14 days
Outcome: Retention in treatment | Higher than treatment without medication and treatment with placebo^73^ | Higher than treatment without OUD medication and treatment with placebo^74^ | Treatment retention with oral naltrexone is no better than with placebo or no medication;^75^ for XR-NTX, treatment retention is higher than for treatment without OUD medication and treatment with placebo;^76,77^ treatment retention is lower than with opioid receptor agonist treatment
Outcome: Suppression of illicit opioid use | Effective | Effective | Effective
Outcome: Overdose mortality | Lower for people in treatment than for those not in it | Lower for people in treatment than for those not in it | Unknown
Location/frequency of office visits | Office/clinic: Begins daily to weekly, then tailored to patient's needs; OTP: Can treat with buprenorphine 6–7 days/week initially; take-homes are allowed without the time-in-treatment requirements of methadone | OTP only: 6–7 days/week initially; take-homes are allowed based on time in treatment and patient progress | Office/clinic: Varies from weekly to monthly
Who can prescribe/order? | Physicians, NPs,^*^ and PAs^*^ possessing federal waiver can prescribe and dispense; can be dispensed by a community pharmacy or an OTP | OTP physicians order the medication; nurses and pharmacists administer and dispense it | Physicians, NPs,^*^ and PAs^*^
Administration | Sublingual/buccal; implant by specially trained provider, and only for stabilized patients | Oral | Oral or intramuscular (Note: Oral naltrexone is less effective than the other OUD medications.)
Misuse/diversion potential | Low in OTPs or other settings with observed dose administration; moderate for take-home doses; risk can be mitigated by providing take-homes to stable patients and a diversion control plan | Low in OTPs with directly observed therapy; moderate for take-home doses; risk can be mitigated by a diversion control plan | None
Sedation | Low unless concurrent substances are present (e.g., alcohol, benzodiazepines) | Low unless dose titration is too quick or dose is not adjusted for the presence of concurrent substances (e.g., alcohol, benzodiazepines) | None
Risk of medication-induced respiratory depression | Very rare; lower than methadone | Rare, although higher than buprenorphine; may be elevated during the first 2 weeks of treatment or in combination with other sedating substances | None
Risk of precipitated withdrawal when starting medication | Can occur if started too prematurely after recent use of other opioids | None | Severe withdrawal is possible if period of abstinence is inadequate before starting medication
Withdrawal symptoms on discontinuation | Present; lower than methadone if abruptly discontinued | Present; higher than buprenorphine if abruptly discontinued | None
Most common side effects | Constipation, vomiting, headache, sweating, insomnia, blurred vision | Constipation, vomiting, sweating, dizziness, sedation | Difficulty sleeping, anxiety, nausea, vomiting, low energy, joint and muscle pain, headache, liver enzyme elevation; XR-NTX: Injection site pain, nasopharyngitis, insomnia, toothache

* NPs and PAs should check with their state to determine whether prescribing buprenorphine, naltrexone, or both is within their allowable scope of practice.

D. Coffa, December 2017 (personal communication). Adapted with permission.

Give patients’ expressed preferences significant weight when making decisions. Patient characteristics can't reliably predict greater likelihood of success with one approved medication or another. For detailed information on medications to treat OUD, refer to Part 3 of this TIP.

Strategies to engage patients in shared decision making include:

• Indicating to patients a desire to collaborate with them to find the best medication and treatment setting for them.
• Including family members in the treatment planning process, if possible (and only with patients’ consent).
• Exploring what patients already know about treatment options and dispelling misconceptions.
• Offering information on medications and their side effects, benefits, and risks (Exhibit 2.14; Part 3).
• Informing patients of the requirements of the various treatment options (e.g., admission criteria to an OTP; frequency of visits to an OBOT or OTP).
• Offering options, giving recommendations after deliberation, and supporting patients’ informed decisions.

Part 1 of this TIP gives an overview of the three FDA-approved medications used to treat OUD. Part 3 covers the details of their use.

### Understanding Treatment Settings and Services

Support patient preferences for treatment settings and services. Some patients prefer to receive OUD medication via physicians’ offices. Others choose outpatient treatment programs that provide opioid receptor agonist treatment for medically supervised withdrawal (with or without naltrexone) or for ongoing opioid receptor agonist maintenance treatment. Still others may want OUD treatment in a residential program with or without pharmacotherapy (Exhibit 2.15).

EXHIBIT 2.15. Treatment Setting Based on Patient's Choice of OUD Medication

MEDICATION | POSSIBLE TREATMENT SETTING
Buprenorphine | Office-based treatment, outpatient or residential SUD treatment programs (prescriber must have a federal waiver), OTP
Methadone | OTP
Naltrexone | Office-based treatment, outpatient or residential SUD treatment programs, OTP

Many patients initially form a preference for a certain treatment without knowing all the risks, benefits, and alternatives. Providers should ensure that patients understand the risks and benefits of all options. Without this understanding, patients can't give truly informed consent.

### Outpatient OUD Treatment Settings

Refer patients who prefer treatment with methadone or buprenorphine via an OTP and explain that:

• They will have to visit the program from 6 to 7 times per week at first.
• Additional methadone take-home doses are possible at every 90 days of demonstrated progress in treatment.
• Buprenorphine take-home doses are not bound by the same limits as methadone.
• Counseling and drug testing are required parts of OTP treatment.
• Some programs also offer case management, peer support, medical services, mental disorder treatment, and other services.

Try to arrange OTP intake appointments for patients before they leave the office. If no immediate openings are available, consider starting buprenorphine as a bridge or alternative to the OTP.

Gauge the appropriate intensity level for patients seeking non-OTP outpatient treatment for OUD. These programs range from low intensity (individual or group counseling once to a few times a week) to high intensity (2 or more hours a day of individual and group counseling several days a week). Appropriate treatment intensity depends on each patient's:^78^

• Social circumstances.
• Severity of addiction.
• Personal preferences.
• Psychiatric/psychological needs.
• Ability to afford treatment at a given intensity.

#### Outpatient medical settings

Healthcare professionals cannot provide methadone in their clinics. Only those with a buprenorphine waiver can provide buprenorphine. Any healthcare professional with a license can provide naltrexone.

Once providers obtain the necessary waiver, they should offer buprenorphine treatment to all patients who present with OUD if such treatment is available and appropriate. Referring them to treatment elsewhere will likely result in delay or lack of patient access to care. Develop a treatment plan to determine where patients will receive continuing care (see the “Treatment Planning” section). Continue to provide naltrexone for patients who were already receiving it from some other setting (e.g., a prison, a specialty addiction treatment program) or for patients who meet opioid abstinence requirements and wish to take a medication for relapse prevention.

#### Residential drug treatment settings

Patients who have OUD, concurrent other substance use problems, unstable living situations, or a combination of the three may be appropriate candidates for residential treatment, which can last from a week to several weeks or more. Inform patients about the services and requirements typical of this treatment setting.

Some patients taking buprenorphine (or methadone) who have other SUDs, such as AUD or cocaine use disorder, can benefit from residential treatment. If such treatment is indicated, determine whether the residential program allows patients to continue their opioid receptor agonist medication while in treatment. Some residential programs require patients to discontinue these medications to receive residential treatment, which could destabilize patients and result in opioid overdose.

Residential treatment programs typically provide:

• Room and board.
• Recovery support.
• Counseling.
• Case management.
• Medically supervised withdrawal (in some programs).
• Starting buprenorphine or naltrexone (in some programs).
• Onsite mental health services (in some cases).
• Buprenorphine or methadone continuation for patients already enrolled in treatment prior to admission if their healthcare professionals have waivers or their OTP permits.

Transitioning out of residential settings requires careful planning. During a patient's stay in residential treatment, plan for his or her transition out of the program. A good transition plan maximizes the likelihood of continuity of care after discharge. Plans should also address overdose risk. Patients who are no longer opioid tolerant are at heightened risk of opioid overdose if they don't get OUD medication at discharge. Providing XR-NTX, buprenorphine, or methadone during treatment and continuing the medication after discharge can help prevent return to opioid use after discharge. Providing a naloxone prescription and overdose prevention information is appropriate.

RESOURCE ALERT

###### Maintaining Confidentiality

Providers who treat patients with addiction must know substance use-related disclosure rules and confidentiality requirements. SAMHSA's webpage lists frequently asked questions on substance use confidentiality and summarizes federal regulations about disclosure and patient records that federal programs maintain on addiction treatment (https://www.samhsa.gov/about-us/who-we-are/laws-regulations/confidentiality-regulations-faqs). Key points include:

• Confidentiality regulations prohibit specialty SUD treatment programs from sharing information with healthcare professionals about patients’ SUD treatment without specific consent from patients.
• Referrals to other behavioral health services require consent for sharing information on treatment progress.
• Healthcare professionals should discuss confidentiality and consent with patients during the referral process.
• OUD pharmacotherapy prescribers may consider requiring patient consent for communicating with treatment programs as a condition of receiving OUD treatment.

Treatment program staff members can help identify returns to substance use, or risk of such, before the prescriber and can work with the prescriber to stabilize patients.

RESOURCE ALERT

###### Treatment and Provider Locator

SAMHSA's Behavioral Health Treatment Services Locator (https://findtreatment.samhsa.gov) provides information on drug and alcohol treatment programs across states. Another SAMHSA tool identifies the locations of buprenorphine providers (www.samhsa.gov/medication-assisted-treatment/physician-program-data/treatment-physician-locator).

### Determining OUD Service Intensity and Ensuring Follow-Through

Use ASAM placement criteria for guidance on selecting the right level of OUD treatment. ASAM criteria define the level of care and key features that may make a given level (e.g., residential, intensive outpatient, standard outpatient) appropriate for a patient^79^ (see the “Treatment Planning” section). To help patients select programs, note that some focus on specific populations (e.g., gender-specific programs; parents with children; lesbian, gay, bisexual, transgender, and questioning populations).

Make an appointment with the referral program during the patient's visit rather than giving the patient a phone number to call. Follow up with the patient later to determine whether he or she kept the appointment. Doing so increases the chances of a successful referral.

#### Referring patients to behavioral health and support services

Discuss patients’ potential need for behavioral health, peer support, and other ancillary services, like:

• Drug and alcohol counseling.
• Mental health services.
• Case management.
• Mutual-help groups.
• Peer recovery support services.

Offer referrals to counseling and tailored psychosocial support to patients receiving OUD medication (Exhibit 2.16).

Drug Addiction Treatment Act of 2000 legislation requires that buprenorphine prescribers be able to refer patients to counseling, but making referrals is not mandatory.^80^ Many patients benefit from referral to mental health services or specialized addiction counseling and recovery support services. However, four randomized trials found no extra benefit to adding adjunctive counseling to well-conducted medical management visits delivered by the buprenorphine prescriber. There is evidence of benefits to adding contingency management to pharmacotherapy.^81,82,83,84,85^

RESOURCE ALERT

###### Mutual-Support Groups

For an introduction to mutual-support groups, see SAMHSA's Substance Abuse in Brief, “An Introduction to Mutual Support Groups for Alcohol and Drug Abuse” (https://store.samhsa.gov/shin/content/SMA08-4336/SMA08-4336.pdf).

EXHIBIT 2.16. Referring Patients Who Receive OUD Pharmacotherapy to Behavioral Health Therapies

Exhibit 2.16. Referring Patients Who Receive OUD Pharmacotherapy to Behavioral Health Therapies A four-level decision tree helps healthcare providers appropriately refer patients who take OUD medication to behavioral health services through a series of “yes” or “no” questions. The first question asks, “Is the patient willing to engage in additional behavior health therapies?” With a yes answer, the next question asks, “Is the patient entering an OTP for methadone or intensive treatment? With a yes answer, the next step is, “Counseling, peer support, and case management will likely be provided through the OTP” and this branch of the tree ends. However, with a no answer to the “willing to engage in additional behavior health therapies” question, the next step is to, “Offer best advice and ongoing motivational interviewing; revisit offer for behavioral health therapies.” The discussion tree ends. The next set of questions from the “patient entering an OTP,” with a no answer, the next step is to “Identify specific needs, and refer appropriately to one or more of the following:” “Counseling: individual, family and/or group;” “Peer support groups: Alcoholics Anonymous, Narcotics Anonymous, SMART Recovery, buprenorphine groups;” “Case management;” “Vocational training;” and/or, “Housing transportation, food, legal and other support programs.”

RESOURCE ALERT

###### Guidance on Providing Integrated Care

Fragmented healthcare services are less likely to meet all patient needs. Integrated medical and behavioral healthcare delivery can effectively provide patient-focused, comprehensive treatments that address the full range of symptoms and service needs patients with OUD often have.^87^ The key components of integration should be in place to make sure that SUD treatment in a primary care setting works. For more information about how to provide integrated services for individuals taking medication for OUD, see:

• The Agency for Healthcare Research and Quality's report Medication-Assisted Treatment Models of Care for Opioid Use Disorder in Primary Care Settings. (www.ncbi.nlm.nih.gov/books/NBK402352).
• The Agency for Healthcare Research and Quality's Academy for Integrating Behavioral Mental Health and Primary Care. (https://integrationacademy.ahrq.gov).
• SAMHSA's Center for Integrated Health Solutions’ Resource Library for providing integrated care. (www.samhsa.gov/integrated-health-solutions/resource-library?combine=substance+abuse&=Apply%20or%20https://www.samhsa.gov/integrated-health-solutions).

Make referrals to mutual-help groups. Patients may wish to participate in mutual-help groups (e.g., Alcoholics Anonymous, Narcotics Anonymous, Methadone Anonymous, Medication-Assisted Recovery Services, SMART Recovery) in addition to or instead of specialized treatment. These programs can be highly supportive, but they may pressure patients to stop taking OUD medication. If possible, refer patients to groups that welcome patients who take OUD medication.

Make referrals to medical and mental health services. Respectful, consistent medical care can support patients’ efforts to recover from OUD and all other SUDs. As for any patient, providers should make appropriate referrals for patients with OUD to receive medical or mental health services beyond the providers’ own scope of practice.

Patients with depression, anxiety disorders, and other mental disorders may be more likely to succeed in addiction treatment if those conditions are managed.^86^ If the severity or type of a patient's psychiatric comorbidity is beyond a provider's scope of practice, the provider should refer the patient to mental health services as appropriate.

Make referrals to ancillary services. Besides medical care and mental health services, OUD patients, like patients with other illnesses, may need more support in some areas, including ancillary services such as:

• Case management.
• Food access.
• Vocational training.
• Housing.
• Transportation.
• Legal assistance.

OPPORTUNITY ALERT

###### Becoming an OUD Medication Treatment Provider

SAMHSA strongly urges physicians, NPs, and PAs to obtain waivers that will qualify them to offer buprenorphine pharmacotherapy. They can become qualified to use buprenorphine to taper appropriate patients with OUD off illicit or prescription opioids or to provide long-term OUD treatment.

Only healthcare professionals with a federal waiver may prescribe buprenorphine for the treatment of OUD. To get waivers, providers must meet set criteria, complete buprenorphine training (online or in person), and apply for a waiver from SAMHSA. Waivered prescribers are assigned an additional DEA registration number (usually their existing number with an added “X”).

NPs and PAs need to meet additional criteria for waivers.^88^ Check with the state licensing board about restrictions and requirements at the state level before applying for a waiver.

Wavier training: ASAM, the American Academy of Addiction Psychiatry, the American Psychiatric Association, and the American Osteopathic Academy of Addiction Medicine all provide the waiver training courses for physicians. Providers’ Clinical Support System for Medication Assisted Treatment (PCSS-MAT) provides the required 8-hour OUD medication waiver course for physicians and 24-hour waiver course for NPs and PAs for free (https://pcssmat.org/education-training/mat-waiver-training). ASAM and others also provide NP and PA courses.

New prescribers can benefit from mentorship from experienced providers in their practice or community. Mentorship is available for free from PCSS-MAT (http://pcssmat.org/mentoring).

For detailed information on prescribing OUD medications, review Part 3 of this TIP.

#### Helping patients who are not ready to engage in OUD treatment

Help reluctant patients be safer and approach readiness. Patients may seem unwilling to discuss their drug use if they're ashamed or fear being judged. Accepting, nonjudgmental attitudes help patients overcome shame and discuss concerns honestly while also instilling hope.

Every visit is a chance to help patients begin healthy changes and move toward treatment and recovery. Patients may not be ready to change right away. Successfully quitting drug use can take many attempts. Returns to substance use, even after periods of remission, are expected parts of the recovery process.

Patients with OUD are much more likely to die than their peers,^89,90^ and HIV, hepatitis C, and skin and soft tissue infections are common among this population. Help reduce these OUD-related risks by educating patients about:

• Using new syringes.
• Avoiding syringe sharing.
• Avoiding sharing other supplies during the injection process.
• Preventing opioid overdose (see the “Preventing Opioid-Related Overdose” section).
• Obtaining overdose prevention information and resources (e.g., SAMHSA Opioid Overdose Prevention Toolkit [https://store.samhsa.gov/product/SAMHSA-Opioid-Overdose-Prevention-Toolkit/SMA16-4742]).
• Obtaining naloxone and instructions for its use.

Refer patients to syringe exchange sites. The North American Syringe Exchange Network provides options (see the “Syringe Exchange” section).

### Preventing Opioid-Related Overdose

Every patient who misuses opioids or has OUD should receive opioid overdose prevention education and a naloxone prescription.^91^ Healthcare professionals should educate patients and their families about overdose risk, prevention, identification, and response (Exhibit 2.17). FDA has approved an autoinjectable naloxone device (Evzio) and a naloxone nasal spray (Narcan) for use by patients and others. For information about all forms of naloxone, prescribing, and patient and community education, see the SAMHSA Opioid Overdose Prevention Toolkit (https://store.samhsa.gov/product/SAMHSA-Opioid-Overdose-Prevention-Toolkit/SMA16-4742).

EXHIBIT 2.17. Opioid Overdose: Risk, Prevention, Identification, and Response

##### Overdose risk

• Using heroin (possibly mixed with illicitly manufactured fentanyl or fentanyl analogs)
• Using prescription opioids that were not prescribed
• Using prescription opioids more frequently or at higher doses than prescribed
• Using opioids after a period of abstinence or reduced use (e.g., after medically supervised withdrawal or incarceration)
• Using opioids with alcohol, benzodiazepines, or both

##### Overdose prevention

• Don't use opioids that were not prescribed.
• Take medications only as prescribed.
• Don't use drugs when you are alone.
• Don't use multiple substances at once.
• Have naloxone available and make sure others know where it is and how to use it.
• Use a small “test dose” if returning to opioid use after a period of abstinence, if the substance appears altered, or if it has been acquired from an unfamiliar source. Beware: This doesn't guarantee safety; illicitly manufactured fentanyl or other substances may be present in the drug, and any use may be fatal.

##### Overdose identification

• Fingernails or lips are blue or purple.
• Breathing or heartbeat is slow or stopped.
• The person is vomiting or making gurgling noises.
• The person can't be awakened or is unable to speak.

##### Overdose response

• Call 9-1-1.
• Administer naloxone (more than one dose may be needed to restore adequate spontaneous breathing).
• Perform rescue breathing. If certified to provide cardiopulmonary resuscitation, perform chest compressions if there is no pulse.
• Put the person in the “recovery position,” on his or her side and with the mouth facing to the side to prevent aspiration of vomit, if he or she is breathing independently.
• Stay with the person until emergency services arrive. Naloxone's duration of action is 30–90 minutes. The person should be observed after this time for a return of opioid overdose symptoms.

Adapted from material in the public domain. ^ 92 ^

The United States is experiencing a death epidemic related to opioid overdose. Opioids (including prescription opioids and heroin) killed more than 33,000 people in 2015, more than in any prior year. Almost half of opioid overdose deaths involve prescription opioids. Since 2010, heroin overdose deaths have more than quadrupled.^93,94^ Overdose deaths from illicit fentanyl have risen sharply.^95^

Municipalities with community-based naloxone distribution programs have seen substantial decreases in opioid overdose death rates.^96,97^ Many syringe exchange programs also dispense naloxone. For information and resources on prescribing naloxone for overdose prevention, including educational patient handouts and videos, see the “Opioid-Related Overdose Prevention” section.

## Resources

The following selected resources address key content presented in Part 2. Part 5 of this TIP includes comprehensive resources on topics pertaining to substance misuse and medications to treat OUD.

### Alcohol and Drug Use Screening

• American Academy of Addiction Psychiatry: Provides Performance in Practice Clinical Modules for screening of tobacco use and AUD. www.aaap.org/education-training/cme-opportunities
• NIAAA, Professional Education Materials: Provides links to screening, treatment planning, and general information for clinicians in outpatient programs. www.niaaa.nih.gov/publications/clinical-guides-and-manuals
• NIDA, Medical and Health Professionals: Provides resources for providers to increase awareness of the impact of substance use on patients’ health and help identify drug use early and prevent it from escalating to misuse or addiction. www.drugabuse.gov/nidamed-medical-health-professionals

### Tobacco Screening

• American Psychiatric Nursing Association, Tobacco & Nicotine Use Screening Tools and Assessments: Provides the Fagerström screening tools for nicotine dependence and smokeless tobacco and a screening checklist for tobacco use. www.apna.org/i4a/pages/index.cfm?pageID=6150
• U.S. Department of Health and Human Services’ Be Tobacco Free: Provides information for individuals struggling with nicotine addiction and links for clinicians that provide guidance on caring for patients with nicotine addiction. https://betobaccofree.hhs.gov/health-effects/nicotine-health
• U.S. Department of Health and Human Services’ Million Hearts Initiative: Provides templates for developing and guidance on implementing tobacco cessation programs and guidance on implementing them as part of clinical care. https://millionhearts.hhs.gov/tools-protocols/protocols.html
• Centers for Disease Control and Prevention (CDC): Offers resources and information for patients and clinicians; includes a webpage with resource links for clinicians on treating tobacco dependence. www.cdc.gov/tobacco/index.htm and www.cdc.gov/tobacco/basic_information/related_links/index.htm

### Buprenorphine Treatment Locator

• SAMHSA, Buprenorphine Treatment Practitioner Locator: Provides a state-by-state list of providers who offer buprenorphine. www.samhsa.gov/medication-assisted-treatment/physician-program-data/treatment-physician-locator

### Buprenorphine Training, Mentorship, and Waivers

• SAMHSA, Buprenorphine Waiver Management: Provides information on buprenorphine waivers with links to waiver applications; explains waiver processes, requirements, and recordkeeping. www.samhsa.gov/medication-assisted-treatment/buprenorphine-waiver-management
• SAMHSA, Buprenorphine Training for Physicians: Provides links to organizations that train physicians on buprenorphine treatment. www.samhsa.gov/medication-assisted-treatment/training-resources/buprenorphine-physician-training
• SAMHSA, Qualify for NPs and PAs Waiver: Provides information for NPs and PAs about the buprenorphine waiver training, with links to trainings and the application process. www.samhsa.gov/medication-assisted-treatment/qualify-nps-pas-waivers
• PCSS-MAT: Provides buprenorphine waiver training and mentorship for healthcare professionals (physicians, NPs, and PAs); includes updates and other resources about medication for OUD. http://pcssmat.org

### Medication Treatment for OUD

• SAMHSA, Medication-Assisted Treatment of Opioid Use Disorder: Provides a clinical pocket guide for medication treatment for OUD. https://store.samhsa.gov/shin/content/SMA16-4892PG/SMA16-4892PG.pdf
• SAMHSA, MATx Mobile App to Support Medication-Assisted Treatment of OUD: Provides a mobile app to support healthcare professionals providing medication treatment for OUD. https://store.samhsa.gov/apps/mat
• SAMHSA, Advisory, Sublingual and Transmucosal Buprenorphine for Opioid Use Disorder: Review and Update: Summarizes information on the use of buprenorphine to treat OUD. https://store.samhsa.gov/product/Advisory-Sublingual-and-Transmucosal-Buprenorphine-for-Opioid-Use-Disorder-Review-and-Update/SMA16-4938
• SAMHSA, Clinical Use of Extended-Release Injectable Naltrexone in the Treatment of Opioid Use Disorder: A Brief Guide: Provides a brief review of the use of XR-NTX. https://store.samhsa.gov/product/Clinical-Use-of-Extended-Release-Injectable-Naltrexone-in-the-Treatment-of-Opioid-Use-Disorder-A-Brief-Guide/SMA14-4892R
• ASAM, The ASAM National Practice Guideline for the Use of Medications in the Treatment of Addiction Involving Opioid Use: Provides national practice guidelines for the use of medications to treat OUD. www.asam.org/docs/default-source/practice-support/guidelines-and-consensus-docs/asam-national-practice-guideline-supplement.pdf
• Department of Veterans Affairs/Department of Defense, VA/DoD Clinical Practice Guideline for the Management of Substance Use Disorders: Provides substance use disorder practice guidelines. www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGRevised22216.pdf
• PCSS-MAT: Provides training and mentorship for healthcare professionals (physicians, NPs, and PAs) on medications for OUD treatment including buprenorphine, naltrexone, and methadone. https://pcssmat.org

### Syringe Exchange

• North American Syringe Exchange Network: Provides a national directory of syringe exchange programs in the United States. https://nasen.org/directory

### Opioid-Related Overdose Prevention

• Prescribe To Prevent: Provides information about naloxone prescribing for overdose prevention, including educational patient handouts and videos. http://prescribetoprevent.org
• SAMHSA Opioid Overdose Prevention Toolkit: Provides healthcare professionals, communities, and local governments with material to develop practices and policies to help prevent opioid-related overdoses and deaths. It addresses issues for healthcare professionals, first responders, treatment providers, and those recovering from opioid overdose as well as their families. https://store.samhsa.gov/product/SAMHSA-Opioid-Overdose-Prevention-Toolkit/SMA16-4742
• CDC—Injury Prevention and Overdose: Provides links and tools for clinicians to help prevent opioid overdose deaths. https://www.cdc.gov/drugoverdose/prevention/index.html
• NIDA, Opioid Overdose Reversal with Naloxone (Narcan, Evzio): Provides naloxone information for providers. www.drugabuse.gov/related-topics/opioid-overdose-reversal-naloxone-narcan-evzio

### Opioid Withdrawal Scales

• WHO Guidelines for the Psychosocially Assisted Pharmacological Treatment of Opioid Dependence: Annex 10: Provides COWS and other opioid withdrawal scales. www.ncbi.nlm.nih.gov/books/NBK143183
• The Clinical Institute Narcotic Assessment Scale for Withdrawal Symptoms: Provides a scale that measures signs and symptoms observed in patients during withdrawal. www.ncpoep.org/wp-content/uploads/2015/02/Appendix_7_Clinical_Institute_Narcotic_Assessment_CINA_Scale_for_Withdrawal_Symptoms.pdf

### Patient and Family Education on Medications To Treat OUD

• SAMHSA Store: Provides patient and family educational resources about OUD and medication treatment for OUD; some resources are available in multiple languages, including Spanish. https://store.samhsa.gov
  - Buprenorphine. https://store.samhsa.gov/product/The-Facts-about-Buprenorphine-for-Treatment-of-Opioid-Addiction/SMA15-4442
  - Methadone. https://store.samhsa.gov/product/What-Every-Individual-Needs-to-Know-About-Methadone-Maintenance/SMA06-4123
• ASAM Resources: Provides patient and family education tools about addiction in general and OUD specifically.
  - Patient Resources. www.asam.org/resources/patientresources
  - Opioid Addiction Treatment: A Guide for Patients, Families, and Friends. https://www.asam.org/docs/default-source/publications/asam-opioid-patient-piece_-5bopt2-5d_3d.pdf

### Referral and Treatment Locators

• SAMHSA, OTP Directory: Provides a state-by-state directory of methadone OTPs. https://dpt2.samhsa.gov/treatment/directory.aspx
• SAMHSA, Behavioral Health Treatment Services Locator: Provides a directory of treatment facilities. https://findtreatment.samhsa.gov
• SAMHSA, Behavioral Health Treatment Services Locator—Self-Help, Peer Support, and Consumer Groups: Provides a directory for mutual-help groups. https://findtreatment.samhsa.gov/locator/link-focSelfGP

### Screening, Assessment, and Drug Testing Resources

• NIDA, Screening, Assessment, and Drug Testing Resources: Provides an evidence-based screening tool chart for adolescents and adults, drug use screening tool support materials, and a clinician resource and quick reference guide for drug screening in general medical settings, including a brief version of the ASSIST-lite. www.drugabuse.gov/nidamed-medical-health-professionals/tool-resources-your-practice/additional-screening-resources
• ASAM, The ASAM Appropriate Use of Drug Testing in Clinical Addiction Medicine: Discusses appropriate use of drug testing in identifying, diagnosing, and treating people with or at risk for SUDs. www.asam.org/quality-practice/guidelines-and-consensus-documents/drug-testing

### Treatment Planning

• The ASAM Criteria: Provides criteria and a comprehensive set of guidelines for placement, continued stay, and transfer/discharge of patients with addiction and co-occurring conditions. The ASAM six-dimensional assessment tool is designed to guide treatment planning and offers a template to organize assessments and to determine level of care.^98^ www.asam.org/quality-practice/guidelines-and-consensus-documents/the-asam-criteria
• SAMHSA, Decisions in Recovery—Treatment for Opioid Use Disorder: Provides an online interactive tool to support people with OUD in making informed decisions about their care. https://archive.samhsa.gov/MAT-Decisions-in-Recovery An accompanying handbook is also available. https://store.samhsa.gov/product/Decisions-in-Recovery-Treatment-for-Opioid-Use-Disorders/SMA16-4993
• SAMHSA, TIP 42, Substance Abuse Treatment for Persons With Co-Occurring Disorders: Provides comprehensive treatment guidance for individuals with co-occurring mental and substance use disorders. https://store.samhsa.gov/shin/content//SMA13-3992/SMA13-3992.pdf

## Appendix

Stable Resource Toolkit

AUDIT-C Questionnaire

Drug Abuse Screening Test (DAST-10)

DSM-5 Opioid Use Disorder Checklist^102^

TAPS Tool Part 1

TAPS Tool Part 2

## Notes

1. Shapiro, B., Coffa, D., & McCance-Katz, E. F. (2013). A primary care approach to substance misuse. American Family Physician, 88(2), 113–121.23939642
2. Center for Behavioral Health Statistics and Quality. (2017). Key substance use and mental health indicators in the United States: Results from the 2016 National Survey on Drug Use and Health. Rockville, MD: Substance Abuse and Mental Health Services Administration.
3. American Society of Addiction Medicine. (2011). Definition of addiction. Retrieved October 30, 2017, from www.asam.org/resources/definition-of-addiction
4. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
5. Department of Health and Human Services, Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: Department of Health and Human Services.
6. Substance Abuse and Mental Health Services Administration. (2015). Federal guidelines for opioid treatment programs. HHS Publication No. (SMA) PEP15-FEDGUIDEOTP. Rockville, MD: Substance Abuse and Mental Health Services Administration.
7. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
8. National Cancer Institute. (n.d.). Remission. In NCI dictionary of cancer terms. Retrieved November 22, 2017, from www.cancer.gov/publications/dictionaries/cancer-terms?cdrid=45867
9. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
10. McNeely, J., Wu, L. T., Subramaniam, G., Sharma, G., Cathers, L. A., Svikis, D., … Schwartz, R. P. (2016). Performance of the Tobacco, Alcohol, Prescription Medication, and Other Substance Use (TAPS) Tool for substance use screening in primary care patients. Annals of Internal Medicine, 165(10), 690–699.27595276
11. Centers for Disease Control and Prevention. (2013). Alcohol and public health: Alcohol-Related Disease Impact (ARDI). Average for United States 2006–2010 alcohol-attributable deaths due to excessive alcohol use. Retrieved October 12, 2017, from https://nccd.cdc.gov/DPH_ARDI/Default/Report.aspx?T=AAM&P=f6d7eda7-036e-4553-9968-9b17ffad620e&R=d7a9b303-48e9-4440-bf47-070a4827e1fd&M=8E1C5233-5640-4EE8-9247-1ECA7DA325B9&F=&D=
12. Warner-Smith, M., Darke, S., Lynskey, M., & Hall, W. (2001). Heroin overdose: Causes and consequences. Addiction, 96(8), 1113–1125.11487418
13. Moyer, V. A. (2013). Screening and behavioral counseling interventions in primary care to reduce alcohol misuse: U.S. Preventive Services Task Force recommendation statement. Annals of Internal Medicine, 159(3), 210–218.23698791
14. U.S. Preventive Services Task Force. (2013). Final recommendation statement: Alcohol misuse: Screening and behavioral counseling interventions in primary care. Retrieved October 12, 2017, from www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/alcohol-misuse-screening-and-behavioral-counseling-interventions-in-primary-care
15. Shapiro, B., Coffa, D., & McCance-Katz, E. F. (2013). A primary care approach to substance misuse. American Family Physician, 88(2), 113–121.23939642
16. Babor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). The Alcohol Use Disorders Identification Test: Guidelines for use in primary care (2nd ed.). Geneva, Switzerland: World Health Organization.
17. Bush, K., Kivlahan, D. R., McDonell, M. B., Fihn, S. D., & Bradley, K. A. (1998). The AUDIT alcohol consumption questions (AUDIT-C): An effective brief screening test for problem drinking. Ambulatory Care Quality Improvement Project (ACQUIP). Alcohol Use Disorders Identification Test. Archives of Internal Medicine, 158(16), 1789–1795.9738608
18. Dawson, D. A., Smith, S. M., Saha, T. D., Rubinsky, A. D., & Grant, B. F. (2012). Comparative performance of the AUDIT-C in screening for DSM-IV and DSM-5 alcohol use disorders. Drug and Alcohol Dependence, 126(3), 384–388.22728044
19. Substance Abuse and Mental Health Services Administration, & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Rockville, MD: Substance Abuse and Mental Health Services Administration.
20. Smith, P. C., Schmidt, S. M., Allensworth-Davies, D., & Saitz, R. (2009). Primary care validation of a single-question alcohol screening test. Journal of General Internal Medicine, 24(7), 783–788.19247718
21. Kalman, D., Morissette, S. B., & George, T. P. (2005). Co-morbidity of smoking in patients with psychiatric and substance use disorders. American Journal of Addictions, 14, 106–123.
22. Department of Health and Human Services. (2014). The health consequences of smoking—50 years of progress: A report of the Surgeon General. Atlanta, GA: Department of Health and Human Services, Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion, Office on Smoking and Health.
23. Lasser, K., Boyd, J. W., Woolhandler, S., Himmelstein, D. U., McCormick, D., & Bor, D. H. (2000). Smoking and mental illness: A population-based prevalence study. JAMA, 284, 2606–2610.11086367
24. Ong, M. O., Zhou, Q., & Sung, H. (2011). Primary care providers advising smokers to quit: Comparing effectiveness between those with and without alcohol, drug, or mental disorders. Nicotine and Tobacco Research, 13(12), 1193–1201.21859810
25. U.S. Preventive Services Task Force. (2015). Tobacco smoking cessation in adults, including pregnant women: Behavioral and pharmacotherapy interventions. Retrieved October 12, 2017, from www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/tobacco-use-in-adults-and-pregnant-women-counseling-and-interventions1
26. Heatherton, T. F., Kozlowski, L. T., Frecker, R. C., & Fagerström, K. O. (1991). The Fagerström Test for Nicotine Dependence: A revision of the Fagerström Tolerance Questionnaire. British Journal of Addiction, 86(9), 1119–1127.1932883
27. John, U., Meyer, C., Schumann, A., Hapke, U., Rumpf, H. J., Adam, C., … Lüdemann, J. (2004). A short form of the Fagerström Test for Nicotine Dependence and the Heaviness of Smoking Index in two adult population samples. Addictive Behaviors, 29(6), 1207–1212.15236824
28. U.S. Preventive Services Task Force. (2008). Drug use, illicit: Screening. Retrieved November 22, 2017, from www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/drug-use-illicit-screening
29. Shapiro, B., Coffa, D., & McCance-Katz, E. F. (2013). A primary care approach to substance misuse. American Family Physician, 88(2), 113–121.23939642
30. McNeely, J., Cleland, C. M., Strauss, S. M., Palamar, J. J., Rotrosen, J., & Saitz, R. (2015). Validation of self-administered single-item screening questions (SISQs) for unhealthy alcohol and drug use in primary care patients. Journal of General Internal Medicine, 30(12), 1757–1764.25986138
31. McNeely, J., Wu, L. T., Subramaniam, G., Sharma, G., Cathers, L. A., Svikis, D., … Schwartz, R. P. (2016). Performance of the Tobacco, Alcohol, Prescription Medication, and Other Substance Use (TAPS) Tool for substance use screening in primary care patients. Annals of Internal Medicine, 165(10), 690–699.27595276
32. Smith, P. C., Schmidt, S. M., Allensworth-Davies, D., & Saitz, R. (2010). A single-question screening test for drug use in primary care. Archives of Internal Medicine, 170(13), 1155–1160.20625025
33. Tiet, Q. Q., Leyva, Y. E., Moos, R. H., Frayne, S. M., Osterberg, L., & Smith, B. (2015). Screen of drug use: Diagnostic accuracy of a new brief tool for primary care. JAMA Internal Medicine, 175(8), 1371–1377.26075352
34. Skinner, H. A. (1982). The Drug Abuse Screening Test. Addictive Behaviors, 7(4), 363–371.7183189
35. Babor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). The Alcohol Use Disorders Identification Test: Guidelines for use in primary care (2nd ed.). Geneva, Switzerland: World Health Organization.
36. Heatherton, T. F., Kozlowski, L. T., Frecker, R. C., & Fagerström, K. O. (1991). The Fagerström Test for Nicotine Dependence: A revision of the Fagerström Tolerance Questionnaire. British Journal of Addiction, 86(9), 1119–1127.1932883
37. McNeely, J., Strauss, S. M., Rotrosen, J., Ramautar, A., & Gourevitch, M. N. (2016). Validation of an audio computer-assisted self-interview (ACASI) version of the Alcohol, Smoking and Substance Involvement Screening Test (ASSIST) in primary care patients. Addiction, 111(2), 233–244.26360315
38. Ali, R., Meena, S., Eastwood, B., Richards, I., & Marsden, J. (2013). Ultra-rapid screening for substance-use disorders: The Alcohol, Smoking and Substance Involvement Screening Test (ASSIST-Lite). Drug and Alcohol Dependence, 132(1–2), 352–361.23561823
39. Smith, P. C., Schmidt, S. M., Allensworth-Davies, D., & Saitz, R. (2010). A single-question screening test for drug use in primary care. Archives of Internal Medicine, 170(13), 1155–1160.20625025
40. Tiet, Q. Q., Leyva, Y. E., Moos, R. H., Frayne, S. M., Osterberg, L., & Smith, B. (2015). Screen of drug use: Diagnostic accuracy of a new brief tool for primary care. JAMA Internal Medicine, 175(8), 1371–1377.26075352
41. McNeely, J., Wu, L. T., Subramaniam, G., Sharma, G., Cathers, L. A., Svikis, D., … Schwartz, R. P. (2016). Performance of the Tobacco, Alcohol, Prescription Medication, and Other Substance Use (TAPS) Tool for substance use screening in primary care patients. Annals of Internal Medicine, 165(10), 690–699.27595276
42. National Institute on Drug Abuse. (2012). Resource guide: Screening for drug use in general medical settings. Rockville, MD: Author.
43. National Institute on Drug Abuse. (n.d.). NIDA Quick Screen V1. Retrieved October 16, 2017, from www.drugabuse.gov/sites/default/files/pdf/nmassist.pdf
44. Ali, R., Meena, S., Eastwood, B., Richards, I., & Marsden, J. (2013). Ultra-rapid screening for substance-use disorders: The Alcohol, Smoking and Substance Involvement Screening Test (ASSIST-Lite). Drug and Alcohol Dependence, 132(1–2), 352–361.23561823
45. Schwartz, R. P., McNeely, J., Wu, L. T., Sharma, G., Wahle, A., Cushing, C., … Subramaniam, G. (2017). Identifying substance misuse in primary care: TAPS Tool compared to the WHO ASSIST. Journal of Substance Abuse Treatment, 76, 69–76.28159441
46. Wang, X., Zhang, T., & Ho, W. Z. (2011). Opioids and HIV/HCV infection. Journal of Neuroimmune Pharmacology, 6(4), 477–489.21755286
47. Wang, X., Zhang, T., & Ho, W. Z. (2011). Opioids and HIV/HCV infection. Journal of Neuroimmune Pharmacology, 6(4), 477–489.21755286
48. Merrill, J. O., Rhodes, L. A., Deyo, R. A., Marlatt, G. A., & Bradley, K. A. (2002). Mutual mistrust in the medical care of drug users: The keys to the “narc” cabinet. Journal of General Internal Medicine, 17(5), 327–333.12047728
49. Shapiro, B., Coffa, D., & McCance-Katz, E. F. (2013). A primary care approach to substance misuse. American Family Physician, 88(2), 113–121.23939642
50. Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
51. Center for Substance Abuse Treatment. (1999). Brief interventions and brief therapies for substance abuse. Treatment Improvement Protocol (TIP) Series. 34. HHS Publication No. (SMA) 12-3952. Rockville, MD: Substance Abuse and Mental Health Services Administration.
52. Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
53. Savant, J. D., Barry, D. T., Cutter, C. J., Joy, M. T., Dinh, A., Schottenfeld, R. S., & Fiellin, D. A. (2013). Prevalence of mood and substance use disorders among patients seeking primary care office-based buprenorphine/naloxone treatment. Drug and Alcohol Dependence, 127(1–3), 243–247.22771144
54. Hassan, A. N., Howe, A. S., Samokhvalov, A. V., Le Foll, B., & George, T. P. (2017). Management of mood and anxiety disorders in patients receiving opioid agonist therapy: Review and meta-analysis. American Journal on Addictions, 26(6), 551–563.28675762
55. Hall, W. D., & Strang, J. (2017). Alcohol problems need more attention in patients receiving long-term opioid substitution therapy. Lancet Psychiatry, 4(4), 265–266.28258832
56. Saitz, R. (2014). Medical and surgical complications of addiction. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), The ASAM principles of addiction medicine (5th ed.). Philadelphia, PA: Wolters Kluwer.
57. Soper, R. G. (2014, October 6). Intimate partner violence and co-occurring substance abuse/addiction. ASAM Magazine. Retrieved October 16, 2017, from www.asam.org/magazine/read/article/2014/10/06/intimate-partner-violence-and-co-occurring-substance-abuse-addiction
58. Stone, A. L., Becker, L. G., Huber, A. M., & Catalano, R. F. (2012). Review of risk and protective factors of substance use and problem use in emerging adulthood. Addictive Behaviors, 37(7), 747–775.22445418
59. American Society of Addiction Medicine. (2017). The ASAM appropriate use of drug testing in clinical addiction medicine. Rockville, MD: ASAM. Retrieved October 30, 2017, through www.asam.org/resources/guidelines-and-consensus-documents/drug-testing
60. Lynch, K. (2014). San Francisco General Hospital laboratory protocol. San Francisco, CA: San Francisco General Hospital.
61. Warner, E., & Lorch, E. (2014). Laboratory diagnosis. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), Principles of addiction medicine (5th ed., pp. 332–343). Philadelphia, PA: Wolters Kluwer.
62. Milone, M. C. (2012). Laboratory testing for prescription opioids. Journal of Medical Toxicology, 8(4), 408–416.23180358
63. Reisfield, G. M., Bertholf, R., Barkin, R. L., Webb, F., & Wilson, G. (2007). Urine drug test interpretation: What do physicians know? Journal of Opioid Management, 3(2), 80–86.17520987
64. Standridge, J. B., Adams, S. M., & Zotos, A. P. (2010). Urine drug screening: A valuable office procedure. American Family Physician, 81(5), 635–640.20187600
65. Warner, E., & Lorch, E. (2014). Laboratory diagnosis. In R. K. Ries, D. A. Fiellin, S. C. Miller, & R. Saitz (Eds.), Principles of addiction medicine (5th ed., pp. 332–343). Philadelphia, PA: Wolters Kluwer.
66. Substance Abuse and Mental Health Services Administration. (2018). Clinical guidance for treating pregnant and parenting women with opioid use disorder and their infants. HHS Publication No. (SMA) 18-5054. Rockville, MD: Substance Abuse and Mental Health Services Administration.
67. American College of Obstetricians and Gynecologists. (2017, August). Opioid use and opioid use disorder in pregnancy. Retrieved October 30, 2017, from www.acog.org/-/media/Committee-Opinions/Committee-on-Obstetric-Practice/co711.pdf?dmc=1&ts=20170929T1541517316
68. Ali, M. M., Dowd, N., Classen, T., Mutter, R., & Scott, P. (2017). Prescription drugs monitoring program, nonmedical use of prescription drug and heroin use: Evidence from the National Survey of Drug Use and Health. Addictive Behaviors, 69, 65–77.28152391
69. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
70. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
71. Clinical Tools. (n.d.). DSM 5 opioid use disorder checklist. Retrieved October 16, 2017, from www.buppractice.com/printpdf/19556
72. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
73. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2014). Buprenorphine maintenance versus placebo or methadone maintenance for opioid dependence. Cochrane Database of Systematic Reviews, 2014(2), 1–84.
74. Mattick, R. P., Breen, C., Kimber, J., & Davoli, M. (2009). Methadone maintenance therapy versus no opioid replacement therapy for opioid dependence. Cochrane Database of Systematic Reviews, 2009(3), 1–19.
75. Minozzi, S., Amato, L., Vecchi, S., Davoli, M., Kirchmayer, U., & Verster, A. (2011). Oral naltrexone maintenance treatment for opioid dependence. Cochrane Database of Systematic Reviews, 4, CD001333.
76. Krupitsky, E., Zvartau, E., Blokhina, E., Verbitskaya, E., Wahlgren, V., Tsoy-Podosenin, M., … Woody, G. E. (2012). Randomized trial of long-acting sustained-release naltrexone implant vs oral naltrexone or placebo for preventing relapse to opioid dependence. Archives of General Psychiatry, 69(9), 973–981.22945623
77. Lee, J. D., Friedmann, P. D., Kinlock, T. W., Nunes, E. V., Boney, T. Y., Hoskinson, R. A., Jr., … O'Brien, C. P. (2016). Extended-release naltrexone to prevent opioid relapse in criminal justice offenders. New England Journal of Medicine, 374(13), 1232–1242.27028913
78. McCarty, D., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., & Delphin-Rittmon, M. E. (2014). Substance abuse intensive outpatient programs: Assessing the evidence. Psychiatric Services, 65(6), 718–726.24445620
79. Mee-Lee, D., Shulman, G. D., Fishman, M. J., Gastfriend, D. R., & Miller, M. M. (Eds.). (2013). The ASAM criteria: Treatment criteria for addictive, substance-related, and co-occurring conditions (3rd ed.). Carson City, NV: The Change Companies.
80. Drug Enforcement Administration. (n.d.). Informational documents. Retrieved November 21, 2017, from www.deadiversion.usdoj.gov/pubs/docs/index.html
81. Carroll, K. M., & Weiss, R. D. (2016). The role of behavioral interventions in buprenorphine maintenance treatment: A review. American Journal of Psychiatry, 174(8), 738–774.27978771
82. Fiellin, D. A., Barry, D. T., Sullivan, L. E., Cutter, C. J., Moore, B. A., O'Connor, P. G., & Schottenfeld, R. S. (2013). A randomized trial of cognitive behavioral therapy in primary care-based buprenorphine. American Journal of Medicine, 126(1), 74.e11–74.e77.
83. Fiellin, D. A., Pantalon, M. V., Chawarski, M. C., Moore, B. A., Sullivan, L. E., O'Connor, P. G., & Schottenfeld, R. S. (2006). Counseling plus buprenorphine-naloxone maintenance therapy for opioid dependence. New England Journal of Medicine, 355(4), 365–374.16870915
84. Ling, W., Hillhouse, M., Ang, A., Jenkins, J., & Fahey, J. (2013). Comparison of behavioral treatment conditions in buprenorphine maintenance. Addiction, 108(10), 1788–1798.23734858
85. Weiss, R. D., Potter, J. S., Fiellin, D. A., Byrne, M., Connery, H. S., Dickinson, W., … Ling, W. (2011). Adjunctive counseling during brief and extended buprenorphine-naloxone treatment for prescription opioid dependence: A 2-phase randomized controlled trial. Archives of General Psychiatry, 68(12), 1238–1246.22065255
86. Pettinati, H. M., O'Brien, C. P., & Dundon, W. D. (2013). Current status of co-occurring mood and substance use disorders: A new therapeutic target. American Journal of Psychiatry, 170(1), 23–30.23223834
87. Chou, R., Korthuis, P. T., Weimer, M., Bougatsos, C., Blazina, I., Zakher, B., … McCarty, D. (2016). Medication-assisted treatment models of care for opioid use disorder in primary care settings. Technical Brief No. 28. Rockville, MD: Agency for Healthcare Research and Quality.
88. American Society of Addiction Medicine. (n.d.). Nurse practitioners and physician assistants prescribing buprenorphine. Retrieved October 16, 2017, from www.asam.org/quality-practice/practice-resources/nurse-practitioners-and-physician-assistants-prescribing-buprenorphine
89. Bogdanowicz, K. M., Stewart, R., Broadbent, M., Hatch, S. L., Hotopf, M., Strang, J., & Hayes, R. D. (2015). Double trouble: Psychiatric comorbidity and opioid addiction—All-cause and cause-specific mortality. Drug and Alcohol Dependence, 148, 85–92.25578253
90. Bogdanowicz, K. M., Stewart, R., Chang, C. K., Downs, J., Khondoker, M., Shetty, H., … Hayes, R. D. (2016). Identifying mortality risks in patients with opioid use disorder using brief screening assessment: Secondary mental health clinical records analysis. Drug and Alcohol Dependence, 164, 82–88.27179824
91. Department of Health and Human Services. (2016). The opioid epidemic: By the numbers. Washington, DC: Department of Health and Human Services.
92. Substance Abuse and Mental Health Services Administration. (2016). SAMHSA opioid overdose prevention toolkit. HHS Publication No. (SMA) 16-4742. Rockville, MD: Author.
93. Centers for Disease Control and Prevention. (2017). Opioid overdose. Retrieved October 16, 2017, from www.cdc.gov/drugoverdose
94. Centers for Disease Control and Prevention. (2017). Heroin overdose data. Retrieved November 20, 2017, from www.cdc.gov/drugoverdose/data/heroin.html
95. Centers for Disease Control and Prevention. (2016). Increases in drug and opioid-involved overdose deaths—United States, 2010–2015. Morbidity and Mortality Weekly Report, 65(50–51), 1445–1452.28033313
96. Albert, S., Brason, F. W., II, Sanford, C. K., Dasgupta, N., Graham, J., & Lovette, B. (2011). Project Lazarus: Community-based overdose prevention in rural North Carolina. Pain Medicine, 12 (Suppl. 2), S77–S85.21668761
97. Walley, A. Y., Xuan, Z., Hackman, H. H., Quinn, E., Doe-Simkins, M., Sorensen-Alawad, A., … Ozonoff, A. (2013). Opioid overdose rates and implementation of overdose education and nasal naloxone distribution in Massachusetts: Interrupted time series analysis. British Medical Journal, 346, f174.23372174
98. Mee-Lee, D. (2013, November–December). How to really use the new edition of The ASAM Criteria: What to do and what not to do. Counselor, 14(6), 34–40.
99. Bush, K., Kivlahan, D. R., McDonell, M. B., Fihn, S. D., & Bradley, K. A. (1998). The AUDIT alcohol consumption questions (AUDIT-C): An effective brief screening test for problem drinking. Ambulatory Care Quality Improvement Project (ACQUIP). Alcohol Use Disorders Identification Test. Archives of Internal Medicine, 158(16), 1789–1795.9738608
100. Skinner, H. A. (1982). The Drug Abuse Screening Test. Addictive Behavior, 7(4), 363–371.
101. Yudko, E., Lozhkina, O., & Fouts, A. (2007). A comprehensive review of the psychometric properties of the Drug Abuse Screening Test. Journal of Substance Abuse Treatment, 32, 189–198.17306727
102. American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed., p. 541). Arlington, VA: American Psychiatric Publishing.
103. McNeely, J., Wu, L. T., Subramaniam, G., Sharma, G., Cathers, L. A., Svikis, D., … Schwartz, R. P. (2016). Performance of the Tobacco, Alcohol, Prescription Medication, and Other Substance Use (TAPS) Tool for substance use screening in primary care patients. Annals of Internal Medicine, 165(10), 690–699.27595276