# Appendix—Bibliography

Abbott, P. J. (1998). Traditional and Western healing practices for alcoholism in American Indians and Alaska Natives. Substance Use and Misuse, 33(13), 2605–2646.9818991
Adekoya, N., Truman, B., & Landen, M. (2015). Incidence of notifiable diseases among American Indians/Alaska Natives—United States, 2007–2011. Morbidity and Mortality Weekly Report, 64(1), 16–19.25590681
Alaska Department of Fish and Game. (n.d.). Subsistence in Alaska: FAQs. Retrieved August 30, 2016, from www.adfg.alaska.gov/index.cfm?adfg=subsistence.faqs#QA17
Alaska Federal Health Care Partnership. (2015). Alaska challenges. Retrieved August 30, 2016, from www.afhcp.org/about/alaska-challenges (page no longer available).
Alaska Native Epidemiology Center. (2014). Statewide data: Adult binge drinking. Anchorage, AK: Author.
Alaska Native Knowledge Network. (2006). Alaska Native values for curriculum: Alaska Native cultures. Retrieved August 30, 2016, from www.ankn.uaf.edu/ancr/Values/index.html
Aldred, L. (2000). Plastic shamans and Astroturf sundances: New Age commercialization of Native American spirituality. American Indian Quarterly, 24(3), 329–352.17086676
Alliance for a Just Society & Council of Athabascan Tribal Governments. (2013). Survival denied: Stories from Alaska Native families living in a broken system. Washington, DC: Alliance for a Just Society.
American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Washington, DC: Author.
American Psychological Association. (2015). Interested in practicing in an underserved area? Retrieved August 30, 2016, from www.apa.org/about/gr/issues/nhsc/practice.aspx
Amnesty International USA. (2007). Maze of injustice: The failure to protect indigenous women from sexual violence in the USA. New York, NY: Author.
Ancis, J. R., & Ladany, N. (2001). A multicultural framework for counselor supervision. In L. J. Bradley & N. Ladany (Eds.), Counselor supervision: Principles, process, and practice (3rd ed., pp. 63–90). New York, NY: Brunner-Routledge.
Anishnawbe Health Toronto. (2000). Traditional healings. Toronto, Canada: Author.
Anishnawbe Health Toronto. (2011). Anishnawbe Health Toronto. Toronto, Canada: Author.
Armed Forces History Museum. (2013). The role of Native Americans during World War II. Retrieved September 26, 2018, from www.lhschools.org/Downloads/Native%20Americans%20in%20WWII.pdf
Arundale, W. (2006). The healing constellation: A conceptual framework for treating trauma among Athabaskan women in Alaska [Unpublished doctoral dissertation]. Union Institute and University, Cincinnati, OH.
Association of American Medical Colleges. (2005). Cultural competence education. Washington, DC: Author.
Attneave, C. L. (1969). Therapy in tribal settings and urban network intervention. Family Process, 8(2), 192–210.
Austin, A. (2013). High unemployment means Native Americans are still waiting for an economic recovery (Issue Brief 372). Washington, DC: Economic Policy Institute.
Bachman, R., Zaykowski, H., Kallmyer, R., Poteyeva, M., & Lanier, C. (2008). Violence against American Indian and Alaska Native women and the criminal justice response: What is known (Document No. 223691). Washington, DC: National Criminal Justice Reference Service.
Bastian, D. E., & Mitchell, J. K. (2004). Handbook of Native American mythology. Handbooks of World Mythology. Santa Barbara, CA: ABC-CLIO.
Battiste, M. (Ed.). Reclaiming indigenous voice and vision. (2000). Vancouver, Canada: University of British Columbia Press.
Beals, J., Novins, D. K., Whitesell, N. R., Spicer, P., Mitchell, C. M., & Manson, S. M. (2005). Prevalence of mental disorders and utilization of mental health services in two American Indian reservation populations: Mental health disparities in a national context. American Journal of Psychiatry, 162(9), 1723–1732.16135633
Benedict, R., & Mead, M. (1959). An anthropologist at work: Writings of Ruth Benedict. Boston, MA: Houghton Mifflin.
Bernard, J. M., & Goodyear, R. K. (2004). Fundamentals of clinical supervision. Boston, MA: Pearson Education.
Bigby, J., & American College of Physicians. (2003). Cross-cultural medicine. Philadelphia, PA: American College of Physicians.
Bigfoot, D. S., & Funderburk, B. W. (2011). Honoring children, making relatives: The cultural translation of parent-child interaction therapy for American Indian and Alaska Native families. Journal of Psychoactive Drugs, 43(4), 309–318.22400462
Black Elk & Neihardt, J. G. (1932). Black Elk speaks. New York, NY: W. Morrow.
Brave Heart, M. Y. H. (1998). Historical trauma and unresolved grief intervention: Implications for clinical research and practice with indigenous peoples of the Americas [PowerPoint presentation]. Retrieved September 25, 2018, from www.ihs.gov/telebehavioral/includes/themes/newihstheme/display_objects/documents/slides/historicaltrauma/historicaltraumaintro_011113.pdf
Brave Heart, M. Y. H. (1999). Gender differences in the historical trauma response among the Lakota. Journal of Health and Social Policy, 10(4), 1–20.10538183
Brave Heart, M. Y. H. (2003). The historical trauma response among natives and its relationship with substance abuse: A Lakota illustration. Journal of Psychoactive Drugs, 35(1), 7–13.12733753
Brave Heart, M. Y. H. (2005). From intergenerational trauma to intergenerational healing: A teaching about how it works and how we can heal. Wellbriety, 6(6), 1–8.
Brave Heart, M. Y. H., Chase, J., Elkins, J., & Altschul, D. B. (2011). Historical trauma among indigenous peoples of the Americas: Concepts, research, and clinical considerations. Journal of Psychoactive Drugs, 43(4), 282–290.22400458
Brave Heart, M. Y. H., & DeBruyn, L. M. (1998). The American Indian holocaust: Healing historical unresolved grief. American Indian and Alaska Native Mental Health Research, 8, 60–82.
Breiding, M. J., Chen, J., & Black, M. C. (2014). Intimate partner violence in the United States—2010. Atlanta, GA: National Center for Injury Prevention and Control, Centers for Disease Control and Prevention.
Britten, T. A. (1997). American Indians in World War I. Albuquerque: University of New Mexico Press.
Brown, J. E., & Cousins, E. (2001). Teaching spirits: Understanding Native American religious traditions. Oxford, England: Oxford University Press.
Campbell, B. (2013). Corbell settlement finalized after years of litigation: Victory at last? American Indian Law Review, 37(2), 629–647.
Campinha-Bacote, J., Claymore-Cuny, D., Cora-Bramble, D., Gilbert, J., Husbands, R. M., Like, R. C., … Tang, G. (2005). Transforming the face of health professions through cultural and linguistic competence education: The role of the HRSA Centers of Excellence. Washington, DC: Department of Health and Human Services, Health Resources and Services Administration.
Castro, F. G. (1998). Cultural competence training in clinical psychology: Assessment, clinical intervention, and research. In A. S. Bellack & M. Hersen (Editors in Chief and Vol. Eds.), Comprehensive Clinical Psychology: Vol. 10, Sociocultural and individual differences (pp. 127–140). Oxford, England: Pergamon.
Census Bureau. (2015). Profile America Facts for Features: American Indian and Alaska Native Heritage Month: November 2015. Washington, DC: Author.
Census Bureau. (2016). Profile America Facts for Features: American Indian and Alaska Native Heritage Month: November 2016. Washington, DC: Author.
Census Bureau. (2018). 2017 American Community Survey 1-year estimates. Washington, DC: Author.
Census Bureau, Population Division. (2018). Annual estimates of the resident population: April 1, 2010 to July 1, 2017. Washington, DC: Author.
Center for Behavioral Health Statistics and Quality. (2015). Behavioral health trends in the United States: Results from the 2014 National Survey on Drug Use and Health. NSDUH Series H-50, HHS Publication No. (SMA) 15-4927. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Military History, United States Army. (2011). Native American Medal of Honor recipients. Retrieved September 25, 2018, from https://history.army.mil/html/topics/natam/natam-moh.html
Center for Substance Abuse Treatment. (2009a). Clinical supervision and professional development of the substance abuse counselor. Treatment Improvement Protocol (TIP) Series 52. HHS Publication No. (SMA) 14-4435. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2009b). Substance abuse treatment: Addressing the specific needs of women. Treatment Improvement Protocol (TIP) Series 51. HHS Publication No. (SMA) 09-4426. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Centers for Disease Control and Prevention. (2008). Alcohol-attributable deaths and years of potential life lost among American Indians and Alaska Natives—United States, 2001–2005. Morbidity and Mortality Weekly Report, 57(34), 938–941.18756193
Centers for Disease Control and Prevention. (2014). Fact sheet: Binge drinking. Atlanta, GA: Author.
Chadwick, J. Q., Copeland, K. C., Daniel, M. R., Erb-Alvarez, J. A., Felton, B. A., Khan, S. I., … Payan, M. L. (2014). Partnering in research: A national research trial exemplifying effective collaboration with American Indian nations and the Indian Health Service. American Journal of Epidemiology, 180(12), 1202–1207.25389367
Chandler, M. J., & Lalonde, C. E. (2008). Cultural continuity as a moderator of suicide risk among Canada's First Nations. In L. Kirmayer & G. Valaskakis (Eds.), Healing traditions: The mental health of Aboriginal peoples in Canada (pp. 221–248). Vancouver, Canada: University of British Columbia Press.
Chinman, M., Hamilton, A., Butler, B., Knight, E., Murray, S., & Young, A. (2008). Mental health consumer providers: A guide for clinical staff. Santa Monica, CA: RAND.
Chino, M., & Debruyn, L. (2006). Building true capacity: Indigenous models for indigenous communities. American Journal of Public Health, 96(4), 596–599.16449598
Chipp, C., Dewane, S., Brems, C., Johnson, M. E., Warner, T. D., & Roberts, L. W. (2011). “If only someone had told me …”: Lessons from rural providers. Journal of Rural Health, 27(1), 122–130.21204979
Clark, J. D., & Winterowd, C. (2012). Correlates and predictors of binge eating among Native American women. Journal of Multicultural Counseling and Development, 40(2), 117–127.
Clark, J. J., Leukefeld, C., & Godlaski, T. (1999). Case management and behavioral contracting: Components of rural substance abuse treatment. Journal of Substance Abuse Treatment, 17(4), 293–304.10587931
Clifford, A., McCalman, J., Bainbridge, R., & Tsey, K. (2015). Interventions to improve cultural competency in health care for indigenous peoples of Australia, New Zealand, Canada and the USA: A systematic review. International Journal for Quality in Health Care, 27(2), 89–98.25758442
Collins, R. L., & McNair, L. D. (2002). Minority women and alcohol use. Alcohol Research and Health, 26(4), 251–256.12875034
Commission on Civil Rights (2004). Broken promises: Evaluating the Native American health care system. Washington, DC: Author.
Corey, G., Haynes, R., Moulton, P., & Muratori, M. (2010). Becoming a multiculturally competent supervisor. In Clinical supervision in the helping professions: A practical guide (2nd ed., pp. 121–138). Alexandria, VA: American Counseling Association.
Coyhis, D. (2007, March). Story of the sacred hoop of 100 eagle feathers. Red Lake, MN: Red Lake Nation Healing Day.
Cruickshank-Penkin, D., & Davidson, M. (1998). Working with Native American clients in alcoholism and substance abuse: A native and non-native perspective, Trainer's manual. Albany, NY: New York State Office of Alcoholism and Substance Abuse Services.
Dakil, S. R., Cox, M., Lin, H., & Flores, G. (2011). Racial and ethnic disparities in physical abuse reporting and child protective services interventions in the United States. Journal of the National Medical Association, 103(9–10), 926–931.22364062
Deloria, V. (1988). Custer died for your sins: An Indian manifesto. Norman: University of Oklahoma Press.
Department of Health and Human Services. (2001). Mental health: Culture, race, and ethnicity—A supplement to mental health: A report of the Surgeon General. HHS Publication No. (SMA) 01-3613. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Department of Health and Human Services. (2003). Developing cultural competence in disaster mental health programs: Guiding principles and recommendations. HHS Publication No. (SMA) 03-3828. Rockville, MD: Center for Mental Health Services, Substance Abuse and Mental Health Services Administration.
Department of Health and Human Services. (2010). To live to see the great day that dawns: Preventing suicide by American Indian and Alaska Native youth and young adults. HHS Publication (SMA) 10-4480, CMHS-NSPL-0196. Rockville, MD: Center for Mental Health Services, Substance Abuse and Mental Health Services Administration.
Department of Health and Human Services, Office of Disease Prevention and Health Promotion. (2002). Understanding our users: How to better deliver health information online to American Indians and Alaska Natives; Report on evaluation set-aside project tailoring web sites for special populations. Washington, DC: Author.
Department of Health and Human Services, Office of Minority Health. (2018). Profile: American Indian/Alaska Native. Retrieved September 24, 2018, from https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=3&lvlid=62
Department of Health and Human Services, Office of the Inspector General. (2011). Access to mental health services at Indian Health Service and tribal facilities (OEI-09-08-00580). Washington, DC: Author.
Department of Health and Human Services, Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment. (2005). Successful strategies for recruiting, training, and utilizing volunteers. A guide for faith- and community-based service providers. HHS Publication No. (SMA) 05-4005. Rockville, MD: Center for Substance Abuse Treatment.
Department of Housing and Urban Development. (2016). Emergency shelters and transitional housing. Retrieved August 30, 2016, from http://portal.hud.gov/hudportal/HUD?src=/states/alaska/homeless/shelters (page no longer available).
Department of Justice, Federal Bureau of Investigation. (2018). Crime in the United States, 2017: Table 43; Arrests by race and ethnicity, 2017. Washington, DC: Author.
Department of Labor, Bureau of Labor Statistics. (2018). Labor force characteristics by race and ethnicity, 2017 (BLS Report 1076). Washington, DC: Author.
Department of the Interior, Office of the Assistant Secretary–Indian Affairs. (2014). 2013 American Indian population and labor force report. Washington, DC: Author.
Dixon, M., & Iron, P. E. (2006). Strategies for cultural competency in Indian health care. Washington, DC: American Public Health Association.
Donovan, D. M., Thomas, L. R., Sigo, R. L., Price, L., Lonczak, H., Lawrence, N., … Bagley, L. (2015). Healing of the canoe: Preliminary results of a culturally tailored intervention to prevent substance abuse and promote tribal identity for native youth in two Pacific Northwest tribes. American Indian and Alaska Native Mental Health Research, 22(1), 42–76.25768390
Ducharme, L. J., Knudsen, H. K., & Roman, P. M. (2008). Emotional exhaustion and turnover intention in human service occupations: The protective role of coworker support. Sociological Spectrum, 28(1), 81–104.
Duran, B., Duran, E., & Brave Heart, M. Y. H. (1998). Native Americans and trauma of history. In R. Thornton (Ed.), Studying Native America: Problems and prospects (pp. 60–76). Madison: University of Wisconsin Press.
Duran, B., Oetzel, J., Parker, T., Malcoe, L. H., Lucero, J., & Jiang, Y. (2009). Intimate partner violence and alcohol, drug, and mental disorders among American Indian women in primary care. American Indian and Alaska Native Mental Health Research, 16(2), 11–27.19639543
Duran, E. (2006). Healing the soul wound: Counseling with American Indians and other native peoples. In A. E. Ivey & D. W. Sue (Series Eds.), Multicultural Foundations of Psychology and Counseling. New York, NY: Teachers College Press.
Duran, E., & Duran, B. (1995). Native American postcolonial psychology. Albany, NY: State University of New York Press.
Dutton, B. P. (1983). American Indians of the Southwest. Albuquerque: University of New Mexico Press.
Earle, K. A., & Cross, A. (2001). Child abuse and neglect among American Indian/Alaska Native children: An analysis of existing data. Seattle, WA: Casey Family Programs.
Eastman, C. A. O. (1907). The school days of an Indian boy: As recalled by himself. Pennsylvania School Journal, 55(12), 519–526.
Eastman, S., & Gray, J. S. (2011, August). Spirituality as a protective factor in American Indian mental health. Paper presented at the meeting of the American Psychological Association, Washington, DC.
Eby, L. T., Burk, H., & Maher, C. P. (2010). How serious of a problem is staff turnover in substance abuse treatment? A longitudinal study of actual turnover. Journal of Substance Abuse Treatment, 39(3), 264–271.20675097
Edwards, D., Burnard, P., Hannigan, B., Cooper, L., Adams, J., Juggessur, T., … Coyle, D. (2006). Clinical supervision and burnout: The influence of clinical supervision for community mental health nurses. Journal of Clinical Nursing, 15(8), 1007–1015.16879545
Ehlers, C. L., Gizer, I. R., Gilder, D. A., Ellingson, J. M., & Yehuda, R. (2013). Measuring historical trauma in an American Indian community sample: Contributions of substance dependence, affective disorder, conduct disorder and PTSD. Drug and Alcohol Dependence, 133(1), 180–187.23791028
Ehlers, C. L., Gizer, I. R., Gilder, D. A., & Yehuda, R. (2013). Lifetime history of traumatic events in an American Indian community sample: Heritability and relation to substance dependence, affective disorder, conduct disorder and PTSD. Journal of Psychiatric Research, 47(2), 155–161.23102628
Evans-Campbell, T. (2008). Historical trauma in American Indian/Native Alaska communities: A multilevel framework for exploring impacts on individuals, families, and communities. Journal of Interpersonal Violence, 23(3), 316–338.18245571
First Alaskan Institute. (n.d.). Culture Camp directory and resource guide: Alaska Native Culture Camps. Retrieved September 19, 2018, from https://firstalaskans.org/wp-content/uploads/2014/03/spirtcamp5.pdf
First Nations Behavioral Health Association. (2009). FNBHA catalogue of effective behavioral health practices for tribal communities. Bellingham, WA: Author.
Fisher, D. G., Pearce, F. W., Statz, D. J., & Wood, M. M. (2003). Employment retention of health care providers in frontier areas of Alaska. International Journal of Circumpolar Health, 62(4), 423–435.14964768
Fisher, P. A., & Ball, T. J. (2003). Tribal participatory research: Mechanisms of a collaborative model. American Journal of Community Psychology, 32(3–4), 207–216.14703257
Flies-Away, J. T., Garrow, C., & Sekaquaptewa, P. (2014). Tribal healing to wellness courts: The key components (2nd ed.). West Hollywood, CA: Tribal Law and Policy Institute.
Galanter, M. (1999). Network therapy for alcohol and drug abuse (Expanded ed.). New York, NY: Guilford Press.
Garner, B. R., Funk, R. R., & Hunter, B. D. (2013). The relationship between clinician turnover and adolescent treatment outcomes: An examination from the client perspective. Journal of Substance Abuse Treatment, 44(4), 444–448.23083980
Garrett, M. (1999). Understanding the “medicine” of Native American traditional values: An integrative review. Counseling and Values, 43(2), 84–98.
Garrett, M. T., & Pichette, E. F. (2000). Red as an apple: Native American acculturation and counseling with or without reservation. Journal of Counseling and Development, 78(1), 3–13.
Garroutte, E. M., Goldberg, J., Beals, J., Herrell, R., & Manson, S. M. (2003). Spirituality and attempted suicide among American Indians. Social Science and Medicine, 56(7), 1571–1579.12614706
Glisson, C., Schoenwald, S. K., Kelleher, K., Landsverk, J., Hoagwood, K. E., Mayberg, S., … The Research Network on Youth Mental Health. (2008). Therapist turnover and new program sustainability in mental health clinics as a function of organizational culture, climate, and service structure. Administration and Policy in Mental Health, 35(1–2), 124–133.18080741
Gone, J. P. (2004). Mental health services for Native Americans in the 21st century United States. Professional Psychology: Research and Practice, 35(1), 10–18.
Gone, J. P. (2013). Redressing First Nations historical trauma: Theorizing mechanisms for indigenous culture as mental health treatment. Transcultural Psychiatry, 50(5), 683–706.23715822
Gone, J. P., & Alcantara, C. (2005). Practice makes perfect? Identifying effective psychological treatments for mental health problems in Indian country. In E. H. Hawkins & R. D. Walker (Eds.), Best practices in behavioral health services for American Indians and Alaska Natives (pp. 113–142). Portland, OR: One Sky Center.
Gone, J. P., & Trimble, J. E. (2012). American Indian and Alaska Native mental health: Diverse perspectives on enduring disparities. Annual Review of Clinical Psychology, 8, 131–160.
Goodkind, J. R., Lanoue, M. D., & Milford, J. (2010). Adaptation and implementation of cognitive behavioral intervention for trauma in schools with American Indian youth. Journal of Clinical Child and Adolescent Psychology, 39(6), 858–872.21058132
Gray, J. S., & Rose, W. J. (2012). Cultural adaptation for therapy with American Indians and Alaska Natives. Journal of Multicultural Counseling and Development, 40(2), 82–92.
Greene, B. (1989). Homecoming: When the soldiers returned from Vietnam. New York, NY: Putnam.
Griner, D., & Smith, T. B. (2006). Culturally adapted mental health intervention: A meta-analytic review. Psychotherapy (Chicago), 43(4), 531–548.
Gurley, D., Novins, D. K., Jones, M. C., Beals, J., Shore, J. H., & Manson, S. M. (2001). Comparative use of biomedical services and traditional healing options by American Indian veterans. Psychiatric Services, 52, 68–74.11141531
Hammond, W. (2010). Principles of strength-based practice. Calgary, Canada: Resiliency Initiatives.
Harding, A., Harper, B., Stone, D., O’Neill, C., Berger, P., Harris, S., & Donatuto, J. (2012). Conducting research with tribal communities: Sovereignty, ethics, and data-sharing issues. Environmental Health Perspectives, 120(1), 6–10.21890450
Harrell, E. (2012). Violent victimization committed by strangers, 1993–2010 (NCJ 239424). Washington, DC: Department of Justice, Office of Justice Programs, Bureau of Justice Statistics.
Hartmann, W. E., & Gone, J. P. (2012). Incorporating traditional healing into an urban American Indian health organization: A case study of community member perspectives. Journal of Counseling Psychology, 59(4), 542–554.22731113
Hawkins, E. H., & Walker, R. D. (2005). Best practices in behavioral health services for American Indians and Alaska Natives. Portland, OR: One Sky National Resource Center.
Hays, H., Carroll, M., Ferguson, S., Fore, C., & Horton, M. (2014). The success of telehealth care in the Indian Health Service. Virtual Mentor, 16(12), 986–996.25493368
Health Research & Educational Trust. (2013). Becoming a culturally competent health care organization. Chicago, IL: Author.
Henderson, J. A. (2009). Legitimacy and contextual issues in traditional Lakota Sioux healing. In M. Incayawar, R. Wintrob, & L. Bouchard (Eds.), Psychiatrists and traditional healers (pp. 13–24). Hoboken, NJ: Wiley.
Henry, M., Watt, R., Rosenthal, L., & Shivji, A. (2017). The 2017 Annual Homeless Assessment Report (AHAR) to Congress. Washington, DC: Department of Housing and Urban Development.
Hilty, D. M., Luo, J. S., Morache, C., Marcelo, D. A., & Nesbitt, T. S. (2002). Telepsychiatry: An overview for psychiatrists. CNS Drugs, 16(8), 527–548.12096934
Hilty, D. M., Marks, S. L., Urness, D., Yellowlees, P. M., & Nesbitt, T. S. (2004). Clinical and educational telepsychiatry applications: A review. Canadian Journal of Psychiatry, 49(1), 12–23.14763673
Hilty, D. M., Nesbitt, T. S., Kuenneth, C. A., Cruz, G. M., & Hales, R. E. (2007). Rural versus suburban primary care needs, utilization, and satisfaction with telepsychiatric consultation. Journal of Rural Health, 23(2), 163–165.17397373
Hilty, D. M., Yellowlees, P. M., Cobb, H. C., Bourgeois, J. A., Neufeld, J. D., & Nesbitt, T. S. (2006). Models of telepsychiatric consultation–liaison service to rural primary care. Psychosomatics, 47(2), 152–157.16508028
Hirschfelder, A. B., & de Montaño, M. K. (1993). The Native American almanac: A portrait of Native America today (1st ed.). New York, NY: Prentice Hall General Reference.
Hoge, M. A., Morris, J. A., Daniels, A. S., Stuart, G. W., Huey, L. Y., & Adams, N. (2007). An action plan on behavioral health workforce development. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Hopper, F. (2015, July 20). Facebook group connects homeless Alaska Natives and their families. Indian Country Today. Available from https://newsmaven.io/indiancountrytoday/archive/facebook-group-connects-homeless-alaska-natives-and-their-families-ncvOn4yQxUyJy9s_nsH0yA
Indian Entities Recognized and Eligible To Receive Services from the United States Bureau of Indian Affairs; Bureau of Indian Affairs Notice, 83 Fed. Reg. 34863 (July 23, 2018).
Indian Health Service. (n.d.). Alaska Area [Factsheet]. Retrieved September 21, 2018, from www.ihs.gov/alaska/includes/themes/newihstheme/display_objects/documents/hf/area.pdf
Indian Health Service. (2011). American Indian/Alaska Native behavioral health briefing book. Rockville, MD: Author.
Indian Health Service. (2014). Community liaisons: Paving the way for incoming Indian health professionals [Brochure]. Rockville, MD: Author.
Indian Health Service. (2015a). New hire quick reference guide. Rockville, MD: Author.
Indian Health Service. (2015b). Trends in Indian health 2014 edition. Rockville, MD: Author.
Indian Health Service. (2017). Indian health focus: Injuries 2017 edition. Rockville, MD: Author.
Indian Law & Order Commission. (2013). A roadmap for making Native America safer: Report to the President & Congress of the United States. Los Angeles, CA: Author.
Indian Youth Suicide: Hearing before the Senate Committee on Indian Affairs, 109th Cong. 22 (2006) (testimony of Jo Ann Kauffman, President, Kauffman and Associates, Inc.).
Inman, A. G. (2008, August). Race and culture in supervision: Challenges and opportunities. Paper presented at the meeting of the American Psychological Association, Boston, MA.
James, R., Tsosie, R., Sahota, P., Parker, M., Dillard, D., Sylvester, I., … Kiana Group. (2014). Exploring pathways to trust: A tribal perspective on data sharing. Genetics in Medicine, 16(11), 820–826.24830328
Jilek-Aall, L. (1981). Acculturation, alcoholism and Indian-style Alcoholics Anonymous. Journal of Studies on Alcohol Supplement, 9, 143–158.7012345
Jiwa, A., Kelly, L., & Pierre-Hansen, N. (2008). Healing the community to heal the individual: Literature review of aboriginal community-based alcohol and substance abuse programs. Canadian Family Physician, 54(7), 1000.18625824
Johnston, S. L. (2002). Native American traditional and alternative medicine. Annals of the American Academy of Political and Social Science, 583(1), 195–213.
Jones, P., & Williams, A. M. (2007). Self care: A guide for addiction professionals. Silver Spring, MD: Central East Addiction Technology Transfer Center.
Jones, R. S. (1981). Alaska Native Claims Settlement Act of 1971 (Public Law 92-203): History and analysis together with subsequent amendments (CRS Report No. 81-127 GOV). Retrieved September 25, 2018, from www.alaskool.org/projects/ancsa/reports/rsjones1981/ancsa_history71.htm
Jumper Thurman, P., Plested, B. A., Edwards, R. W., Foley, R., & Burnside, M. (2004). Community readiness: The journey to community healing. In E. Nebelkopf & M. Phillips (Eds.), Healing and mental health for Native Americans: Speaking in red (pp. 77–86). Walnut Creek, CA: AltaMira Press.
Kadis, J. (2014). Workforce planning: How to recruit and retain mental health workers. Community Living Briefs, 2(1), 1–9.
Kalt, J. P., Cornell, S., Henson, E. C., Taylor, J. B., Curtis, C., Grant, K. W., … Lee, A. J. (2008). The state of the native nations: Conditions under U.S. policies of self-determination; The Harvard Project on American Indian Economic Development. New York, NY: Oxford University Press.
Katz, C. L., & Schuetz-Mueller, J. (2015). A guide to global mental health practice: Seeing the unseen. New York: Routledge.
Katz, J. R., O’Neal, G., Strickland, C. J., & Doutrich, D. (2010). Retention of Native American nurses working in their communities. Journal of Transcultural Nursing, 21(4), 393–401.20592062
Kaufman, C. E., Beals, J., Croy, C., Jiang, L., & Novins, D. K. (2013). Multilevel context of depression in two American Indian tribes. Journal of Consulting and Clinical Psychology, 81(6), 1040–1051.24016293
Keltner, B., Kelley, F. J., & Smith, D. (2004). Leadership to reduce health disparities: A model for nursing leadership in American Indian communities. Nursing Administration Quarterly, 28(3), 181–190.15446606
Kim, C. (2000). Recruitment and retention in the Navajo Area Indian Health Service. Western Journal of Medicine, 173(4), 240–243.11017982
King, J., Trimble, J. E., Morse, G. S., & Thomas, L. R. (2014). North American Indian and Alaska Native spirituality and psychotherapy. In P. S. Richards & A. E. Bergin (Eds.), Handbook of psychotherapy and religious diversity (2nd ed., pp. 451–471). Washington, DC: American Psychological Association.
King, M., Smith, A., & Gracey, M. (2009). Indigenous health part 2: The underlying causes of the health gap. Lancet, 374(9683), 76–85.19577696
Knudsen, H. K., Ducharme, L. J., & Roman, P. M. (2008). Clinical supervision, emotional exhaustion, and turnover intention: A study of substance abuse treatment counselors in the Clinical Trials Network of the National Institute on Drug Abuse. Journal of Substance Abuse Treatment, 35(4), 387–395.18424048
Knudsen, H. K., Johnson, J. A., & Roman, P. M. (2003). Retaining counseling staff at substance abuse treatment centers: Effects of management practices. Journal of Substance Abuse Treatment, 24(2), 129–135.12745030
Kochanek, K. D., Murphy, S. L., Xu, J., & Tejada-Vera, B. (2016). Deaths: Final data for 2014. National Vital Statistics Reports, 65(4), 1–122.
Korhonen, M. (2006). Suicide prevention: Inuit traditional practices that encouraged resilience and coping. Ottawa, Canada: National Aboriginal Health Organization.
Korsmo, F. L. (1994). The Alaska Natives. In F. L. Korsmo (Ed.), Polar peoples: Self-determination and development (pp. 81–104). London, England: Minority Rights Group.
LaBelle, J. (2005). Boarding school: Historical trauma among Alaska's native people. Anchorage, AK: National Resource Center for American Indian, Alaska Native, and Native Hawaiian Elders.
LaFromboise, T. (1995). Counseling and therapy with Native American Indians [Video]. Available from https://search.alexanderstreet.com/preview/work/bibliographic_entity%7Cvideo_work%7C1778779?ssotoken=anonymous
LaFromboise, T. D., & Fleming, C. (1990). Keeper of the fire: A profile of Carolyn Attneave. Journal of Counseling and Development, 68(5), 537–547.
Langdon, S. J. (2002). The native people of Alaska: Traditional living in a northern land. Homer, AK: Wizard Works.
Le, T. N., & Gobert, J. M. (2013). Translating and implementing a mindfulness-based youth suicide prevention intervention in a Native American community. Journal of Child and Family Studies, 24, 12–23.
Lewinsohn, P. M., Antonuccio, D. O., Breckenridge, J. S., & Teri, L. (1984). The Coping With Depression Course: A psychoeducational intervention for unipolar depression. Eugene, OR: Castalia.
Libby, A. M., Orton, H. D., Novins, D. K., Beals, J., & Manson, S. M. (2005). Childhood physical and sexual abuse and subsequent depressive and anxiety disorders for two American Indian tribes. Psychological Medicine, 35(3), 329–340.15841869
Libby, A. M., Orton, H. D., Novins, D. K., Spicer, P., Buchwald, D., Beals, J., … AI-SUPERPFP Team. (2004). Childhood physical and sexual abuse and subsequent alcohol and drug use disorders in two American-Indian tribes. Journal of Studies on Alcohol, 65(1), 74–83.15000506
Lobo, S., & Vaughan, M. M. (2003). Substance dependency among homeless American Indians. Journal of Psychoactive Drugs, 35(1), 63–70.12733760
Lowe, J., Riggs, C., & Henson, J. (2011). Principles for establishing trust when developing a substance abuse intervention with a Native American community. Creative Nursing, 17(2), 68–73.21563633
Lowe, J., & Struthers, R. (2001). A conceptual framework of nursing in Native American culture. Journal of Nursing Scholarship, 33(3), 279–283.11552556
Lucero, E. (2011). From tradition to evidence: Decolonization of the evidence-based practice system. Journal of Psychoactive Drugs, 43(4), 319–324.22400463
Mackey, D., & Zavadil, F. (2003a). Native American Cultural Assessment Survey of Accredited Substance Abuse Programs in South Dakota. Iowa City, IA: Prairielands Addiction Technology Transfer Center.
Mackey, D., & Zavadil, F. (2003b). Native American curriculum for state accredited, non-tribal substance abuse programs in South Dakota: Pre-test. Iowa City, IA: Prairielands Addiction Technology Transfer Center.
Mackey, D., Zavadil, F., Skinstad, A. H., Peters, C., & Summers, K. M. (2008). Outcomes of a Native American cultural education program for non-native counselors. Poster session presented at the meeting of the Midwest Consortium on Problem Gambling & Substance Abuse. Retrieved September 27, 2018, from www.888betsoff.org/links/08_presentations/handouts/1B.pdf
Manatowa-Bailey, J. (2007). On the brink. Cultural Survival Quarterly, 31(2). Retrieved September 19, 2018, from www.culturalsurvival.org/publications/cultural-survival-quarterly/brink
Manson, S. M., Beals, J., Klein, S. A., Croy, C. D., & AI-SUPERPFP Team. (2005). Social epidemiology of trauma among 2 American Indian reservation populations. American Journal of Public Health, 95(5), 851–859.15855465
Manson, S. M., & Brenneman, D. L. (1995). Chronic disease among older American Indians: Preventing depressive symptoms and related problems of coping. In D. Padgett (Ed.), Handbook on ethnicity, aging, and mental health (pp. 284–303). Westport, CT: Greenwood Press.
Marbella, A. M., Harris, M. C., Diehr, S., Ignace, G., & Ignace, G. (1998). Use of Native American healers among Native American patients in an urban Native American health center. Archives of Family Medicine, 7(2), 182–185.9519925
Martin, J. E. (2003). “The greatest evil”: Interpretations of Indian prohibition laws, 1832–1953. Great Plains Quarterly, 23(1), 35–53.
Martin, S., & Hill, A. (2009, July). The changing economic status of Alaska Natives, 1970–2007 (Web Note No. 5). Retrieved September 19, 2018, from https://pubs.iseralaska.org/media/991d5687-00f8-4151-ba1a-cae4be5d2346/WebNote5.pdf
Matrix Institute on Addictions. (2014). Matrix Model: Culturally designed client handouts for American Indians/Native Alaskans. Los Angeles, CA: Author.
Mays, V. M., Gallardo, M., Shorter-Gooden, K., Robinson-Zanartu, C., Smith, M., McClure, F., … Ahhaity, G. (2009). Expanding the circle: Decreasing American Indian mental health disparities through culturally competent teaching about American Indian mental health. American Indian Culture and Research Journal, 33(3), 61–83.25284917
McCormick, R. M. (1998). Ethical considerations in First Nations counselling and research. Canadian Journal of Counselling, 32(4), 284–297.
McDonald, J. D., & Gonzales, J. (2006). Cognitive behavioral therapy with American Indians. In P. A. Hays & G. Iwamasa (Eds.), Culturally responsive cognitive-behavioral therapy: Assessment, practice, and supervision (1st ed., pp. 23–45). Washington, DC: American Psychological Association.
McFarland, B. H., Gabriel, R. M., Bigelow, D. A., & Walker, R. D. (2006). Organization and financing of alcohol and substance abuse programs for American Indians and Alaska Natives. American Journal of Public Health, 96(8), 1469–1477.16809606
McKay, J. R., Lynch, K. G., Shepard, D. S., & Pettinati, H. M. (2005). The effectiveness of telephone-based continuing care for alcohol and cocaine dependence: 24-month outcomes. Archives of General Psychiatry, 62(2), 199–207.15699297
Mehl-Madrona, L. (1997). Coyote medicine: Lessons from Native American healing. New York, NY: Scribner.
Mehl-Madrona, L. E. (1999). Native American medicine in the treatment of chronic illness: Developing an integrated program and evaluating its effectiveness. Alternative Therapies in Health and Medicine, 5(1), 36–44.
Mehl-Madrona, L., & Mainguy, B. (2014). Introducing healing circles and talking circles into primary care. Permanente Journal, 18(2), 4–9.
Meyer, D., Hamel-Lambert, J., Tice, C., Safran, S., Bolon, D., & Rose-Grippa, K. (2005). Recruiting and retaining mental health professionals to rural communities: An interdisciplinary course in Appalachia. Journal of Rural Health, 21(1), 86–91.15667015
Middelton-Moz, J. (1989). Children of trauma: Rediscovering your discarded self. Deerfield Beach, FL: Health Communications.
Middelton-Moz, J., & Dwinell, L. (2010). After the tears: Helping adult children of alcoholics heal their childhood trauma (Rev. and expanded ed.). Deerfield Beach, FL: Health Communications.
Miller, W. R., Meyers, R. J., & Hiller-Sturmhöfel, S. (1999). The community-reinforcement approach. Alcohol Research and Health, 23(2), 116–121.10890805
Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
Miller, W. R., & Rose, S. G. (2009). Toward a theory of motivational interviewing. American Psychologist, 64(6), 527–537.19739882
Moghaddam, J. F., & Momper, S. L. (2011). Integrating spiritual and Western treatment modalities in a Native American substance user center: Provider perspectives. Substance Use and Misuse, 46(11), 1431–1437.21810077
Mohatt, D. F., Adams, S. J., Bradley, M. M., & Morris, C. D. (2005). Mental health and rural America: 1994–2005. Rockville, MD: Department of Health and Human Services, Health Resources and Services Administration, Office of Rural Health Policy.
Mohatt, G. V., Fok, C. C. T., Henry, D., People Awakening Team, & Allen, J. (2014). Feasibility of a community intervention for the prevention of suicide and alcohol abuse with Yup'ik Alaska Native youth: The Elluam Tungiinun and Yupiucimta Asvairtuumallerkaa studies. American Journal of Community Psychology, 54(1–2), 153–169.24952248
Momaday, N. S. (1976). The names: A memoir. New York, NY: Harper & Row.
Morgan, R., & Freeman, L. (2009). The healing of our people: Substance abuse and historical trauma. Substance Use and Misuse, 44(1), 84–98.19137484
Moss, R. K., Taylor, T., & May, P. A. (2003). Robert Wood Johnson Foundation Healthy Nations Initiative evaluation: The stories and lessons of fighting substance abuse in Native American communities. Princeton, NJ: Robert Wood Johnson Foundation.
Napoleon, H. (1996). Yuuyaraq: The way of the human being. Fairbanks: Alaska Native Knowledge Network, University of Alaska Fairbanks.
Naquin, V., Trojan, J., O’Neil, G., & Manson, S. M. (2006). The Therapeutic Village of Care: An Alaska Native alcohol treatment model. Therapeutic Communities, 27(1), 106–121.
National American Indian and Alaska Native Addiction Technology Transfer Center. (2015). American Indian & Alaska Native Leadership Academy 2015–2016: Mentor application. Iowa City, IA: Author.
National Association of Community Health Centers. (2011). Clinical recruitment and retention toolkit. Bethesda, MD: Author.
National Association of Resource & Development Councils. (2007). Workbook for understanding and improving partnerships with American Indian and Alaska Natives. Washington, DC: Author.
National Association of State Mental Health Program Directors. (2015). Assessment #4: Partnering with tribal governments to meet the mental health needs of American Indian/Alaska Native consumers. Alexandria, VA: Author.
National Center for Health Statistics. (2014). Health, United States, 2013: With special feature on prescription drugs. HHS Publication No. 2014-1232. Hyattsville, MD: Author.
National Congress of American Indians. (2006). Methamphetamines in Indian Country: An American problem uniquely affecting Indian Country. Washington, DC: Author.
National Drug Court Resource Center. (2012). What is a Tribal Healing to Wellness Court? Retrieved August 30, 2016, from http://ndcrc.org/node/351 (page with post no longer available).
National Indian Child Welfare Association. (2015, September). Lessons learned: Observations and reflections on 20 years of tribal systems of care. Honoring Innovations. Retrieved October 2, 2018, from www.nicwa.org/wp-content/uploads/2016/11/2015_LessonsLearned_Newsletter.pdf
National Museum of the American Indian. (2007). Native words, native warriors [Companion website to exhibit]. Retrieved September 21, 2018, from https://americanindian.si.edu/static/education/codetalkers/html/index.html
National Rural Recruitment and Retention Network. (2013). Recruiting for retention: The recruitment and retention manual of the National Rural Recruitment and Retention Network, Inc. (Rev.). Fountain City, WI: Author.
National Urban Indian Family Coalition. (2009). Urban Indian America: The status of American Indian and Alaska Native children and families today. Seattle, WA: Author.
Native American Alliance Foundation. (2006). Tribal healing to wellness court. Albuquerque, NM: Author.
Native American Center for Excellence. (n.d.). Steps for conducting research and evaluation in Native communities. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Nebelkopf, E., & Phillips, M. (Eds.). (2004). Healing and mental health for Native Americans: Speaking in red. Walnut Creek, CA: AltaMira Press.
Niven, J. A. (2010). Client-centered, culture-friendly behavioral health care techniques for work with Alaska natives in the Bering Strait region. Social Work in Mental Health, 8(4), 398–420.
Northwest Frontier Addiction Technology Transfer Center. (2003). Co-occurring disorders Part 2: Native Americans. Addiction Messenger, 6(5), 1–3.
Oetzel, J., & Duran, B. (2004). Intimate partner violence in American Indian and/or Alaska Native communities: A social ecological framework of determinants and interventions. American Indian and Alaska Native Mental Health Research, 11, 49–69.15536589
Ogunwole, S. U. (2006). We the people: American Indians and Alaska Natives in the United States (CENSR-28). Census 2000 Special Reports. Washington, DC: Census Bureau.
Ongtooguk, P. (n.d.). Alaska's cultures: Alaska Natives fight for civil rights. Retrieved November 6, 2018, from https://alaskadigitalacademy.org/akh/articles/article498a.html
Oregon Addictions & Mental Health Division. (n.d.). Oregon Addictions & Mental Health Division Evidence-Based Programs Tribal Practice Approval Form. Retrieved October 25, 2018, through www.oneskycenter.org/osc/health-care-issues/evidence-based-practices-and-best-practices
Payne, D., Olson, K., & Parrish, J. W. (2013). Pathway to hope: An indigenous approach to healing child sexual abuse. International Journal of Circumpolar Health, 72(1).
Peate, W. F. (2003). Listening with your heart: Lessons from Native America. Tucson, AZ: Rio Nuevo.
Perry, S. W. (2004). American Indians and crime: A BJS statistical profile, 1992–2002 (NCJ 203097). Washington, DC: Department of Justice.
Pettit, K. L. S., Kingsley, G. T., Biess, J., Bertumen, K., Pindus, N., Narducci, C., & Budde, A. (2014). Continuity and change: Demographic, socioeconomic, and housing conditions of American Indians and Alaska Natives. Washington, DC: Department of Housing and Urban Development.
Pew Forum on Religion & Public Life. (2008). U.S. Religious Landscape Survey: Religious affiliation; Diverse and dynamic. Washington, DC: Author.
Picou, J. S. (2000). The “Talking Circle” as sociological practice: Cultural transformation of chronic disaster impacts. Sociological Practice, 2(2), 77–97.
Plested, B. A., Jumper-Thurman, P., & Edwards, R. W. (2014). Community readiness manual on suicide prevention in Native communities (Community Readiness Model handbook) (Rev. ed.). Retrieved November 6, 2018, from www.samhsa.gov/sites/default/files/tribal_tta_center_.3.b_commreadinessmanual_final_3.6.14.pdf
Poupart, J., Red Horse, J., Martinez, C., & Scharnberg, D. (2001). To build a bridge: Working with American Indian communities. St. Paul, MN: American Indian Policy Center.
Pritzker, B. (1998). Native Americans: An encyclopedia of history, culture, and peoples. Santa Barbara, CA: ABC-CLIO.
Prochaska, J. O., DiClemente, C. C., & Norcross, J. C. (1992). In search of how people change: Applications to addictive behaviors. American Psychologist, 47(9), 1102–1114.1329589
Reese, R. J., Conoley, C. W., & Brossart, D. F. (2002). Effectiveness of telephone counseling: A field-based investigation. Journal of Counseling Psychology, 49(2), 233–242.
Reynaga-Abiko, G. (2006). A guide for culturally sensitive clinical practice with Native Americans [Review of the book Mental health care for urban Indians: Clinical insights from native practitioners by T. M. Witko (Ed.)]. PsycCRITIQUES, 51(34).
Rhoades, E. R. (2009). The Indian Health Service and traditional Indian medicine. Virtual Mentor, 11(10), 793–798.23206946
Robbins, R., Asetoyer, D., Nelson, D., Stilen, P., & Tall Bear, C. (2011). Through the diamond threshold: Promoting cultural competency in understanding American Indian substance misuse. Kansas City, MO: Mid-America Addiction Technology Transfer Center.
Roebuck, M. (2007). The strength-based approach: Philosophy and principles for practice. Cornwall, Canada: Youth Now Intervention Services.
Rosay, A. B. (2016, May). Violence against American Indian and Alaska Native women and men: 2010 findings from the National Intimate Partner and Sexual Violence Survey (NCJ 249736). Department of Justice, National Institute of Justice.
Rothrauff, T. C., Abraham, A. J., Bride, B. E., & Roman, P. M. (2011). Occupational turnover intentions among substance abuse counselors. Journal of Substance Abuse Treatment, 40(1), 67–76.20947285
Saskatchewan Indian Cultural Center. (2014). Plains Cree elders’ quotes. Retrieved September 24, 2018, from www.sicc.sk.ca/plains-cree-elders-quotes.html
Satir, V., & Baldwin, M. (1983). Satir step by step: A guide to creating change in families. Palo Alto, CA: Science and Behavior Books.
Schacht, R. M., & White, M. (2003). Improving employment outcomes for American Indians and Alaska Natives with alcohol dependency: Vocational rehabilitation strategies. Journal of Ethnicity in Substance Abuse, 2(4), 31–62.
Sealaska Heritage Institute. (2009). Sealaska Heritage Institute cultural values. Juneau, AK: Author.
Shore, J. H., Shore, J. H., & Manson, S. M. (2009). American Indian healers and psychiatrists. In M. Incayawar, R. Wintrob, & L. Bouchard (Eds.), Psychiatrists and traditional healers: Unwitting partners in global mental health (pp. 123–134). Hoboken, NJ: Wiley.
Siebens, J., & Julian, T. (2011). Native North American languages spoken at home in the United States and Puerto Rico: 2006–2010. Washington, DC: Census Bureau.
Skinstad, A. H. (2013). It takes a village—a community—to help our children stay healthy: Recovery oriented system of care (ROSC) in American Indian and Alaska Native communities. Prevention and Recovery, 2(5), 6–7.
Smith, L. T. (1999). Articulating an indigenous research agenda. In L. T. Smith (Ed.), Decolonizing methodologies: Research and indigenous peoples (pp. 123–141). London, England: Zed Books.
Sotero, M. (2006). A conceptual model of historical trauma: Implications for public health practice and research. Journal of Health Disparities Research and Practice, 1(1), 93–108.
Spillane, N. S., & Smith, G. T. (2007). A theory of reservation-dwelling American Indian alcohol use risk. Psychological Bulletin, 133(3), 395–418.17469984
Stein, L. I., & Santos, A. B. (1998). Assertive community treatment of persons with severe mental illness. New York, NY: Norton.
Stone, R. A., Whitbeck, L. B., Chen, X., Johnson, K., & Olson, D. M. (2006). Traditional practices, traditional spirituality, and alcohol cessation among American Indians. Journal of Studies on Alcohol, 67(2), 236–244.16562405
Substance Abuse and Mental Health Services Administration. (2010). Recovery oriented systems of care (ROSC) resource guide. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2013a). Behavioral health services for people who are homeless. Treatment Improvement Protocol (TIP) Series 55. HHS Publication No. (SMA) 13-4734. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2013b). Results from the 2012 National Survey on Drug Use and Health: Summary of national findings. NSDUH Series H-46, HHS Publication No. (SMA) 13-4795. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2014a). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2014b). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 14-4816. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2015). Using technology-based therapeutic tools in behavioral health services. Treatment Improvement Protocol (TIP) Series 60. HHS Publication No. (SMA) 15-4924. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration, Center for Mental Health Services, & Child, Adolescent and Family Branch. (2003). American Indian/Alaska Native Sustainability Strategic Planning Template. American Indian/Alaska Native Sustainability Self-Assessment Tool. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Prevention. (2014). Building the evaluation capacity of local programs serving American Indian/Alaska Native populations: Lessons learned. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration, Trauma and Justice Strategic Initiative. (2012). SAMHSA's working definition of trauma and guidance for trauma-informed approach. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration, Tribal Training and Technical Assistance Center. (2014). Evidence-based programs and practices handout. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Sue, D. W., Capodilupo, C. M., Torino, G. C., Bucceri, J. M., Holder, A. M. B., Nadal, K. L., & Esquilin, M. (2007). Racial microaggressions in everyday life: Implications for clinical practice. American Psychologist, 62(4), 271–286.17516773
Sue, D. W., & Sue, D. (2013). Counseling the culturally diverse: Theory and practice (6th ed.). Hoboken, NJ: Wiley.
Sutton, C. T., & Broken Nose, M. A. (1996). American Indian families: An overview. In M. McGoldrick, J. Giordano, & J. K. Pearce (Eds.), Ethnicity and family therapy (2nd ed., pp. 31–44). New York, NY: Guilford Press.
Sutton, C. T., & Broken Nose, M. A. (2005). American Indian families: An overview. In M. McGoldrick, J. Giordano, & N. Garcia-Preto (Eds.), Ethnicity and family therapy (3rd ed., pp. 43–54). New York, NY: Guilford Press.
Tamminen, A. W., Smaby, M. H., Powless, R. E., & Gum, M. F. (1980). Preparing Native American counselors for the chemically dependent Native American. Counselor Education and Supervision, 19, 311–317.
Taylor, J. B., & Kalt, J. P. (2005). American Indians on reservations: A databook of socioeconomic change between the 1990 and 2000 Censuses. Cambridge, MA: Harvard Project on American Indian Economic Development.
Thomson, L. (2000). Subsistence: Hunting and fishing rights—an essential part of life for many Native Alaskans—were put in peril with the Alaska Native Claims Settlement Act. Juneau Empire. Retrieved October 19, 2018, through http://eastnet1.asdk12.org/~Christopherson_Alaska_Studies3/S00318BCD.18/Booklet_13_Statehood_web.pdf
Tjaden, P., & Thoennes, N. (2006). Extent, nature, and consequences of rape victimization: Findings from the National Violence Against Women Survey (NCJ 210346). Washington, DC: Department of Justice, National Institute of Justice.
Tomlin, K., Walker, R. D., & Grover, J. (2014). Trainer's guide to Motivational interviewing: Enhancing motivation for change; A learner's manual for the American Indian/Alaska Native counselor. Portland, OR: One Sky Center.
Towle, A., Godolphin, W., & Alexander, T. (2006). Doctor–patient communications in the Aboriginal community: Towards the development of educational programs. Patient Education and Counseling, 62(3), 340–346.16860965
Tribal Law & Policy Institute. (2003). Tribal healing to wellness courts: The key components. (NCJ 188154). Washington, DC: Department of Justice, Office of Justice Programs.
Trimble, J. E., Scharron-del-Rio, M. R., & Hill, J. S. (2012). Ethical considerations in the application of cultural adaptation models with ethnocultural populations. In G. Bernal (Ed.), Cultural adaptations: Tools for evidence-based practice with diverse populations (pp. 45–67). Washington, DC: American Psychological Association.
Tullar, J. M., Amick, B. C., III, Brewer, S., Diamond, P. M., Kelder, S. H., & Mikhail, O. (2016). Improve employee engagement to retain your workforce. Health Care Management Review, 41(4), 316–324.26207655
Ukpeagvik Iñupiat Corporation. (2015). Shareholder highlight - Kelsey Campbell Haake. Nasirvik, 11(3), 5.
University of Alaska Fairbanks. (2013). Science in relation to traditional native ways. Fairbanks, AK: Author.
Urban Indian Health Commission. (2007). Invisible tribes: Urban Indians and their health in a changing world. Seattle, WA: Author.
Urban Indian Health Institute. (2008). Reported health and health-influencing behaviors among urban American Indians and Alaska Natives: An analysis of data collected by the Behavioral Risk Factor Surveillance System. Seattle, WA: Author.
Urban Indian Health Institute. (2014). Supporting wellness: Substance abuse services at urban Indian health organizations. Seattle, WA: Author.
Urban Indian Health Institute, Seattle Indian Health Board. (2015). Supporting sobriety among American Indians and Alaska Natives: A literature review. Seattle, WA: Author.
Venner, K. L., Feldstein, S. W., & Tafoya, N. (2006). Native American motivational interviewing: Weaving Native American and Western practices; A manual for counselors in Native American communities. Retrieved September 25, 2018, from https://casaa.unm.edu/download/nami.pdf
Walls, M. L., Johnson, K. D., Whitbeck, L. B., & Hoyt, D. R. (2006). Mental health and substance abuse services preferences among American Indian people of the Northern Midwest. Community Mental Health Journal, 42, 521–535.17143732
Walter R. McDonald & Associates & ICF Macro. (2009). National evaluation of the Comprehensive Community Mental Health Services for Children and Their Families Program: Exploratory description of financing and sustainability in American Indian and Alaska Native system of care communities; Summary report & appendices. Rockville, MD: Authors.
Walters, K. L., & Simoni, J. M. (2002). Reconceptualizing native women's health: An “indigenist” stress-coping model. American Journal of Public Health, 92(4), 520–524.11919043
Western Interstate Commission for Higher Education. (1998). Cultural competence guidelines in managed care mental health services for Native American populations. Boulder, CO: Author.
Whitbeck, L. B., Adams, G. W., Hoyt, D. R., & Chen, X. (2004). Conceptualizing and measuring historical trauma among American Indian people. American Journal of Community Psychology, 33(3–4), 119–130.15212173
Whitbeck, L. B., Walls, M. L., Johnson, K. D., Morrisseau, A. D., & McDougall, C. M. (2009). Depressed affect and historical loss among North American indigenous adolescents. American Indian and Alaska Native Mental Health Research, 16(3), 16–41.20052631
White Bison. (2002). The Red Road to Wellbriety: In the Native American way. Colorado Springs, CO: Author.
Witherspoon, G. (1977). Language and art in the Navajo universe. Ann Arbor: University of Michigan Press.
Witkiewitz, K., Greenfield, B. L., & Bowen, S. (2013). Mindfulness-based relapse prevention with racial and ethnic minority women. Addictive Behaviors, 38(12), 2821–2824.24018224
Wolpe, J., & Abrams, J. (1991). Post-traumatic stress disorder overcome by eye-movement desensitization: A case report. Journal of Behavior Therapy and Experimental Psychiatry, 22(1), 39–43.1680883
Yuan, N. P., Bartgis, J., & Demers, D. (2014). Promoting ethical research with American Indian and Alaska Native people living in urban areas. American Journal of Public Health, 104(11), 2085–2091.25211730
Yutrzenka, B. A., Todd-Bazemore, E., & Caraway, S. J. (1999). FourWinds: The evolution of culturally inclusive clinical psychology training for Native Americans. International Review of Psychiatry, 11, 129–135.