# Part 2, Chapter 2

## Introduction

“If you have one hundred people who live together, and if each one cares for the rest, there is one mind.”

—Shining Arrow, Crow

The final chapter of this TIP provides you with organizational tools to help you, as administrators and program managers, address a number of the challenges mentioned in Part 2, Chapter 1. As you discover your unique pathways to designing and implementing programs and services specifically tailored to meet the behavioral health needs of American Indian and Alaska Native clients, this chapter offers you tools for:

• Developing a culturally competent and responsive workforce.
• Developing native evidence-based practices (EBPs).
• Integrating care, including traditional practices in behavioral health programs.
• Creating sustainability.

Some of these tools were originally developed for a specific American Indian or Alaska Native tribe or community, so in some circumstances, the material was revised to make it suitable for a pan-native population. Further adaptations may be required if your program is serving a specific tribe or community to make the material more culturally relevant. The tools presented in this chapter are either in the public domain, have been adapted from the original, or have been reprinted with permission from the author for use in your program.

## Developing a Culturally Competent and Responsive Workforce

The first step in developing a culturally competent and responsive workforce in American Indian and Alaska Native communities is hiring and then orienting new staff to the community, culture, and traditions of the people they will be serving. The Indian Health Service (IHS) has produced a number of publications (available at www.ihs.gov/retention/retentionstrategies) that may be helpful to your program in recruiting and retaining staff. The New Hire Quick Reference Guide (IHS, 2015a) describes specific tasks for working with newly hired staff in your organization, including the community liaison (see “The Role of the Community Liaison”). The tasks are organized chronologically beginning prior to the employee's start date and continuing through the first 6 months.

THE ROLE OF THE COMMUNITY LIAISON

A key staff member involved in the orientation of new behavioral health employees is the community liaison. The community liaison keeps the lines of communication open between the local community and the Indian health facility or behavioral health program. A tribal leader, an accepted community member, an elder, or a supervisor at your program may act as the liaison. He or she takes on specific roles, such as:

• An ambassador who understands your program's mission and fosters goodwill and respect in the community, while also promoting the vision and values of the local tribe.
• A leader who maintains strong, collaborative relationships between your program and the local community and shares information about local events and community issues with your program, tribal entities, and community stakeholders.
• A guide who will introduce new staff to the community and expose staff to many aspects of the tribal culture, including ceremonial events, observances, and traditions.

Source: IHS, 2014.

NEW HIRE QUICK REFERENCE GUIDE

1. Prior to the Start Date

Welcoming an employee to your Indian health facility and paving the way for long-term success is easy if you set up an action plan that appropriately addresses his or her ability to succeed within the organization from the start. Your plan to integrate him or her into your facility should begin immediately following his or her acceptance of the job offer and incorporate the essential steps below.

ACTION | TO BE COMPLETED BY
One of the most important documents a new hire needs is an official letter of hire from Human Resources (HR) detailing the position, responsibilities, salary, and specific hiring terms. This letter provides official documentation of employment, which is necessary for mortgage lenders, school enrollment, health insurance, benefits, and utility activation, as well as other key tasks needed to settle in. Include a “Welcome” letter and an information packet containing information about the facility, community (background, traditions, observances), local site amenities (housing, transportation, schools, businesses, services, etc.), and other pertinent information about your site 1 month prior to the new hire coming on board. Include a point of contact such as a liaison or mentor at the facility. | Chief Executive Officer (CEO)/Clinical Director/Supervisor
Identify staff with similar responsibilities to function as the new employee's coach/mentor for work-related processes and procedures. | CEO/Clinical Director/Supervisor
Work closely with your HR representative and arrange to have all necessary paperwork ready for the new employee's arrival. | CEO/Clinical Director/ Supervisor/HR Representative
Likewise, notify your Information Technology (IT) department of the new hire and arrange to have all the necessary technology and telecommunications equipment set up prior to his or her arrival (computer, email, phone, beeper, etc.). | CEO/Clinical Director/ Supervisor/IT Department
Prepare the new employee's work area with any necessary office supplies prior to arrival date. | CEO/Clinical Director/Supervisor
Add the new employee to the department or unit's organizational contact and routing lists within a week of reporting date. | CEO/Clinical Director/Supervisor
Schedule the new employee's first-week activities and prepare his or her agenda, including names, titles, and departments/areas of key contacts with whom he or she will meet. | CEO/Clinical Director/Supervisor
Send an introductory email to staff announcing the new employee's arrival, function, and location. | CEO/Clinical Director/Supervisor
Make plans to have lunch with the new employee or arrange to have lunch brought in to the facility for a meet-and-greet with the staff on the first day. | CEO/Clinical Director/Supervisor
Identify an appropriate community/facility representative to serve as a cultural liaison for the new hire. Arrange to have the chosen liaison available to meet with the new hire during his or her first week to ensure he or she has an appropriate understanding of the community and tribal ways. | CEO/Clinical Director/ Supervisor/Cultural Liaison

2. The First Day

Although a new job can be exciting for someone new to your team, it can also bring first-day jitters and an overwhelming sense of stress while trying to remember names, learn new processes, and find his or her way around the facility. You can help to alleviate these concerns by putting the new hire at ease, assuring him or her that an organizational chart is available to use as a “who's who” resource and to map out each team within each department. Also, let the new hire know that you have an open-door policy should he or she have any questions or concerns. In doing so, you will immediately establish a sense of value and an understanding that your support is always available. Also, take the first day to confirm the new hire's schedule, daily responsibilities and, if applicable, any previously agreed-upon telecommuting arrangement, and then share that information with the HR department representative who's responsible for going over the new hire's employee orientation. It is important to let the employee know that he or she should allow a few hours that first day to go over all necessary documentation and employment benefits with HR.

ACTION | TO BE COMPLETED BY
Be available to personally greet the new employee as he or she arrives. Schedule meetings, conferences, and phone calls for later in the day. | CEO/Clinical Director/ Supervisor
Personally, lead the new employee through a tour of the facility. Orient him or her to specific locations, such as:; • Lunchroom or break room; • Bathrooms; • Conference rooms; • Office equipment and supplies; • Parking | CEO/Clinical Director/ Supervisor
Introduce the new employee to the HR representative responsible for going over all paperwork, benefits, etc. | CEO/HR Representative
Introduce the new employee to all staff and the chosen mentor with whom he or she will work. | CEO/Clinical Director/ Supervisor
Orient the new hire to all technology:; • Phone/intercom systems; • Computer system; • IT/security; • Time-management software; • Meeting schedules | CEO/Clinical Director/ Supervisor/IT Department
Introduce the new employee to the executive staff—CEO (if other than the supervisor), Chief Marketing Officer, Chief Financial Officer, etc.—to acquaint him or her with management and to serve as a welcome to the entire facility team. | CEO/Clinical Director/ Supervisor

3. The First Week

Orientation sessions are not just important to new employees. They are also essential to the Indian health program because they address the organization's policies and procedures and new-hire concerns and help staff members form accurate expectations about the job they have just taken on. Performing the tasks below will ensure that your new employees are fully on board right from the beginning.

ACTION | TO BE COMPLETED BY
Meet to review and discuss the new hire's IHS orientation, including explaining the following:; • IHS Mission; • Introduction to IHS (IHS 101); • Employee ethics; • Communication; • Customer service | Supervisor
Identify training and development activities needed within the first 6 months and sign up the new employee for appropriate classes. | Supervisor
Set performance expectations and discuss how and when the employee will be evaluated. | Supervisor
Review and discuss the employee's first week, answer his or her questions, and solicit his or her feedback. | Supervisor
Introduce the new hire to the community liaison chosen to help with his or her immersion to the community. Ensure the new hire understands the local traditions, heritage, cultural observances and ceremonies. | Supervisor/Community Liaison

4. Within the First 6 Months

Inspiring a new employee to want to remain at your Indian health facility is an ongoing task. Retention is a process that must be actively nurtured and developed during the tenure of each employee. This includes giving your employees the attention they require and deserve, offering encouragement and support, acknowledging a job well done and ensuring that he or she has a voice within your organization and that his or her input—as well as the input of all staff members—is key to the success of your facility. In short—give your employees a reason to stay!

ACTION | TO BE COMPLETED BY
Check in regularly with the new employee to see if there are any questions or concerns. Provide feedback often, including positive reinforcement. | CEO/Clinical Director/ Supervisor
Schedule a 6-month new-hire evaluation. | Supervisor
Provide monthly feedback to new employees regarding their job performance, including a formal performance evaluation in their third month. | Supervisor
Celebrate each new hire's 6-month anniversary with a planned lunch or other form of recognition. | CEO/Clinical Director/ Supervisor

Adapted from material in the public domain.

Once your staff is in place, it is essential to provide culturally appropriate education opportunities for immersion into tribal culture, training, and culturally appropriate clinical supervision for all staff, but particularly for non-native providers. Two instruments, the Native American Cultural Assessment Survey and the Sample Pretest for Non-Native Counselors, provided below, are adapted from the Native American Curriculum for State Accredited, Non-Tribal Mental Health & Substance Abuse Programs in South Dakota offered by the National American Indian and Alaska Native Addiction Technology Transfer Center.

A NOTE TO ADMINISTRATORS AND PROGRAM MANAGERS

The original training curriculum was developed to be applicable to a particular group of tribes, but in adapting these materials, the attempt was made to identify cultural practices that are common to a number of American Indian and Alaska Native cultures or are now considered pan-Native American. Not all of these practices may be relevant to a given native culture. These documents should be tailored, as appropriate, to specific cultures (e.g., highlighting specific traditional practices, introducing words from that culture's language). These surveys were intended to assess the cultural knowledge of substance abuse providers, but they are relevant in any behavioral health setting that offers services to American Indian and Alaska Native clients.

The Native American Cultural Assessment Survey is a useful tool to help you evaluate the cultural competence of your entire program, but it can also be used to give you a sense of how well your organization is doing in recruitment and hiring, providing culturally responsive training and supervision to your staff, and offering opportunities for staff immersion in the local tribal culture.

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

NATIVE AMERICAN CULTURAL ASSESSMENT SURVEY (CONTINUED)

You can use the Sample Pretest for Non-Native Counselors to assess the knowledge of non-native providers before and after cultural competence training to evaluate how effective the training was in educating providers on key items of American Indian and Alaska Native culture.

SAMPLE PRETEST FOR NON-NATIVE COUNSELORS

1 What is the theoretical basis for the high prevalence of type 2 diabetes among Native American populations?
  a The shortage of medical personnel (doctors, nurses, etc.) in healthcare facilities on reservations
  b Being overweight and having insufficient physical activity
  c A lack of education about the prevention of diabetes
  d A common virus that is unique to American Indians
2 What are the language dialects of the tribal groups of tribes in your state?
  a INSERT
  b APPROPRIATE
  c LANGUAGE
  d GROUPS
3 “Vision quest” ceremonies are primarily held to:
  a Learn how to interpret dreams
  b Learn how to become a medicine person
  c Treat diabetes and health conditions related to alcohol abuse
  d Offer prayers
4 In relationships with the federal government, what distinguishes the Native American tribal groups from other ethnic minorities?
  a Tribal groups have different languages, songs, dances, dress, and customs
  b Tribal groups live primarily in remote areas
  c Tribal groups are sovereign nations with their own governments
  d Tribal groups can be members of the National Congress of American Indians
5 What states are included in the (insert area that includes your state) area of IHS?
  a INSERT
  b APPROPRIATE
  c STATES
  d HERE
6 The primary purpose of sweat lodge ceremonies is to:
  a Offer prayers
  b Provide opportunities to learn about tribal lore
  c Create a sauna-like experience
  d Offer opportunities for social interaction outside of the treatment setting
7 To be recognized as a Native American by the U.S. federal government, what is the minimum amount of American Indian blood required?
  a 1/2
  b 1/3
  c 1/4
  d 1/8
8 A pow wow is:
  a A Native American extended family
  b A social gathering of Native Americans
  c A religious ceremony
  d None of the above
9 Treaties, negotiated between the U.S. government and various tribal nations, usually contained which one of the following provisions?
  a Tribes ceding lands for various resources (e.g., food, education, health benefits)
  b The right of the federal government to employ Native Americans as scouts for the U.S. Army
  c The right of individual Native Americans to vote in national elections
  d The right for tribal nations to hunt buffalo
10 On the national level, the BIA is a part of the:
  a Department of Agriculture
  b Department of Tribal Relations
  c Department of Justice
  d Department of the Interior
11 The Indian Reorganization Act was passed in 1934 to:
  a Establish reservations
  b Reorganize the BIA
  c Allow most tribes to manage their own affairs
  d Establish reservation boundaries
12 Which of the following is NOT a part of Grant's Peace Policy?
  a Indians were placed on reservations so that the “dictates of humanity and Christian civilization” could be met
  b Schools and churches were to be established so that Indians would be taught a better way of life
  c The government would hire “competent, upright and moral” agents to care for the Indians
  d Profiteers could make money on the supplies needed by the Indians
13 Native American substance abuse programs receive their funding primarily from:
  a The BIA
  b The IHS
  c The Department of Justice
  d The Congress of American Indians
14 In which year were all American Indians granted U.S. citizenship?
  a 1924
  b 1990
  c 1920
  d 1936
15 Pan-Indianism as it relates to American Indians is:
  a The belief that all American Indians are related
  b A movement that promotes unity of American Indians of all tribes, pueblos, etc.
  c A Native American musical tradition
  d None of the above
16 Which of the following is a hypothetical cause of substance abuse among the American Indian population?
  a American Indians have a genetic make-up that makes them more susceptible to substance addiction
  b When the future looks hopeless, risky behaviors such as substance abuse are less costly since there is less to lose
  c Heavy alcohol consumption was adopted as a norm from whites which was then transferred from generation to generation
  d Native American cultural patterns allow heavy alcohol consumption as an acceptable social behavior that produces positive bonding among tribal members
  e All of the above
17 The Native American Freedom of Religion Act of 1978 allowed for Native Americans to:
  a Travel overseas to attend religious events
  b Practice their own tribal spiritual beliefs and practices
  c Become members of various church denominations
  d Become missionaries
18 All restrictions limiting Native Americans' ability to purchase liquor from retail establishments (e.g., bars, saloons, etc.) the same as other U.S. citizens were lifted in which year?
  a 1924
  b 1934
  c 1953
  d 1975
19 Native Americans:
  a Get monthly checks from the U.S. government
  b Get free monies for higher education
  c Get free health care
  d None of the above
20 Historical trauma for Native Americans refers to:
  a Disappointment concerning historical events
  b The idea that traumatic events in the past continue to cause trauma among Native Americans today
  c An attempt to gain reparations for actions of the U.S. government
  d A painful childhood
21 The entities that provide managed health care for Native Americans are:
  a IHS, Tribal Health, BIA, and Public Health
  b IHS, County Government, BIA, and Public Health
  c IHS, BIA, Tribal Government, and Private Clinics
  d IHS, Tribal Health, Urban Indian Health Programs, Veterans Administration, and Medicine People
22 Generally, the preferred learning style of the more traditional Native American is:
  a Visual
  b Kinesthetic
  c Auditory
  d All of the above
23 The Red Road approach to treatment and recovery primarily includes:
  a Adapting the 12 Steps to fit Native American cultural groups
  b The cultural and spiritual ways of Native American tribal groups
  c The services of guest speakers who are knowledgeable about Native American history
  d The cognitive model that includes the book Wounded Warriors
24 Which of the following use peyote in their ceremonies?
  a The traditional medicine man
  b The traditional medicine woman
  c The Native American Church
  d None of the above

Answer Key:

1) B | 6) A | 11) C | 16) E | 21) D
2) C | 7) C | 12) D | 17) B | 22) D
3) D | 8) A | 13) B | 18) B | 23) B
4) C | 9) A | 14) A | 19) D | 24) C
5) B | 10) D | 15) D | 20) A

Source: Mackey & Zavadil, 2003b. Adapted with permission.

American Indian and Alaska Native Workforce Development Resources

The following table highlights additional resources available to assist you in your efforts to develop a culturally competent and responsive workforce.

FIRST NATIONS BEHAVIORAL HEALTH ASSOCIATION (FNBHA) LISTING OF NATIVE WORKFORCE DEVELOPMENT PROGRAMS

PROGRAM TITLE/AUTHOR | DESCRIPTION | OUTCOMES | WEBSITE
Alaskan Rural Human Service Program, University of Alaska Fairbanks and State of Alaska | Paraprofessional training and clinical supervision to serve remote villages with small populations and minimal access to licensed providers. Addresses substance abuse, suicide prevention, social services. | Provided culturally congruent interventions with professional support via telemedicine and scheduled visits. | www.uaf.edu/rhs
Consultation Model With Traditional Healers, IHS policy, PL 95-341. American Indian Religious Freedom Act | IHS and tribally operated health and behavioral health programs. Includes cultural orientation for new staff, providing space and time for ceremonies and linguistic and diagnostic consultations. | Provided licensed and certified care and treatment and local validation process for healers and practices. | www.ihs.gov
Project Making Medicine, Dolores Bigfoot, Ph.D., University of Oklahoma | One year of clinical training for providers for tribally based treatment of child traumatic stress disorders. Includes cultural adaptations of trauma-focused cognitive–behavioral therapy. | Improved local providers' clinical child treatment skills, increased cultural effectiveness of treatment and cultural competence of non-native providers. | ———
HHS, Mental Health Technicians, Counselor Aide Positions, IHS | Paraprofessional training with clinical supervision and consultation by licensed staff, funded positions; able to serve as interpreters; may include telemedicine, addressing recruitment and retention issues for rural locations, and language and cultural barriers. | Increased cultural competence of care, career ladder opportunities for tribal providers. | www.ihs.gov

Source: FNBHA, 2009. Adapted with permission.

ADDITIONAL TRAINING AND WORKFORCE DEVELOPMENT RESOURCES

• Information on the effectiveness of the Native American Curriculum for State Accredited, Non-Tribal Mental Health & Substance Abuse Programs in South Dakota training for non-native providers is available in the form of a conference poster (Mackey, Zavadil, Skinstad, Peters, & Summers, 2008) and can be downloaded online (www.888betsoff.com/links/08_presentations/handouts/1B.pdf).
• Through the Diamond Threshold: Promoting Cultural Competency in Understanding American Indian Substance Misuse (Robbins, Asetoyer, Nelson, Stilen, & Tall Bear, 2011) includes a number of exercises that can be used with non-native providers and other staff members to better understand issues related to American Indian and Alaska Native behavioral health issues and services. Twelve training activities are included, along with training agendas for using the activities in a half-day, whole-day, or 2-day training.
• The Substance Abuse and Mental Health Services Administration's (SAMHSA's) Tribal Training and Technical Assistance (TTA) Center supports native community self-determination through infrastructure development, capacity building, and program planning and implementation. The TTA website offers a series of training webinars on a variety of behavioral health topics (https://www.samhsa.gov/tribal-ttac/webinars).
• The Alaska Commission for Behavioral Health Certification (ACBHC) has established a process to nominate a traditional provider who offers services in your behavioral health program for lifetime certification. The ACBHC defines a traditional provider as an individual who is either an Alaska Native or who has been raised with traditional values, provided voluntary services, and been a positive force in reducing substance abuse in the community. This certificate is a way to acknowledge and validate the knowledge and wisdom of traditional healers. You can download the application form online (www.akcertification.org/wp-content/uploads/sites/13/2018/08/Traditional-Counselor-Recognition.pdf).

## Developing Native EBPs

As you consider developing and implementing EBPs in your behavioral health service program, a good first step is to review current practices and programs that are specifically designed for American Indians and Alaska Natives. The table below presents summaries of these evidence- and practice-based programs and interventions that you might want to consider. It is based on criteria developed by an expert panel at a meeting sponsored by FNBHA in 2008 at Portland State University in Portland, OR.

FNBHA CATALOG OF EFFECTIVE BEHAVIORAL HEALTH PRACTICES FOR TRIBAL COMMUNITIES

Community Prevention and Education; Cultural and Subsistence Skill Development

PROGRAM TITLE/AUTHOR | DESCRIPTION | OUTCOMES | WEBSITE
Community Readiness Model, National Center for Community Readiness, Colorado State University | Semi-structured surveys of key community stakeholders to assess readiness for prevention or intervention on identified problems including mental health, substance abuse, HIV; all ages | Community outreach, capacity building | www.triethniccenter.colostate.edu/community-readiness-2
Gathering of Native Americans (GONA), Tribal Tech, LLC and Kauffman & Associates, Inc. | Structured 4-day journey to promote community wellness and healing to address a variety of problems including substance abuse, historical trauma, suicide, behavioral health; all ages | Pending | www.samhsa.gov/sites/default/files/gona-goan-curriculum-facilitator-guide.pdf
Cultural Immersion Events: Camps, rides, walks, canoe journeys, fish camps, extended family gatherings, indigenous food and herb gathering, indigenous arts and crafts | Events planned by local tribal populations to address historical trauma, substance abuse, family dysfunction, gangs, teen pregnancies, obesity and diabetes; all ages | Community outreach and engagement; promote healing; increase self-image; strengthen family and community relationships; increase social, recreational, and subsistence skills | ———
Circles of Care, University of Colorado and National Indian Child Welfare Association (NICWA) | 3-year participatory community training and evaluation to address children and families with emotional problems | Community capacity building, engagement, use of data | www.ucdenver.edu/academics/colleges/PublicHealth/research/centers/CAIANH/coc/Pages/ProgramOverview.aspx and www.nicwa.org

Early Intervention/Skill Building

PROGRAM TITLE/AUTHOR | DESCRIPTION | OUTCOMES | WEBSITE
To Live To See the Great Day That Dawns, Department of Health and Human Services (HHS) | Community-based suicide prevention, using a menu of evidence- and culture-based practices | Local workforce training and community mobilization to reduce suicide risk | https://store.samhsa.gov
Positive Indian Parenting, NICWA | Parenting curriculum, developed by American Indian/Alaska Native Organization. Widely adopted and open to local cultural adaptations. Addresses child welfare and early intervention | Increased parenting skills, incorporating tribal cultural features | https://www.nicwa.org/training-institutes
Native H.O.P.E., Clayton Small, Ph.D., and One Sky Center | Native Youth Training Manual, includes school and community screening tools, focusing on suicide prevention | Increasing strengths, identifying warning signs, incorporating culture and ceremony | www.oneskycenter.org/wp-content/uploads/2014/03/NativeHopeYouthTrainingManual_000.pdf

Individual and Family Treatment

PROGRAM TITLE/AUTHOR | DESCRIPTION | OUTCOMES | WEBSITE
Honoring Children Series, Dolores Bigfoot, Ph.D., University of Oklahoma | Adaptation of Parent–Child Interaction Therapy; mental health promotion addressing child trauma | Improved parenting skills, early childhood intervention of child trauma | www.icctc.org/HCMC%20TFCBT%20Adaptation%200711.pdf
Wraparound in Indian Country, Deb Painte, Native American Training Institute, University of Texas and University of Denver | Family consultation in multidisciplinary care planning; tribal adaptation of practice-based wraparound services | Family and youth advocacy and empowerment | www.nativeinstitute.org
Talking Circles, Public Domain | Facilitated discussion; participants sit in a circle and pass object clockwise, signifying one's turn to speak; addresses substance abuse and mental health issues | Peer support, also used as a type of focus group to engage community interest in a topic | ———

PROGRAM TITLE/AUTHOR | DESCRIPTION | OUTCOMES | WEBSITE
Equine-Assisted Therapy, Numerous tribal and private-sector practitioners | Equine-assisted therapy for tribes incorporates cultural and historical issues and addresses substance abuse prevention and treatment, developmental disabilities, and incarcerated populations | Increased trust, relationship- and skill building | ———

Recovery Services and Supports

PROGRAM TITLE/AUTHOR | DESCRIPTION | OUTCOMES | WEBSITE
American Indian and Alaska Native 12-step meetings and fellowship, Public Domain | Structured meetings to address alcohol, drug abuse, and gambling addictions; adults and youth | Peer support for sobriety and rehabilitation | www.nai-aa.com
Sobriety Campouts, Public Domain | Intertribal event addressing individual, family, and community substance abuse | Peer support, family and community focus | ———
Healing Forest, Wellbriety, Sons and Daughters of Tradition, White Bison, Inc. | Community events and structured prevention and treatment addressing historical trauma, adult and youth substance abuse, violence, self-destructive behaviors | Community healing, reduced substance abuse, mentoring/skill building for youth | www.whitebison.org
Native American Church, Public Domain | Guided intertribal ceremony | Peer support, community cohesion, cultural enhancement | ———
Sobriety pow wows | Intertribal cultural event | Builds social and recreational skills, community cohesion | ———
Sweat lodge ceremonies | Spiritual purification ceremony | Builds connection to Creation/Creator | ———

Source: FNBHA, 2009. Adapted with permission.

## Integrating Care: Traditional Practices in Behavioral Health Programs

As mentioned previously, the American Indian and Alaska Native perspective on healing is holistic. In addition to integrating primary health care and other social services into your program, it is critically important to integrate traditional healing practices and healers into your behavioral health services for American Indian and Alaska Native clients. Likewise, you need to determine what tribal practices to include in American Indian and Alaska Native clients' treatment and recovery plans and evaluate what benefit might be expected from them. This section contains an administrative tool, a Tribal Practice Approval Form, which can help you with this task.

The Oregon Addictions & Mental Health Division (n.d.) has created a process for approving evidence-based tribal practices. The application form and instructions can help you identify, evaluate, and monitor American Indian and Alaska Native cultural and healing practices unique to your tribal community that you might want to include in your behavioral health service program.

OREGON ADDICTIONS & MENTAL HEALTH DIVISION EVIDENCE-BASED PROGRAMS TRIBAL PRACTICE APPROVAL FORM

OREGON ADDICTIONS & MENTAL HEALTH DIVISION EVIDENCE-BASED PROGRAMS TRIBAL PRACTICE APPROVAL FORM (CONTINUED)

OREGON ADDICTIONS & MENTAL HEALTH DIVISION EVIDENCE-BASED PROGRAMS TRIBAL PRACTICE APPROVAL FORM (CONTINUED)

OREGON ADDICTIONS & MENTAL HEALTH DIVISION EVIDENCE-BASED PROGRAMS TRIBAL PRACTICE APPROVAL FORM (CONTINUED)

OREGON ADDICTIONS & MENTAL HEALTH DIVISION EVIDENCE-BASED PROGRAMS TRIBAL PRACTICE APPROVAL FORM (CONTINUED)

## Creating Sustainability

Sustaining programs and systems of behavioral health care is an especially important issue in many American Indian and Alaska Native communities, where time-limited funding may be available to initiate a new service but not to support long-range services. The self-assessment tool that follows, developed by SAMHSA's Center for Mental Health Services (CMHS) and the Child, Adolescent and Family Branch (2003), is intended to help communities and systems of care (SOCs) plan for sustaining their behavioral health initiatives. The self-assessment tool developed for American Indian and Alaska Native communities and SOCs should be used prior to developing a sustainability plan.

AMERICAN INDIAN/ALASKA NATIVE SUSTAINABILITY SELF-ASSESSMENT TOOL

The American Indian/Alaska Native Sustainability Self-Assessment Tool is intended to help you evaluate the progress that your community has made in developing and implementing strategic plans for sustaining an integrated behavioral health SOC and explore barriers that may need to be addressed to move forward. You can use the results of this self-assessment to complete a sustainability strategic plan, assess your community's progress in implementing sustainability plan strategies, or determine changes or modifications to your existing sustainability plan to increase the likelihood for success. This tool is designed to facilitate discussion among stakeholders, including representatives of behavioral health service programs, tribal representatives, and youth/family members. Although this particular tool is focused on assessing sustainability of youth and family services, it could be adapted to assess behavioral health services for adults, as well. The term “tribal” is used broadly throughout this document and refers to the 573 federally recognized American Indian tribes and Alaska Native villages. However, state-recognized tribes and off-reservation native communities may be included as part of the target population of non-native SOC communities.

Consider the following broad questions as you complete this assessment. When exploring SOC elements and sustainability objectives, ask yourself, “Where do we want to be?” and, “What do we want to sustain?” For key indicators of success, ask, “How will we know when we have gotten there?” (For examples of key indicators, see the checklist at the end of this tool.) For progress ratings, use the “rating of progress” scale below. To identify barriers to achievement, ask, “What is standing in the way of our progress?”

Vision and Philosophy

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
A clear vision for sustaining the SOC framework has been defined and disseminated.
Vision links with and supports local tribal culture.

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Through social marketing practices, the needs of tribal children, youth, families, community partners, and stakeholders are integrated into the vision, philosophy, and goals of the SOC.
The right key stakeholders, representing the diversity of the tribal community served, have been involved in defining and disseminating the vision.
Clear-cut objectives for the cooperative agreement/grant have been identified through a planning process and are developed and disseminated to tribal leadership and the tribal community.
SOC values and principles are continually redefining the larger community-based service delivery system.
A definition for sustainability of the SOC framework to implement change at the policy, system, and practice level has been written in language that supports cultural values and is easily understood by the tribal community and disseminated.
Ongoing education and training on SOC vision, philosophy, goals, and operation is being provided to tribal leadership, the tribal community, and key stakeholders.

Service Array

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Services that families and youth (inclusive of the full diversity of the community) prefer and find useful, including integration of traditional practices, are continually being created as needs change.
Partner agencies and state, federal, tribal, or private resources support or fund the full array of services (including traditional practices).
Access to appropriate and effective services and supports, including traditional practices, has been increased to meet needs.
Ongoing mechanisms for providing individualized (with full recognition and support of cultural and linguistic preferences), integrated, and coordinated care are being implemented. Mechanisms include (a) appropriately trained or credentialed paraprofessional or professional staff, (b) supervision and professional development plans for staff, (c) appropriate level of community and cultural knowledge, and (d) incentive and rewards in place for consistency in promotion of SOC principles in family services.
Mechanisms are in place to assure a service array that meets the relevant needs of the demographics of the community (based on age, race, ethnicity, language, spiritual identity, physical ability/disability, language, legal status, etc.).

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Ongoing mechanisms have been developed to decrease reliance on out-of-community and out-of-state placements and are being implemented. Includes a strong link with tribal courts, tribal child welfare, juvenile and other jurisdictional decision-makers; tracking decreases in the number of out-of-community placements; tracking increases in the number of in-community placement resources; and ensuring that in-community placement resources have adequate resources and a high level of family involvement.
Ongoing training and technical assistance on culturally and linguistically competent service delivery, and on culturally and linguistically competent evidence-based and promising practices to SOC staff, family members, youth, community providers, and other stakeholders is being provided within the context of a well-thought out, long-term training plan.

Management and Coordination

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Centralized location for management of SOC implementation has been identified and is fully operational.
Leadership for sustainability of SOC implementation efforts is maintained with a focus on continuity through continual training, workforce development, skill-building, and leadership development.

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Ongoing mechanisms for using data and evaluation to support planning, development, and maintenance of implementation efforts have been created, with particular emphasis on partnership with the tribal community and ongoing community feedback loops.
The leadership framework, administrative and service policies, and organizational structures reflect the flexibility and innovation required of an effective SOC.

Interagency Planning and Coordination

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Ongoing mechanisms for interagency planning and coordination at the state/tribal/territorial and local policy and system level are in place.
Ongoing, shared administrative processes (e.g., memorandums of agreement) among two or more agencies that involve family members and youth are in place.

Family and Youth Involvement

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Families and youth (reflective of the full demographics and diversity of the community) are actively involved in policymaking and system reform, and they fill administrative or consultative roles at the system level.
Families and youth (reflective of the full demographics of the community) are active participants in evaluation efforts.

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Families and youth (reflective of the full demographics and diversity of the community) are active participants in evaluation efforts, with good understanding of how the evaluation efforts protect confidentiality and can serve to improve community services.
Families and youth (reflective of the full demographics and diversity of the community) are involved in the service planning and delivery process, through serving on planning teams or other ways of providing their perspective.
Families and youth (reflective of the full demographics and diversity of the community) participate in training, both as trainers and as participants in training activities.
Peer-to-peer support is in place within the local provider network and among the other tribal SOC communities across the country.

Cultural Competence

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Cultural and linguistic competence is evident at the system, policy, and practice levels and demonstrated by system administrators who value the cultural strengths and cultural resources of the community; service policies that clearly state that the system values and seeks ways to increase partnership with cultural resources; and practices that routinely include the use of cultural resources as part of the treatment/care plan, as appropriate to the family.

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Social marketing practices ensure that messages, images, and outreach strategies are culturally and linguistically appropriate.
Systemwide leadership, including tribal officials, is committed to continuing the lead for change processes that result in culturally competent services that families respond to positively.
Cultural and linguistic competence is adopted as a personal mission for each individual staff person and volunteer involved in the SOC network.
Policies are established that ensure cultural and linguistic competence is the required standard of service.
Structures are established to ensure the planning and implementation of culturally and linguistically competent services.
Adequate resources—spiritual, cultural, financial, personnel, and volunteer—to support cultural and linguistic competence are established.
The service array is constructed to provide appropriate and acceptable services tailored for, and responsive to, the unique range of families served by the SOC.
Management information systems (MIS) are designed to track services (with consideration of the cultural appropriateness and usefulness of counting traditional practices), clinical and functional outcomes, and service satisfaction based on the unique demographics of persons served.

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Quality management/quality improvement systems are designed to measure impact of services tailored to the unique demographics of the community.
Cultural competence is infused into the core plans and operations of agencies, programs, and organizations involved in the SOC.
Diverse cultural and linguistic communities are meaningfully involved in all components of the SOC: planning, administration, care coordination, service provision, and evaluation, etc.
Cultural competence is a focus of systemwide collaboration.
Mechanisms are in place to support attitudinal change of all members of the system (tribal governance, executive, tribal and nontribal provider, practitioner, families and youth, community at large).
Mechanisms are in place to facilitate continual cultural knowledge development of all members of the SOC at institutional, supervisory, and individual levels.
Mechanisms are in place to provide linguistic access throughout the entire system in compliance with Title VI of the Civil Rights Act and to others with limitations in communication (e.g., limited literacy or disability).

Political and Economic Support

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
An analysis has been conducted to determine the full range of financial and other available resources that have been, or could be, available to sustain the SOC.
Partnerships at federal, state, tribal, and other local levels are developed and maintained to effect mutually beneficial outcomes.
Tribal community members have been involved in interpreting the findings of their community's evaluation effort, and the findings are integrated in the design and implementation of the SOC framework.
Key stakeholders representing the diversity of the community (including federal, state, tribal, and local public officials) are involved in the initiative and are committed to sustaining and expanding the SOC.
Political and policy-level support for the SOC approach has been generated at the federal, state, tribal, and local level.
Policies have been reformed or developed to support system change at the federal, state, tribal, and local levels to sustain the initiative.
Coalition-building among advocates, including those representing specific cultural, racial, ethnic, linguistic, religious, and other communities, is being supported to impact change.
Strong interagency relationships, both within and outside of the tribal community, are being cultivated or are in place.

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
A strong family organization that reflects and effectively supports the diversity of families in the community is evolving or in place and is supported by the community at large.
The SOC framework and its values and principles are infused within the broad tribal service delivery system.

Strategic Financing Strategies

SOC ELEMENTS AND SUSTAINABILITY OBJECTIVES | KEY INDICATORS OF SUCCESS | PROGRESS RATING | BARRIERS TO ACHIEVEMENT
Determination of available financial resources (known and untapped), including matched resources, is being conducted.
A plan for maximizing federal, state, tribal, and other local revenue is in place and is being implemented.
Strategies for creating more flexibility in existing funding streams have been developed and implemented.
Partnerships among the tribal–public–private sectors have been developed.
Financing strategies are developed that ensure continued access to appropriate and acceptable services for all demographic groups within the community.

AMERICAN INDIAN/ALASKA NATIVE SUSTAINABILITY SELF-ASSESSMENT TOOL (CONTINUED)

AMERICAN INDIAN/ALASKA NATIVE SUSTAINABILITY SELF-ASSESSMENT TOOL (CONTINUED)

AMERICAN INDIAN/ALASKA NATIVE SUSTAINABILITY SELF-ASSESSMENT TOOL (CONTINUED)

AMERICAN INDIAN/ALASKA NATIVE SUSTAINABILITY SELF-ASSESSMENT TOOL (CONTINUED)

AMERICAN INDIAN/ALASKA NATIVE SUSTAINABILITY SELF-ASSESSMENT TOOL (CONTINUED)

The tools presented in this chapter can help you, your staff, and your community build a sustainable program and system of services designed to meet the behavioral health needs of American Indian and Alaska Native clients. As an administrator or program manager, you are in a central position to know which of these tools will best serve your mission and how best to adapt them to your organization's and community's particular needs.

“Let us put our minds together and see what life we can make for our children.”

—Sitting Bull (1831–1890), Hunkpapa Lakota