# Part 2, Chapter 1

## Introduction

### An Overview of Part 2

In Part 1, this Treatment Improvement Protocol (TIP) focused on the knowledge, skills, and application of cultural competence in counseling. In Part 2, attention turns to implementing this knowledge on an administrative level. This chapter reflects the voices of consensus panel members and others who have contributed ideas to the development of this TIP. This section highlights the knowledge, challenges, and strategies important to program development, implementation, and sustainability. It is designed for administrative staff, including program directors, managers, and clinical supervisors providing services in villages, in rural and urban areas, and on reservations. It is written for those who have less cultural knowledge or experience in providing services and for others looking for ideas on how to meet the day-to-day challenges in program management, including workforce development. Whether you are a native or non-native provider, the information serves as a guide on how to remain culturally responsive to your clients and community.

Chapter 1 first addresses key ingredients in developing a culturally responsive organization. The next section highlights organizational challenges and paths to solutions. Then, the chapter addresses workforce and professional development with emphasis on activities that support investment in staff and future leadership. The chapter ends with a review of culturally responsive behavioral health competencies to serve as a guide for staff development and program aspirations. Chapter 2 contains samples of additional resources and materials that support day-to-day administrative and programmatic activities. Part 1 is equally important for administrators, program managers, and clinical supervisors to read, as it sets the course for Part 2.

It's not how you integrate culture into services but how you integrate services into the culture.”

—Deborah Painte

Source: National Indian Child Welfare Association, 2015, p. 3.

## Becoming a Culturally Responsive Organization

Cultural competence refers to the ability to effectively provide services to clients with diverse values, beliefs, and behaviors. Within an organization, it involves the ability to tailor services and service delivery in a culturally relevant and meaningful way. For a guide to creating a culturally responsive organization, refer to TIP 59, Improving Cultural Competence, Chapter 4 (Substance Abuse and Mental Health Services Administration [SAMHSA], 2014a).

As noted in Part 1, Chapter 1, of this TIP, serious health disparities exist among American Indians and Alaska Natives, leading to poorer health outcomes when compared with the general population nationally. Many factors contribute to native health disparities, including an inadequate healthcare delivery system, insufficient funding, absence of culturally appropriate education, language barriers, inaccessible and unavailable services, poor infrastructure, and the lack of culturally responsive services and trauma-informed care.

Approximately 6.8 million people in the United States identified as American Indian or Alaska Native in 2017 (Census Bureau, Population Division, 2018). Tribes and villages have a unique government-to-government relationship with the United States that has been shaped by colonialism, nation-to-nation treaties, federal laws, executive orders, and Supreme Court decisions. Although you might think of American Indians or Alaska Natives as a single racial or ethnic group, there are 573 federally recognized tribes. Each individual nation has its own history and culture with wide variations in language, membership, and resources. This is significant for you as an administrator, particularly if your program serves a community where clients come from different tribes—such as programs that provide services in urban communities. By developing your organization's capacity for culturally responsive care, you will more likely meet the needs of a diverse American Indian and Alaska Native population. Part 3, the online literature review of this TIP, contains more information about variations in behavioral health needs within native populations. “Why It Matters: The Organizational Benefits of Culturally Responsive Care” (see above) outlines the benefits of an organization's cultural responsiveness.

WHY IT MATTERS: THE ORGANIZATIONAL BENEFITS OF CULTURALLY RESPONSIVE CARE

A 2013 report by the Health Research & Educational Trust outlines numerous benefits to organizations that take a culturally responsive approach to care.

Social Benefits

• Increases mutual respect and understanding between patient and organization
• Increases trust
• Promotes inclusion of all community members
• Increases community participation and involvement in health issues
• Assists patients and families in their care
• Promotes patient and family responsibilities for health

Health Benefits

• Improves patient data collection
• Increases preventive care by patients
• Reduces care disparities in the patient population
• Increases cost savings by reducing medical errors, number of treatments, and legal costs
• Reduces the number of missed medical visits

Business Benefits

• Incorporates different perspectives, ideas, and strategies into the decision-making process
• Decreases barriers that slow progress
• Moves toward meeting legal and regulatory guidelines
• Improves efficiency of care services

See the full report, Becoming a Culturally Competent Health Care Organization (Health Research & Educational Trust, 2013), for more information.

### Qualities of a Culturally Responsive Organization

This section briefly describes some distinguishing characteristics of a culturally responsive organization serving American Indian and Alaska Native clients and communities, along with suggestions for specific actions to take to make them a reality. Please note that this list, although comprehensive, is not definitive. You may find that your organization needs to respond differently to meet the needs of your community.

#### Involve the community and take an active role

Communities can play an important role in improving the provision of behavioral health services and treatment. Creating culturally responsive services requires the participation of the native community, including leaders, council members, community members, potential clients, and their families. Engaging and establishing a positive relationship with local leadership and the native community can work to alleviate initial feelings of mistrust and can serve as a resource to strengthen your program's effectiveness. For example, community leaders who support your program may be able to conduct more effective outreach than the program can by itself. Similarly, community involvement can lead to a sense of ownership and pride in the services.

By involving the community, providers can identify potential obstacles early on and develop ways to overcome these challenges with the help and advice of tribal community partners. Community members can also provide invaluable assistance in other areas, such as providing information about the most pressing behavioral health problems within the community, coordinating the services of traditional healers for your services, and recommending individuals who can provide staff education and training on local native culture(s) and history.

Likewise, make it a point to engage with the community outside of the program. This will help the community become more familiar with the organization's presence and may potentially increase awareness and use of program services.

#### Pursue a collaborative relationship with tribal leadership

The support of tribal leadership is critical to establishing a positive, trust-based relationship with the American Indian and Alaska Native community and to helping ensure the program's success and sustainability over the long term. Reach out to a tribal leader (e.g., a council member or health board director), but remember to listen when you meet. As a service provider, you are working for him or her. Show an interest in and learn from the information people share with you. It may help if you or a senior staff member serves as community liaison to keep tribal leaders and representatives up-to-date about the program and to respond to any questions, comments, or concerns.

ENGAGING WITH TRIBAL COMMUNITIES

Etiquette Do's

• Listen and observe; be comfortable with silence.
• Correctly pronounce names (use American Indian/Alaska Native names when appropriate).
• Be transparent about your role and expectations.
• Establish rapport.
• Invite questions and knowledge seeking.
• Accept offers.
• Shake hands respectfully.

Etiquette Don'ts

• Don't talk too loud or fast.
• Don't impose personal values or beliefs.
• Don't claim a vague tribal affiliation.
• Don't point your finger.
• Don't rush things.
• Don't touch sacred items.
• Don't take pictures without permission.
• Don't shake hands aggressively or assertively.

Source: Kauffman & Associates (personal email and document attachments, March 1, 2016).

#### Understand and respect tribal and community differences

American Indian and Alaska Native history, traditional practices, protocols, and ceremonies vary across tribes. For example, you will often find a blend of traditional spiritual practices and organized religion within a single tribal community. It is important to inquire and educate yourself about these differences rather than making assumptions. Ultimately, each American Indian and Alaska Native client experiences his or her culture in a unique way. It is up to the organization to work with the client to understand the client's experience and to tailor services accordingly by asking about his or her tribe and cultural identity.

#### Gain knowledge of tribal history and understand its impact and the impact of historical trauma in the community

Clients and the community may express an initial lack of trust when you first attempt to engage them. This behavior is often rooted in negative experiences with past providers and in the effects of historical trauma, recent traumas, and racism. The organization must openly acknowledge these experiences and their effects on the community. Most importantly, the program needs to incorporate trauma-informed care across all levels of service—ensuring that each staff member approaches interactions with clients from this perspective.

#### Engage in honest, open, and culturally appropriate communication

Trust is established in part through honest communication. When communicating with clients or the native community, be clear in meaning and realistic in regard to expectations about your services. Follow through with your message and promises to clients and the community, as your behavior will serve as evidence of your trustworthiness and commitment as a provider. In addition, remember that culturally responsive communication operates in two directions, and although your program disseminates information to clients, be open to receiving information and feedback as well. Actively listen to this input, as it can help you revise your program's services or approach to better meet community needs.

In addition to honest communication, it is important to use culturally appropriate communication when engaging with American Indian and Alaska Native clients and community members. Use clients' preferred language when either speaking in person or using written materials. This may require the use of an interpreter. In many communities, it is customary to let tribal elders speak first without interruption. Thus, when engaging with elder tribal members—either in conversation or as clients—you should expect to be silent and actively listen as the elder speaks. When sharing information or a specific message, try using stories or real-life examples rather than technical language where possible.

TRAUMA-INFORMED CARE: A CRITICAL APPROACH IN PROVIDING CULTURALLY RESPONSIVE SERVICES FOR AMERICAN INDIANS AND ALASKA NATIVES

“In our view, community healing along with individual and family healing are necessary to thoroughly address historical unresolved grief and its present manifestations. The process is not quick nor is it easy. However, without such a commitment to healing the past, we will not be able to address the resultant trauma and prevent the continuation of such atrocities in the present. Nor will we be able to provide the positive and healthy community activism needed to stop and prevent the social pathologies of suicide, homicide, domestic violence, child abuse, and alcoholism so prevalent in American Indian communities—as in society at large—today.

“The crux of our argument has far-reaching implications for other colonized, oppressed peoples throughout history and those being oppressed, as we write, that are obvious to us. Wherever peoples are being decimated and destroyed, subsequent generations will suffer. We need only heed the traditional American Indian wisdom that, in decisions made today, we must consider the impact upon the next seven generations. The concept of historical unresolved grief has powerful implications not only for healing from our past but for giving us the strength and commitment to save ourselves and future generations.”

Source: Brave Heart & DeBruyn, 1998, p. 75.

What Is Trauma-Informed Care?

“A program, organization, or system that is trauma informed realizes the widespread impact of trauma and understands potential paths for recovery; recognizes the signs and symptoms of trauma in clients, families, staff, and others involved with the system; and responds by fully integrating knowledge about trauma into policies, procedures, practices, and settings, and seeks to actively resist re-traumatization.”

Source: SAMHSA, Trauma and Justice Strategic Initiative, 2012, p. 4.

For a comprehensive guide to creating a trauma-informed behavioral health service, refer to TIP 57, Trauma-Informed Care in Behavioral Health Services (SAMHSA, 2014b).

#### Respect and value native knowledge and cultural worldviews

A culturally responsive organization understands the inherent value of tribal knowledge and demonstrates respect for tribal values and worldviews. For example, a tribal welcome may involve an offer, such as shared food or a gift. It would be rude to refuse this welcoming gesture. You might also offer food—particularly traditional foods—during program activities or client intakes when appropriate. You may need to make a similar effort to integrate cultural and traditional practices into program services and interventions as appropriate for each client. For example, a treatment plan for a client who prefers the use of traditional healing methods may include the use of healing circles, sessions with a traditional healer, or (if the client is physically capable) sweat lodges or fasting. Policies and procedures need to reflect the value of traditional practices, and leadership needs to afford clients and staff opportunities either on facility grounds or at an alternative place in the community to access these healing traditions. In addition, the organization needs to honor native knowledge in determining evidence-based and best practices.

#### Commit and support the importance of cultural knowledge and culturally responsive services at all levels

As an administrator, you need to demonstrate that leadership is committed to supporting and integrating culturally responsive services at all levels, from office manager to board members. Set aside a portion of the organization's operational budget or pursue grant and other funding opportunities to support costs and activities targeting cultural responsiveness, including staff training, interpreter services, and community outreach efforts. Include language that reflects the organization's commitment to cultural responsiveness in the mission and vision statements as well as in policies and procedures manuals. Consider creating an advisory board or internal workgroup dedicated to evaluating and promoting the organization's efforts to effectively respond to the cultural needs of clients and the community (i.e., implementing an organizational self-assessment).

At a staff level, make staff education and training in cultural competence a part of the orientation process for new hires and a regularly scheduled professional development activity for current program personnel. Institute recruitment and hiring policies aimed at diversifying the organization's workforce and at promoting an American Indian and Alaska Native behavioral health workforce and leadership for the next generation.

#### Recognize tribal community strengths

One of the benefits of engaging with American Indian and Alaska Native communities as partners is that it offers an opportunity to identify and make use of tribal resources and strengths, such as family ties, larger community networks, physical resources, intergenerational knowledge and wisdom, and community resilience. It may also involve other tribal departments or partner agencies that can offer resources and support. This strengths-based approach builds on the strengths and resilience of the community to create solutions, rather than focusing solely on issues or areas in need of improvement.

STRENGTHS OF TRIBAL SYSTEMS OF CARE

• Grassroots foundation
• Local leadership
• Culture as core
• Influence of language
• Vision for the future
• Power of communication
• Organizational infrastructure
• Tribal college and state university partnerships
• Integration of new treatments
• Tribal wraparound services
• Investment in advocacy
• Tribal–borough–county–state relationship
• Tribal peer support

Source: National Indian Child Welfare Association, 2015.

“Historically, the Indian Health Service (IHS) was an entirely federal system, but in recent decades it has evolved in a profound way. Tribal governments now directly manage more than half of IHS-appropriated funds and the great majority of physical facilities under self-governance contracts and compacts. In addition, 34 nonprofit Urban Indian Health centers provide care for AI/AN [American Indian/Alaska Native] people and other underserved communities in urban locations. The IHS, Tribal, and Urban health care facilities have come to be known collectively [as] the Indian Health System.”

Source: Hays, Carroll, Ferguson, Fore, & Horton, 2014, p. 986.

### Administrative Challenges and Paths to Solutions

Program administrators may face a wide range of challenges when attempting to design and implement programs and services specifically tailored to meet the needs of American Indian and Alaska Native clients. Although some of these challenges include operational concerns about funding sources and reporting requirements, certification, and staffing, others are more often encountered when working with native communities in different settings. For example, programs that provide services to clients on a reservation must learn to work collaboratively with the community and tribal leadership. Programs serving clients in an off-reservation urban setting will need to work with the communities and tribal services, and also tailor services and staff training to effectively meet the needs of clients from different tribes who present a more diverse range of history, culture, and values. Although daunting, it is possible for programs to plan for and effectively address these challenges. What's more, these issues provide an opportunity for program administrators to effectively engage with tribal, rural, and urban Indian communities throughout the program implementation process. This collaborative relationship not only helps ensure that services provided are culturally responsive, but also helps position the program for long-term success by using community buy-in, commitment, and support.

Although the challenges listed below involve operational and workforce development issues, many difficulties stem from administrative staff giving insufficient attention to the importance of engaging in culturally competent practices. By overlooking these practices, administrators themselves avoid recognition of their own cultural awareness and bias, fail to invest in learning about local culture(s) and American Indian and Alaska Native history, neglect to understand and use the principles of culturally responsive services and processes, and disregard the involvement of local native governance and communities before planning and implementing a specific service or program for American Indians and Alaska Natives.

The consensus panel identified several administrative challenges. The items below draw attention to core challenges that most programs face in developing, implementing, evaluating, and sustaining services, yet they do not represent every obstacle. In the following section, several core challenges are presented along with ideas on how to address them. These suggestions are called the “path to solutions.”

#### Determining how best to collect, organize, and manage data

Service providers may have limited infrastructure to gather, manage, and maintain data, including limited access to computers, software applications, and culturally relevant digitized intake, assessment, and planning tools.

Path to solutions

• Contact well-established American Indian and Alaska Native treatment services and organizations to gain knowledge about culturally relevant digitized tools. It is not likely that you, as the administrator or program manager, will need to create these tools. Instead, you may need to adapt existing tools to reflect more tribe-specific information.
• Seek grants that assist in building infrastructure to implement services.
• Crowdsource for acquisition of computers and software applications.
• Seek technical assistance from other American Indian and Alaska Native service providers.

#### Analyzing data for reporting purposes and for securing funding

Service providers typically face considerable reporting requirements, especially when the service uses multiple funding sources. Although extensive data may be already available within the treatment service program, service providers may not know how to analyze the data for reporting purposes. Likewise, service providers may not have access to technical assistance or resources to summarize and interpret the data in a meaningful way to validate service needs, outcomes, or impact to obtain future grants or other funding resources. (Service providers who are already fiscally challenged in implementing programs are less likely to view data analysis to be as important as care.)

BUILDING THE EVALUATION CAPACITY: GATHERING, ANALYZING, AND USING DATA

Factors that facilitate evaluation capacity of local programs serving American Indian and Alaska Native populations include but are not limited to the accessibility of culturally competent technical assistance providers, investment in building strong program–provider relationships, support of innovative and cultural adaptations of evidence-based strategies, respect for circular views on change, use of culturally responsive evaluation methods, and focus on strengths-based programming. For more information on building evaluation capacity serving American Indian and Alaska Native populations, see SAMHSA, Center for Substance Abuse Prevention (CSAP), 2014.

Path to solutions

• Gain culturally competent technical assistance from the outset either from the grant source or other similar programs using the same funding source to learn how best to gather and analyze data.
• Whether you are a native or non-native service provider, remember that tribes have experienced a long history of abuse surrounding data misuse. Tribes have faced significant negative consequences when their identified data have been used for research, including loss of contracts and resources, disregard for tribal community member or tribe-specific confidentiality, loss of employment, and so forth. As a provider, you need to develop a plan in collaboration with native community leadership on how the information is used with integrity.
• Research needs to be approved through the tribe's institutional review board or tribal council. Data are property, and property ownership needs to be determined and agreed upon with tribal governance. Keep in mind that staff may also be reluctant to gather certain or consistent data because their value is not understood; data collection takes too much time away from building relationships; or there is concern about data misuse, confidentiality, or gathering information in a manner that is not culturally responsive. These concerns need to be addressed through conversations with staff, supervision, and staff trainings.

#### Obtaining program funding

First and foremost, service providers need to understand how to access the funds necessary to maintain or expand behavioral health services in American Indian and Alaska Native communities. Programs with limited resources often need to obtain funds from multiple sources. Although this is a viable option, it can also create competing and conflicting interests and reporting demands from the different funding sources. With limited resources, service providers not only have to make difficult decisions on service provisions; they also need to be quite creative in using these funds to maximize the benefits.

Path to solutions

• Diversify funding streams. Funding limitations can cause a program to fail before implementation even begins. Programs should be prepared to secure funding from a diverse range of sources. Potential funding sources include IHS, Medicaid, Medicare, state and local coffers, discretionary federal funds, the Bureau of Indian Affairs, and tribal budgets. This kind of variation in funding options is necessary to sustain a program over time.
• Partner or contract with established programs to maximize the use of available funds for services.

#### Increasing access to services

Providers working with American Indian and Alaska Native populations frequently face challenges implementing effective programs in remote communities where clients have difficulty accessing services because of a lack of service awareness, transportation, phone or Internet services, child care, or insurance or healthcare financing. For some, the distance to the service provider is prohibitive. Programs may also not have viable options to refer clients who have geographic hardships or would prefer to use a different service provider. Even if a referral is feasible, the challenges that often exist in interagency communication and collaboration may create additional obstacles for clients in gaining access to equitable and appropriate care.

Path to solutions

• Incorporate a client needs assessment and evaluation as part of the program's operation. By identifying service needs, providers can tailor services to meet the current cultural and treatment needs of the community. A needs assessment allows a program to identify and build on the community's strengths and resources and provides another avenue through which to engage tribal leaders and community members. Regular evaluation will help programs assess the impact of their efforts, identify strengths and weaknesses, and guide program development, capacity building, and sustainability efforts.
• Provide one-stop services so that clients and their families can access services at one location, including outreach activities to connect individuals with available services.
• Offer a “warm handoff” whereby clients are physically taken and introduced to the new service to bridge the referral gap. Under these circumstances, clients are more likely to follow through with the referral.
• Develop outreach, educational programs, and community events in multiple languages.
• Provide mobile or telehealth services. Bring the services to the client rather than the client to the services. In planning these services, think through the process carefully. Will the client or family members need child care during the mobile service? Is the community educated about how telehealth works at the health clinic?
• Form partnerships between states and tribes. Refer to Partnering With Tribal Governments To Meet the Mental Health Needs of American Indian/Alaska Native Consumers (National Association of State Mental Health Program Directors, 2015).

#### Integrating care

American Indian and Alaska Native perspectives on healing are holistic. The beliefs surrounding the path to illness as well as healing are integrated; the mind, body, spirit, or environment are seen as one; all is connected. When programs do not integrate behavioral health services, primary health care, and other social services, they fail to encompass a culturally responsive approach to treatment, and ultimately can have a significant negative impact on treatment seeking, quality of and responsiveness to care, and outcome.

Path to solutions

• Build alliances between services to coordinate care.
• Include a cultural component in services, if possible (e.g., craft workshops).
• Create accessible one-stop services.
• Include health and behavioral health service providers. For example, use a psychiatric nurse practitioner in house to assess for co-occurring conditions.

#### Developing native evidence-based practices

For years, considerable focus has been placed on employing mainstream evidence-based practices (EBPs) in native programs and in communities. Although mainstream EBPs can be effective avenues of intervention, they are perceived as mainstream approaches while ignoring or failing to honor native practices, knowledge, and culture. For many years, funding has been tied to these mainstream EBPs, while representation of American Indian and Alaska Native participants in the research that supports these mainstream EBPs is nearly nonexistent. Changes are now occurring, including increases in native-specific, culturally adaptive research and in representation of American Indian and Alaska Native individuals among research participants. We now see an increase in respect, acknowledgment, and focus on native ways of knowing; the establishment of community-based and tribal participatory research; and the development of research mentor programs for American Indians and Alaska Natives, such as the National Institute on Drug Abuse's American Indian/Alaska Native Researchers and Scholars Work Group's Native-to-Native Mentoring program.

Path to solutions

• Gain technical assistance or support from SAMHSA's National American Indian and Alaska Native Addiction Technology Transfer Center (NAI & AN ATTC) to review EBPs that may be culturally adapted to your clients and their needs.
• Use a Native American framework in creating criteria for evidence-based tribal practices (Exhibit 2.1-1; refer to Exhibit 2.1-2 for a sample curriculum).

EXHIBIT 2.1-1. Evidence-Based Tribal Practices

In the Native American framework, there are several specific criteria for evidence-based tribal practices. These criteria are:

1. Longevity: A tribal practice rooted in long-held traditions (e.g., canoe journey, sweat lodge, and subsistence practices).
2. Teachings: A tribal practice based on specific teachings (e.g., the medicine wheel, origin stories).
3. Values: A tribal practice that incorporates the values and worldview of American Indian and Alaska Native cultures (e.g., a holistic tribal treatment practice focused on harmony and acceptance).
4. Principles: A tribal practice that is rooted in traditional principles (e.g., Mehl-Medrona's principles of treatment of chronic illness; 1997).
5. Elders: A tribal practice that is reviewed and approved by elders. It constitutes evidence of appropriateness and effectiveness within the Native American framework.
6. Community: A tribal practice that is guided by community feedback.

Source: Oregon Addictions & Mental Health Division, n.d.

EXHIBIT 2.1-2. Navigating Life Curriculum Sessions

SESSION TITLE | SESSION GOALS/FOCUS^*^
1. Canoe Journey as a Metaphor for Healing | • Introduce and discuss the Four Seasons/Four Winds, a traditional Suquamish/S'Klallam concept used to frame daily life and teach life skills, a schedule set by nature that traditional livelihood revolved around.; • Discuss the Northwest native traditional canoe journey and how it can serve as a metaphor for life. Each session ends with a reflection back to this concept. Other traditional beliefs are also discussed.; • Information about alcohol is also included.
2. Who Am I? Beginning at the Center | • Learn about S'Klallam and Suquamish values, traditional ways to introduce oneself, self-awareness genealogy, family ties and integrity, and how to use the concept of the Four Seasons/Four Winds as a part of self-definition. Participants are encouraged to explore the idea of a physical self, mental self, emotional self, and spiritual self.; • Information about marijuana is also included.
3. How Am I Perceived? Media Awareness and Literacy | • Focus on how American Indians/Alaska Natives and, specifically, how the Suquamish and S'Klallam people are portrayed in the media; learn how to recognize when stereotypes are being used, how American Indian and Alaska Native culture has been exploited and history has been misrepresented, and how to stand up against stereotypes.; • Information about prescription drugs is also included.
4. Community Help and Support: Help on the Journey | • Learn about the importance of community, how they are a part of many communities, and the importance of giving back to their community; learn how to identify where they can go for help in their own community; learn what it means to be a mentor and how they can become mentors for those around them.; • Information about club drugs and stimulants is also included.
5. Moods and Coping With Negative Emotions | • Learn about different emotions and positive and negative self-talk; learn about depression and suicide, how to cope with negative emotions and difficult situations, and how to find a safe person or place to express emotions.; • Information about inhalants is also included.
6. Who Will I Become? Goal Setting | • Explore what kinds of goals are important and learn a step-by-step approach to setting goals; begin to understand the importance of goal setting and learn how to cope with obstacles that might hinder achieving set goals.; • Information about hallucinogens is also included.
7. Overcoming Obstacles: Solving Problems | • Learn how to recognize when there is a problem, learn ways to solve problems and make good decisions, and discuss where to go when there is a problem; learn how to define a problem, brainstorm solutions, pick the best solution, make and act on a plan, and review/revise the plan if needed.; • Information about nicotine is also included.
8. Listening | • Teach listening skills: Effective listening is discussed and the importance of listening is illustrated through Suquamish and S'Klallam storytelling and other traditional activities. Traditional values stress respect and the belief that you must be an effective listener before you can become an effective communicator.; • Information about methamphetamines is also included.
9. Effective Communication: Expressing Thoughts and Feelings | • Teach effective communications skills, including how to disagree respectfully, how to use refusal and assertiveness skills, and how to deal with peer reactions to assertiveness. Participants practice positive ways to resolve conflict and to express feelings.; • Information about opiates is also included.
10. Safe Journey Without Alcohol/Drugs | • Learn about addictions, how expectancies influence perception, and about the consequences of drug and alcohol use/abuse.; • Reflecting on the “canoe way of life” as an example of “life's journey.”
11. Strengthening Our Community | • Focus on finding leaders within the tribal community to serve as role models; learning about the Boldt decision, tribal sovereignty, leadership, and how to make good choices within the community.; • This session includes field trips into the community to volunteer with important community projects.
12. Honoring Ceremony | • This ceremony is a way to acknowledge youth for program completion and honor their unique attributes. Mentors are invited by the youth to attend and can talk about the youth and their accomplishments. Tribal elders, leaders, and families are also invited to witness the ceremony and share a meal.; • Gifts are prepared and given formally, and digital stories are shared.

* Traditional stories, cultural activities, and speakers from the community are woven throughout the sessions.

Source: Donovan et al., 2015. Adapted with permission.

#### Creating sustainability

Although many service providers face funding issues from the outset, the more formidable task is maintaining interventions and programs for the long term after initial funding has ended. The consensus panel emphasized that service programs often face sustainability issues after initiation of newly funded programs. Although well-established programs and tribal organizations can dedicate more resources for fund development to secure long-term financial sustainability, most programs, regardless of current status, are concerned with sustainability for the future.

SAMHSA'S TRIBAL TRAINING AND TECHNICAL ASSISTANCE CENTER

This Center supports native community self-determination through infrastructure development, capacity building, and program planning and implementation.

Path to solutions

The following suggestions are adapted from the National Evaluation of the Comprehensive Community Mental Health Services for Children and Their Families Program: Exploratory Description of Financing and Sustainability in American Indian and Alaska Native System of Care Communities (Walter R. McDonald & Associates & ICF Macro, 2009). The comprehensive report highlights the key elements of sustainability and steps to develop a flexible sustainability plan. Some examples of the report's recommendations are highlighted next:

• Begin planning for long-term financial sustainability on the first day funding begins, or even before actually receiving the grant, taking care to build planning on the foundation of local cultural strengths (p. 16).
• Create a sustainability planning team that includes key decision makers (e.g., tribal-elected officials, administrators, program planners, finance staff) (p. 16).
• Conduct a site visit to another tribal system that has successfully implemented a sustainability strategy for a peer-to-peer learning opportunity (p. 18).
• Develop a staff training curriculum based on local tribal values and service design to advance staff service skills and credentials (p. 17).
• Meet with the state credentialing board for licensed behavioral health service providers to discuss the tribal curriculum concept and ensure that the state licensing board will approve the tribal curriculum (p. 17).
• Develop a data-driven argument that shows the need for tribal system of care funding, emphasizing human and financial cost-savings by redeploying funds from high-cost state services that tend to be less effective to lower cost tribal services that tend to be more effective (p. 17).

#### Developing a culturally competent and responsive workforce

Program administrators struggle to meet the demands of staff development. Immediate demands, often caused by staff shortages and turnover, take precedence over long-term strategies to invest in the future workforce. However, program administrators need to be committed to developing a culturally competent workforce when providing services to American Indian and Alaska Native clients. This commitment involves attracting, supporting, and retaining native staff; creating or obtaining relevant tribal-specific curriculums that increase cultural competence; and implementing strategies to promote ongoing professional development to increase competence and promote leadership skills, such as the provision of clinical supervision and professional mentoring.

The Native American Center for Health Professions created a digital mentoring website called We Are Healers. The website showcases short, engaging videos of American Indians working in health professions and provides a behind-the-scenes look at their jobs. These stories help American Indian students explore health fields and connect to mentorship tools and resources. See more at www.wearehealers.org/home-video.

Path to solutions

• Connect with tribal colleges and create internships.
• Conduct outreach to elementary and secondary schools and organizations serving younger people in native communities to promote interest in the field at an early age.
• Develop facilitator-led educational groups to promote interest.
• Create mentoring programs for clinical and administrative roles.
• Become a resource for how to find educational assistance (e.g., federal traineeships, internships, scholarships).
• Encourage tribal colleges to incorporate certifications into their programs, including in-class and online courses.
• Create opportunities with state universities to develop American Indian curriculums along with internships and work-study programs in tribal communities.

#### Collaborating with native communities and tribal leadership on a regular basis

American Indian and Alaska Native cultural beliefs revolve around the value of connectedness and the importance of relationships. Relationship building needs to be the center supporting pole in developing services. Native communities have considerable cause not to trust behavioral health services, which historically have imposed culturally blind diagnoses; employed institutionalism, such as boarding schools and mandated state hospitalizations; have failed to provide adequate funds or have misappropriated funds; have tied the availability of resources to adopting mainstream EBPs or certification processes that inadequately represent native populations and force assimilation; and failed to recognize and honor American Indian and Alaska Native sovereignty. Without investment and involvement in native communities and their leadership to gain guidance, services will be poorly matched to the population and underutilized by the community, and funding for these services will further strain agency and tribal resources.

WORKFORCE DEVELOPMENT IN PRACTICE: THE SPOKANE TRIBE HEALTH AND HUMAN SERVICES BEHAVIORAL HEALTH PROGRAM

To address staff shortages in a geographically remote area, the Behavioral Health Program implemented two workforce development strategies. The first focuses on providing professional development opportunities for qualified tribal member employees over a 2-year period. The second strategy involves a partnership with the National Health Service Corps (NHSC) Loan Repayment Program as an approved service site. This program attracts staff by reducing and eliminating student loans in exchange for the provision of medical, dental, and behavioral and mental health services to underserved populations.

Source: IHS, 2011.

Path to solutions

• Engage the community and tribal leadership early and regularly. Community and tribal governance involvement in behavioral health service planning and implementation is a key factor in achieving long-term success.
• Plan ahead to allow significant time for relationship building. Often, the time required to build trusting connections is underestimated.
• Make sure community members are involved in program service implementation, including staff assignments, board appointments, inclusion of traditional healers and elders, and use of native peer specialists.
• Develop local community focus and advisory groups to discuss key service needs.
• Engage the community by housing community events at the facility as well as attending local community events, when appropriate.
• Honor sovereignty. Most federally recognized tribes in the Unites States exist as sovereign nations. Providers who serve American Indian and Alaska Native clients must acknowledge and respect this sovereignty by working with the community and their tribal leadership when planning for and implementing behavioral health services. Understanding sovereignty is critical to successful service provision and program sustainability. Specific laws, codes, regulations, and procedures vary from tribe to tribe and may be quite different from state laws (e.g., employment regulations).
• Use community-based models for intervention and prevention, such as the Community Readiness Model (Plested, Jumper Thurman, & Edwards, 2014).

Fifty-four percent of the mental health programs and 84 percent of the alcohol and substance abuse programs [in native communities] are now operated by tribes. This evolution in behavioral healthcare delivery and management is changing the face of behavioral health services in Indian Country. In the last decade, tribes have increasingly used the Indian Self-Determination and Education Assistance Act to establish and provide their own behavioral health services (IHS, 2011, p. 1).

ENGAGING NATIVE COMMUNITIES: THE COMMUNITY READINESS MODEL

The Community Readiness Model was developed in 1994 at Colorado State University with the aim of building the capacity of tribal communities/nations so that they might recognize and build on the strengths from within to begin a healing process of healthy change.

The Community Readiness Model will help you assess the community's readiness for change, the needs of the community, and strategies to address needs related to the identified specific issue (e.g., HIV/AIDS, suicide, substance abuse).

The Community Readiness Model:

• Provides the community “truth” about an issue, which may or may not be the real “truth,” thus setting strategies based on the community's readiness.
• Models community change that integrates a community's culture, resources, and level of readiness to more effectively address the identified issue.
• Allows communities to define issues and strategies in their own contexts.
• Builds cooperation among systems and individuals.
• Increases capacity for the identified issue and intervention.
• Encourages community investment in the issue and awareness.
• Is applicable to any community (geographic, issue-based, organizational, etc.).
• Can address a wide range of issues.
• Guides the complex process of system and community change.

Sample Content of Manual: Dimensions of Readiness

Dimensions of readiness are key factors that influence your community's preparedness to take action on (THE ISSUE). The six dimensions identified and measured in the Community Readiness Model are comprehensive in nature. They are an excellent tool for diagnosing your community's needs and for developing strategies that meet those needs.

A. Community Efforts: To what extent are there efforts, programs, and policies that address (THE ISSUE)?
B. Community Knowledge of the Efforts: To what extent do community members know about local efforts and their effectiveness, and are the efforts accessible to all segments of the community?
C. Leadership: To what extent are appointed leaders and influential community members supportive of (THE ISSUE)?
D. Community Climate: What is the prevailing attitude of the community toward (THE ISSUE)? Is it one of helplessness or one of responsibility and empowerment?
E. Community Knowledge About the Issue: To what extent do community members know about or have access to information on (THE ISSUE), and how it impacts your community?
F. Resources Related to the Issue: To what extent are local resources (e.g., people, time, money, space) available to support efforts?

Your community's status with respect to each of the dimensions forms the basis of the overall level of community readiness.

Source: Plested et al., 2014.

## Workforce Professional Development

As an administrator, your responsibilities include providing staff with the resources to effectively meet the needs of clients and the community. A core resource is the investment in building and improving the skills and capabilities of behavioral health staff through education, training, clinical supervision, and other activities. These professional development activities can play a powerful role in building clinical competence, in creating leadership opportunities, and in recruiting and retaining staff. In turn, your commitment to professional development may improve client treatment engagement from the initial intake to continuing care, treatment outcomes, and treatment acceptance in the community.

Staff training and education are important elements in building skills, including personal strategies in how to develop therapeutic relationships. However, skill training never replaces the importance of investing in the relationship. Although this is old knowledge, science related to substance abuse supports it: the provider's empathy and interpersonal ways have the greatest impact on outcome among individuals seeking treatment (Miller & Rose, 2009).

As with most actions, the effects of professional development are circular. Staff members see training and education as a benefit, the training improves the functioning of your organization, clients have better treatment experiences and outcomes, the program becomes more accepted and respected in the community, the program attracts more individuals to the program (including others who develop an interest in providing services), and the process continues. The following sections address training and education, clinical supervision, and mentoring.

### Training and Education

The immediate goal of education and training is to improve the capacity of staff members to effectively perform their duties in their current roles. In other words, you are helping staff members to become better providers to meet the needs of your clients. However, if the goal of education and training ended here, it would be a disservice to staff and American Indian and Alaska Native communities. Education and training goals should extend beyond current needs. With the current challenges in building an American Indian and Alaska Native workforce as well as a culturally competent non-native behavioral health workforce, education and training also need to focus on the development of leadership and administrative skills for the next generation.

“When you see a new trail, or a footprint you do not know, follow it to the point of knowing.”

—Santee Sioux

Source: C. A. O. Eastman, 1907, p. 522.

CSAP'S PREVENTION FELLOWSHIP PROGRAM

Developing the Next Generation of Prevention Leaders: Prevention Internship Program for Tribes and Tribal Organizations

The Prevention Internship Program, a component of CSAP's Prevention Fellowship Program, invites qualified individuals with strong interest in substance abuse prevention and behavioral health for a 10-week paid internship program in participating tribal organizations throughout the United States. The Prevention Internship Program prepares interns to provide capacity-building technical assistance to support integration of mental and substance use disorder prevention services within tribal organization systems. Interns benefit from hands-on experience and trainings in mental and substance use disorder prevention, the Strategic Prevention Framework, workforce development, and evaluation. Interns learn new techniques, best practices, and knowledge from their professional and cultural experiences.

In addition to using basic provider and intervention materials to guide your education and training activities, supplementary information on the community itself can inform you of the potential training needs of your staff. This information can be obtained from a community needs assessment; client, family, and community feedback on clinical services; and reports on current events in the community (e.g., suicide rates in the community, the availability of new drugs of abuse, the incidence of diabetes, the occurrence of traumatic events). Although these areas are essential in guiding your plans, cultural training is paramount in laying a strong foundation when serving American Indian and Alaska Native clients and communities.

THE ADDICTION TECHNOLOGY TRANSFER CENTER NETWORK

The Addiction Technology Transfer Center (ATTC) Network offers a variety of training and educational opportunities for behavioral health service providers serving Indian Country. The ATTC Network strives to improve the health and well-being of American Indians and Alaska Natives through access to “high-quality, evidence-based, culturally appropriate, self-directed behavioral health services and recovery supports … that both honor and contribute to the health and well-being of native communities, tribes, and individuals.” The ATTC Network offers access to resources, including training curriculums, webinar presentations, online trainings, evidence-based best practices, and various informational print materials on topics such as:

• Culturally informed clinical supervision.
• The impact of colonization on native communities.
• The Native American lesbian, gay, bisexual, transgender, and questioning (LGBTQ)/Two-Spirit curriculum.
• Professional readiness: Attitudes and values.
• The Native American curriculum for state-accredited, nontribal mental health and substance abuse programs in South Dakota.

See https://attcnetwork.org/centers/national-american-indian-and-alaska-native-attc/home.

Program staff serving American Indians and Alaska Natives in rural areas may benefit from training in computer use and phone technologies that can deliver care over a distance rather than exclusively in person. (See TIP 60, Using Technology-Based Therapeutic Tools in Behavioral Health Services [SAMHSA, 2015]).

Providing cultural training and developing cultural competence form a main pathway in reducing health inequalities. We know that understanding tribal history and culture results in better healthcare communications with American Indian and Alaska Native clients and improved client outcomes (see review by Clifford, McCalman, Bainbridge, & Tsey, 2015). The following segments focus on cultural training, with an emphasis on resources, content, and logistics.

“It is critical that [behavioral] healthcare professionals understand the stress and anxiety associated with AI/AN identity, the AI/AN acculturation and deculturation that trigger mental health disorders, and the need for traditional and cultural practices as a part of the treatment and prevention process.”

Source: IHS, 2011, p. 10.

#### Staff training on American Indian and Alaska Native history and culture

Staff training on American Indian and Alaska Native history and culture is essential in providing culturally competent care. Training provides an orientation to cultural worldviews, practices, and historical events and an opportunity for participants to examine their own cultural identity and beliefs and how these beliefs influence their perspectives on healing, communication, relationships, and clinical practice. But staff training on culture also necessitates a relearning of history. For many non-native and American Indian and Alaska Native people, formal education has either misrepresented historical events, failed to address American Indian and Alaska Native history, or minimized the dire consequences of “forced assimilation” policies that led to historical trauma and subsequent conditions that survive today. Embracing this relearning from a native perspective provides an opportunity to see native nations and American Indian and Alaska Native people with “eyes wide open.” Please see Part 1, Chapter 1, for an overview of historical events.

Staff training also needs to incorporate the culture and history of the specific tribes and communities who will use your services. Remember that each tribe and community has its own history. Staff training on American Indian and Alaska Native culture and history represents an opportunity to affect staff attitudes toward clients and increase cultural awareness of themselves and others. Appropriate training can strengthen the rationale for trauma-informed care; help staff become more cognizant of the impact of racism, microaggressions, prejudice, and historical trauma on clients, their families, and their communities; and encourage the exchange of knowledge between non-native and native staff and clients.

Some staff members may not see the need for cultural training either because they see themselves as experts, believe that they already have cultural knowledge, disregard outright the value of cultural competence, or are culturally blind, failing to see that differences exist (e.g., “I treat everyone the same”). This attitude gives administrative or clinical supervisors an opportunity to provide a rationale, to discuss, and to reinforce the importance of cultural competence as a provider in the organization. Nonetheless, it may be a sign that your organization needs to conduct an organizational assessment on cultural competence, followed by the development and implementation of a plan to raise awareness, improve practices, and endorse polices that improve cultural competence with staff members and with organizational leadership. For specific information on how to become a culturally responsive organization, refer to the step-by-step guidelines outlined in TIP 59, Improving Cultural Competence (SAMHSA, 2014a).

“Often, each level of the organization (leadership, staff, and clients) views cultural competence in differing ways. The key is flexibility—the flexibility to change and make things better. We worked with an organization [that] had concerns about serving their American Indian and Alaska Native clientele in a culturally appropriate way. They decided to use Community Readiness [Model] as the assessment tool for cultural competence. They treated the Board, the program management, the staff, and clients as separate communities during the organizational assessment. By doing this, they had four separate and distinct communities and readiness scores. Results were interesting. The Board and management thought the organization was very culturally responsive, but the frontline staff and clients did not agree. This was a wakeup call for the Board and program management. They immediately took the readiness scores into an all-day staff retreat, and each ‘community’ put together a strategic plan to raise readiness levels related to cultural competence. It was wonderful to see the change in the organization. The assessment itself was the intervention.”

—Pamela Jumper Thurman, Ph.D., Western Cherokee, TIP Chair and Panel Member

WHAT IS CULTURAL COMPETENCE?

The U.S. Department of Health and Human Services (HHS) defines cultural competence as “the ability to honor and respect the beliefs, languages, interpersonal styles, and behaviors of individuals and families receiving services, as well as staff members who are providing such services” (HHS, 2003, p. 12). Cultural competence is an ongoing developmental process achieved over time and, as a result, requires a long-term commitment if it is to succeed.

#### Arranging staff cultural training

You can choose from a wide range of formal and informal instructional methods, including the use of a curriculum during group supervision or as a peer-led supervision group, regularly scheduled training sessions or educational lunches with various presenters or trainers, staff support to attend and participate in training and cultural activities in the local tribal community, and cultural programs led by American Indian and Alaska Native elders or other community members, including immersion programs. Part 1 of this TIP provides material that can be easily adapted for training.

SAMHSA's American Indian and Alaska Native Culture Card: A Guide to Build Cultural Awareness is an example of material available for staff education and training. This informative material and similar resources are available for free from SAMHSA's website (https://store.samhsa.gov).

As an administrator, you may have specific questions or concerns related to staff education and training on American Indian and Alaska Native history and culture. Before scheduling any kind of education and training, it is important to keep a few things in mind:

• Your support of and commitment to education and training as an administrator is vital to the success of such efforts.
• You need to be willing to commit program resources, including allowing time for trainings, rearranging schedules, and devoting funds for a trainer. If funds are limited, do not assume that you cannot provide the training. You may want to contact the NAI & AN ATTC, local trainers, or tribal colleges. Some trainers may volunteer their services if they know that the program has limited funds.
• Community leaders and cultural advisors should be involved in or lead the design of the cultural training. This will not only help focus staff education and training on the history, culture, and values unique to your clients, but it will also help build community partnerships.
• Learning and training styles need to be culturally responsive; that is, favoring engagement over abiding strictly to schedules or using experiential group activities rather than lectures.
• You need to obtain feedback and evaluate the training to guide the selection of future training content, trainer selection, style of presentation, and location of training.

NATIVE AMERICAN REHABILITATION ASSOCIATION'S CULTURAL ADVISORS

The Native American Rehabilitation Association of the Northwest, Inc. (NARA) provides culturally appropriate education, physical and mental health services, and substance abuse treatment services to American Indians and Alaska Natives in the region. Culture and traditional practices are central components of the agency's mission and activities. To help ensure the appropriate and accurate representation of American Indian and Alaska Native culture, NARA has established and collaborates with staff Cultural Advisors. These Advisors lead NARA's Cultural and Community Services and work with all NARA programs to provide cultural competence training for staff and cultural activities and services for NARA's clients.

#### Identifying potential cultural trainers

Selecting someone to train staff members in American Indian and Alaska Native culture(s) and history involves careful consideration, as having someone who provides inaccurate information will do more harm than providing no training at all. Whom you choose to serve as your program's cultural trainer will depend on answers to several questions:

• Are clients mainly from a single tribe or community, or is there representation from various tribes?
• How often will staff members need training?
• Will the trainer receive financial compensation for services?
• Is the trainer American Indian or Alaska Native?
• What specific cultural knowledge and experience does the trainer need to have that clearly matches client needs?
• Is the trainer endorsed by the local community and tribal governance?
• Does the trainer have a good reputation for engaging staff members?
• Have you asked for guidance from tribal and community leaders in trainer selection?
• Are you working collaboratively with tribal leadership and community leaders to design the cultural training with the trainer?
• Are you going to conduct a one-time training or ongoing training to promote knowledge adoption?

#### Selecting training materials for cultural training

General recommendations on selecting content center around several principles: relevance and accuracy of content, adaptability to practice, ease of understanding, tribal endorsement, and ability to engage participants. For cultural training, a number of online resources recommend content, training tools tailored to specific tribes and communities, and training guidelines. The last section in this chapter, “Provider Competencies,” can also guide you in selecting content areas. Refer to Part 2, Chapter 2, for cultural training resources for nontribal behavioral health service providers.

WHAT MAKES SOMEONE A QUALIFIED CULTURAL TRAINER?

Dixon and Iron (2006) include a list of qualifications for cultural trainers used by an Alaskan hospital. In their work, a qualified cultural trainer is someone who:

• Has knowledge of the specific topic(s).
• Is respected by his or her community.
• Has good rapport with people, including people outside his or her community (e.g., healthcare providers).
• Is comfortable with public speaking.
• Can speak, read, and write in the local tribal language.
• Has experience providing training and lives a traditional subsistence way of life.

Trainings need to be designed specific to the tribe(s) represented in your program, the services provided, and constraints of the geographic region, such as trainings for health clinics in remote villages. Along with tribe-specific training materials and other resources, Part 1, Chapters 1 and 2, can be used as a supporting resource for trainings. The case histories and vignettes in Part 1, Chapter 2, can be adapted and used as role plays to engage participants. The following is a sample list of content areas for cultural training:

• Tribal history
• Family structure, dynamics, and parenting practices
• Common terminology and languages
• Tribal governance
• Role of elders
• Tribal justice and wellness court system
• History of U.S. government policies and treaties with tribe(s)
• Tribal and state relations
• Worldviews
• Historical traumas, including those specific to the tribe, village, or region (e.g., Trail of Tears, chemical contamination of water, boarding schools, sexual assaults, kidnappings, loss of land and resources, sweeping epidemics)
• Tribe-specific artwork and food
• Beliefs and attitudes about illness and healing
• Tribal constitutions and codes
• Role of health clinics
• Tribal sovereignty
• Children services and the Indian Child Welfare Act
• Educational system
• Attitudes toward alcohol and drugs
• Cultural practices (e.g., potlatches)
• Traditional healing
• History of ceremonies
• Cultural etiquette and respect
• Cultural awareness and humility
• History of health services and experiences among American Indians and Alaska Natives, including the changing patterns of governance
• Influence of geographic regions
• Role of public safety officers
• Native EBPs

NATIVE AMERICAN CURRICULUM FOR STATE ACCREDITED, NON-TRIBAL MENTAL HEALTH & SUBSTANCE ABUSE PROGRAMS IN SOUTH DAKOTA

This training program offers professionals an opportunity to improve their awareness of Native American culture, resulting in an enhanced treatment experience for Native American clients. The primary intent of this substance abuse-related curriculum is to provide an educational experience primarily for non-native staff members of state-accredited, nontribal mental health and substance abuse programs in South Dakota. The curriculum is also relevant for those working to address other aspects of behavioral health. Although this curriculum focuses primarily on Dakota, Lakota, and Nakota groups located in South Dakota, it has the potential to be adapted to reflect the ways of other indigenous groups located in other states. This curriculum contains 19 modules. For certification hours and other pertinent information, contact the NAI & AN ATTC (see https://attcnetwork.org/centers/national-american-indian-and-alaska-native-attc/home).

Leaving Footprints: Cultural Training

Duane Mackey, Ed.D., a Santee Sioux tribal member, received his M.A. and Ed.D. from the University of South Dakota. He taught middle school and high school and coached football, golf, and basketball. He practiced as a guidance counselor and became the first Director of Indian Education for the Sioux City School System. His team twice won the Nebraska state boys basketball tournament, which later led to his very strong commitment to human rights for American Indians.

He dedicated his life to improving American Indian human rights and enhancing American Indian opportunities in education and research. He became a faculty member at the University of South Dakota, Addiction Studies Program, and was a Director of Native American Initiatives in the Prairielands ATTC, now known as the NAI & AN ATTC. In particular, Dr. Mackey developed American Indian curriculums specifically designed for nontribal substance abuse treatment providers and has significantly influenced the field's recognition that cultural training is paramount. He has left footprints that will continue to influence care offered by native and non-native providers.

In memory of Dr. Duane Mackey, “Waktaya Naji,” TIP Consensus Panel Member.

The Dr. Duane Mackey “Waktaya Naji” Award

This award acknowledges individuals who, in their addiction study careers, have made significant contributions in education, research, mentoring, and service among American Indian and Alaska Native peoples. The award signifies the promise of continued success of an individual and serves to inspire others to contribute to the addiction treatment field for American Indian and Alaska Native people. It also recognizes individuals who, through their concerted efforts, have untiringly promoted and espoused the ideals of equality and justice for all peoples.

#### Providing education resources: Staff opportunities

Educational opportunity is another important ingredient of promoting professional development, improving the quality and outcome of services and supporting future leadership. Likewise, it can serve as a recruitment and retention strategy. Several specialized education and scholarship programs are available for students who wish to enter the behavioral health field, as well as for recent graduates just entering the health field. Several programs are available, such as the IHS Extern Program; IHS preparatory, pregraduate, and professional scholarship programs; and the NHSC Loan Repayment Program, for individuals in the healthcare field who are willing to commit to filling needed positions within IHS. The IHS Loan Repayment Program offers assistance repaying health education student loans for qualified candidates (both native and non-native) in exchange for a multiyear service commitment at a program or facility that serves an American Indian or Alaska Native community (see the IHS website for more information: www.ihs.gov/loanrepayment). Several states offer similar programs. In addition, the American Psychological Association offers a Pre- and Postdoctoral Minority Fellowship Program funded through SAMHSA.

EDUCATIONAL INTERNSHIPS AND FELLOWSHIPS

• The IHS Externship Program: www.ihs.gov/scholarship/ihsexternprogram
• SAMHSA: Minority Fellowship Program: www.samhsa.gov/minority-fellowship-program
• Centers for Disease Control and Prevention: Public Health Training Fellowships: www.cdc.gov/Fellowships

Loan Opportunities

• The NHSC Loan Repayment Program: https://nhsc.hrsa.gov/loanrepayment
• The IHS Loan Repayment Program: https://www.ihs.gov/loanrepayment
• (Alaska) SHARP-II: Providing Support-for-Service to Health Care Practitioners: http://dhss.alaska.gov/dph/HealthPlanning/Pages/sharp/default.aspx
• The Idaho State Loan Repayment Program: https://healthandwelfare.idaho.gov/Portals/0/Health/Rural%20Health/SLRP%20FAQs%207-18.pdf

### Clinical Supervision

Providing culturally competent clinical supervision is an important ingredient in professional development. Done well, it can help providers meet client needs in a culturally competent way; reinforce a community atmosphere among program staff; promote a nonjudgmental approach to learning; bridge the gap between education and day-to-day experience in the field; help you, the administrator, retain staff; reduce health inequalities; and improve intervention outcomes. TIP 52, Clinical Supervision and Professional Development of the Substance Abuse Counselor (Center for Substance Abuse Treatment [CSAT], 2009a), provides considerable information on clinical supervision in behavioral health organizations, and it can serve as a primer for implementing clinical supervision. This section addresses the dynamics and challenges of clinical supervision that may arise when working cross-culturally with non-native and native supervisors, supervisees, and clients.

If you, as a clinical supervisor, are going to serve as a resource and mentor in Indian Country, you need skills in providing trauma-informed care, culturally adaptive and native EBPs, family therapy, and motivational interviewing (MI). You also need to have knowledge about traditional healing practices and build relationships and connections with spiritual advisors, traditional healers, elders, and others in the community.

If you are an administrator managing a small tribal program or other community service, you may doubt that you can provide clinical supervision with limited funding, staff resources, and time constraints. Foremost, clinical supervisors do not have to be full-time employees or work within the same program; they can be professionals who serve in a consulting role. Although licensing requirements and laws may restrict how you use supervisors; you may be able to find alternative ways of providing clinical supervision, such as telehealth supervision, facilitated group supervision, and peer-to-peer supervision groups.

WHAT DO WE MEAN BY CLINICAL SUPERVISION?

Clinical supervision is “a social influence process that occurs over time, in which the supervisor participates with supervisees to ensure quality of clinical care. Effective supervisors observe, mentor, coach, evaluate, inspire, and create an atmosphere that promotes self-motivation, learning, and professional development. They build teams, create cohesion, resolve conflict, and shape agency culture, while attending to ethical and diversity issues in all aspects of the process. Such supervision is key to both quality improvement and the successful implementation of consensus- and evidence-based practices.”

Source: CSAT, 2009a, p. 3.

Most importantly, clinical supervision needs to occur in a safe, supportive, and nonjudgmental environment. Not unlike previous recommendations on embracing the spirit and philosophy of MI in counseling, the spirit of MI can be culturally responsive in supervision. Although several models of supervision exist, one model, Bernard and Goodyear's (2004) four roles of clinical supervision, is compatible with MI and can be culturally adapted. Each role is an important element in building supervisor–supervisee relationships, and the roles change according to the needs of the supervisee as well as the supervisee's client. For example, one moment you may be educating about the importance of traditional practices, whereas in the next moment you may be encouraging your supervisee to try something different in a session. The authors caution against using one particular role; instead, they advise supervisors to step out of their comfort zone to share knowledge, to encourage, to guide, and to collaborate.

As reinforced throughout this TIP, relationships in American Indian and Alaska Native cultures are often not formed in prescribed environments or roles. Generally speaking, American Indians and Alaska Natives do not define relationships based on titles, degrees, or positions; instead, relationships are often formed by the knowledge that you are known and accepted in the community and that you have a genuine interest in the community.

SIX AREAS OF COMPETENCE AS A CULTURALLY COMPETENT SUPERVISOR

1. Supervisor-Focused Personal Development: Supervisor has done extensive self-exploration regarding personal values, biases, and personal limitations.
2. Supervisee-Focused Personal Development: Supervisor fosters supervisee self-exploration, awareness, and knowledge.
3. Conceptualization: Supervisor promotes an understanding of the impact of individual and contextual factors on clients' lives, such as the influence of stereotypes and personal identity.
4. Skill Development: Supervisor encourages flexibility between mainstream and both traditional and alternative interventions (for example, talking circles) as appropriate.
5. Process: The supervisor–supervisee relationship is characterized by open and respectful communication.
6. Outcome/Evaluation: Supervisors evaluate supervisees on their cultural competence, recommending additional or remedial education and training to address performance areas in need of improvement.

Sources: Ancis & Ladany, 2001; Inman, 2008.

#### Establishing a cross-cultural supervisor–supervisee relationship

Culture is a major factor that influences the relationship in clinical supervision. Differences in individual worldviews, values, traditions, history, and experiences inherently influence a person's biases, expectations, and behaviors. These differences get played out in clinical supervision. Remember there are at least three players: the supervisor, the supervisee, and the client—each with unique experiences, history, culture, and expectations that influence the supervisor–supervisee relationship. From the outset, clinical supervision discussions should center on these areas. Initiating early discussions with supervisees regarding individual backgrounds and expectations can help establish a foundation on which to develop trust and empathy, and it demonstrates to staff your awareness of and willingness to discuss issues related to race and culture in a safe and supportive manner (Inman, 2008).

Here are some questions to help guide your own self-awareness as a supervisor and facilitate a collaborative exploration with your supervisee (Corey, Haynes, Moulton, & Muratori, 2010):

• How do you describe your (both supervisor and supervisee) ethnic and cultural identity?
• What are the various cultural groups to which you belong?
• In what ways do your worldviews (e.g., values, views, cultural practices) influence how you work with clients and staff?
• How might your cultural differences or similarities affect your clinical supervisory relationship?
• How would you rate your knowledge of and comfort with discussing cultural issues, on a scale from 1 (very uncomfortable) to 10 (very comfortable)? Discuss what would need to happen to make you more comfortable or less comfortable. For example, if your supervisee initially responds with a 9 as very comfortable, you could ask, “What would need to happen to make it less comfortable, let's say a 7. What would need to happen to make it a 10?” These questions make the discussion more informative and engaging rather than just talking about the rationale of the initial rating.
• What challenges have you faced working with clients or coworkers whose culture differed from your own?

CONDUCTING A CULTURAL AWARENESS SELF-EVALUATION

An effective supervisor can acknowledge that he or she may have preexisting assumptions or experiences regarding different cultures that could influence his or her interactions with staff members. It is crucial, then, that you be willing to evaluate your personal values, attitudes, experiences, and practices and how they could affect your interactions with supervisees and clients. Corey et al. (2010) offer some questions to consider as part of this self-evaluation:

• How did I learn my cultural values?
• What is my experience with other cultures and my perception of these cultures?
• How might my beliefs affect the ability to supervise effectively?
• How do I define the relationship between culture and therapy?

For additional resources and assessment tools, refer to TIP 59 (SAMHSA, 2014a).

#### Supervision dynamics: Non-native supervisor with American Indian or Alaska Native supervisee

A non-native supervisor of native supervisees should be able to demonstrate an understanding of the history, values, and culture of American Indians and Alaska Natives. However, it is not enough to know about the history and culture. You, as the clinical supervisor, need to demonstrate openness and humility to learn, including the willingness to learn about the history and culture specific to the tribe or tribes represented in the program and among staff. You are not the expert on American Indian or Alaska Native history or ways, regardless of your background. Instead, you should remain receptive and flexible in modifying supervision styles and techniques to match your supervisees' needs and to improve your listening and relational skills when working with American Indian and Alaska Native staff and clients.

“It is important to be flexible and humble as a clinical supervisor. I was thinking about gardening in our community, and how staff from the community would show up. We would come together to harvest the garden. During this time, there was a lot of ‘talk’ occurring, a coming together to listen, learn, and honor the wisdom of each other and our journey.”

—Betty Poitra, Turtle Mountain Band of Chippewa, Belcourt, ND, TIP Contributor

Equally important, clinical supervisors need to monitor the supervisor–supervisee power dynamic, which is often affected by differences in race and culture. For example, White supervisors need to recognize that they may symbolically represent a history of oppression to an American Indian or Alaska Native supervisee. Although they should pay attention, listen, and help supervisees discuss their experiences in the role of supervisee, White supervisors should not refocus the session on their own feelings of “White guilt” or shame; nor should they attempt to share past experiences that may appear similar. In simple terms, it is not about you; rather, it is about your listening and learning. Similar to the role of provider in MI, your supervisees are the experts on their own experiences. You are there to help facilitate and guide the process.

SUPERVISION AND CLIENT EXPERIENCES: THE INFLUENCE OF CULTURE

American Indian and Alaska Native staff members working with American Indian and Alaska Native clients may encounter challenges that differ from those experienced by their non-native colleagues. Native supervisees may find that American Indian and Alaska Native clients want to discuss and obtain more personal information from them. As a supervisor, your role is to facilitate a discussion about what is culturally and clinically appropriate and find a balance that honors self-disclosure as well as boundaries. Remember that different cultures have different needs and expectations about personal space, emotional boundaries, and interpersonal boundaries.

Relationships are particularly influenced by community size. For example, if you live in a village of 600 people, it is likely that your clients will be the store clerk, the pilot, and your child's teacher or coach. In this scenario, there is no feasible way you can avoid many multiple relationships. Multiple relationships occur when a provider is in a professional role and another role with the same person, which raises ethical concerns for providers. Boundaries among American Indians and Alaska Natives are more flexible, so it takes some effort to balance boundaries and relationships.

Another experience among native and non-native supervisees is the request from clients to meet needs outside the program's parameters. For example, the provider has a client who asks directly for his or her advice and assistance in helping his niece who is depressed. Although he may be court-ordered to attend treatment, the client is more focused on getting help for his niece, even bringing her for his session at the center. As a clinical supervisor, you may believe it is inappropriate to comply with the client's request. You may go further and assess that the client is focusing away from the reasons for his admission. Yet, it is not uncommon that American Indian and Alaska Native clients will seek assistance for others, especially after trust is formed in the relationship. Although your program may not be able to provide assessment and treatment services for his niece, you may be able to link the client to services and to anticipate that this will naturally happen if the program has developed good relations with the community. By anticipating that this is likely to happen, you can plan ahead on how best to manage informal requests for services and facilitate the access to care that falls out of the scope of services within your program.

#### Supervision dynamics: Non-native supervisor with non-native supervisee

In the non-native supervisor–supervisee relationship serving American Indian and Alaska Native clients, supervisors need to understand the history, culture, and beliefs of the community. They also need to become lifelong learners in cultural competence by seeking cultural consultation and further education and training, and by participating, when appropriate, in native community activities. When supervising non-native staff, a significant responsibility as a supervisor is reinforcing the value of and need for culturally responsive care while providing the resources to do so. Supervisors should attempt to increase their own and their supervisees' awareness of how mainstream values and privilege affect treatment. Also, supervisors need to promote a strengths-based and trauma-informed approach, rather than a perspective that views clients' presenting concerns through the lens of deficits or pathology (e.g., framing clients' behavioral reactions through a trauma-informed lens rather than interpreting the reaction as a diagnostic symptom of a personality disorder). For specific suggestions and questions on how to facilitate cultural awareness during supervision, refer to “How To Engage in Self-Reflection: A Tool for Counselor Training and Supervision,” TIP 59 (SAMHSA, 2014a, p. 93).

#### Supervision dynamics: American Indian or Alaska Native supervisor with non-native supervisee

American Indian and Alaska Native supervisors should be cognizant of their beliefs and assumptions about non-native staff and how those beliefs may affect their relationships with non-native supervisees. At the same time, supervisors should also be aware of and make it a point to address supervisee beliefs and biases that may affect supervisee relationships and interactions with American Indian or Alaska Native clients. Using the self-awareness and self-reflection questions highlighted in this chapter; the South direction in Part 1, Chapter 1, in this TIP; and TIP 59 (SAMHSA, 2014a); supervisors can guide discussions to further promote the development of cultural competence.

#### Supervision dynamics: American Indian or Alaska Native supervisor with native supervisee

Supervisors should be conscious of differences and issues that may arise in native supervisee–supervisor relationships, especially cultural identity and compe-tence. Foremost, do not assume that native supervisees are culturally competent or knowledgeable about the specific tribes you serve. Cultural identity may vary widely between you and your supervisees. You may be more traditional; they may have limited lifetime exposure to American Indian and Alaska Native cultures. You may have lived on a reservation your entire life; they may have lived in urban areas disconnected from their heritage. You may use traditional healing and ceremonies; they may rely on mainstream health care only. As a supervisor, build a bridge that enables supervisees to become culturally competent while honoring their path in cultural identity.

POTENTIAL BENEFITS OF MENTORING PROGRAMS

• Take the behavioral health services field into the next generation.
• Provide professional networking opportunities.
• Develop mentee's leadership qualities.
• Encourage intellectual and professional development and stimulation.
• Support professionals currently providing behavioral health services.
• Provide a learning opportunity for both the mentee and mentor.
• Offer opportunities to share knowledge and experiences and build collaborations.
• Foster agency growth and workforce development.
• Source: NAI & AN ATTC, 2015.

### Mentoring

Mentoring is another professional development activity that helps build and improve the skills and capabilities of staff members. It is evolving into a key workforce development approach in preparing the next generation of American Indian and Alaska Native behavioral health leaders and professionals. It complements native ways of knowing.

Mentoring is typically a collaboration between two entities or individuals who have different levels of experience, such as a mentor–mentee relationship, whereby one person has more experience or a different experience to share; an organization that supports mentorship programs using its expertise to further develop the skills of an early career professional, including programs for youth; or an agency-to-agency mentorship program that shares knowledge and leadership skills to improve service capacity and sustainability.

Mentoring is key to building an American Indian and Alaska Native behavioral health workforce. Although staff members may have educational degrees, certifications, and licenses that have required practicum and internship experiences, mentorship programs do not have to require educational levels, licenses, or certifications or even have specific age requirements, depending on the goals of the mentorship. Mentoring can be tailored formally or informally to match the needs and desired outcome for the individual or organization.

A NOTE TO ADMINISTRATORS

Ethics in Research With American Indian and Alaska Native Communities and Clients

Researchers and administrators have an ethical responsibility to seek approval for research from tribal governance when working with American Indian and Alaska Native clients, tribes, and communities, regardless of location (e.g., Alaska Native Corporations, Urban Indian Health Organizations, American Indian tribal governments). Tribes need to give informed consent using a formal memorandum of agreement. This document clarifies the exact nature of the research; information that will be shared; how it will be shared; who will be involved in the research; what level of community involvement is required; who owns the data; who has copyright control; and how confidentiality is protected for the individual, tribe, and community. As an administrator, remain vigilant in respecting American Indian and Alaska Native intellectual, cultural, and spiritual property, including the acquisition and use of data.

### Provider Competencies

Competence means capability. Are your staff members knowledgeable about American Indian and Alaska Native culture? Is this knowledge tribe specific? Do they possess an understanding of American Indian as well as Alaska Native history and its effects on native families and communities today? What knowledge do they have about traditional healing and beliefs about illness and health? As an administrator or clinical supervisor, you want to determine the knowledge, understanding, skills, and attitudes needed for providers to be culturally competent to meet the needs of your clients.

The text that follows lists provider competencies focused on the training, knowledge, understanding, skills, and attitudes needed to work with American Indians and Alaska Natives. The Western Interstate Commission for Higher Education (1998) convened an expert panel that compiled this list of competencies to serve as guidelines for managed care organizations providing mental health services to American Indian and Alaska Native clients. These competencies can guide the selection of your professional development activities as outlined in the previous section. This list is not exhaustive, and the order of items does not reflect priority or the sequence in which to acquire certain skills and knowledge. An understanding of American Indian and Alaska Native history should support all the competencies discussed below. Although these competencies focus primarily on mental health, the majority of these factors also are important to effective substance abuse treatment and interventions with American Indian and Alaska Native clients.

#### Training competencies

The following list identifies specific training needs for providers working with American Indian and Alaska Native clients and communities. The training includes:

1. Specialized assessment and service delivery techniques that meet the cultural needs of American Indian and Alaska Native clients.
2. Recognition and integration of the unique features of traditional, transitional or acculturating, and multicultural and multiracial clients and families.
3. Appreciation of culturally based traditional healing systems and traditions of American Indian and Alaska Native communities served.
4. Techniques to engage and build alliances with communities, as well as culturally acceptable and therapeutic boundary-setting with American Indian and Alaska Native clients.
5. Interdisciplinary team interaction and functioning to promote effective care.
6. Use of clients' preferred language in the treatment process.
7. Treatment of American Indian and Alaska Native LGBTQ/Two-Spirit people, with attention to issues related to combined prejudice regarding mental illness, ethnicity, sexuality, and gender roles.
8. Documentation or communication of specialized assessment and service delivery methods such that staff who are not culturally competent will be able to benefit from it.

#### Knowledge competencies

Knowledge competencies should begin with self-awareness and self-knowledge about personal beliefs, values, norms, stereotypes, and biases and how these may influence personal and professional interactions, particularly with clients. The following list identifies the areas of knowledge necessary to be culturally responsive toward American Indian and Alaska Native clients, supervisors, and other staff members. Areas of culturally responsive knowledge include:

1. Differences in symptom expression, symptom language, and symptomatic patterns presented by American Indian and Alaska Native clients.
2. Differences in thresholds of individual and social distress in American Indian and Alaska Native clients and tolerance of symptoms exhibited by their natural support systems, including individuals, families, and individuals' or families' informal and formal social context.
3. Differences in the attribution of mental illness and issues around prejudice/shame specific to American Indian and Alaska Native cultures.
4. Differences in the acceptability and effectiveness of different treatment modalities in American Indian and Alaska Native populations.
5. Culture-bound syndromes associated with the American Indian and Alaska Native communities served by the program.
6. Use of formally trained interpreters by clinicians unable to communicate with clients using clients' preferred language.
7. Effects of class and ethnicity on behavior, attitudes, and values.
8. Help-seeking behaviors common among American Indians and Alaska Natives.
9. Self-treatment behaviors often found among American Indians and Alaska Natives, including substance misuse and self-medication.
10. Roles and manifestations of spirituality, tradition, and faith in American Indian and Alaska Native communities.
11. Roles of verbal and nonverbal language, speech patterns, and communication styles in American Indian and Alaska Native communities.
12. Effects of human service policies on American Indians and Alaska Natives and reduction of barriers through informed participation in systems change efforts.
13. Resources (e.g., agencies, individuals, informal helping networks, research) that can be used on behalf of American Indian and Alaska Native clients and communities.
14. Roles and types of power relationships within the community, agency, or institution and their impact on American Indians and Alaska Natives.
15. Recognition of the ways that mainstream professional values may conflict with or be responsive to the needs of American Indians and Alaska Natives.

#### Understanding competencies

The following list describes areas of understanding that are particularly salient when working with American Indian and Alaska Native clients and communities, such as understanding historical factors that affect health, the effects of historical traumas, and traditional medicine. These areas include:

1. Historical trauma that affects the mental health of Native Americans, such as racism, forced relocation, loss of sacred lands, and boarding school experiences.
2. Factors that define cultural differences among sovereign tribal nations and communities, including differences related to history, traditions, values, belief systems, acculturation and migration history, and language; this information is particularly important for providers who serve multiple tribes.
3. Particular psychosocial stressors and traumas relevant for American Indian and Alaska Native clients, including war, personal trauma, unique aspects of cultural survival and maintenance, and socioeconomic status.
4. Cultural variations across Indian Country.
5. Native clients in a family life cycle and intergenerational conceptual framework, in addition to individual identity development in relation to family and cultural developmental frameworks.
6. Differences in culturally acceptable behavior or psychopathological characteristics of American Indians and Alaska Natives.
7. Traditional healing practices and the role of belief systems (e.g., religion, spirituality) in the treatment of American Indians and Alaska Natives.
8. A community-based system of mental health services for American Indians and Alaska Natives, including appropriate, culturally relevant components and characteristics.
9. Public administrative issues in developing, implementing, and evaluating programs for American Indians and Alaska Natives.
10. Dynamics of language use and conceptual frameworks among monolingual and bilingual clients.
11. The effects of the acculturation process on American Indians and Alaska Natives.

#### Skill competencies

The following list provides an overview of culturally responsive clinical skills necessary for behavioral health service providers. These skills include the ability to:

1. Interview and assess minority clients and families based on psychological, social, biological, cultural, political, spiritual, environmental, and economic models.
2. Communicate and listen effectively across cultures.
3. Assess American Indian and Alaska Native clients with an understanding of cultural differences in psychopathology.
4. Formulate culturally responsive service plans (case management and treatment) that are appropriate for clients' and their families' concept of mental illness.
5. Create and implement multidisciplinary service plans (case management and treatment), including culture, family, and community.
6. Use culturally appropriate community resources (e.g., family, clans, societies, church, community members, other groups).
7. Provide psychotherapeutic and psychopharmacological interventions with an understanding of the cultural differences in treatment expectations and biological response to medications.
8. Recognize the limitations of standardized psychological tests and testing procedures when used with American Indian and Alaska Native clients.
9. Use a culturally sensitive approach to conducting research.
10. Provide education and advocacy interventions that promote clients' and families' voices and ownership in shaping the service delivery system.
11. When feasible, use the clients' language to elicit the range and nuances of emotions, feelings, dynamics, and so forth.
12. Know when and how to use interpreters and understand the limitations of using interpreters. Be aware of how interpreters (knowingly or unknowingly) may censor and modify information during the process of interpretation.
13. Learn the particulars of social conventions (from engaging protocols to termination rituals) within American Indian and Alaska Native cultures.
14. Be open to continually learning the cultures of American Indian and Alaska Native clients and families through varied and multiple techniques (e.g., conferences, visiting in community, reading books, hanging out, attending community forums). Cultural competence is a learning process, not a product.
15. Be aware of racial and ethnic differences and know when to respond to culturally based cues.
16. Assess the meaning of race and ethnicity for individual clients.
17. Differentiate symptoms of intrapsychic stress from stress arising from the social structure.
18. Work toward empowerment of clients and minority communities.
19. Use community resources on behalf of American Indian and Alaska Native clients and their communities.
20. Use agency resources on behalf of American Indian and Alaska Native clients and their communities.
21. Recognize and combat racism, racial stereotypes, and myths held by individuals and institutions.
22. Evaluate new techniques, exemplary practices, research, and knowledge for their validity and applicability in working with American Indians and Alaska Natives.

#### Attitudinal competencies

The following list identifies attitudes and values that providers need to cultivate to work effectively with American Indian and Alaska Native clients and communities. They include:

1. Personal qualities that reflect genuineness, accurate empathy, nonpossessive warmth, and a capacity to respond flexibly to a range of possible solutions.
2. Acceptance of ethnic differences between people and how these differences affect the treatment process.
3. Willingness to work with clients of various ethnic minority groups.
4. Respect for the immigrant, migration, colonization, and dissolution of culture experience.

### Before You Leave

As an administrator, your greatest challenges include funding and sustainability of your services, recruitment and retention of staff, implementing of workforce development activities, and employing strategies to support future leadership among American Indian and Alaska Native youth. Through collaboration with other organizations, making use of available resources, and involving community leadership, the route across rough waters will be safely navigated with others. The next chapter provides many hands-on resources that support the administrative issues, needs, and tasks outlined in this chapter.

“It must not be forgotten that our old ones aspired and dreamed, created and struggled, and cared for one another. This generation and future generations must remember that their greatest legacy is the teaching that everyone has healing gifts to build our common decency and wholeness.”

—Martin Waukazoo, Lakota

Source: Nebelkopf & Phillips, 2004, p. 5.