# Part 2 Implementation Guide for Behavioral Health Program Administrators Serving American Indians and Alaska Natives

For Behavioral Health Service Providers, Program Administrators, and Clinical Supervisors

Part 2 of this Treatment Improvement Protocol addresses how to improve treatment outcomes for American Indian and Alaska Native clients by increasing provider competencies; providing holistic, trauma-informed services; and adopting culturally responsive program policies and procedures.