# Part 1 Practical Guide to the Provision of Behavioral Health Services for American Indians and Alaska Natives

For Behavioral Health Service Providers

Part 1 of this Treatment Improvement Protocol addresses historical trauma among American Indians and Alaska Natives. It describes native perspectives on help-seeking behaviors. It also presents culturally adapted strategies for the prevention and treatment of addiction and mental illness.