# Part 1 Clinical Supervision and Professional Development of the Substance Abuse Counselor

## Overview of Part 1

### Chapter 1: Information You Need To Know

This chapter presents the basic information about clinical supervision in the substance abuse treatment field and is organized as follows:

• Introduction (pp. 3–4)
• Central Principles of Clinical Supervision (pp. 5–6)
• Guidelines for New Supervisors (pp. 6–8)
• Models of Clinical Supervision (pp. 8–9)
• Developmental Stages of Counselors (pp. 9–10)
• Developmental Stages of Supervisors (pp. 10–11)
• Cultural and Contextual Factors (pp. 11–13)
• Ethical and Legal Issues (pp. 13–17)
• Monitoring Performance (pp. 17–20)
• Methods of Observation (pp. 20–24)
• Practical Issues in Clinical Supervision (pp. 24–29)
• Methods and Techniques of Clinical Supervision (pp. 30–32)
• Administrative Supervision (pp. 33–34)
• Resources (p. 34)

### Chapter 2: Clinical Scenarios Showing How To Apply the Information

This chapter presents several realistic clinical supervision scenarios that could take place in a substance abuse treatment agency to demonstrate the material presented in chapter 1. Master Supervisor Notes are provided to explain the thinking behind these actions. How-to Notes instruct supervisors on using a specific technique. The scenarios should be useful to both counselors and supervisors.