# SAMHSA TIPs and Publications Based on TIPs

## What Is a TIP?

Treatment Improvement Protocols (TIPs) are the products of a systematic and innovative process that brings together clinicians, researchers, program managers, policymakers, and other Federal and non-Federal experts to reach consensus on state-of-the-art treatment practices. TIPs are developed under the Substance Abuse and Mental Health Services Administration's (SAMHSA's) KnowledgeApplication Program (KAP) to improve the treatment capabilities of the Nation's alcohol and drug abuse treatment service system.

## What Is a Quick Guide?

A Quick Guide clearly and concisely presents the primary information from a TIP in a pocket-sized booklet. Each Quick Guide is divided into sections to help readers quickly locate relevant material. Some contain glossaries of terms or lists of resources. Page numbers from the original TIP are referenced so providers can refer back to the source document for more information.

## What Are KAP Keys?

Also based on TIPs, KAP Keys are handy, durable tools. Keys may include assessment or screening in-struments, checklists, and summaries of treatment phases. Printed on coated paper, each KAP Keys set is fastened together with a key ring and can be kept within a treatment provider's reach and consulted fre-quently. The Keys allow you, the busy clinician or program administrator, to locate information easily and to use this information to enhance treatment services.

## Ordering Information

Publications may be ordered or downloaded for free at http://store.samhsa.gov. To order over the phone, please call 1-877-SAMHSA-7 (1-877-726-4727) (English and Español).

TIP 1 State Methadone Treatment Guidelines—Replaced by TIP 43
TIP 2 Pregnant, Substance-Using Women—Replaced by TIP 51
TIP 3 Screening and Assessment of Alcohol- and Other Drug-Abusing Adolescents—Replaced by TIP 31
TIP 4 Guidelines for the Treatment of Alcohol- and Other Drug-Abusing Adolescents—Replaced by TIP 32
TIP 5 Improving Treatment for Drug-Exposed Infants
TIP 6 Screening for Infectious Diseases Among Substance Abusers—Archived
TIP 7 Screening and Assessment for Alcohol and Other Drug Abuse Among Adults in the Criminal Justice System—Replaced by TIP 44
TIP 8 Intensive Outpatient Treatment for Alcohol and Other Drug Abuse—Replaced by TIPs 46 and 47
TIP 9 Assessment and Treatment of Patients With Coexisting Mental Illness and Alcohol and Other Drug Abuse—Replaced by TIP 42
TIP 10 Assessment and Treatment of Cocaine- Abusing Methadone-Maintained Patients—Replaced by TIP 43
TIP 11 Simple Screening Instruments for Outreach for Alcohol and Other Drug Abuse and Infectious Diseases—Replaced by TIP 53
TIP 12 Combining Substance Abuse Treatment With Intermediate Sanctions for Adults in the Criminal Justice System—Replaced by TIP 44
TIP 13 Role and Current Status of Patient Placement Criteria in the Treatment of Substance Use Disorders
  Quick Guide for Clinicians
  Quick Guide for Administrators
  KAP Keys for Clinicians
TIP 14 Developing State Outcomes Monitoring Systems for Alcohol and Other Drug Abuse Treatment
TIP 15 Treatment for HIV-Infected Alcohol and Other Drug Abusers—Replaced by TIP 37
TIP 16 Alcohol and Other Drug Screening of Hospitalized Trauma Patients
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 17 Planning for Alcohol and Other Drug Abuse Treatment for Adults in the Criminal Justice System—Replaced by TIP 44
TIP 18 The Tuberculosis Epidemic: Legal and Ethical Issues for Alcohol and Other Drug Abuse Treatment Providers—Archived
TIP 19 Detoxification From Alcohol and Other Drugs—Replaced by TIP 45
TIP 20 Matching Treatment to Patient Needs in Opioid Substitution Therapy—Replaced by TIP 43
TIP 21 Combining Alcohol and Other Drug Abuse Treatment With Diversion for Juveniles in the Justice System
  Quick Guide for Clinicians and Administrators
TIP 22 LAAM in the Treatment of Opiate Addiction—Replaced by TIP 43
TIP 23 Treatment Drug Courts: Integrating Substance Abuse Treatment With Legal Case Processing
  Quick Guide for Administrators
TIP 24 A Guide to Substance Abuse Services for Primary Care Clinicians
  Concise Desk Reference Guide
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 25 Substance Abuse Treatment and Domestic Violence
  Linking Substance Abuse Treatment and Domestic
  Violence Services: A Guide for Treatment Providers
  Linking Substance Abuse Treatment and Domestic
  Violence Services: A Guide for Administrators
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 26 Substance Abuse Among Older Adults
  Substance Abuse Among Older Adults: A Guide for Treatment Providers
  Substance Abuse Among Older Adults: A Guide for Social Service Providers
  Substance Abuse Among Older Adults: Physician's Guide
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 27 Comprehensive Case Management for Substance Abuse Treatment
  Case Management for Substance Abuse Treatment: A Guide for Treatment Providers
  Case Management for Substance Abuse Treatment: A Guide for Administrators
  Quick Guide for Clinicians
  Quick Guide for Administrators
TIP 28 Naltrexone and Alcoholism Treatment—Replaced by TIP 49
TIP 29 Substance Use Disorder Treatment for People With Physical and Cognitive Disabilities
  Quick Guide for Clinicians
  Quick Guide for Administrators
  KAP Keys for Clinicians
TIP 30 Continuity of Offender Treatment for Substance Use Disorders From Institution to Community
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 31 Screening and Assessing Adolescents for Substance Use Disorders
  See companion products for TIP 32.
TIP 32 Treatment of Adolescents With Substance Use Disorders
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 33 Treatment for Stimulant Use Disorders
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 34 Brief Interventions and Brief Therapies for Substance Abuse
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 35 Enhancing Motivation for Change in Substance Abuse Treatment
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 36 Substance Abuse Treatment for Persons With Child Abuse and Neglect Issues
  Quick Guide for Clinicians
  KAP Keys for Clinicians
  Helping Yourself Heal: A Recovering Woman's Guide to Coping With Childhood Abuse Issues
  Also available in Spanish
  Helping Yourself Heal: A Recovering Man's Guide to Coping With the Effects of Childhood Abuse
  Also available in Spanish
TIP 37 Substance Abuse Treatment for Persons With HIV/AIDS
  Quick Guide for Clinicians
  KAP Keys for Clinicians
  Drugs, Alcohol, and HIV/AIDS: A Consumer Guide Also available in Spanish
  Drugs, Alcohol, and HIV/AIDS: A Consumer Guide for African Americans
TIP 38 Integrating Substance Abuse Treatment and Vocational Services
  Quick Guide for Clinicians
  Quick Guide for Administrators
  KAP Keys for Clinicians
TIP 39 Substance Abuse Treatment and Family Therapy
  Quick Guide for Clinicians
  Quick Guide for Administrators
  Family Therapy Can Help: For People in Recovery
  From Mental Illness or Addiction
TIP 40 Clinical Guidelines for the Use of Buprenorphine in the Treatment of Opioid Addiction
  Quick Guide for Physicians
  KAP Keys for Physicians
TIP 41 Substance Abuse Treatment: Group Therapy
  Quick Guide for Clinicians
TIP 42 Substance Abuse Treatment for Persons With Co-Occurring Disorders
  Quick Guide for Clinicians
  Quick Guide for Administrators
  KAP Keys for Clinicians
TIP 43 Medication-Assisted Treatment for Opioid Addiction in Opioid Treatment Programs
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 44 Substance Abuse Treatment for Adults in the Criminal Justice System
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 45 Detoxification and Substance Abuse Treatment
  Quick Guide for Clinicians
  Quick Guide for Administrators
  KAP Keys for Clinicians
TIP 46 Substance Abuse: Administrative Issues in Outpatient Treatment
  Quick Guide for Administrators
TIP 47 Substance Abuse: Clinical Issues in Outpatient Treatment
  Quick Guide for Clinicians
  KAP Keys for Clinicians
TIP 48 Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery
TIP 49 Incorporating Alcohol Pharmacotherapies Into Medical Practice
  Quick Guide for Counselors
  Quick Guide for Physicians
  KAP Keys for Clinicians
TIP 50 Addressing Suicidal Thoughts and Behaviors in Substance Abuse Treatment
  Quick Guide for Clinicians
  Quick Guide for Administrators
TIP 51 Substance Abuse Treatment: Addressing the Specific Needs of Women
  Quick Guide for Clinicians
  Quick Guide for Administrators
TIP 52 Clinical Supervision and Professional Development of the Substance Abuse Counselor
  Quick Guide for Clinical Supervisors
  Quick Guide for Administrators
TIP 53 Addressing Viral Hepatitis in People With Substance Use Disorders
  Quick Guide for Clinicians and Administrators
  KAP Keys for Clinicians
TIP 54 Managing Chronic Pain in Adults With or in Recovery From Substance Use Disorders
  Quick Guide for Clinicians
  KAP Keys for Clinicians
  You Can Manage Your Chronic Pain To Live a Good Life: A Guide for People in Recovery From Mental Illness or Addiction
TIP 55 Behavioral Health Services for People Who Are Homeless
TIP 56 Addressing the Specific Behavioral Health Needs of Men
TIP 57 Trauma-Informed Care in Behavioral Health Services TIP 58 Addressing Fetal Alcohol Spectrum Disorders (FASD)
TIP 59 Improving Cultural Competence