# How This TIP Is Organized

This TIP is divided into three parts:

• Clinical Supervision and Professional Development of the Substance Abuse Counselor, Part 1.
• Clinical Supervision and Professional Development of the Substance Abuse Counselor: An Implementation Guide for Administrators, Part 2.
• Clinical Supervision and Professional Development of the Substance Abuse Counselor: A Review of the Literature, Part 3.

Parts 1 and Part 2 are presented in this publication; Part 3 is available only online at http://store.samhsa.gov.

Part 1 of the TIP is for clinical supervisors and consists of two chapters. Chapter 1 presents basic information about clinical supervision in the substance abuse treatment field. It covers:

• Central principles of clinical supervision and guidelines for new supervisors, including the functions of a clinical supervisor.
• The developmental levels of counselors and clinical supervisors.
• Information on cultural competence, ethical and legal issues such as direct and vicarious liability, dual relationships and boundary issues, informed consent, confidentiality, and supervisor ethics.
• Information about monitoring clinical performance of counselors, the various methods commonly used for observing counselors, the methods and techniques of supervision and administrative supervision, and practical issues such as balancing one's clinical and administrative duties, finding the time to do clinical supervision, documentation, and structuring clinical supervision sessions.

Chapter 2 presents the “how to” of clinical supervision. Chapter 2 contains:

• Representative vignettes of clinical supervision scenarios.
• Master supervisor notes and comments that help you understand the thinking behind the supervisor's approach in each vignette.
• “How-to” descriptions of specific techniques.

It is strongly recommended that you read Chapter 1 before reading Chapter 2.

Part 2 is an implementation guide for program administrators and consists of two chapters. Chapter 1 lays out the rationale for the approach taken in chapter 2 and will help administrators understand the benefits and rationale behind providing clinical supervision for their program's substance abuse counselors. Chapter 2 provides tools for making the tasks associated with implementing a clinical supervision system easier.

The following topics are addressed in Part 2:

• How to develop a model for clinical supervision and implement a clinical supervision program.
• Key issues for administrators to consider, including assessing organizational structure and readiness.
• Legal and ethical issues to consider.
• Cultural competence issues.
• Providing professional development for clinical supervisors.

Part 3 of this TIP is a literature review on the topic of clinical supervision and is available for use by clinical supervisors, interested counselors, and administrators. Part 3 consists of three sections: an analysis of the available literature, an annotated bibliography of the literature most central to the topic, and a bibliography of other available literature. It includes literature that addresses both clinical and administrative concerns. To facilitate ongoing updates (which will be performed every 6 months for up to 5 years from first publication), the literature review will be available only online at http://store.samhsa.gov.