# Consensus Panel

Note: The information given indicates each participant's affiliation as of 2007, when the panel was convened, and may no longer reflect the individual's current affiliation.

## Chair, Part 1 and Part 2 Consensus Panels

David J. Powell, Ph.D. (Chair)
President
International Center for Health Concerns, Inc.
East Granby, Connecticut

## Part 1 Consensus Panel Members

Bruce Carruth, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Bettye Harrison
Opioid Treatment Program Accreditation Director
CARF International
Tucson, Arizona

Sharon Hartman, M.B.A., LSW
Director of Professional Training and Education
Caron Treatment Centers
Wernersville, Pennsylvania

Pamela Mattel, M.S.W., LCSW-R, ACSW, CASAC
Executive Deputy Director
BASICS, Inc.
New York, New York

John Porter, M.S.
Northwest Frontier Addiction Technology Transfer Center
Wilsonville, Oregon

## Part 2 Consensus Panel Members

Bruce Carruth, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Charles F. Gressard, Ph.D., LPC, NCC
Associate Professor, School of Education
College of William & Mary
Williamsburg, Virginia

Pamela Mattel, M.S.W., LCSW-R, ACSW, CASAC
Executive Deputy Director
BASICS, Inc.
New York, New York