# Section 3: Bibliography of Available Literature

Alderfer, C. J. (1991). “The Effects of Gender on the Supervisory Process.” Amherst, MA: University of Massachusetts. Video Recording.
American Counseling Association (2005). ACA Code of Ethics. Alexandria, VA: American Counseling Association. Retrieved August 14, 2007, from http://www.cacd.org/ACA_2005_Ethical_Code10405.pdf
American Psychological Association (2007). Record keeping guidelines. American Psychologist, 62, 993–1004.
Ancis, J. R., & Ladany, N. (2001). A multicultural framework for counselor supervision. In L. J. Bradley & N. Ladany (Eds.), Counselor supervision: Principles, process, and practice (3rd ed.) (pp. 63–90). New York: Brunner-Routledge.
Anderson, C. E. (2000). Supervision of substance abuse counselors using the integrated developmental model. Clinical Supervisor, 19, 185–195.
Arkin, N. (1999). Culturally sensitive student supervision: Difficulties and challenges. Clinical Supervisor, 18, 1–16.
Arthur, N., & Achenbach, K. (2002). Developing multicultural counseling competencies through experiential learning. Counselor Education and Supervision, 42, 2–14.
Baker, S. B., Exum, H. A., & Tyler, R. E. (2002). The developmental process of clinical supervisors in training: An investigation of the supervisor complexity model. Counselor Education and Supervision, 42, 15–30.
Bascue, L. O., & Yalof, J. A. (1991). Descriptive dimensions of psychotherapy supervision. Clinical Supervisor, 9, 19–30.
Beauchamp, T. L., & Childress, J. F. (2001). Principles of Biomedical Ethics (5th ed.). New York: Oxford University Press.
Berkel, L. A., Constantine, M. G., & Olson, E. A. (2007). Supervisor multicultural competence: Addressing religious and spiritual issues with counseling students in supervision. Clinical Supervisor, 26, 3–15.
Bernard, J. M., & Goodyear, R. K. (1998). Fundamentals of Clinical Supervision (2nd ed.). Needham Heights MA: Allyn & Bacon.
Bernard, J. M., & Goodyear, R. K. (2004). Fundamentals of Clinical Supervision (3rd ed.). Boston: Pearson Education.
Bernard, J. M. (1979). Supervisor training: A discrimination model. Counselor Education and Supervision, 19, 60–69.
Bernard, J. M. (1994). Multicultural supervision: A reaction to Leong and Wagner, Cook, Priest, and Fukuyama. Counselor Education and Supervision, 34, 159–171.
Bishop, D. R., Vila-Juarbe, E., & Thumme, B. (2003). Recognizing spirituality as an important factor in counselor supervision. Counseling and Values, 48, 34–46.
Boethius, S. B., & Ogren, M. L. (2000). Role patterns in group supervision. Clinical Supervisor, 19, 45–69.
Borders, L. D., & Brown, L. L. (2005). The New Handbook of Counseling Supervision. Mahwah, NJ: Lawrence Erlbaum Associates.
Bradley, L. J., & Gould, L. J. (2001). Psychotherapy-based models of counselor supervision. In L. J. Bradley & N. Ladany (Eds.), Counselor Supervision: Principles, Process, and Practice (3rd ed.) (pp. 147–180). New York: Brunner-Routledge.
Bradley, L. J., & Whiting, P. P. (2001). Supervision training: A model. In L. J. Bradley & N. Ladany (Eds.), Counselor Supervision: Principles, process, and Practice (3rd ed.) (pp. 361–387). New York: Brunner-Routledge.
Bradley, L. J., Gould, L. J., & Parr, G. D. (2001). Supervision-based integrative models of counselor supervision. In L. J. Bradley & N. Ladany (Eds.), Counselor supervision: Principles, Process, and Practice (3rd ed.) (pp. 93–124). New York: Brunner-Routledge.
Bradley, L. J., & Ladany, N. (Eds.). Counselor Supervision: Principles, Process, and Practice (3rd ed.) (2001). New York: Brunner-Routledge.
Bradshaw, W. H., Jr. (1982). Supervision in black and white: Race as a factor in supervision. In M. Blumenfield (Ed.), Applied Supervision in Psychotherapy (pp. 199–220). New York: Grune & Stratton.
Briggs, J. R., & Miller, G. (2005). Success enhancing supervision. Journal of Family Psychotherapy, 16, 199–222.
Burkard, A. W., Johnson, A. J., Madson, M. B., Pruitt, N. T., Contreras-Tadych, D. A., Kozlowski, J. M., et al. (2006). Supervisor cultural responsiveness and unresponsiveness in cross-cultural supervision. Journal of Counseling Psychology, 53, 288–301.
Burke, P. A., Carruth, B., & Prichard, D. (2006). Counselor self-care in work with traumatized addicted people. In B. Carruth (Ed.), Psychological Trauma and Addiction Treatment (pp. 283–302). New York: Haworth Press.
Caligor, L., Bromberg, P. M., & Meltzer, J. D. (1984). Clinical Perspectives on the Supervision of Psychoanalysis and Psychotherapy. New York: Plenum Press.
Campbell, J. M. (2000). Becoming an Effective Supervisor: A Workbook for Counselors and Psychotherapists, Philadelphia: Accelerated Development.
Campbell, J. M. (2006). Essentials of Clinical Supervision. Hoboken, NJ: John Wiley & Sons.
Carlson, M. H., Brack, C. J., Laygo, R., Cohen, R., & Kirkscey, M. (1998). An exploratory study of multicultural competence of counselors in training: Support for experiential skills building. Clinical Supervisor, 17, 75–87.
Carroll, M., & Holloway, E. (1999). Counseling Supervision in Context. Thousand Oaks, CA: Sage Publications.
Carroll, M. (1997). Clinical supervision: Luxury or necessity? In I. Horton & V. Varma (Eds.), The Needs of Counselors and Psychotherapists (pp. 135–151). Thousand Oaks, CA: Sage Publications.
Cary, D., & Marques, P. (2007). From expert to collaborator: Developing cultural competency in clinical supervision. Clinical Supervisor, 26, 141–157.
Center for Substance Abuse Treatment (1999). Enhancing Motivation for Change in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 35 (HHS Publication No. (SMA) 99-3354). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment (2003). Manpower Development Study. Rockville, MD: Substance Abuse and Mental Health Services Administration, U. S. Department of Health and Human Services.
Center for Substance Abuse Treatment (2006). Addiction Counseling Competencies: The Knowledge, Skills, and Attitudes of Professional Practice. Technical Assistance Publication (TAP) Series 21 (HHS Publication No. (SMA) 07-4243). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2006). Enhancing Motivation for Change Inservice Training. (HHS Publication No. (SMA) 06-4190). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2007). Competencies for Substance Abuse Treatment Clinical Supervisors. Technical Assistance Publication (TAP) Series 21-A (HHS Publication No. (SMA) 07-4243). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Chang, C. Y., Hays, D. G., & Shoffner, M. F. (2003). Cross-racial supervision: A developmental approach for white supervisors working with supervisees of color. Clinical Supervisor, 22, 121–138.
Christensen, T. M., & Kline, W. B. (2000). A qualitative investigation of the process of group supervision with group counselors. Journal for Specialists in Group Work, 25, 376–393.
Collins, J. C., & Porras, J. I. (1994). Built to Last: Successful Habits of Visionary Companies (1st ed.). New York: HarperBusiness.
Constantine, M. G., & Sue, D. W. (2007). Perceptions of racial micoraggressions among black supervisees in cross-racial dyads. Journal of Counseling, 54, 142–153.
Constantine, M. G. (1997). Facilitating multicultural competency in counseling supervision: Operationalizing a practical framework. In Pope-Davis, D. B. & Coleman, H. L. K. (Eds.), Multicultural Counseling Competencies: Assessment, Education and Training, and Supervision (pp. 310–324). Thousand Oaks, CA: Sage Publications.
Constantine, M. G. (2001). The relationship between general counseling self-efficacy and self-perceived multicultural counseling competence in supervisees. Clinical Supervisor, 20, 81–90.
Constantine, M. G. (2003). Multicultural competence in supervision: Issues, processes, and outcomes. In PopeDavis, D. B., Coleman, H. L. K., Liu, W. M. & Toporek, R. L. (Eds.), Handbook of Multicultural Competencies: In Counseling & Psychology (pp. 383–391). Thousand Oaks, CA: Sage Publications.
Cook, D. A. (1994). Racial identity in supervision. Counselor Education and Supervision, 34, 132–141.
Covey, S. R. (2004). The 7 Habits of Highly Effective People: Powerful Lessons in Personal Change (Rev. ed.). New York: Free Press.
Culbreth, J. R., & Borders, L. D. (1999). Perceptions of the supervisory relationship: Recovering and nonrecovering substance abuse counselors. Journal of Counseling & Development, 77, 330–338.
Culbreth, J. R. (1999). Clinical supervision of substance abuse counselors: Current and preferred practices. Journal of Addictions & Offender Counseling, 20, 15–25.
Culbreth, J. R. (2003). Chemical dependency counselor supervisors’ perceptions of supervisee anxiety and resistance in clinical supervision. Journal of Teaching in the Addictions, 2, 39–49.
Cutcliffe, J. R., Butterworth, T., and Proctor, B. (Eds.) (2001). Fundamental Themes In Clinical Supervision. London; New York: Routledge.
Daniels, J., D'Andrea, M., & Kim, B. S. K. (1999). Assessing the barriers and changes of cross-cultural supervision: A case study. Counselor Education and Supervision, 38, 191–204.
Delaney, D. J. (1972). A behavioral model for the supervision of counselor candidates. Counselor Education and Supervision, 12, 46–50.
Derrig-Palumbo, K., & Zeine, F. (2005). Online Therapy: A Therapist's Guide to Expanding Your Practice (1st ed.). New York: W.W. Norton & Company.
Dixon, G. D. (2004). Clinical supervision: A key to treatment success. Southern Coast Beacon, Tallahassee, FL: Southern Coast ATTC. Retrieved August 14, 2007, from http://www.scattc.org/pdf_upload/Beacon004.pdf
Durham, T. G. (2001). Counselors: An Independent Study Course. East Hartford, CT: ETP Inc.
Durham, T. G. (2003). The Relationship Between Live Supervision, Counselor Development and Self-Efficacy for Substance Abuse Counselors in the U.S. Navy. Prescott Valley, AZ: Northcentral University.
Eby, L. T., McCleese, C. S., Baranik, L., & Owen, C. (2007). Project MERITS: Year 1 Summary Report. Athens, GA: University of Georgia. Retrieved April 29, 2008, from http://projectmerits.files.wordpress.com/2007/12/yr01-small-summary-reportifinal.pdf
Eby, L. T., McCleese, C. S., Baranik, L., & Owen, C. (2007). Project MERITS: Managing Effective Relationships in Treatment Services: Year 01 Summary Report. Athens, GA: University of Georgia.
Edmundson, E., & McCarty, D. (Eds.). Implementing Evidence-Based Practices for Treatment of Alcohol and Drug Disorders (2005). Binghamton, NY: Haworth Medical Press.
Ekstein, R., & Wallerstein, R. (1972). The Teaching and Learning of Psychotherapy (2nd ed.). New York: International Universities Press.
Ellis, M. V., & Ladany, N. (1997). Inferences concerning supervisees and clients in clinical supervision: An integrative review. In Watkins, J. (Ed.), Handbook of Psychotherapy Supervision (pp. 447–507). Hoboken, NJ: John Wiley & Sons, Inc.
Evans, W. N., & Hohenshil, T. H. (1997). Job satisfaction of substance abuse counselors. Alcoholism Treatment Quarterly, 15, 1–13.
Falender, C. A., & Shafranske, E. P. (2004). Clinical Supervision: A Competency-Based Approach. Washington, DC: American Psychological Association.
Falender, C. A., & Shafranske, E. P. (2004). Contemporary clinical practice of supervision. In Clinical Supervision: A Competency-Based Approach (pp. 1–37). Washington, DC: American Psychological Association.
Falender, C. A., & Shafranske, E. P. (2004). Ethical and legal perspectives and risk management. In Clinical Supervision: A Competency-Based Approach (pp. 151–194). Washington, DC: American Psychological Association.
Falender, C. A., & Shafranske, E. P. (2004). The practice of clinical supervision. In Clinical Supervision: A Competency-Based Approach (pp. 3–35). Washington, DC: American Psychological Association.
Falicov, C. J. (1988). Learning to think culturally. In Liddle, H. A., Breunlin, D. C. & Schwartz, R. C. (Eds.), Handbook of Family Therapy Training and Supervision (pp. 335–357). New York: Guilford Press.
Fall, M., & Sutton, J. M. J. (2004). Clinical Supervision: A Handbook for Practitioners. Boston: Pearson.
Falvey, J. E. (2002). Managing Clinical Supervision: Ethical Practice and Legal Risk Management. Pacific Grove, CA: Brooks/Cole-Thomson Learning.
Falvey, J. E., Caldwell, C. F., & Cohen, C. R. (2002). Documentation in Supervision: The Focused Risk Management Supervision System (FoRMSS). Pacific Grove, CA: Brooks/Cole.
“Feminist Models in Supervising Women,” for Institute on Supervisee-Focused Supervision at American Association for Marriage and Family Therapy (annual conference). Dallas, TX: October 29-November 2, 1991.
Fernando, D. M., & Hulse-Killacky, D. (2005). The relationship of supervisory styles to satisfaction with supervision and the perceived self-efficacy of master's-level counseling students. Counselor Education and Supervision, 44, 293–304.
Fitch, T., Gillam, L., & Baltimore, M. (2004). Consistency of clinical skills assessment among supervisors. Clinical Supervisor, 23, 71–81.
Fleming, I., & Steen, L. (Eds.) (2004). Supervision and Clinical Psychology: Theory, Practice and Perspectives. New York: Brunner-Routledge.
Fong, M. L., & Lease, S. H. (1997). Cross-cultural supervision: Issues for the white supervisor. In Pope-Davis, D. B. & Coleman, H. L. K. (Eds.), Multicultural Counseling Competencies: Assessment, Education and Training and Supervision (pp. 387–405). Thousand Oaks, CA: Sage Publications.
Fortune, L., & Watts, M. (2000). Examining supervision: Comparing the beliefs of those who deliver and those who receive. Counseling Psychology Review, 15, 5–15.
Freitas, G. J. (2002). The impact of psychotherapy supervision on client outcome: A critical examination of 2 decades of research. Psychotherapy: Theory, Research, Practice, Training, 39, 354–367.
Friedlander, M. L., & Ward, L. G. (1984). Development and validation of the Supervisory Styles Inventory. Journal of Counseling Psychology, 31, 541–557.
Fuertes, J. N. (2004). Supervision in bilingual counseling: Service delivery, training, and research considerations. Journal of Multicultural Counseling and Development, 32, 84–94.
Gallon, S. L., Gabriel, R. M., & Knudsen, J. R. (2003). The toughest job you'll ever love: A Pacific Northwest Treatment Workforce Survey. Journal of Substance Abuse Treatment, 24, 183–196.12810139
Garcia, B. (1998). Professional development of AODA practice with Latinos: The utility of supervision, in-service training and consultation. Alcoholism Treatment Quarterly, 16, 85–108.
Gardner, R. M. D. (2002). Cross cultural perspectives in supervision. Western Journal of Black Studies, 26, 98–106.
Gatmon, D., Jackson, D., Koshkarian, L., Martos-Perry, N., Molina, A., Patel, N., et al. (2001). Exploring ethnic, gender, and sexual orientation variables in supervision: Do they really matter? Journal of Multicultural Counseling and Development, 29, 102–113.
Gillig, P. M., & Barr, A. (1999). A model for multidisciplinary peer review and supervision of behavioral health clinicians. Community Mental Health Journal, 35, 361–365.10452702
Glenn, E., & Serovich, J. M. (1994). Documentation of family therapy supervision: A rationale and method. American Journal of Family Therapy, 22, 345–355.
Goodyear, R. K., Bunch, K., & Claiborn, C. D. (2006). Current supervision scholarship in psychology: A five year review. In Shulman, L. & Safyer, A. (Eds.), Supervision in Counseling: Interdisciplinary Issues and Research (pp. 135–146). New York: Haworth Press.
Granello, D. H. (2003). Influence strategies in the supervisory dyad: An investigation into the effects of gender and age. Counselor Education and Supervision, 42, 189–202.
Grant, P. (1999). Supervision and racial issues. In M. Carroll & E. Holloway (Eds.), Counseling Supervision in Context (pp. 7–22). Thousand Oaks, CA: Sage Publications.
Greben, S. E., & Ruskin, R. (1994). Clinical Perspectives on Psychotherapy Supervision (1st ed.). Washington, DC: American Psychiatric Press.
Green, S., Shilts, L., & Bacigalupe, G. (2001). When approved is not enough: Development of a supervision consultation model. Journal of Marital & Family Therapy, 27, 515–525.11594019
Guanipa, C. (2002). A preliminary instrument to evaluate multicultural issues in marriage and family therapy supervision. Clinical Supervisor, 21, 59–75.
Guest, C. L., & Dooley, K. (1999). Supervisor malpractice: Liability to the supervisee in clinical supervision. Counselor Education and Supervision, 38, 269–279.
Gutheil, T. G., & Brodsky, A. (2008). Preventing Boundary Violations in Clinical Practice. New York: Guilford Press.
Hall, M. N., Amodeo, M., Shaffer, H. J., & Vander, B. J. (2000). Social workers employed in substance abuse treatment agencies: A training needs assessment. Social Work, 45, 141–155.10710987
Hawkins, P., & Shohet, R. (2000). Supervision in the Helping Professions: An Individual, Group and Organizational Approach. Philadelphia: Open University.
Health Insurance Portability and Accountability Act of 1996 (1996). Public Law 104–191 104th Congress. Retrieved July 23, 2008, from http://www.cms.hhs.gov/HIPAAGenInfo/Downloads/HIPAALaw.pdf
Hendrickson, E. L. (2006). Clinical supervision of treatment services for co-occurring disorders. In Designing, Implementing, and Managing Treatment Services for Individuals With Co-Occurring Mental Health and Substance Use Disorders: Blueprints For Action (pp. 121–146). New York: Haworth Press.
Hendrickson, E. L. (2006). Designing, Implementing, and Managing Treatment Services for Individuals With Co-Occurring Mental Health and Substance Use Disorders: Blueprints for Action. New York: Haworth Press.
Hendrickson, S. M., Veach, P. M., & LeRoy, B. S. (2002). A qualitative investigation of student and supervisor perceptions of live supervision in genetic counseling. Journal of Genetic Counseling, 11, 25–49.26141560
Herbert, J. T. (2004). Analysis of clinical supervision practices as documented in rehabilitation counseling syllabi and fieldwork manuals. Rehabilitation Education, 18, 13–33.
Herman, K. C. (1993). Reassessing predictors of therapist competence. Journal of Counseling & Development, 72, 29–32.
Hess, A. K. (1986). Growth in supervision: Stages of supervisee and supervisor development. In Kaslow, F. W. (Ed.), Supervision and Training: Models, Dilemas, and Challenges (pp. 51–67). New York: Haworth Press.
Hill, N. R. (2003). Promoting and celebrating multicultural competence in counselor trainees. Counselor Education and Supervision, 43, 39–51.
Hird, J. S., Tao, K. W., & Gloria, A. M. (2004). Examining supervisors’ multicultural competence in racially similar and different supervision dyads. Clinical Supervisor, 23, 107–122.
Hitchings, P. (1999). Supervision and sexual orientation. In Carroll, M. & Holloway, E. (Eds.) Counseling Supervision in Context (pp. 54–82). Thousand Oaks, CA: Sage Publications.
Hogan, R. A. (1964). Issues and approaches in supervision. Psychotherapy: Theory, Research, Practice, Training, 1, 139–141.
Hoge, M. A., Morris, J. A., Daniels, A. S., Stuart, G. W., Huey, L. Y., & Adams, N. (2007). An Action Plan on Behavioral Health Workforce Development. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved March 30, 2007, from http://www.samhsa.gov/Workforce/Annapolis/WorkforceActionPlan.pdf
Holloway, E., & Carroll, M. (1999). Training Counseling Supervisors: Strategies, Methods, and Techniques. Thousand Oaks, CA: Sage Publications.
Holloway, E. (1995). Clinical Supervision: A Systems Approach. Thousand Oaks, CA: Sage Publications.
Hubble, M. A., Duncan, B. L., and Miller, S. D. (Eds). The Heart and Soul of Change: What Works in Therapy. (1999). Washington, DC: American Psychological Association.
Inman, A. G. (2006). Supervisor multicultural competence and its relation to supervisory process and outcome. Journal of Marital & Family Therapy, 32, 73–85.16468682
International Certification & Reciprocity Consortium & Alcohol and Other Drug Abuse, I. (2000). Clinical Supervisor of Alcohol and Other Drug Abuse Counselors Role Delineation Study. Research Triangle Park, NC: CASTLE Worldwide, Inc.
Juhnke, G. A., & Culbreth, J. R. (1994). Clinical supervision in addictions counseling: Special challenges and solutions. ERIC Digest, Greensboro, NC: ERIC Clearinghouse on Counseling and Student Services. Retrieved July 17, 2007, from http://www.ericdigests.org/1995-1/clinical.htm
Kadushin, A. (1974). Supervisor-supervisee: A survey. Social Work, 19, 288–297.
Kadushin, A. (2002). Supervision in Social Work (4th ed.). New York: Columbia University Press.
Kaplan, L. (2003). Substance Abuse Treatment Workforce Environmental Scan. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Kavanagh, D. J., Spence, S. H., Strong, J., Wilson, J., Sturk, H., & Crow, N. (2003). Supervision practices in allied mental health: Relationships of supervision characteristics to perceived impact and job satisfaction. Mental Health Services Research, 5, 187–195.14672498
Kavanagh, D. J., Spence, S. H., Wilson, J., & Crow, N. (2002). Achieving effective supervision. Drug and Alcohol Review, 21, 247–252.12270075
Keller, D. S., & Galanter, M. (1999). Technology transfer of network therapy to community-based addictions counselors. Journal of Substance Abuse Treatment, 16, 183–189.10023618
Kenna, G. A., & Lewis, D. C. (2008). Risk factors for alcohol and other drug use by healthcare professionals. Substance Abuse Treatment, Prevention and Policy, 3, 3.
Kerwin, M. E., Walker-Smith, K., & Kirby, K. C. (2006). Comparative analysis of state requirements for the training of substance abuse and mental health counselors. Journal of Substance Abuse Treatment, 30, 173–181.16616160
King, D., & Wheeler, S. (1999). The responsibilities of counsellor supervisors: A qualitative study. British Journal of Guidance & Counselling, 27, 215–229.
Knudsen, H. K., Ducharme, L. J., & Roman, P. M. (2006). Counselor emotional exhaustion and turnover intention in therapeutic communities. Journal of Substance Abuse Treatment, 31, 173–180.16919745
Knudsen, H. K., Johnson, J. A., & Roman, P. M. (2003). Retaining counseling staff at substance abuse treatment centers: Effects of management practices. Journal of Substance Abuse Treatment, 24, 129–135.12745030
Korinek, A. W., & Kimball, T. G. (2003). Managing and resolving conflict in the supervisory system. Contemporary Family Therapy: An International Journal, 25, 295–310.
Kraus, R., Zack, J. S., & Stricker, G. (Eds.) (2004). Online Counseling: A Handbook for Mental Health Professionals. Elsevier Science: New York.
Kugler, P. (Eds.) Jungian Perspectives on Clinical Supervision. (1995). Zurich, Switzerland: Daimon.
Ladany, N., & Lehrman-Waterman, D. E. (1999). The content and frequency of supervisor self-disclosures and their relationship to supervisor style and the supervisory working alliance. Counselor Education and Supervision, 38, 143–160.
Ladany, N., Friedlander, M. L., & Nelson, M. L. (2005). Addressing problematic emotions, attitudes, and behaviors: Counseling in versus counseling out. In Critical Events in Psychotherapy Supervision: An Interpersonal Approach (pp. 183–210). Washington, DC: American Psychological Association.
Ladany, N., Lehrman-Waterman, D., Molinaro, M., & Wolgast, B. (1999). Psychotherapy supervisor ethical practices: Adherence to guidelines, the supervisory working alliance, and supervisee satisfaction. Counseling Psychologist, 27, 443–475.
Ladany, N., Walker, J. A., & Melincoff, D. S. (2001). Supervisory style: Its relation to the supervisory working alliance and supervisor self-disclosure. Counselor Education and Supervision, 40, 263–275.
Lambert, M. J., & Hawkins, E. J. (2001). Using information about patient progress in supervision: Are outcomes enhanced? Australian Psychologist, 36, 131–138.
Lambie, G. W. (2006). Burnout prevention: A humanistic perspective and structured group supervision activity. Journal of Humanistic Counseling, Education & Development, 45, 32–44.
Lane, R. C. (1990). Psychoanalytic Approaches to Supervision. New York: Brunner/Mazel.
Lassiter, P. S., Napolitano, L., Culbreth, J. R., & Kok-Mun, N. (2008). Developing multicultural competence using the structured peer group supervision model. Counselor Education & Supervision, 47, 164–178.
Lewis, J. A., Cheek, J. R., & Hendricks, C. B. (2001). Advocacy in supervision. In Bradley, L. J. & Ladany, N. (Eds.), Counselor Supervision: Principles, Process, and Practice (3rd ed.) (pp. 330–341). New York: Brunner-Routledge.
Liddle, H. A., Breunlin, D. C., and Schwartz, R. C. (Eds.). Handbook of Family Therapy Training and Supervision (1988). New York: Guilford Press.
Lindbloom, G., Eyck, T. G. T., & Gallon, S. L. (2005). Clinical Supervision I: Building Chemical Dependency Counselor Skills: Instructor Guide. Salem, OR: Northwest Frontier Addiction Technology Transfer Center. Retrieved August 14, 2007, from http://www.mattc.org/_media/publications/pdf/Clinical_InstructorGuide1-05_3rd_ed.pdf
Lindbloom, G., Eyck, T. G. T., & Gallon, S. L. (2005). Clinical Supervision I: Building Chemical Dependency Counselor Skills: Participant Manual. Salem, OR: Northwest Frontier Addiction Technology Transfer Center. Retrieved October 3, 2006, from http://www.mattc.org/_media/publications/pdf/Clinical_ParticipantManual1-05_3rd_ed2.pdf
Loganbill, C., Hardy, E., & Delworth, U. (1982). Supervision: A conceptual model. Counseling Psychologist, 10, 3–42.
Magnuson, S., Norem, K., Jones, N. K., McCrary, J. C., & Gentry, J. (2000). The triad model as a cross-cultural training intervention for supervisors. Clinical Supervisor, 19, 197–210.
Magnuson, S., Wilcoxon, S. A., & Norem, K. (2000). A profile of lousy supervision: Experienced counselors’ perspectives. Counselor Education and Supervision, 39, 189–202.
Magnuson, S., Wilcoxon, S. A., & Norem, K. (2000). Exemplary supervision practices: Retrospective observations of experienced counselors. TCA Journal, 28, 93–101.
Mattel, P. (2007). Designing and Implementing Clinical Supervision. Unpublished Work.
McCleese, C. S., Baranik, L., & Wowen, C. (2007). Project MERITS. Athens, GA: University of Georgia. Retrieved February 14, 2008, from http://projectmerits.wordpress.com/
McGuigan, W. M., Katzev, A. R., & Pratt, C. C. (2003). Multi-level determinants of retention in a home-visiting child abuse prevention program. Child Abuse & Neglect, 27, 363–380.12686322
McMahon, M. (2003). Supervision and career counsellors: A little-explored practice with an uncertain future. British Journal of Guidance & Counselling, 31, 177–187.
McNamara, J., & Gillies, R. M. (2003). Support requirements and effects of supervision on telephone counsellors. Australian Journal of Guidance & Counselling, 13, 192–204.
McRoy, R. G., Freeman, E. M., Logan, S. L., & Blackmon, B. (1986). Cross cultural field supervision: Implications for social work education. Journal of Social Work Education, 22, 50–56.
Mead, D. E. (1990). Effective Supervision: A Task-Oriented Model for the Mental Health Professions. New York: Brunner/Mazel.
Messinger, L. (2007). Supervision of lesbian, gay, and bisexual social work students by heterosexual field instructors: A qualitative dyad analysis. Clinical Supervisor, 26, 195–222.
Milne, D. L., & James, I. A. (2002). The observed impact of training on competence in clinical supervision. British Journal of Clinical Psychology, 41, 55–72.
Minkoff, K. (2001). Program components of a comprehensive integrated care system for serious mentally ill patients with substance disorders. New Directions for Mental Health Services, 91, 17–30.
Minuchin, S., & Fishman, H. C. (1981). Family Therapy Techniques. Cambridge, MA: Harvard University Press.
Moyers, T. B., Martin, T., Manuel, J. K., & Miller, W. R. (2003). The Motivational Interviewing Treatment Integrity (MITI) Code: Version 2.0 (Draft). Albuquerque, NM: Center on Alcoholism, Substance Abuse and Addictions (CASAA), University of New Mexico. Retrieved August 5, 2008, from http://casaa.unm.edu/download/miti.pdf
Moyers, T. B., Martin, T., Manuel, J. K., Hendrickson, S. M., & Miller, W. R. (2005). Assessing competence in the use of motivational interviewing. Journal of Substance Abuse Treatment, 28, 19–26.15723728
Mulvey, K. P., Hubbard, S., & Hayashi, S. (2003). A national study of the substance abuse treatment workforce. Journal of Substance Abuse Treatment, 24, 51–57.12646330
Munson, C. E. (1979). Social Work Supervision: Classic Statements and Critical Issues. New York: Free Press.
Munson, C. E. (1993). Clinical Social Work Supervision (2nd ed.). New York: Haworth Press.
Munson, C. E. (2002). Handbook of Clinical Social Work Supervision (3rd ed.). Binghamton, NY: Haworth Social Work Practice.
Muse-Burke, J. L., Ladany, N., & Deck, M. D. (2001). The supervisory relationship. In Bradley, L. J. & Ladany, N. (Eds.), Counselor Supervision: Principles, Process, and Practice (3rd ed.) (pp. 28–62). New York: Brunner-Routledge.
NAADAC, The Association for Addiction Professionals (2003). NAADAC, The Association for Addiction Professionals Practitioner Services Network Year 2 Final Report: A Survey of Early Career Substance Abuse Counselors. Washington, DC: NAADAC, The Association for Addiction Professionals. Retrieved August 14, 2007, from http://naadac.org/pressroom/files/Year2SurveyReport.pdf
Nelson, M. L., & Holloway, E. (1999). Supervision and gender issues. In Carroll, M. & Holloway, E. (Eds.), Counseling Supervision in Context (pp. 23–35). Thousand Oaks, CA: Sage Publications.
Neufeldt, S. A. (1999). Supervision Strategies for the First Practicum (2nd ed.). Alexandria, VA: American Counseling Association.
New Freedom Commission on Mental Health (2003). Achieving the Promise: Transforming Mental Health Care in America. Final Report. (HHS Publication No. (SMA) 03-3832). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Newgent, R. A., Davis, H., & Farley, R. C. (2004). Perceptions of individual, triadic, and group models of supervision: A pilot study. Clinical Supervisor, 23, 65–79.
Nichols, W. C., Nichols, D. P., & Hardy, K. V. (1990). Supervision in family therapy: A decade restudy. Journal of Marital & Family Therapy, 16, 275–285.
Northeast Addiction Technology Transfer Center (2004). Taking Action to Build a Stronger Addiction Workforce. Workforce development summit January 27, 2004. Pittsburgh, PA: Northeast Addiction Technology Transfer Center. Retrieved January 3, 2007, from http://www.ireta.org/wfmono.pdf
Northwest Frontier ATTC (2005). Clinical supervision - Part 1: Models of clinical supervision (Series 20). Addiction Messenger, 8, 10. Retrieved August 14, 2007, from http://www.nfattc.org/uploads/Vol.%208%20Issue%2010.pdf
Northwest Frontier ATTC (2005). Clinical supervision - Part 2: What happens in good supervision? (Series 20). Addiction Messenger, 8, 9. Retrieved August 14, 2007, from http://www.nfattc.org/uploads/Vol.%208%20Issue11.pdf
Patton, M. J., & Kivlighan, D. M. (1997). Relevance of the supervisory alliance to the counseling alliance and to treatment adherence in counselor training. Journal of Counseling Psychology, 44, 108–115.
Peake, T. H., Nussbaum, B. D., & Tindell, S. D. (2002). Clinical and counseling supervision references: Trends and needs. Psychotherapy: Theory, Research, Practice, Training, 39, 114–125.
Pearson, Q. M. (2004). Getting the most out of clinical supervision: Strategies for mental health. Journal of Mental Health Counseling, 26, 361–373.
Pederson, P. B. (1991). Multiculturalism as a generic approach to counseling. Journal of Counseling & Development, 70, 6–12.
Pfohl, A. H. (2004). The intersection of personal and professional identity: The heterosexual supervisor's role in fostering the development of sexual minority supervisees. Clinical Supervisor, 23, 139–164.
Pope-Davis, D. B., & Coleman, H. L. K. (Eds.) (1997). Multicultural Counseling Competencies: Assessment, Education and Training, and Supervision. Thousand Oaks, CA: Sage Publications.
Porter, J., & Gallon, S. L. (2006). Clinical Supervision II: Addressing Supervisory Problems in Addictions Treatment. Salem, OR: Northwest Frontier Addiction Technology Transfer Center.
Powell, D. J., & Brodsky, A. (1993). Clinical Supervision in Alcohol and Drug Abuse Counseling: Principles, Models, Methods. New York: Lexington Books.
Powell, D. J., & Brodsky, A. (2004). Clinical Supervision in Alcohol and Drug Abuse Counseling: Principles, Models, Methods (Rev. ed.). San Francisco, CA: Jossey-Bass.
Powell, D. J. (2003). The new blended model of clinical supervision. Counselor, the Magazine for Addiction Professionals, 4, 1–7.
Powell, D. J. (2006). Maximizing the benefits of online therapy. Addiction Professional, 4, 26–32.
Proctor, B. (1997). Supervision for counsellors in organizations. In Carroll, M. & Walton, M. (Eds.), Handbook of Counselling in Organizations (pp. 342–358). Thousand Oaks, CA: Sage Publications.
Ramirez, N. (2002). Supervisors’ personal-professional attributes and approaches to supervision in organizations providing clinical services to Mexican-American persons. Clinical Supervisor, 21, 67–82.
Rando, R. A. (2001). Adaptive supervision in counselor training. Clinical Supervisor, 20, 173–182.
Ray, D., & Altekruse, M. (2000). Effectiveness of group supervision versus combined group and individual supervision. Counselor Education and Supervision, 40, 19–30.
Reamer, F. G. (2001). Tangled Relationships: Managing Boundary Issues in the Human Services. New York: Columbia University Press.
Reamer, F. G. (2006). Social Work Values and Ethics (3rd ed.). New York: Columbia University Press.
Reeves, D., Culbreth, J. R., & Greene, A. (2001). Effect of sex, age, and education level on the supervisory styles of substance abuse counselor supervisors. Journal of Alcohol and Drug Education, 47, 76–86.
Rizzo, M. D. (2003). Clinical supervision: A working model for substance abuse acute care settings. The Health Care Manager (Frederick), 22, 136–143.
Roche, A. M., Todd, C. L., & O'Connor, J. (2007). Clinical supervision in the alcohol and other drugs field: An imperative or an option? Drug and Alcohol Review, 26, 241–249.17454013
Roman, P. M., Johnson, A., Knudsen, H. K., & Ducharme, L. J. (2006). Workforce Retention in Addiction Treatment: Findings From the National Treatment Center Study. Athens, GA: University of Georgia. Retrieved May 30, 2007, from #368,1, Workforce Retention in Addiction Treatment: Findings from the National Treatment Center Study
Schoener, E. P., Madeja, C. L., Henderson, M. J., Ondersma, S. J., & Janisse, J. J. (2006). Effects of motivational interviewing training on mental health therapist behavior. Drug and Alcohol Dependence, 82, 269–275.16289396
School of Social Work, University of Texas at Austin (2001). Clinical Supervision: Mental Health and Chemical Dependency. Austin, TX: University of Texas.
Shipton, Geraldine (Eds.) 1997. Supervision of Psychotherapy and Counselling: Making a Place to Think. Buckingham, England: Open University Press.
Shoptaw, S., Stein, J. A., & Rawson, R. A. (2000). Burnout in substance abuse counselors: Impact of environment, attitudes, and clients with HIV. Journal of Substance Abuse Treatment, 19, 117–126.10963923
Shulman, L. (1982). Skills of Supervision and Staff Management. Itasca, IL: F.E. Peacock Publishers.
Shulman, L. (2006). The clinical supervisor-practitioner working alliance: A parallel process. In Shulman, L. & Safyer, A. (Eds.), Supervision In Counseling: Interdisciplinary Issues and Research (pp. 23–46). New York: Haworth Press.
Shulman, L. (1993). Interactional Supervision. Washington, DC: NASW Press.
Siqueland, L., Crits-Christoph, P., Barber, J. P., Butler, S. F., Thase, M., Najavits, L., et al. (2000). The role of therapist characteristics in training effects in cognitive, supportive-expressive, and drug counseling therapies for cocaine dependence. Journal of Psychotherapy Practice & Research, 9, 123–130.
Sommer, C. A., & Cox, J. A. (2005). Elements of supervision in sexual violence counselors’ narratives: A qualitative analysis. Counselor Education and Supervision, 45, 119–134.
Spice, C. G., & Spice, W. H. (1976). A triadic method of supervision in the training of counselors and counseling supervisors. Counselor Education and Supervision, 15, 251–258.
Stewart, N. (2004). Supervising the primary care counsellor within the psychodynamic frame. Psychodynamic Practice: Individuals, Groups and Organisations, 10, 354–372.
Stoltenberg, C. D., & Delworth, U. (1987). Supervising Counselors and Therapists: A Developmental Approach. San Francisco, CA: Jossey-Bass Publishers.
Stoltenberg, C. D., McNeill, B., & Delworth, U. (1998). IDM supervision: An Integrated Developmental Model for Supervising Counselors and Therapists (1st ed.). San Francisco, CA: Jossey-Bass Publishers.
Storti, S. A., Roget, N. A., Albers, E. A., Clinkinbeard, S., & Skinstad, A. H. (2006). The Changing Face of the Substance Abuse Treatment Workforce: Is a Crisis Imminent: Implications for Researchers, Providers, and Educators. MWATTC Presented Posters at the College on Problems of Drug Dependence (CPDD) Conference, Phoenix, AZ, June 10–17, 2006.
Sue, D. W., & Sue, D. (2007). Counseling the Culturally Diverse: Theory and Practice (5th ed.). Hoboken, N.J: John Wiley.
Title 42—Public Health PART 2—Confidentiality of Alcohol and Drug Abuse Patient Records (2002). 42 C.F.R. Part 2. Retrieved July 23, 2008, from http://www.access.gpo.gov/nara/cfr/waisidx_02/42cfr2_02.html
Toporek, R. L., Ortega-Villalobos, L., & Pope-Davis, D. (2004). Critical incidents in multicultural supervision: Exploring supervisees’ and supervisors’ experiences. Journal of Multicultural Counseling and Development, 32, 66–83.
Triantafillou, N. (1997). A solution-focused approach to mental health supervision. Journal of Systemic Therapies, 16, 305–328.
Tromski-Klingshirn, D. (2007). Should the clinical supervisor be the administrative supervisor? The ethics versus the reality. Clinical Supervisor, 25, 53–67.
U.S. Department of Health and Human Services (2003). Developing Cultural Competence in Disaster Mental Health Programs: Guiding Principles and Recommendations. (HHS Pub. No. (SMA) 3828). Rockville, MD: Center for Mental Health Services, Substance Abuse and Mental Health Services Administration.
Utsey, S. O., Gernat, C. A., & Hammar, L. (2005). Examining white counselor trainees’ reactions to racial issues in counseling and supervision dyads. Counseling Psychologist, 33, 449–478.
Vallance, K. (2004). Exploring counsellor perceptions of the impact of counselling supervision on clients. British Journal of Guidance & Counselling, 32, 559–574.
Vasquez, M. J., & McKinley, D. L. (1982). Supervision: A conceptual model: Reactions and an extension. Counseling Psychologist, 10, 59–63.
Vespia, K. M., Heckman-Stone, C., & Delworth, U. (2002). Describing and facilitating effective supervision behavior in counseling trainees. Psychotherapy: Theory, Research, Practice, Training, 39, 56–65.
Walker, M., & Jacobs, M. (2004). Supervision: Questions and Answers for Counselors and Therapists. Philadelphia: Whurr Publishers.
Watkins, C. E., Jr. (1993). Development of the psychotherapy supervisor: Concepts, assumptions, and hypotheses of the supervisor complexity model. American Journal of Psychotherapy, 47, 58–74.8434698
Watkins, C. E., Jr. (Ed.). Handbook of Psychotherapy Supervision (1997). New York: Wiley.
Whisenhunt, B. J., Romans, J. S. C., Boswell, D. L., & Carlozzi, A. F. (1997). Counseling students’ perceptions of supervisory modalities. Clinical Supervisor, 15, 79–90.
White, W. L., & Popovits, R. M. (2001). Critical Incidents: Ethical Issues in the Prevention and Treatment of Addiction (2nd ed.). Bloomington, IL: Chestnut Health Systems.
White, W. L. (1993). Critical incidents: Ethical Issues in Substance Abuse Prevention and Treatment. Bloomington, IL: Lighthouse Training Institute.
White, W. L. (1998). Slaying the Dragon: The History of Addiction Treatment and Recovery in America. Bloomington, IL: Chestnut Health Systems.
White, W. L., Sharar, D. A., & Funk, R. (2001). Elevating the business ethics of employee assistance. Behavioral Health Management, 21, 38–42.
Whiting, P. P., Bradley, L. J., & Planny, K. J. (2001). Supervision-based developmental models of counselor supervision. In Bradley, L. J. & Ladany, N. (Eds.), Counselor Supervision: Principles, Process, and Practice (3rd ed.) (pp. 125–146). New York: Brunner-Routledge.
Whitter, M., Bell, E. L., Gaumond, P., Gwaltney, M., Magana, C. A., & Moreaux, M. (2006). Strengthening Professional Identity: Challenges of Addictions Treatment Workforce. A Framework for Discussion. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved August 14, 2007, from http://www.samhsa.gov/Workforce/WorkforceReportFinal.pdf
Wilbur, M. P., Roberts-Wilbur, J., Hart, G. M., Morris, J. R., & Betz, R. L. (1994). Structured group supervision (SGS): A pilot study. Counselor Education and Supervision, 33, 262–279.
Wilcoxon, S. A., & Magnuson, S. (2002). Concurrent academic and pre-licensure supervision: When supervision is not just supervision. Clinical Supervisor, 21, 55–66.
Williams, L. (1994). A tool for training supervisors: Using the supervision feedback form (SFF). Journal of Marital & Family Therapy, 20, 311–315.