# Section 2: Annotated Bibliography

## Research-Related Studies

Reference: Borders, L. D. (2005). Snapshot of clinical supervision in counseling and counselor education: A five-year review. Clinical Supervisor, 24, 69–113.

Purpose: To review recent literature on clinical supervision for counselors and counselor trainees.

Conclusions: The topics covered in this review give insight into the issues involved in clinical supervision that are important to researchers and practitioners at this point in time.

Methodology: The authors reviewed literature from a 5-year period in journals published by the American Counseling Association or two international journals on counseling. They divide literature into quantitative studies, qualitative studies, and conceptual pieces, subdivide according to specific topics in those categories (e.g., multicultural supervision, developmental models, etc.), and provide short reviews of the literature relating to each sub-topic.

Summary of Results: Major topics of interest in clinical supervision literature during this period include concerns over the lack of clinical supervision in specific settings (or misunderstandings over what constitutes clinical supervision), the importance of the supervisory relationship, problems involved in addressing relationship issues in supervision, the role of cultural differences in multicultural supervision, the need to extend research to address a more diverse group of providers, the role of feedback in supervision, other training needs, the role of supervision in certain specialized counseling situations (e.g., schools), the viability of group supervision, developmental models for providing a framework for supervision, and the use of technology in supervision.

Reference: Burkard, A. W., Johnson, A. J., Madson, M. B., Pruitt, N. T., Contreras-Tadych, D. A., Kozlowski, J. M., et al. (2006). Supervisor cultural responsiveness and unresponsiveness in cross-cultural supervision. Journal of Counseling Psychology, 53, 288–301.

Purpose: To examine how cultural competence (or the lack thereof) affects supervisory relationships for supervisees of either European or non-European descent.

Conclusions: Supervisees of non-European (i.e., non-White) descent experience greater dissatisfaction with supervisory relationships as a result of culturally insensitive interactions than do supervisees of European descent. Supervisors in cross-cultural supervisory relationships (regardless of whether they are of European or non-European descent) should address with their supervisees the effects of culture on client treatment.

Methodology: The authors interviewed 26 female doctoral psychology students, 13 of whom were of European descent and 13 of whom were not (6 of these individuals were African American, 6 were Asian American, and 1 was Latina. Interviewers used a semi-structured interview protocol that was aimed at evaluating how cross-cultural supervisory relationships have affected participants. Interviewees were asked to discuss specific events in which the supervisor was and was not culturally responsive. Participants were identified through Listserv requests or by asking other students with whom the authors were already familiar (those students were also eligible for study inclusion).

Summary of Results: Respondents of both European and non-European descent had similar responses to situations in which supervisors from cultural backgrounds different than their own were culturally responsive (i.e., responded to them in a culturally competent manner). Culturally responsive interactions were ones in which the supervisor helped the supervisee become more sensitive to the role of culture in therapy. For supervisees of European descent, such interactions made them more comfortable dealing with cross-cultural interactions in therapy, while for those of non-European descent, such interactions made them feel supported and validated their own concerns. Some respondents of non-European descent did express a level of discomfort in culturally responsive exchanges, particularly when a supervisor challenged the supervisee by suggesting that they did not focus enough on the cultural concerns of a client. Respondents, regardless of cultural background, generally felt greater satisfaction with their supervisor when the supervisor discussed cultural issues. In response to culturally unresponsive interactions (i.e., ones in which the supervisor ignored the effect of culture in the treatment of a client), supervisees of both European and non-European descent experienced a negative reaction to their supervisors and found that the event made them less satisfied with their supervisor. However, supervisees of non-European descent experienced a much greater level of dissatisfaction as a result of such events and often found themselves completely dissatisfied with the supervisory relationship afterward. Supervisees of non-European descent were also more likely to report experiencing culturally unresponsive interactions with supervisors. While respondents of European descent typically felt that their relationship to their supervisor was good prior to the culturally unresponsive event, those of non-European descent did not.

Reference: Culbreth, J. R., & Borders, L. D. (1999). Perceptions of the supervisory relationship: Recovering and nonrecovering substance abuse counselors. Journal of Counseling & Development, 77, 330–338.

Purpose: To determine if counselor/supervisee and supervisor recovery status affect the nature of the supervisory relationship.

Conclusions: Substance abuse treatment counselors experience the most satisfaction when their supervisor has the same recovery status as they themselves have.

Methodology: The authors mailed surveys concerning the counselor-supervisor relationship to 566 substance abuse treatment counselors working in a State public mental health system, of which 385 were returned. The surveys included five assessment instruments intended to evaluate satisfaction with supervision, supervisory style, social influence of supervisor, working alliance with supervisor, and the core conditions for creating behavioral change within the supervisory relationship.

Summary of Results: The authors found no difference in how counselors who were and were not in recovery rated satisfaction with their supervisors. There were also no significant differences in respondents’ perceptions of the nature of their relationship (as measured on the five assessment instruments) according to the client's own recovery status. However, the authors did find that counselors reported significantly greater satisfaction with their counselors when their own recovery status matched that of their supervisor (e.g., when counselors in recovery had supervisors who were also in recovery).

Reference: Culbreth, J. R. (1999). Clinical supervision of substance abuse counselors: Current and preferred practices. Journal of Addictions & Offender Counseling, 20, 15–25.

Purpose: To determine the current and preferred methods of supervision for substance abuse treatment counselors.

Conclusions: The majority of substance abuse treatment counselors receive clinical supervision and are satisfied with the supervision they receive.

Methodology: The authors surveyed a random selection of 400 members of the National Association of Alcohol and Drug Abuse Counselors, 134 (35 percent) of whom responded. The mailed surveys asked about demographic factors relating to the counselors and their typical clients, the current supervisory practices experienced by the counselors, and their preferred supervisory practices.

Summary of Results: Respondents had a mean age of 49, were more likely to be female (55 percent), more likely to be in recovery than not (58 percent considered themselves to be in recovery), and more likely to be White than members of other ethnic/racial groups (87 percent). Their typical clients were most likely to be male, White, and have a mean age of 32. Clinical supervision was the primary means of supervision for 58 percent of the respondents, a combination of individual and group supervision was the second most common means of supervision (34 percent). Thirty percent reported receiving no supervision. Supervisors were most likely to be male (53 percent), and most (64 percent) carried their own caseloads in addition to supervising others. Half of the supervisors, according to supervisees, had a substance abuse counselor license and 39 percent had a master's degree. The majority of respondents (82 percent) did not have a say in selecting their supervisors. Most respondents were moderately to very satisfied with their supervision (the mean rating, on a five-point Likert scale, was 3.57). When asked about the focus of their supervision, the most common responses were ethical standards, adherence to agency policies, facilitating personal growth, and improving clinical skills (in that order). When asked to consider what type of supervisory relationship they preferred, most respondents did not express either a gender preference (76 percent) or a preference as to whether the individual had personal recovery experiences (59 percent). Seventy-four percent of respondents expressed a preference for supervisors who were certified substance abuse treatment counselors, 36 percent preferred a supervisor with at least a master's degree, and 35 percent preferred someone who was a nationally certified counselor. When asked about preferred methods of supervision, 46.6 percent expressed a preference for a combination of group and individual supervision, 72.2 percent preferred that supervision be required for their position, and 35 percent wanted supervision provided by an experienced colleague or peer. Supervisees preferred that their supervisors focused on facilitating growth and awareness, followed by improving clinical skills and adhering to ethical standards. Respondents, in ranking different approaches to supervision, had the greatest preference for self-reports of sessions, followed by co-therapy with a supervisor, and live observations of a supervisor with a client. There were some differences between the preferences of counselors who were themselves in recovery and those who were not. Counselors in recovery indicated a significantly greater preference for supervisors that used more influence and support in the supervisory session, spent more time discussing legal and ethical questions, and provided more frequent supervisory sessions. They were also more likely to prefer a supervisor who was also in recovery.

Reference: Daniels, J., D'Andrea, M., & Kim, B. S. K. (1999). Assessing the barriers and changes of cross-cultural supervision: A case study. Counselor Education and Supervision, 38, 191–204.

Purpose: To examine how cross-cultural supervisor-supervisee relationships are complicated by cultural differences and how those differences may result in communication problems and/or interpersonal conflicts.

Conclusions: Supervisors need to be open to discussing cultural issues with supervisees who have different cultural backgrounds from their own.

Methodology: The authors use a case study to examine how problems can arise in cross-cultural supervisory relationships when issues of cultural difference are not addressed.

Summary of Results: Based on their analysis of the case study they present, the authors determine that in situations in which their supervisees have cultural backgrounds that are different from their own, supervisors need to be willing to initiate discussions about cultural issues, discuss their own roles and responsibilities in the supervisory relationship, establish guidelines for getting feedback from supervisees, and explain the ways in which culturally based miscommunication or conflict can be resolved. Supervisors from the dominant culture who are in cross-cultural supervisory situations also need to express interest in hearing supervisee's ideas about the cultural difference and how it may affect the supervisory relationship.

Reference: Eby, L. T., McCleese, C. S., Baranik, L., & Owen, C. (2007). Project MERITS Year 1 Summary Report. Athens, GA: University of Georgia Institute for Behavioral Research.

Purpose: To report early findings from a large, 5-year study on the relationship of clinical supervision and employee turnover/burnout for staff in substance abuse treatment programs.

Conclusions: Having positive experiences in the course of clinical supervision is associated with less burnout and less intention to leave substance abuse treatment counseling.

Methodology: The Managing Effective Relationships in Treatment Services (MERIT) Project is a 5-year study funded by the National Institute on Drug Abuse (NIDA) and drew its sample of 740 substance abuse treatment counselors and 198 clinical supervisors from 27 substance abuse treatment programs that were associated with NIDA's Clinical Trials Network. Respondents answered questions about demographics, supervisory and clinical practice, job satisfaction, positive and negative experiences with clinical supervision, and related topics.

Summary of Results: The initial round of surveys indicate that clinical supervisors and the counselors they supervise are both only moderately satisfied with their supervisory relationships, although supervisors indicate somewhat higher satisfaction than supervisees. Both supervisors and supervisees have a moderately high level of professional satisfaction and are generally satisfied with their jobs, have a moderate level of loyalty towards the programs for which they work, feel that they have a moderate level of support from their programs, are generally satisfied with the work they do and their choice of profession, and are generally dissatisfied with their pay and opportunities for advancement. Both supervisors and supervisees report a moderate level of stress and some role-related overload and job-related burnout. However, the mean level of burnout reported is no higher than that reported by other human service professionals. Supervisees do report a high level of intention to leave their current position—somewhere between 35 and 40 report such an intention as do 22 percent of supervisors. Supervisees who have more favorable responses to their clinical supervision also report greater job satisfaction, greater commitment to their employer, a greater sense of support from their employer, less role-related overload, less stress, less burnout, and less intention to leave their current place of employment. Supervisees who report greater job satisfaction, greater commitment to the organization for which they work, greater commitment to their profession, a greater sense of support from the organization for which they work, and lower levels of role-related overload also report less intention to leave their current position. The authors conclude that this preliminary research suggests that more positive experiences in clinical supervision are associated with less burnout and less intention to leave one's current position and that organizations can improve retention and decrease burnout with better clinical supervision.

Reference: Evans, W. N., & Hohenshil, T. H. (1997). Job satisfaction of substance abuse counselors. Alcoholism Treatment Quarterly, 15, 1–13.

Purpose: To evaluate the level and sources of job satisfaction and the relationship of job satisfaction to clinical supervision for certified substance abuse treatment counselors.

Conclusions: Substance abuse treatment counselors have a relatively high level of job satisfaction compared with other professionals, and overall they are very satisfied with their jobs. However, lack of opportunities for advancement present the biggest challenge to that satisfaction.

Methodology: The authors sent surveys to 505 substance abuse treatment counselors—365 responded and 231 responses were usable. Surveys used the Minnesota Satisfaction Questionnaire to evaluate job satisfaction and an individual information form to gather information that could be used to assess the relationship of job satisfaction to clinical supervision.

Summary of Results: According to mean scores on survey responses, counselors were “very satisfied” overall with their jobs. All respondents were at least slightly satisfied. As for specific sources of job satisfaction, social service provided the greatest satisfaction and opportunities for advancement provided the least. The mean score for satisfaction with advancement fell in the “slightly satisfied” level. The factors that appeared to have the greatest relation to satisfaction with clinical supervision were the number of hours of supervision received per week, the length of time the supervisor had been in that role, the degree level of the supervisor, and whether or not the clinical supervisor was also the counselor's administrative supervisor.

Reference: Fernando, D. M., & Hulse-Killacky, D. (2005). The relationship of supervisory styles to satisfaction with supervision and the perceived self-efficacy of Master's-level counseling students. Counselor Education and Supervision, 44, 293–304.

Purpose: To determine if there is a relationship between supervisors’ supervisory styles and both supervisee satisfaction and self-efficacy for masters-level students.

Conclusions: The use of an interpersonally sensitive supervisory style is associated with increased satisfaction with supervision among supervisees and the use of a task-oriented style is associated with increased self-efficacy among supervisees.

Methodology: The authors surveyed 82 students in masters-level counseling programs at six different universities and their supervisors. They administered the Supervisory Styles Inventory, the Supervisory Satisfaction Questionnaire, and the Counseling Self-Estimate Inventory.

Summary of Results: The only variable studied that was significantly related to satisfaction with supervision was the supervisor's use of an interpersonally sensitive supervisory style. The only significant variable in predicting supervisees’ self-efficacy was the use of a task-oriented supervisory style. There was no significant relationship between ratings of self-efficacy and satisfaction with supervision among supervisees.

Reference: Freitas, G. J. (2002). The impact of psychotherapy supervision on client outcome: A critical examination of 2 decades of research. Psychotherapy: Theory, Research, Practice, Training, 39, 354–367.

Purpose: To review literature regarding the effects of clinical supervision on client outcomes.

Conclusions: More rigorous research is needed to understand the relationship between clinical supervision and client treatment outcomes.

Methodology: The author identified a total of ten studies published between 1981 and 1997 for detailed review.

Summary of Results: Research on this topic has had a number of potential problems such as lack of psychometric data, a failure to focus on supervisors who have a limited range of experience/professional background, and a failure to randomize clients. While this research gives some indication of how clinical supervision may affect treatment outcomes for clients, more research is needed to better understand the relation of supervision to client outcomes.

Reference: International Certification & Reciprocity Consortium/Alcohol and Other Drug Abuse (ICRC/AODA). (2000). Clinical Supervisor of Alcohol and Other Drug Abuse Counselors Role Delineation Study. Research Triangle Park, NC: Castle Worldwide, Inc.

Purpose: To determine roles and activities of clinical supervisors who supervise substance abuse treatment counselors.

Conclusions: ICRC/AODA clinical supervisors indicate that they spend significantly more time on activities that they view as less important (management and administration) than on that they believe is most important (professional responsibility).

Methodology: ICRC/AODA undertook a survey of roles as an initial step toward developing a credentialing program for clinical supervisors. An expert panel identified questions for the survey relating to four major domains of activity (assessment and evaluation, counselor development, professional responsibility, management and administration).

Summary of Results: The respondents were mostly between the ages of 42 and 60, held certifications in both clinical supervision and substance abuse treatment counseling, had more than 15 years of counseling experience, and had a master's degree or higher. According to the mean response, respondents granted the greatest importance to the domain of professional responsibility, followed by assessment and evaluation, and counselor development (these rankings differed from the expert panel who created the survey who considered counselor development most important). When asked to rank domains according to how much time they spent on them, respondents said they spent the most time (27 percent) on management and administration, followed by assessment and evaluation, and counselor development.

Reference: Kavanagh, D. J., Spence, S. H., Strong, J., Wilson, J., Sturk, H., & Crow, N. (2003). Supervision practices in allied mental health: Relationships of supervision characteristics to perceived impact and job satisfaction. Mental Health Services Research, 5, 187–195.

Purpose: To determine if supervisor characteristics have an effect on mental health treatment and staff morale. Also, to give a preliminary evaluation of a new instrument for assessing supervisory relationships, the Supervision Attitude Scale.

Conclusions: The degree to which supervisees believe their supervision affects their clinical practice is related to the amount of impact that supervision has on their discipline-related skills, their satisfaction with supervision, and the frequency of contact with supervisors who come from their own discipline. Empathy and praise from supervisors increased supervisees’ satisfaction with the counseling relationship.

Methodology: The authors used a database of public mental health staff in Queensland, Australia to select 375 individuals to receive a telephone survey, 272 of whom agreed to participate. Participants were interviewed using a survey designed specifically for this study as well as the supervisor and/or supervisee versions of a new instrument developed by the authors, the Supervision Attitude Scale (SAS), designed to evaluate the positive and negative aspects of the supervisory relationship. Telephone interviews were conducted in June and July 2000.

Summary of Results: The authors found that supervisors were more likely than supervisees to state that a specific supervisory contract was in place. Supervisors were also somewhat more likely to state that discipline-specific competencies were the focus of the supervisory relationship, while supervisees were more likely to state generic practice skills were the focus. Supervisees were, on average, moderately satisfied with their supervision and most believed that supervision had a positive effect on their effectiveness as clinicians (6 percent). When evaluating the effect of different factors on the impact of supervision on clinical practice, most of the factors measured did not have a significant relationship (e.g., gender, discipline, location). The factors that were significantly related were satisfaction with supervision, positive attitudes towards supervisors, time spent on discipline-specific skills (but not time spent on generic skills) and frequency of contact (the latter only with supervisors from the same disciplinary background). They did not find any relationship between job satisfaction and amount of supervision, availability of supervisors, level of specificity in the supervisory contract, or priority of discipline specific skills. The factors that appeared to have the greatest effect on satisfaction were the perceived impact of supervision on practice, a positive attitude from supervisors, and the receipt of empathy from supervisors. The only specific supervisory strategy that had a significant relationship with satisfaction was the level of praise of the supervisee's performance. Both the supervisor and supervisee version of the SAS had high internal consistency and its intercorrelations demonstrated that it measured how positive the supervisory relationship was appropriately.

Reference: Ladany, N., & Lehrman-Waterman, D. E. (1999). The content and frequency of supervisor self-disclosures and their relationship to supervisor style and the supervisory working alliance. Counselor Education and Supervision, 38, 143–160.

Purpose: To evaluate how counselor trainees perceive the content and frequency of self-disclosures from supervisors and how supervisor style is related to the frequency of self-disclosure.

Conclusions: The type and frequency of supervisor self-disclosures are related to supervisor style and the perceived quality of the supervisory relationship.

Methodology: The authors interviewed 105 counselor trainees (out of an original sample of 525) using four instruments (i.e., the Supervisor Self-Disclosure Questionnaire, the Supervisor Self-Disclosure Index, the Supervisory Styles Inventory, and the Working Alliance Inventory-Trainee Version) and a demographic questionnaire.

Summary of Results: On average, trainees reported 5.46 self-disclosures from their supervisors. A greater number of self-disclosures was associated with a more attractive supervisory style (as measured on the Supervisory Styles Inventory), while an interpersonally sensitive or task-oriented styles were not. Specifically, an attractive supervisory style was related to a greater likelihood of disclosing neutral counseling experiences rather than personal issues or counseling struggles. On the other hand, an interpersonally sensitive supervisory style was related to a less likelihood of disclosing neutral counseling experiences. A task-oriented style was also associated with greater likelihood of disclosing neutral counseling experiences. More frequent supervisor self-disclosures were associated with a greater perceived agreement (between supervisor and supervisee) regarding the goals of supervision and with a stronger perceived emotional bond with the supervisor. The strength of the emotional bond was associated specifically with more frequent disclosures of counseling struggles.

Reference: Ladany, N., Walker, J. A., & Melincoff, D. S. (2001). Supervisory style: Its relation to the supervisory working alliance and supervisor self-disclosure. Counselor Education and Supervision, 40, 263–275.

Purpose: To examine supervisor perceptions of their own supervisory styles and how it affects the supervisory relationship, especially in relation to working alliance and self-disclosure.

Conclusions: Supervisors who are flexible in regards to their supervisory style are best able to attend to all aspects of the supervisory relationship. However, supervisors who believe they use an attractive supervisory style appear to be most attentive to all primary aspects of the supervisory relationship.

Methodology: The authors interviewed 137 clinical supervisors working in a variety of counseling settings. In conducting the interviews, the authors used the Supervisory Styles Inventory, the Working Alliance Inventory-Supervisor Version, Supervisor Self-Disclosure Inventory, and a demographic questionnaire.

Summary of Results: The authors found that supervisors who identified themselves as warm, friendly, and supportive (i.e., attractive in style) were more likely to see their supervisory relationship as being mutually trusting and in agreement in regards to both the tasks and goals of supervision (i.e., the three primary aspects of the supervisory relationship). When supervisors primarily believed themselves to have a task-oriented style they perceived a high level of agreement with supervisees regarding supervisory tasks (but not supervisory goals or a high level of mutual trust). Supervisors who saw themselves as engaging in a supervisory style that was high in empathic understanding believed themselves to understand supervisees’ goals in relation to supervision. Supervisors who saw themselves as attractive in style as well as those who saw themselves as interpersonally sensitive were more likely to also perceive themselves as self-disclosing than were supervisors who saw themselves as task-oriented in style.

Reference: Magnuson, S., Wilcoxon, S. A., & Norem, K. (2000). A profile of lousy supervision: Experienced counselors’ perspectives. Counselor Education and Supervision, 39, 189–202.

Purpose: To analyze the elements of poor clinical supervision.

Conclusions: Lousy supervision is one end of a continuum of supervisory practice characterized by both the absence of effective practices and the presence of harmful ones.

Methodology: The authors conducted in depth interviews with ten experienced clinical supervisors (and one with less experience) who supervised counselors/students in a variety of settings. They conducted semi-structured interviews either in person or by phone, depending on the respondent's location.

Summary of Results: From the interviews they conducted, the authors were able to discern six overarching principles that defined poor or “lousy” supervision. Such supervision was unbalanced, developmentally inappropriate, intolerant of differences, untrained, professionally apathetic, and/or poorly modeled professional/personal attributes. The authors also discuss how these overarching principles applied specifically in three general spheres: (1) the organizational/administrative, (2) the technical/cognitive, and (3) the relational/affective. So, for example, developmentally inappropriate supervision in the administrative sphere may result in a failure to assess supervisee needs, while in the relational sphere it may result in insensitivity to the supervisee's professional and developmental needs.

Reference: Magnuson, S., Wilcoxon, S. A., & Norem, K. (2000). Exemplary supervision practices: Retrospective observations of experienced counselors. TCA Journal, 28, 93–101.

Purpose: To determine the elements of exemplary supervision.

Conclusions: Experienced supervisors believe that exemplary supervision involves competent preparation, the ability to successfully demonstrate, the ability to elicit participation from supervisees, and the ability to stimulate supervisees.

Methodology: The authors conducted in depth interviews with ten experienced clinical supervisors (and one with less experience) who supervised counselors/students in a variety of settings. They conducted semi-structured interviews either in person or by phone, depending on the respondent's location.

Summary of Results: The authors found that respondents presented four dimensions that were involved in exemplary supervision: competent preparation, the ability to successfully demonstrate, the ability to elicit participation from supervisees, and the ability to stimulate supervisees.

Reference: NAADAC, The Association for Addiction Professionals. (2003). NAADAC, The Association for Addiction Professionals Practitioner Services Network Year 2 Final Report: A Survey of Early Career Substance Abuse Counselors. Washington, DC: NAADAC, The Association for Addiction Professionals. Retrieved October 27, 2008, from http://naadac.org/pressroom/files/Year2SurveyReport.pdf

Purpose: To better understand the education, work settings, and satisfaction of substance abuse treatment counselors who have been working in the field for 4 years or less.

Conclusions: Substance abuse treatment counselors find that on-the-job supervision is the most useful method of further educating themselves and the majority are satisfied or greatly satisfied with their current supervision.

Methodology: The NAADAC sent surveys to 662 of its members (who had previously indicated that they had 3 or fewer years working in the substance abuse treatment field) regarding their education, qualifications, work settings, personal background, and characteristics of their typical clients. The final sample of 140 respondents, however, included individuals with 4 years or less of experience in the field. The survey instrument consisted of 72 questions and is included in the report. Data from the survey were compared to information available from other sources concerning the entire membership of NAADAC.

Summary of Results: Respondents, in noting their reasons for entering the substance abuse treatment field, were most likely to state that they believed the work would be challenging or interesting, followed by having had a desire to work in a helping profession, having seen substance abuse problems in their communities, and having friends/family who had substance abuse problems or they themselves had substance abuse problems. In ranking eight sources of counselor education, participants ranked on-the-job supervision highest, followed by internships and mentoring programs (in that order), and ranked Internet materials lowest with continuing education second lowest. Almost all respondents were at least a little or somewhat satisfied with their supervision, and about 65 percent were satisfied to greatly satisfied.

Reference: Ray, D. & Altekruse, M. (2000). Effectiveness of group supervision versus combined group and individual supervision. Counselor Education and Supervision, 40, 19–30.

Purpose: To determine if different methods of clinical supervision are related to different ratings of counselor effectiveness for masters-level students.

Conclusions: Large group, small group, or group plus individual methods of supervision all appear to improve counseling effectiveness equally for masters-level students.

Methodology: The author randomly assigned 64 students who were enrolled in a masters-level practicum during one of two successive semesters to one of three supervisory situations: (1) combined individual and group supervision, (2) large group supervision, or (3) small group supervision. Faculty practicum supervisors for nine different practicum sections were assigned to supervise students in one of the three groups. In addition, 11 doctoral students participated as individual supervisors in the combined individual-group condition. As part of their practicum, students were assigned at least two clients who had sought help through the university's clinic. The Counselor Rating Form-Short Version and Supervisee Levels Questionnaire-Revised were used to assess the supervisory relationship. Tapes of counseling sessions were assessed by independent raters to evaluate counselor effectiveness at the beginning and end of the semester. Students were also asked to rate their preferences regarding methods of supervision.

Summary of Results: According to independent raters, all participants improved their counseling scores over the course of the study, with no significant difference according to the method of supervision (i.e., individual plus group, large group alone, small group alone). Preferences for supervision were not related to ratings of counseling effectiveness, although participants did express a preference for individual over group supervision.

Reference: Reeves, D., Culbreth, J. R., & Greene, A. (1997). Effect of sex, age, and education level on the supervisory styles of substance abuse counselor supervisors. Journal of Alcohol and Drug Education, 43, 76–86.

Purpose: To better understand substance abuse treatment counselor supervisors’ perceptions of their own supervisory styles and the relation of those perceptions to age, gender, and education level.

Conclusions: Younger supervisors (under the age of 50) considered themselves more flexible in some matters of supervision.

Methodology: The authors solicited participation from 171 certified clinical supervisors who had been accredited by the North Carolina Substance Abuse Professional Certification Board, 72 of whom agreed to participate. Participants completed two questionnaires intended to assess their supervisory style (i.e., the Supervisory Styles Inventory and the Supervisory Styles Index), as well as questions concerning demographics.

Summary of Results: There were no significant differences in supervisory styles according to gender. Supervisors under the age of 50 were significantly less likely than those over 50 to decide ahead of time what to discuss in supervision sessions and felt more comfortable sharing personal experiences with supervisees. Younger supervisors were also somewhat less likely to insist that supervisees adhere strictly to their direction. Overall, this group of respondents were significantly more likely to label their supervisory style as attractive or interpersonally sensitive than task-oriented.

Reference: Vespia, K. M., Heckman-Stone, C., & Delworth, U. (2002). Describing and facilitating effective supervision behavior in counseling trainees. Psychotherapy: Theory, Research, Practice, Training, 39, 56–65.

Purpose: To understand what factors are associated with better use of supervision by supervisees, according to both supervisors and supervisees.

Conclusions: The most important behaviors for effective use of supervision, according to both supervisees and supervisors, are demonstrating a willingness to grow, taking responsibility for the consequences of one's own behavior, actively participating in supervision sessions, demonstrating respect and appreciation for individual differences, and demonstrating an understanding of one's personal dynamics as they relate to both counseling and supervision.

Methodology: The authors surveyed both supervisees and supervisors who were involved in internship programs at universities or counseling centers. They selected some programs with which they were affiliated or familiar and selected others randomly from a list of American Psychological Association-accredited programs. Of the 335 supervisees and 61 supervisors contacted, 145 supervisees and 31 supervisors returned completed forms. Participants came from one of 13 academic programs or 10 counseling centers. All completed a survey instrument specifically designed for this study, the Supervision Utilization Rating Form (SURF), that asked respondents to rate the importance of specific behaviors for supervisees to use supervision effectively.

Summary of Results: The SURF was found to be an accurate measure of the behaviors that both supervisors and supervisees believed indicated the ability of supervisees to use supervision effectively. The items that were most often endorsed as important behaviors for good supervision by both supervisors and supervisees were demonstrating a willingness to grow, taking responsibility for the consequences of one's own behavior, actively participating in supervision sessions, demonstrating respect and appreciation for individual differences, and demonstrating an understanding of one's personal dynamics as they relate to both counseling and supervision. For most items, supervisors and supervisees did not differ significantly in the importance they granted the behaviors. However, on six items there were significant differences. On all of these items, supervisees gave a greater mean rating of importance than supervisors to the following behaviors: (1) listening attentively to the supervisor, (2) identifying ones own developmental needs, (3) inviting feedback from the supervisor, (4) demonstrating an understanding of one's personal dynamics as they relate to both counseling and supervision, (5) critiquing ones own work, and (6) discussing one's own level of development in domains such as therapy and assessment.