# Chapter 2

## Introduction

In this chapter, through vignettes, you will meet eight clinical supervisors with a variety of skill levels, a number of their supervisees, and an administrator. The supervisors face counselors with a variety of issues. One is unfamiliar with supervision, one has ethical issues, one is resistant to change, and another is a problem employee. The supervisors also have issues of their own. One grapples with the challenges of a new position, and another works to create a legacy. The vignettes, which incorporate these issues along with the principles outlined in Part 1, chapter 1, are designed to show how clinical supervisors might manage some fairly typical situations.

Each vignette provides an overview of the agency and of the backgrounds of the supervisor and other individuals in the dialog. A list of the learning objectives for each vignette is also included. Embedded in the dialog are additional features:

Master Supervisor Notes are comments from an experienced clinical supervisor about the strategies used, what the supervisor may be thinking, how supervisors with different levels of experience and competence might have managed the situation, and information supervisors should have.

“How-to” Notes contain information on how to implement a specific method or strategy.

The master supervisor represents the combined experience and wisdom of the TIP Consensus Panel and provides insights into the counselor's relationships with clients and suggests possible approaches. The notes provide some indication of the breadth of the master supervisor's clinical skills as well as the extent to which the supervisor moves effortlessly among clinical, supportive, evaluative, and administrative roles.

“How-to” notes reflect the collected experience of the TIP Consensus Panel along with information gleaned from a variety of textbooks, manuals, and workbooks on clinical supervision. Not all “how-tos” will apply in every situation, but this information can be adapted to meet the specific needs of your case.

This format was chosen to assist clinical supervisors at all levels of mastery, including those who are new in the position, those who have some experience but need more diversity and depth, and those with years of experience and training who are true master supervisors. The Consensus Panel has made significant efforts to present realistic scenes in supervision using clinical approaches that include motivational interviewing (MI), cognitive–behavioral therapy (CBT), supportive psychotherapy, crisis intervention methods, and a variety of supervisory methodologies including live observation, education, and ethical decisionmaking. In all of these efforts, basic dynamics of supervision, such as relationship building, managing rapport in stressful situations, giving feedback, assessing, and understanding and responding to the needs expressed by the counselor are demonstrated. The Panel does not intend to imply that the approach used by the supervisor is the “gold standard,” although the approach shown does represent competent supervision that can be performed in real settings.

## Vignette 1—Establishing a New Approach for Clinical Supervision

### Overview

This vignette illustrates the tasks of a clinical supervisor in describing a range of supervision methods to clinical staff, including establishing a consistent model of direct observation. The vignette begins with the supervisor describing to staff how he will implement a new method of supervision.

### Background

Walt has been assigned to redesign the supervision program for a community-based substance abuse treatment program, which includes an inpatient program, intensive outpatient program, family therapy, impaired driver treatment, drug court program, halfway house, and educational services. The decision was made to establish an integrated system of supervision. The agency's staff, with ten full-time-equivalent counseling positions, has a broad range of professional training and experience, from entry-level certified addiction counselors to licensed social workers and licensed professional counselors. All staff, regardless of degrees and training, basically have the same duties.

Until now, staff received primarily administrative supervision with an emphasis on meeting job performance standards. Walt wants to make the supervision more clinical in nature, using direct methods of observation (videotape and live observation). He anticipates program growth in the next few years and wants to mentor key staff who can assume supervisory responsibilities in the future.

Walt has been meeting with clinical staff in small groups organized along work teams into dyads and triads to describe the changes and new opportunities. The vignette begins with Walt meeting with two staff members to discuss their learning needs and to present the new clinical supervision system. Al is in recovery, with 5 years of sobriety and 3 years of experience as a counselor. Carrie has an M.S.W. degree with 6 years of work experience.

### Learning Goals

1. To demonstrate a range of supervision methods, with an emphasis on direct observation through videotaping and live observation.
2. To illustrate the mentoring, coaching, and educational functions of supervision.
3. To demonstrate how these functions can be integrated into a consistent model of clinical supervision with fidelity to the methods and adaptability to the unique needs of each organization.

[After greetings, Walt begins the discussion about the new supervision approach.]

WALT: As you know, our CEO and senior staff have agreed that we need to establish a program of staff training and supervision that will help achieve the goals of the agency and, at the same time, help counselors improve their skills. We've done a good job developing other administrative systems, and the next step is to implement clinical supervision to address both agency goals and your individual goals for professional development. People are moving into new roles, so new skills will be required of us.

AL: I'm not sure what I need. How will supervision enhance my skills?

WALT: Al, I think that is a great place to start. We've had administrative supervision so far. As we continue to grow individually and together, we'll need new skills. Perhaps a place for us to start is to discuss what will be asked of us in the future, what skills we'll need. How would it be if we had that discussion now?

AL: That sounds a little frightening. We need to know and do more? How much more blood can they get out of us?

[image] Master Supervisor Note: A new supervisor might respond differently to Al's comment, in a more mechanical or authoritarian manner, asserting authority, wanting to be the expert, creating an “us vs. them” scenario. Such an approach might discourage staff from embracing the new supervision system. An experienced supervisor would be less confrontive and authoritarian and would adopt a more consultative posture. He would be direct but not necessarily confrontational.

CARRIE: I remember the good supervision I had in my M.S.W. program. This sort of reminds me of that—that you're suggesting we have more clinical supervision. Not to sound selfish, but what's in it for me, to get more supervision?

WALT: That's a great question, Carrie. We all want to know what's in it for us. I'd like to hear about your experiences in supervision. How did you learn from that process? What direct observation did you have?

How To Provide a Rationale for Clinical Supervision

[image] Clinical supervision has several benefits, which Walt can offer Carrie at this point:

1. Administrative benefits: ensuring quality care, providing a tool to evaluate the staffs strengths and learning needs
2. Clinical benefits: improving counselors' knowledge and skills and offering a forum to implement evidence-based practices within an organization
3. Professional and workforce development: enhancing staff retention, improving morale, providing a benefit to enhance staff recruitment, and upgrading the qualifications and credentials of personnel
4. Program evaluation and research: providing valuable information to determine program outcome and patient success

CARRIE: In school I found observation both frightening and helpful. At first I hated being observed and taped. Very quickly, though, I really saw the benefits of observation and learned a lot from the experience.

WALT: It's been my experience that almost everybody has some initial reservations about direct observation, but at the same time nearly everyone finds it beneficial, too. I think one thing to keep in mind is that good direct observation doesn't focus on the negative—on what somebody did wrong. The objective is to help us look at what we do well, give us new options, build a bigger tool box of skills, and help us to look at the larger process of our counseling, rather than just getting stuck in applying techniques with people. As we look at our goals and what we need to learn, I hope we can see how supervision, and particularly direct observation, will help all of us.

CARRIE: I'm told I'll be doing more group counseling. I certainly need further training and feedback on my group skills. This is something we didn't focus on much in grad school. There are other areas that I'd also like to be more proficient in, such as doing marriage and family counseling.

WALT: Okay. That would be one place for us to begin, Carrie. How about you, Al?

AL: I'm excited. I've wanted to do more counseling, moving out of running DWI groups and doing assessments. I need more training but I have concerns about being videotaped or observed. I'm going to make mistakes. I'll be self-conscious about that. I think videotaping a session or having a supervisor sit in will make the clients nervous, too.

How To Help Counselors and Clients Become Comfortable With Live Observation

[image] The following steps are recommended:

1. Acknowledge and understand the clients' and/or counselors' anxiety about observation or taping.
2. Listen reflectively to these concerns without being dismissive or ignoring the anxiety; noting that these feelings are common may help normalize the counselor's concerns.
3. Clearly state the value of direct observation and reinforce the idea that such methods are “part of how we do business at this agency. We want to be respectful of your concerns. And we believe strongly that it is important for us to do so for quality assurance and improved client service.”
4. Keep the door open with the clients and counselors to continue to address their concerns and feelings as part of their normal clinical or supervisory process.
5. Help the counselor to allay clients' anxiety or concerns by coaching the counselor through methods for presenting the direct observation methods to the client.

WALT: I can sure understand your sense of feeling self-conscious and your concerns that clients will, too. You've never been either videotaped or observed before?

AL: No, I haven't. In the DWI program, my supervisor sat in a few times when I first started, but it was more a question of whether I was following the curriculum.

WALT: So, although you did have some observation before, this seems like it will be different for you. Perhaps we could look at your goals and how supervision with observation can assist us in meeting your goals.

[A discussion follows where Al and Carrie present their ideas for supervision needs. They then discuss what skills they need to develop in the next year.]

WALT: Perhaps we can discuss what the new supervision system will look like, how it will work, and what's in it for you. First, we're going to have regular observation of all clinical staff, through either one-way mirror (if we can get the audio working in the room), videotaping (my preferred method), or one of the supervisors will sit in and observe counselors with clients. We hope to observe each counselor at least once a month. We'll meet as a group for supervision for an hour a week, and we'll discuss the session that was videotaped or observed that week, with one of you leading the discussion. Each person will get a turn at bat over the course of 1 or 2 months.

[Walt explains the “how-tos” of live observation and videotaping, including the concept of saliency, bringing to supervision the one issue the counselor wishes to address. Walt presents a step-by-step process to begin doing direct observation.]

How To Implement Direct Observation or Videotaping

[image]

1. Obtain written and verbal agreement from the clients and all concerned parties to be videotaped. Clients should be informed on admission that:
  • Counselor–client contact may be observed by supervisors, and/or audio or videotaped.
  • The conditions under which the tape will be used for training.
  • How the taped material will be stored and destroyed after use.
2. Counselors should briefly explore client concerns about taping and observation, and respect their right not to be observed. If the client objects after the initial exploration, the counselor must respect that choice and ask another client.
3. On the visit before the observation occurs, remind the client that on their next visit, their session will be taped for quality assurance purposes. Ask them if they have any questions about that. If the client strongly objects to the taping, discuss those concerns. If the client repeatedly objects to any form of observation, the counselor should explore the client's resistance, and attempt to understand the client's concerns and point of view. Even though a client has signed an informed consent that discusses the possibility of direct observation by supervisors, a client always has the right to decline any aspect of treatment. Remember, no method of observation should ever exceed the client's level of comfort so as to be detrimental to the therapeutic process.
4. At the beginning of the taping or observation, restate to the client the limits of confidentiality and how the videotape or observation notes will be used by the clinical supervisor and/or the counseling team. Clarify whether or how the supervisor will observe and/or cofacilitate the session or simply observe and intervene only as needed.
5. Be attentive to the counselor's concerns about direct observation. It may be helpful to begin with the idea that “observation gives us a chance to learn from each other.” Then you can move into a discussion about the benefits and cost-effectiveness of certain observation methods.
6. Ask the counselor to cue the tape to the most salient points of the session and bring that section to their next supervisory session. In the beginning, counselors might be encouraged to choose the section of a session in which they thought they did well.

CARRIE: I'd like to hear more about why you prefer videotaping.

WALT: I prefer videotaping for several reasons: First, it is the most cost-effective way for us to observe a session. Second, videotaping helps us allocate staff time better; we don't have to sit in on an entire session but can just look at the most salient points in the tape. It gives us all a chance to observe and learn from each other. Sometimes we get a tape where a counselor has done something really special, and we can use that tape again before destroying it, teaching a particularly powerful and effective technique. We can all learn from each other's experiences.

[Walt describes how direct observation works, including the legal requirements such as signed releases by clients, preparation and procedures for observation, and procedures for using tapes and observations and maintaining confidentiality.]

[image] Master Supervisor Note: It is important for you to prepare the counselor for what will happen during the session. If you are sitting in the session to observe, you should explain if and/or when you might intervene in the session, seating arrangements for the session, nonverbal ways of communicating during the session, and how other interruptions, should they occur, might be handled.

AL: As I said before, I've never been observed or taped, and that makes me nervous.

CARRIE: Well Al, I think you'll get comfortable with it, and you'll find it to be very helpful when it comes to areas that you have concerns about. You said that you were concerned about mistakes, but it really won't be about mistakes. My supervisor in grad school had a motto I liked; she always tried to “catch counselors doing something right.” I liked that. So, hopefully this is not about making mistakes but learning from each other. When you see yourself on the videotape and you have someone go over it with you, they can give you pointers about what worked and how you might have done other things differently. Over time you become comfortable with it. Observation was very helpful to me. I think your misgivings will go away after a couple of sessions with Walt. You'll be surprised.

[image] Master Supervisor Note: It may be helpful for you, as a supervisor, to find a “champion”—someone who's experienced direct observation and found it helpful. Hearing positive statements about supervision from a colleague is often more acceptable than hearing it from superiors.

WALT: That's been my experience, too, with videotaping and direct observation. Al, you said it would make the client nervous. Actually, we're the ones who're most nervous. We all want to know how we're doing, but often we're afraid to ask, to get feedback and be observed.

AL: Maybe it would be better if I saw tapes of others doing counseling first.

WALT: That's a great idea. I can present a videotape of a session I conduct. Then we can all sit and discuss what I did. How would that work for you if we were to look at a videotape of one of my sessions for our next supervisory meeting? I'd benefit from your reflections. It might be a good place for us to start the process.

How To Encourage Acceptance of Direct Observation

[image] Since you should never ask a staff member to do something you are unwilling to do, it might be helpful for you to:

1. Be the first to be taped or observed.
2. Be open to feedback from staff, setting the tone of acceptance and vulnerability to feedback.
3. Solicit comments and suggestions from the counselors concerning what they might have done differently and why.
4. Model acceptance by committing to trying out these suggestions in future counseling sessions.

AL: Yeah, I like that idea.

CARRIE: That would be fine with me. I'll volunteer to be second. It's been a while since I was observed, but I don't have any problem with it.

WALT: Thanks, Carrie. So, since I'm up to bat first, let's talk about some of the processes of observation.

[A discussion follows about what will happen in supervision when Walt presents his case.]

[image] Master Supervisor Note: You will want to state clearly what is expected from counselors in supervision. A supervision contract forms the basis of this statement, and explains the ramifications of missing supervision sessions and what they can expect from you and each other. For example, if a supervisee repeatedly misses supervision sessions, this might be considered an administrative or disciplinary issue, much as if an employee was repeatedly late filling out paperwork or getting to work. Also, if the supervisee does not provide the required videotape of a counseling session for review by the supervisor, the supervisor might need to take action, following the organization's policies for progressive discipline.

WALT: There are different methods that we can use, besides videotaping, that might work better for some clients or situations. We want to have an integrated supervision system, one that includes reviewing cases together; periodic review of our files, such as client progress notes and treatment plans; training that meets the needs of a variety of staff; and review of our client evaluation surveys. While I'm on that topic, we also want to receive more input from clients about how we're doing. There's a new tool we hope to incorporate that routinely asks for input from clients after each counseling session, and at the end of each day for our residential units.

AL: I have reservations about how useful information from clients might be. After all, for clients in early recovery, their brains are still foggy.

WALT: Good point Al. If we ask clients regularly, though, we should get useful information about our ability to address clients' needs and the quality of our relationships with them. This is helpful information when we link it to our direct observation and supervision. Sort of like watching a TV program and getting the Nielsen Ratings about the show at the same time.

[Laughter.]

[In the discussion that follows, Walt acknowledges Al's concerns, and Al, Carrie, and Walt talk about those concerns. Walt asks how they can get past those concerns, how they can work together to have further client input into the process.]

[image] Master Supervisor Note: At times it is necessary for a supervisor to openly address staff resistance. The skill is in knowing when to address and when to deflect the resistance. Sometimes, it is useful to talk about staff resistance, to soothe people's discomfort before launching into the specifics of how supervision will be accomplished. MI suggests that it is most helpful to “roll with resistance” by reflecting back to counselors both sides of their ambivalence about the new supervision format. Often it is best to return to the issue at a later time.

WALT: And that's what we want to see happen with an integrated system of supervision. It will help us identify what we need to learn, the skills and competencies. To start the process, each of us will bring in a counseling session that we think is going well, that we feel good about. How does that sound to each of you?

CARRIE: I like that: a chance for each of us to “show off” a bit.

AL: Well, if you go first, Walt, as you said. I'll go the week after Carrie. I have all kinds of sessions where I'm doing a good job.

[Laughter.]

CARRIE: I found it helpful in grad school for us to help each other, to avoid throwing anyone into the process alone. Will that be possible for us?

WALT: That's a great idea, Carrie. How did peer supervision work in grad school?

[Carrie discusses how peer supervision and team coaching work.]

[image] Master Supervisor Note: Peer supervision is an effective form of group supervision. Supervisees confer in the group, discuss key topics of their counseling, and suggest solutions for difficult situations. The participants learn better ways to manage clinical issues, thus increasing their professionalism.

Peer supervision and team coaching have the following advantages and disadvantages:

1. The strengths and success of peer group supervision depend on the composition of the group, the individual members' strengths, and the clarity of the peer group contract. Members must agree on the time, location, and frequency of meetings, as well as the organizational structure and goals of the meetings and limits of confidentiality. In these dimensions, peer supervision differs from occasional and unplanned peer consultation, a more informal process.
2. Peer group supervision decreases professional isolation, increases professional support and networking, normalizes the stress of clinical work, and offers multiple perspectives on any concern. Peer supervision has the added benefits of being of low or no cost, intellectually stimulating, and fun for supervisees.
3. Vague, ambiguous, or ambivalent goals and structure often lead to difficulties in peer supervision. As with individual or clinical supervision, an interpersonal atmosphere of reasonable safety (including respect, warmth, honesty, and a collaborative openness) are critical.
4. Effectiveness and supervisee enjoyment diminish when competitiveness, criticism, inconsistency of members, and absence of support are prevalent.
5. The success of peer group supervision is affected by supervisees' varying commitment and irregular attendance.

WALT: So, we've identified how this works. This is a new role for me, too, so I can use your feedback and suggestions. Supervision involves a different set of skills than being a counselor.

CARRIE: Right. I took a course in school on clinical supervision and that's exactly what the professor said.

How To Choose a Course on Clinical Supervision

[image] Look for the following components:

1. The training should be approved by credentialing organizations to fulfill the requirements for certification as a clinical supervisor.
2. It should meet the minimum training requirements of 30 hours.
3. The training should be provided by a trainer with the following skills: Level 3 counselor, Level 3 supervisor, excellent training experience, and ability to provide information on both administrative and clinical supervisory issues.
4. The training should teach practical clinical supervisory skills through roleplays and demonstrations, video- and audiotapes of supervision sessions, and opportunities to practice clinical supervisory skills.
5. The training should be provided by a reputable training individual or organization.
6. Online courses are also available. However, an organization should first verify if online courses are approved by their State certification board.

WALT: Let's summarize what we've said. We're moving into new treatment program strategies. Each of us has an Individual Development Plan (IDP) stating our individual learning goals. Mentorship is an important aspect of helping us all meet our IDP goals.

[Walt describes the process of mentorship, that each staff member will have a mentor. Some staff will mentor each other. Walt discusses the relationship between the IDPs, clinical supervision, and the mentorship system. Walt also discusses the issue of stages of readiness and how that affects the form and extent of mentorship each person will receive.]

[image] Master Supervisor Note: Mentorship is a formalized relationship between a skilled professional and a mentee and is established to enhance the mentee's career by building skills and knowledge. In a series of structured sessions, a person of greater experience instructs, guides, advises, provides feedback, and coaches someone of lesser experience.

WALT: One of my tasks is to ensure that all of us get training so that any one of you could take over for me if need be. I love to surround myself with people who can take over my job on a given day.

CARRIE: I'd be happy to both be mentored and serve as a mentor to others, if that's what you wish. I'm feeling a lot better than when we began this discussion today.

[Walt starts a discussion on clinical issues that might be topics for discussion in supervision, such as caseload size and complexity, work with clients with co-occurring disorders, the impact of dual relationships with clients, and confidentiality. The session ends with the group establishing the times for their group supervision and the procedures for tape review and live observation.]

## Vignette 2—Defining and Building the Supervisory Alliance

### Overview

This vignette illustrates the tasks of defining and building a supervisory alliance, particularly when working with an entry-level counselor with an academic background different from that of the supervisor. The dialog is the initial supervisory session. It illustrates how to introduce direct observation and the establishment of an IDP.

### Background

Bill is a certified clinical supervisor who worked his way up through the ranks, starting as a substance abuse counselor 20 years ago, 3 years into his own sobriety. Ten years ago he enrolled in a part-time master's degree program in counseling and completed the degree in 5 years. Since receiving his master's degree, he has worked as a clinician and supervisor in a community-based substance abuse treatment program. In addition to his supervisory duties, he is director of the program's intensive outpatient program (IOP).

Jan is in her first month at the agency, right out of graduate school. She is a Level 1 counselor, her first employment since receiving her M.S.W. She had limited substance abuse treatment experience in a field work placement and sees her current employment as a stepping stone to private practice after she receives her social work license. Her supervision in the field placement assignment focused on social work skills and integrating field work learning with her academic program. She averaged ten cases during her second year of field work.

The agency is a private, nonprofit organization providing comprehensive addiction treatment and education services. Jan has been assigned to the IOP and is expected to participate in a structured internship program of 3 months wherein she will receive training in the substance abuse treatment field. The agency has a well-established system for clinical supervision.

### Learning Goals

1. To illustrate how to initiate supervision with a new counselor.
2. To demonstrate how to establish a supportive supervisory relationship and build rapport.
3. To define goals and boundaries of supervision.
4. To demonstrate how to identify supervision expectations and goals of the supervisee.
5. To illustrate how to address the developmental needs of a new counselor.
6. To show the start of a discussion on an IDP.

[After brief introductions, the discussion begins about what will occur in supervision.]

BILL: We're excited to have you here, Jan. You may already know that supervision is an essential part of how we help counselors in the agency. Since this is our first session together, perhaps we can explore what you want from supervision and how I can help you. Building on your training and experience, maybe you can give me some ideas about the areas where you wish to grow professionally.

JAN: Well, I haven't thought about that yet. I had excellent training and experience at the EAP [Employee Assistance Program] in the county health clinic. I'm not sure where to begin or even what I need. I recognize the need for supervision, certainly for orientation to the agency. I'd like to know about how much supervision I'll get and the focus and style of supervision here. I also need supervision to meet the requirements for licensure as a social worker.

BILL: I can understand that you're really excited about starting a new job and career. You had an excellent experience in your placement at the health clinic. I'd love to hear more about it, so perhaps you might tell me something about that placement, what you learned, and what treatment models they used there.

JAN: Wow, there is so much to tell you about that. I averaged ten clients on my caseload. Some were just assessments, but I did get to work longer term with several clients. I sat in on several counseling sessions, observed the senior counselor conduct the sessions, and co-led a group and several family sessions. I had weekly clinical supervision with my supervisor and the senior counselors. We used process recordings in school and that was really sufficient because I would write the verbatim, give it to my supervisor, she'd make comments, and we'd talk about it. So I didn't really need to have her watch me work. I've heard from Margaret [another counselor in the agency] that in supervision you do direct observation of counselors here and that idea is new to me. Frankly, I'm not sure if I really need that. My model for counseling is eclectic, whatever is needed for the client. They used a lot of cognitive–behavioral counseling approaches at the EAP. I try to meet the clients where they are and focus my therapeutic approach to meet their needs.

[Discussion continues about Jan's experience at her placement and academic training.]

BILL: So, we have a good sense of your background and experience. If it's OK, I'd like to return to the earlier question about whether you have any thoughts about what you want from our supervision together.

JAN: I'm not sure. Do all counselors here get supervision and are they all observed? I'm not sure I need that observation, especially since the placement didn't do that.

BILL: I appreciate your concerns about supervision. All our counselors here receive supervision. Some agencies don't do much direct observation of staff, but we've found it very helpful for a number of reasons. Here, we see supervision as an essential aspect of all we do. We believe you have a right to supervision for your professional development. We have great respect for our counselors and their skills and also understand that we have a legal and ethical obligation to supervise, for the well-being of the clients.

[image] Master Supervisor Note: Notice how Bill is laying the foundation and rationale for why clinical supervision is essential to this agency. Whereas every agency needs to develop its own, unique clinical supervision approach, there are models and standards of clinical supervision, as discussed in Part 1, chapter 1, which seem to be most effective. Agencies might benefit from adapting aspects of these models.

JAN: So, everyone must have supervision and observation?

BILL: We take our legal and ethical obligations seriously. We want all of our counselors—even the most experienced ones—to grow professionally, to be the best counselors they can be, for their own development and for the welfare of the clients. As you probably learned in your M.S.W. program, vicarious liability is an emerging issue for agencies. Counselors are legally liable for their actions. Vicariously, so are the agency and the supervisor.

We need to make a “reasonable effort to supervise.”

JAN: OK, so what do you expect of me?

BILL: I'd like to explore that with you. I'm really interested in both what you expect of yourself and what you expect of us.

JAN: Again, I never really thought about that. I want to grow as a counselor and to develop skills that I can use in my future employment. I understood when I took this position that you do an excellent job of providing training opportunities for staff, something I really liked about the organization.

BILL: In our agency, clinical supervision is part of a larger package of staff development efforts. We try to help counselors improve their skills by offering the opportunity to work with a variety of different clients, using a variety of treatment modalities, such as individual, group, couples therapy, family therapy, and psychoeducation. Also, we want staff to be able to obtain their social work or substance abuse license or certification in the future. We want counselors to develop new skills by attending training both in-house and in workshops around the State. We encourage and support any efforts you might make toward professional development, such as getting your various levels of social work licensure. Our philosophy is that one of our greatest assets is our clinical staff and as they develop, the agency grows too. We believe clinical supervision is critically important in this mix. We both—you and the agency—benefit as a result.

[A discussion continues about Jan's course work in school and her training in the field placement, and how she can continue that learning in the agency. She articulates her clinical strengths.]

BILL: That sounds good. Those are the skills we saw in you that we thought would be helpful to our agency. In what ways do you wish to grow professionally?

JAN: I could learn other counseling techniques beyond CBT. What do you think I need?

BILL: That's what we can explore in supervision. I'll need to have a sense of what you've learned and where you see your skills. In addition to talking about your skills, we find it helpful to learn through observation of our staff in action, by either sitting in with you on a session or by viewing videotapes of counseling sessions. That way, we can explore your specific learning objectives. We all learn from watching each other work, finding new ways of dealing with clinical issues. What do you think of that process?

JAN: As I said, I wasn't observed in my placement and find it anxiety provoking. I don't really like the idea of your taping my session. It feels a bit demeaning. After all, I do have my M.S.W. I don't recall anyone saying anything in my interview about being videotaped. Now, that's intimidating, to me and the clients.

BILL: Being anxious about being taped is a fairly common experience. Most counselors question how clients will accept it. You might speak with Margaret and some of your other coworkers about their early experiences with taping, what it was like for them, and how they feel about it now.

JAN: How often do we have to meet for supervision?

BILL: Generally I meet each counselor individually for an hour each week. Then we do weekly group supervision where each counselor, on a regular basis, gets a chance to present a case and videotape, and we, as a group, discuss the case, and talk about what the counselor did well and how other things might have been handled differently. When you present a case, we all grow and benefit.

JAN: I want to be a proficient therapist, ultimately, to work as a private practitioner. If supervision can help me professionally, that's good.

[image] Master Supervisor Note: It is important for Bill to be aware of what feelings are arising within him, particularly concerning Jan's seeming desire to pass through and use the agency as a route to private practice. This has happened to Bill and the agency before. Bill acknowledges to himself his feelings of being used by these clinicians in the past. Bill's self-awareness of these feelings is critical and he does not respond out of anger or resentment but makes a conscious effort to remain present to what the issues are with Jan.

BILL: I'm glad you see the value of supervision. And I admire your professional goals of wanting to be in private practice although I must say that I have difficulties with people just “passing through our agency” on the way to something else. But, that's my issue, and I'll address those concerns if they come up in our relationship.

[image] Master Supervisor Note: In his own supervision, Bill might explore his feelings about people passing through the agency, his anger or resentment, and how he can effectively address those feelings. For example, Bill's supervisor might wish to explore with Bill the following questions:

1. What feelings does Jan bring out in you? When have you had these similar feelings in the past?
2. How do you deal with negative feelings about a supervisee?
3. How do you keep from being drawn into a defensive posture where you are justifying the agency's use of direct methods?

JAN: Will I be criticized by others, perhaps those without as much formal training as I have? I understand you have several nondegreed counselors here—certified addictions professionals, with lots of life experience but without advanced degrees.

[image] Master Supervisor Note: A Level 1 supervisor might respond angrily here. A Level 2 supervisor might get into an argument about the quality of counselors at the agency. Bill, as a Level 3 supervisor, does not react to Jan's seeming criticism of the nondegreed counselors. He responds in a supportive but direct manner, as you will see. But perhaps Jan is making this comment in response to Bill's previous statement that he has “difficulties with people just passing through” and this is another reason for Bill to address this in his own supervision.

As discussed in Part 1, chapter 1, just as there are levels of counselor development, there are also levels of supervisor development. Level 1 supervisors might have a tendency to be somewhat mechanical in their methods, perhaps needing to assert their leadership and position, and approaching situations somewhat anxiously. This is especially so for supervisors who have been promoted from within the organization. Their peers, with whom they have worked side-by-side before, know they do not know their strengths and limitations, and hence the new Level 1 supervisor may feel that she has to assert her authority (see vignette 6). A Level 2 supervisor is much like the Level 2 counselor, who is driven by alternating anxiety and self-confidence and who feels the need to be independent, even though she might not as yet be able to act independently. Finally, Level 3 supervisors have balanced their levels of self-awareness, motivation, and autonomy. For further descriptive information on levels of counselors and supervisors, see Part 1, chapter 1, pp. 9–11.

BILL: Perhaps it would be a good idea if you began by observing in one of my groups. Then, when you're feeling more comfortable with it, we can discuss what times work best for you to be observed, and what cases you'd like me to observe. This will give you time to schedule the observation. The first time, maybe I could sit in when you're working on a case that you have confidence about so we can see how you accomplish the session's goals.

JAN: OK, that makes sense to me. I like the idea of talking to others and getting their impressions of the process and their suggestions on how to best make it work.

BILL: We also need to develop a learning plan for you, an IDP that all staff have, so that you can continue to learn. That's part of a supervision contract that we work on together. How does that sound?

[image] Master Supervisor Note: It is important to develop an IDP for each supervisee, and counselors should understand why an IDP is important for the supervisory relationship. Jan's IDP might focus on:

1. Increasing her understanding of addiction by reading texts on the subject and beginning the credentialing process.
2. Discussing this material in supervision, in reference to clients in treatment.
3. Finding a social worker within or outside the agency who can assist her in fulfilling the requirements for her social work licensure.
4. Beginning direct observation of her counseling sessions within 2–3 months with monthly videotaping and discussion of a session.

JAN: It will be a new experience for me but it sounds like it might be helpful. I'd appreciate your helping me look at my skills and growing as a social worker in substance abuse treatment.

BILL: I'll provide you with as much background in substance abuse treatment as I can and also try to help you develop as a social worker to meet your career goals.

[image] Master Supervisor Note: Bill is working with Jan to establish a supervisory alliance, through listening, reflection, and mutual goal setting.

JAN: Good. I hope it will broaden my skills and further my career goals. I can learn more about working with clients' substance abuse. I think I can learn from people in other disciplines.

BILL: Although each discipline has its unique perspective, we have a multidisciplinary team approach and value each staff member's contributions. We teach one another. For example, Margaret has worked in this unit for 10 years and has a lot of experience working with the kinds of clients you'll be treating. She is a useful resource for you to use to improve your skills so that you can be successful here and in your career. How will that work for you?

JAN: I've heard about Margaret. People have a high regard for her clinical skills. So I'm sure I can learn something from her. I still would like some more details about how the supervision works, who else is involved, and how do we do this together.

BILL: We do individual observation and group supervision where we find common issues in our counseling, using videotape and case presentation to trigger discussion of related issues. Everyone learns from the presenter's experience. Each counselor takes a turn presenting a case, including a videotape. We can cue the tape to the session segment you want us to discuss. After your brief introduction of the case, we discuss how the session went, what skills were effective, and what areas might be further developed. How does that sound?

JAN: That sounds great. Can I come to you at other times to review cases, especially while I am learning the ropes of how things are done here?

BILL: Yes. I appreciate your wanting immediate feedback. I have an open-door policy. Although I may look busy, I'll try to find time when we can discuss whatever you want. You can also meet with others if you feel comfortable doing so. We encourage teamwork. Does that seem reasonable?

JAN: Yeah. I'm pretty autonomous at this point. I think it's great that there are other counselors and social workers I can collaborate with. It will be really helpful for me especially since I'm new at the job, and it's good to be able to work together. I'm OK with supervision, and I like the fact that we're both going to have an agenda, so that's fine.

BILL: So, let's go back to your experience. I'd love to hear more details about your internship and what you learned there.

[Jan explains her work experience in her internship.]

JAN: In my second year I was at an EAP clinic. I had a great supervisor, Jackie. Several of my clients were alcoholics, my first introduction to substance abuse. There was something that attracted me, to understand more about the disorder and to contribute what I was learning in social work. Jackie was a social worker and a really good role model. I need to understand more about substance abuse treatment, and try to marry the social work and substance abuse fields.

[Bill and Jan continue to discuss her experience with supervision, what worked best, what she found most useful and supportive.]

JAN: I'm a little worried about how I'll meet my licensure requirements about being supervised by a social worker. Will that be a problem for me?

BILL: Not at all. Margaret is an LCSW and we can ask her to provide the supervision you need for social work licensure. This will allow Margaret to develop her supervision skills. I also think that an important part of developing a professional identity is receiving coaching from an experienced person, and perhaps Margaret can assist in that area too.

JAN: That sounds fair and helpful.

BILL: You mentioned that Jackie was a good supervisor. Can you tell me what she was like and what she did that made her a good supervisor?

JAN: She was really smart. I could learn from her. When I went to talk to her she always gave me good advice. She trusted that I knew what I was doing and didn't micromanage me. She was open about her theories and made linkages to issues. She trusted me to just go ahead and implement what I learned. She was easy to talk to. If I had a problem, I could say so.

BILL: It sounds like Jackie and I have a similar orientation as supervisors, and that should make the transition easier. I hope you'll observe from your perspective how the supervision is developing, and give me feedback on the relationship, the process, and the outcomes from your point of view. Our first step will be to expand your training by introducing you to a broad range of substance abuse issues. Perhaps at our next session we can start developing a learning plan to apply your studies to clinical work. What do you think of that?

How To Write a Supervision Contract

[image] The following elements might be included:

1. The purpose, goals, and objectives of supervision.
2. The context of services to be provided.
3. The criteria and methods of evaluation and outcome measures.
4. The duties and responsibilities of the supervisor and supervisee.
5. Procedural considerations.
6. The supervisees' scope of practice and competence.
7. The rewards for fulfillment of the contract (such as clinical privileging or increased compensation).
8. The frequency and method of observation and length of supervision sessions.
9. The legal and ethical contexts of supervision as well as sanctions for noncompliance by either the supervisee or supervisor.

JAN: That'd be good. I like that you're interested in my experience, about who I am. I'd like to know a bit about you. Jackie would talk about who she was, her model of supervision, and why this work was important to her. I felt I could trust her because I knew where she was coming from. Would you tell me more about yourself?

Bill: I'd be happy to.

[Bill provides an overview of his work, academic experiences, and primary model of counseling and supervision.]

JAN: I have a beginning understanding of the type of supervisor you are. I like that you're direct so I don't have to guess at the agenda. So, we'll work on a training plan and I'll suggest times for you to observe a session and videotape. Is that correct?

BILL: That seems fair and clear. Any other concerns we should talk about today?

[Further discussion follows about Jan's anxiety about supervision. They discuss how supervision would work to help reduce her anxiety about being scrutinized and critiqued.]

BILL: So, although you're a bit nervous about the process, you're ready to begin. We'll start with your observation of me to give you an opportunity to get your feet wet. Then you can tell me when you're ready for me to come in and observe, maybe in the next 6 or 8 weeks.

JAN [jokingly] I think sometime in the next 6 months.

[image] Master Supervisor Note: As a Level 3 supervisor, Bill doesn't react to this comment. A Level 1 supervisor might respond by saying “The timeframe is not negotiable. You'll begin the observation in 6 weeks.” Another response might be to avoid the issue without affirming her. When she is noncompliant after 6–8 weeks, he'd blame her for her lack of follow through. Such responses might negatively affect the relationship. A supervision of supervision issue might be to explore what was happening for Bill and his possible ambivalence about Jan.

BILL: Thanks for your willingness to begin and try the process.

JAN: OK. So, I can pick the client?

BILL: Yes. You can pick the client or group. We'll meet every week for about an hour.

[Bill and Jan set the time for the next supervision session and discuss what is expected for the next session and end the discussion with both excited about the process.]

## Vignette 3—Addressing Ethical Standards

### Overview

This vignette illustrates the role of the supervisor as a monitor of ethical and professional standards for clinicians, with the goal of protecting the welfare of the client. The vignette begins with a discussion about a potential ethical boundary violation and illustrates how to address this issue in clinical supervision.

### Background

Stan has provided clinical supervision for Eloise for 2 years. He's watched her grow professionally in her skills and in her professional identity. Lately, Stan's been concerned about Eloise's relationship with a younger female client, Alicia, who completed the 10-week IOP 2 months ago and participates weekly in a continuing care group. Alicia comes to the agency weekly to visit with her continuing care counselor. She also stops by Eloise's office to chat. Stan became aware of her visits after noticing her in the waiting room on numerous occasions. Earlier in the day, Stan saw Eloise greet Alicia with a hug in the hall and commented that she will see Alicia “at the barbecue.” Stan is aware that Alicia and Eloise see each other at 12-Step meetings, as both are in recovery. Eloise feels she is offering a role model to Alicia who never had a mother figure in her life. Eloise expresses no reservations about the relationship. Stan sees the relationship between Eloise and Alicia as a potential boundary violation.

### Learning Goals

1. To illustrate monitoring professional boundary issues of counselors in clinical supervision.
2. To demonstrate supervisory interventions to help the counselor find appropriate professional boundaries with clients.
3. To help counselors learn and integrate a process of ethical decisionmaking into their clinical practice.
4. To demonstrate skills in addressing transference and countertransference issues as they arise in clinical supervision.

[After brief introductory comments, the discussion begins with how Alicia is progressing in her recovery.]

STAN: If it's OK, I'd like to share some concerns I have about Alicia.

ELOISE: Sure, I'm always ready for feedback.

STAN: When I walked through the lobby a few minutes ago I heard you say something to Alicia about seeing her at a barbecue.

ELOISE: Right. Sarah is one of my sponsees in AA, and we're having a barbeque at her house for some people in recovery. She and Alicia have gotten really close, so Alicia will probably go, too.

STAN: And that's a barbecue you might be attending?

ELOISE: Yeah. I'm fairly active with all my 12-Step friends and sponsees.

STAN: I would like to raise a concern I have about your relationship with Alicia. You take great pride in working with recovering people, helping them, and doing everything you possibly can to ensure their recovery.

ELOISE: Yes, it means the world to me. Alicia reminds me of myself when I was in early recovery. When I see her and how hard she's working, it inspires me because I know that struggle.

STAN: I'm pleased that you care so much about your clients and that you can identify with their struggles. I do have concerns though, when I hear you are going to see her at a barbeque. It seems like a possible dual relationship issue for you, and I would like to know what you think about this?

ELOISE: Well, I certainly know not to sleep with my clients, or borrow money from them, or hire them to mow my lawn, or take them on trips. But seeing Alicia at a barbecue? Come on, Stan.

[image] Master Supervisor Note: At this point Stan might be feeling somewhat defensive and may need to restrain his urge to begin disciplinary action against Eloise for her attitude. A Level 1 supervisor might react angrily to Eloise's tone of voice, seeing this as a clear disciplinary issue. A Level 2 supervisor might get caught up in an argument with Eloise about the extent of the violation. The skill of a Level 3 supervisor is to be clear with Eloise about what a dual relationship is without responding out of anger. As shown below, Stan needs to help her identify what a boundary violation is, how to make ethical decisions, and how to have this discussion in the context of a supportive supervisory relationship. It is important for Stan to help her be more aware in future situations with similar clients and dynamics.

STAN: I'm glad we agree on those kinds of extremes because dual relationships are a big concern of our agency and staff. A dual relationship occurs when a counselor has two relationships with a client, one personal, one professional. Our mission is to provide professional clinical services to clients. Within those services there is a scope of practice. When a personal relationship with a client or former client intrudes on that professional clinical service, then we may have a relationship that is considered outside the parameters of what's considered solely professional.

ELOISE: What I understand about dual relationships is that it … well, help me here. For example, I know I'm not supposed to hire anybody for any personal services or any form of exchange of money or buy anything from a client. If they've been a client here, I can't contract with them for private practice or anything like that.

STAN: Let's talk about your relationship with Alicia and what the intent is now. You want to do everything you can to build a safety net for her recovery. I appreciate your concern for her recovery. One goal of recovery is for the client to achieve a sense of autonomy and make decisions on her own, to take care of herself. You play a role. So, if we can, let's discuss what that professional role is, and what it isn't. When I walked through the lobby and heard you say “I'll see you at the barbecue,” I had some concerns.

ELOISE: You mean I shouldn't say that in a public place?

STAN: My concern is whether going to a barbecue with a client is appropriate behavior, to have a relationship with her outside your professional relationship as defined by our agency. When I heard your remark, I thought, “I wonder what Eloise's intent was and where that's going or what might that lead to? Let me check it out to see if I am being clear.”

ELOISE: Are you saying I shouldn't see clients in other contexts? How reasonable is that? We live in a small town here and run into clients all the time in the supermarket and at 12-Step meetings. So what are you saying?

[image] Master Supervisor Note: There is a difference between a dual quality to a relationship and a dual professional and personal relationship. Dual qualities are inevitable in certain communities. A dual relationship has the potential for the abusive use of power, where harm might be done to the client through manipulation or inappropriate self-disclosure. Actions in one context might be acceptable, whereas in another they might be harmful. A skillful supervisor would help Eloise see this distinction and help her be better able to make sound ethical decisions concerning the line between dual qualities and dual relationships.

STAN: Great observation. Yes, we find ourselves in situations that potentially have a dual quality to them. The difference between running into clients in the supermarket and going to social activities together involves the potential impact that action might have on the client and our use of the power we have in the relationship. You were her counselor.

ELOISE: Yes, but I'm not her counselor anymore. She's in continuing care now.

STAN: Okay, but she's still a client of the agency. The ethical question is how long is a client a client? According to our substance abuse counselor's code of ethics, once a client, always a client in terms of our professional responsibilities.

ELOISE: Yes, but she just stops by when she's here. She pops in just to say hi, for not more than 5 minutes. I don't counsel her anymore.

STAN: Okay, that might be reasonable. Perhaps we can discuss that relationship and the impact of seeing her outside the agency at functions.

ELOISE: Well, she goes to the women's AA meeting that I go to. And she knows some of my sponsees. What should we do, leave our home group because clients attend the meetings also?

STAN: It is inevitable that we will run into clients at meetings. When does that cross over the ethical boundary and become a dual relationship? I'd like to hear your ideas about where you see that line for you.

ELOISE: I don't want to do the wrong thing, Stan, to hurt her. My intent is to be helpful.

STAN: Again, I know you don't want to hurt her, and I know you're trying to help her in her recovery. We have to be mindful of not being drawn into relationships that hurt the client or that could be perceived as dual relationships.

ELOISE: She doesn't call me or come see me. I want you to know I'm not sponsoring her. But I didn't know that going to the barbecue was wrong. So, I won't go.

[image] Master Supervisor Note: Stan really wants to keep the focus on the larger issue of dual relationships. Once Stan and Eloise have clarified this larger perspective, then it might be more appropriate to come back to the specific issue of the barbecue. A more inexperienced supervisor might be tempted to just establish the boundary about socializing with clients with a comment like “That would be a wise decision (not to attend the barbecue)” but would possibly lose the potential of helping Eloise develop more effective ethical decisionmaking skills in the process. It would, in effect, run the risk of making the decision for Eloise, rather than helping her come to an ethical decision on her own.

STAN: With your permission, perhaps we can talk about how we make ethical decisions about the nature of a relationship with a client or a former client, and what's not professionally appropriate. If it's okay, let's use the conversation with Alicia in the agency lobby. How do you think that conversation might be perceived by anyone who is walking by who hears you say you'll meet at the barbecue?

ELOISE: I've never really thought about it. Well, I guess if it was someone who didn't know me, they might think that I was personal friends with her. That's not a perception I want others to have.

STAN: So, you want others to see you as a professional, upholding boundaries and your code of ethics?

ELOISE: Yes, of course.

STAN: I reread the code of ethics to help evaluate whether or not there might be an issue. I was reminded of the power differential in all counseling relationships and that as professionals in our field we need to be careful to not engage in social relationships (or relationships that might be seen by others as social relationships) with clients or former clients. You may recall we recently had a lawsuit over dual relationships that put the agency in jeopardy. It got resolved in our favor but we're particularly sensitive about our liability. It was a wake-up call to all of us. So how can we clarify this boundary issue with your relationship with Alicia?

ELOISE: Wow, I never saw going to the barbecue as pursuing a friendship, and I certainly would not want to jeopardize our agency's relationship with her. I certainly don't seek any personal gain from our time together. Although I must admit, she does remind me of myself when I was in early recovery. Besides, she has never had a strong, positive, maternal figure in her life. That's something I think I can help her with. What do you think?

STAN: I admire your concern for her and it sounds like you are becoming aware of some maternal feelings for her that might be coming close to stepping over that professional boundary. When our relationships with others, and particularly with clients or former clients, begin to even have the possibility of affecting their recovery in a potentially negative way, then we might be edging close to an ethical boundary violation.

ELOISE: I understand, but part of my recovery program is being in touch with other people in recovery, other people from meetings, like Alicia.

STAN: I agree. It's important for your own recovery that you stay connected to other people in recovery. So, the question is: What's the difference between seeing people in recovery at meetings, such as your sponsees or your sponsor, and relating to clients active in treatment at our agency whom you encounter at a meeting?

ELOISE: Do I have to cut off all my recovery relationships and not go for coffee after meetings?

[image] Master Supervisor Note: It is important for supervisors to take into account cultural variables that might affect clinical relationships, such as differences in ethnic, religious, and geographic factors and their impact on the counselor–client relationship. This is not to condone unethical behavior but to be mindful of cultural issues as they affect the context of counseling. For example, in some Latino cultures some form of socializing may be expected. In Asian cultures, it is not uncommon for a client to ask the counselor personal questions as a means of establishing trust. Skillful supervisors assist counselors in understanding cultural variables while continuing to make sound ethical decisions.

STAN: I understand the dilemma we find ourselves in as counselors. We have to go on living our lives in our small rural community. So, how do we reconcile our daily lives with the Federal laws, agency policies, and our code of ethics? We need to be mindful of those boundaries just because of the closeness of our community. The interesting thing is that the clients are not bound by the same rules as we are. So, they might not see it as a boundary violation. In fact, as often as not, clients and former clients are flattered by contact with their current or former counselor and invite such relationships. How will we reconcile these differences? How do we know what the ethical wall looks like before we hit it?

ELOISE: Well, I guess we need to be careful about what contexts we see clients in, whether they are actively being counseled by us or not. Is that what you're saying?

STAN: Yes, we do need to be mindful of the various relationships we develop with clients. I'd like to use the barbeque as an example to discuss. Okay?

ELOISE: Sure. First, I have six sponsees. They've all been in recovery for different lengths of time, and they like to get together every 3 months, all six of them, and do some kind of activity. And they invite over a bunch of people from the 12-Step group. Sarah was having this barbecue and asked me because we go to the same home group. She also invited Alicia. I'm not sponsoring Alicia. Does that mean I can't go?

How To Perform Ethical Decisionmaking

[image] Stan's task here is to help Eloise identify potential boundary issues in a broader context and aid her in her ethical decisionmaking. The following are steps to ethical decisionmaking:

1. Recognize the ethical issues by asking whether there is potentially something harmful personally, professionally, or clinically. In what way might this go beyond a personal issue to the agency, the profession?
2. Get the facts. What are the relevant facts? What facts are unknown to us at this time? Who has a stake in the decisionmaking? What are the options for action? Have all of the affected parties been consulted?
3. Evaluate alternative actions through an ethics lens. Which options will produce the most good and least harm? What action most respects the rights of all parties? What action treats everyone fairly?
4. Make a decision and test it. If you told someone you respected what you did, how would they react?
5. Act, then reflect again later on the decision. If you had to do it all over again, how would you react differently?

STAN: It might help to ask yourself what happens for you when you find yourself in such a dilemma, to be your own problemsolver.

ELOISE: Well, it's hard to not go to social activities in this small community when I'm invited. But I can see how some might see me in a different light because I'm a counselor. At one party, someone came up to me and started to ask questions about problems in their marriage. I guess she figured that since I'm a counselor, she could get some free assistance. I was really uncomfortable in that situation.

STAN: What did you do?

[image] Master Supervisor Note: At this point Stan might:

1. Have Eloise consider her own solution.
2. Use her solution in a dialog to expand the context so she can generalize the solution to other situations she may encounter.
3. Conclude with Eloise's restatement of what she has learned for the future from this discussion.

ELOISE: I told her I could not be her counselor and was there at the activity in my “civilian” clothes. [Chuckling.] Ah, I see what you're getting at. It's hard to be in two relationships, a professional and a personal one, with the same person. And I can see what you mean by how a reasonable uninvolved person might view this situation. At the party, when that woman wanted free counseling, it was clear that that was not the context or the relationship for that. That's unprofessional. But Alicia is different.

STAN: So, you see that it is unprofessional to counsel someone outside of a professionally defined relationship. I'd like to hear how it is different with Alicia.

ELOISE: Well, I really care for her. She reminds me of myself when I was younger. I am the mother she never had. I feel bad for her that she's never had a positive female, maternal role model in her life.

[Eloise cries as she expresses her concern for Alicia.]

STAN: This is difficult for you. You care very deeply for her. I can understand that in some ways she reminds you of yourself at that point in your recovery.

ELOISE: Yes, she does.

[Her crying continues, and Eloise speaks of her concern for Alicia. After a few minutes, the two sit quietly.]

ELOISE: The last thing I want to do is to hurt her or to act in an unprofessional manner.

STAN: I value your concern for Alicia and your desire to be professional. It is difficult when we care so deeply for our clients. We're asked to show empathy and caring for clients, and sometimes it can be confusing if we care too deeply. It's like, as caring professionals, we're always living close to that ethical slippery slope. We can retreat into “professional white coats” and separate ourselves emotionally from clients. But that turns counseling into a sterile activity, and we're detached and removed from their pain. But, when we care deeply, we are drawn into the emotional world of our clients. And the boundaries can become fuzzy for us.

ELOISE: I see what you mean. I guess we can rationalize a lot of our behavior when we care so deeply. We call that enabling behavior, don't we, when family members do that with the person in substance abuse treatment? So, how do we walk close to that ethical slippery slope without falling over the edge?

STAN: That's an excellent question. Ethical decisionmaking can be difficult at times. Intent is an important part of ethical decisionmaking.

How To Ask Questions in Ethical Decisionmaking

[image] The following are key questions to ask at this point:

1. What would a reasonable person, counselor, or colleague do in a similar situation?
2. What are the relevant issues regarding justice, fairness, self-advocacy, non-malfeasance?
3. How would a person discern his or her intentions? How do you keep yourself from self-deception about your motives, remembering that the best test for your motives is time?

ELOISE: What do you mean by “intent?” It was my intent with Alicia to be helpful, certainly not to hurt her in any way or to be disrespectful of our agency or of me as a professional.

STAN: When we commit to a professional relationship with a client, there is always a power differential. When someone like Alicia comes with her need for a maternal figure, as you well described, we need to be careful of our role in offering to fulfill that need. The power differential alone can create some opportunities for people to misperceive what's going on. What do you think?

ELOISE: Can it be that I took advantage of her because of my own need to be a mother figure in someone's life?

STAN: That is always a risk we have. It could be perceived that way.

ELOISE: I feel bad that I wasn't being very professional with her and my own needs came out.

[image] Master Supervisor Note: It is important to remember the power differential between supervisor and supervisee. How might key audiences (colleagues, the community, board of directors, the press, peers) see or experience the counselor's behavior? What is the risk? There are many stakeholders involved who each view the situation from their own perspective. For example, stakeholders (such as the board of directors) might be concerned about the risks of legal liability for the agency, the media and community with the public image of the organization, and peers with the clinical implications of a possible boundary violation.

STAN: That's a key insight. It's great that you could step back from the situation and see how your caring deeply for her spilled over in other ways.

ELOISE: You think I had power over Alicia?

STAN: As I said, when you're a counselor to a client, there is always a power differential that we have to be very cautious and very aware of. It may not be something we do so much as the power that the client gives us. Now, if it is okay with you, I'd like to summarize a little.

[Stan and Eloise review what has been discussed and what actions might be appropriate for Eloise to take at this point. They express their concerns about Alicia and how she might be hurt if Eloise abruptly cuts off the relationship with Alicia. They strategize on how to best handle the situation in a way that would be clinically supportive of Alicia.]

STAN: I want to talk a little about ethical decisionmaking and how we can keep within certain guidelines. There are some questions to be asked, such as how that behavior is experienced by someone else. How would your actions be perceived by colleagues, the community, a supervisor, and clients?

ELOISE: I appreciate your saying that; I need to think about it. It makes sense.

STAN: I'd like to review what we've discussed and your understanding of the issues.

ELOISE: I have a clearer understanding of how my relationship with clients after they're discharged is as important as when they are my active clients. I need to think and give more consideration to how that's perceived, to consider my role with clients from their perspective. In my relationship with Alicia, I've thought of myself primarily as a recovering person, but I need to remember that she may perceive me primarily as her counselor. In other words, I am wearing two hats—a counselor and a person in recovery—and I need to be clear which hat I am wearing and when those hats are on.

STAN: So you have a sense of the potential conflict of interest depending on what hat you're wearing and how that might be perceived.

ELOISE: Yes. I need to think about how that reflects on the agency and how the community sees it.

[The supervision session ends with Eloise making a commitment to rethink the relationship with Alicia and strategies for making ethical decisions in the future.]

## Vignette 4—Implementing an Evidence-Based Practice

### Overview

This vignette portrays supervision of two counselors at different levels of experience and orientation to implement an evidence-based practice (EBP) into their clinical work. Both counselors have reservations about adapting the way they practice and have some resistance to undertaking the new EBP. The clinical supervisor has to address their resistance while achieving the mandate of the agency.

### Background

The executive director (ED) of a mid-sized substance abuse treatment program has issued a statement to all staff that, according to State requirements, the agency must incorporate EBPs, now a necessity for State funding. Therefore, the ED has directed the three clinical supervisors to begin the implementation of MI as a primary treatment method for treatment staff, first on a pilot basis then agency-wide. Gloria, one of the supervisiors, is meeting with Larry and Jaime, two program counselors, to discuss implementation of MI with their clients. Both Larry and Jaime are aware of the mandate but have not had an opportunity to discuss the change with Gloria until their regularly scheduled supervisory session this morning. Both have, in the last year, expressed some resistance to undertaking a new treatment approach when they were required to attend MI basic training.

### Learning Goals

1. To demonstrate leadership by a clinical supervisor toward meeting agency goals and mission.
2. To demonstrate leadership in the face of staff who are resistant and reluctant to incorporate EBPs into their counseling.
3. To model MI in the supervisor/supervisee relationship.
4. To illustrate fostering a spirit of learning and professional development among counselors.
5. To illustrate how a clinical supervisor can help counselors build new clinical skills, especially those that are science-based practices.
6. To understand the resistance and impediments in the field to the implementation of EBPs.

GLORIA: I know you have some reservations about the MI implementation program. Today I want to spend time discussing your reservations and how MI can be good for our clients and for the agency. You have both done a tremendous service for our programs. We want to be responsive to your needs, not just impose something on you. When you've been doing a good job and you know that what you're doing works, it's hard to take on something new that you're uncomfortable with. I know that you're concerned that taking on something new could, at least initially, potentially interrupt the normal flow you have with clients.

So, there are several things that I think are important for us to consider today. First, let's review why we are implementing MI for staff as a tool in their counseling. Perhaps we can explore any concerns you might have, then review why it is important to implement MI.

Second, let's look at your concerns about how those changes might affect client care.

Third, let's focus on how we can keep the strengths you have with your clients and be sure they don't get lost in the transition process. One of the beauties of MI is that it integrates well with what good counselors do naturally: active listening, respect for others' views, an appreciation of the role of resistance, good goal setting practices, and the like. Most important, MI aids in establishing and enhancing the therapeutic alliance between the counselor and the client.

Finally, I want to spend a little time talking about where we go from here and how we are going to make the implementation process as smooth as possible.

How To Introduce Changes in Clinical Practices

[image] Changes in counseling methods are difficult for staff who are attached to their model of counseling and know that it is working for them. When presenting new policies and directions to staff, it is important that you follow these guidelines:

1. Be respectful of staffs resistance. Instead of exhorting, arguing with, or threatening the counselor if they do not “play ball,” seek to understand the counselor's concerns with words such as “Yes, this is difficult. So how can we resolve the issue?”
2. Show respect for counselors and for the experience each brings.
3. Depending on the individual counselor, you may need to be flexible yet firm in your approach with staff who are expressing resistance to or ambivalence about change, being clear that the change is needed yet allowing time for the person to adjust and providing the resources needed to aid the counselor in making that change.
4. Recall when you were in the counselor's role and perhaps how you experienced resistance to change in supervision.
5. Consider using self-disclosure to address defensiveness with supervisees. You can either give an example from your own training or experience, such as, “I know it was difficult for me too when I was a supervisee,” or by describing your own ambivalence in the present, such as, “I also have concerns about the change we have to undertake and want to ensure that it works in the best way for clients, now—what can I do?” These self-involving statements can engage supervisees in the discussion and problemsolving.

LARRY: Well, Gloria, we've had the MI training, and I like its focus on active listening, the attention it gives to the relationship and respect for the client's perspective. But, you know, I'm basically a 12-Step facilitation guy. That works for me and for my clients. I don't see changing horses in the middle of the stream to achieve political correctness.

GLORIA: Your 12-Step approach works for you, and we heartily endorse it, too. 12-Step facilitation is an essential part of everything we do at the agency. And I definitely don't want to see us throw out the baby with the bathwater. As you know, counseling is an ever-evolving process, and I think our task is to be able to take what we do well and build on it with new approaches. I think MI can add to your repertoire. I think your concerns are realistic, and we need to consider that as we move into adopting new methods. What about you, Jaime?

[image] Master Supervisor Note: At times a supervisor might feel caught in the middle, representing policies and procedures coming down from funding sources, yet posing implementation difficulties. An effective supervisor plays this dual role of advocating for both administrators and leadership and the line worker and client. Whether working on a factory floor or in a clinical setting, it is difficult being in the middle. To aid you in this position, it is helpful to:

1. Understand the rationale of both administrators and line staff.
2. Never lose sight of where you came from. At some point in your career, you were a supervisee. It is useful to remember what it felt like being in that position.
3. In the example of MI, practice reflective and active listening to understand the concerns of those above and below, and to empathize with each group's concerns.

JAIME: All of this discussion is really above me. I just want my Latino clients to get good care and for their treatment needs to be respected. My clients need decent jobs and to be accepted as Latino men being sober in their community. That's what's important to me. I just want to serve my clients. I know that may not be what you want to hear, but that's how I feel.

[image] Master Supervisor Note: A Level 1 supervisor might respond either in a defensive or overly directive fashion here, telling Jaime that this is something he must do. A Level 2 supervisor might get into a struggle over what really matters, defending MI as good for Jaime's clients, or disrespecting his statement about what matters most to him, his clients. A Level 3 supervisor listens to Jaime's statement, affirms and supports him in that, and tries to engage Jaime in the discussion. Further, Gloria is working with two counselors at different levels of proficiency, so she has different expectations for their contributions and recognizes that they have different learning needs. An effective supervisor understands the stages of counselor development and varies the approach depending on the stage of each staff member.

GLORIA: Jaime, I respect your commitment to the Latino clients. Larry is clear about one of the things he knows works, 12-Step facilitation. In your experience, what works with Latino men?

JAIME: I'd agree with Larry, 12-Steps, because I go to AA myself, and I know AA works. But what's also important is jobs, not feeling discriminated against, not being asked for ID papers if you've lived here all your life. What helps is to be with a group of sober men. That's what helps my clients.

GLORIA: You both seem to be clear on what you see works for you and your clients. That's a good start for us. As you know from the recent ED's memo to staff, the State has required all agencies to implement an EBP to continue to receive State funds. There has been a lot of discussion at all levels about this. We've talked before about our desire to move from being a good agency to a great one, being one of the best in the State. Over the past year we've made incredible progress toward this goal, thanks to all the staff's efforts. And all through this process, we've been able to stay true to our 12-Step philosophy. Honestly, when I first heard about the new State policy, I, too, was skeptical, saying to myself, “Here we go again.” But then I was reminded of the agency's mission to keep improving our skills for the well-being of the clients. So, discussing this together now is helpful. I'd like to hear more from you about your concerns regarding MI.

LARRY: I don't really give a darn about MI versus CBT versus 12-Step facilitation versus the next thing to come down the pike. I've been in the field for a long time, and I know what works is my relationship with people. I know 12-Step works, and I have to be convinced that this doesn't interfere with having a strong relationship with my clients. I think that's the most important thing. I'm not sure I need a new way to do this. I don't want to have to be worried about whether I have to use this science-based thing.

GLORIA: Wow, Larry! I really hear that the most important thing to you is building strong relationships with your clients, and it's not so important what method you use to build strong relationships, but that the method helps you accomplish that goal. Perhaps we can look at how MI's approach to active listening with clients and reflection enhances that relationship. If it builds the therapeutic alliance with the clients, that's good. I'm curious how you feel about that.

LARRY: What I want to be sure of is that we're not moving away from our roots: that this is not taking us away from 12-Step. That's what this agency is founded on, and that's what we stood for all these years. I need to hear that from you.

GLORIA: That's a really excellent point. How do MI and other approaches keep us close to our roots of 12-Step work? What do you think?

LARRY: If an approach builds the relationship with the client, I'm all for it. I know that 12-Step facilitation does that. And I know from the course I took on MI that it also emphasizes the counselor–client relationship. But it is also a new way of thinking and a whole new vocabulary and I don't want to get so bogged down in catchy phrases that I lose contact with my client.

GLORIA: Larry, I clearly hear your concerns about interfering with your relationship with your clients and about us losing our roots.

LARRY: Maybe Jaime can do the MI stuff and I can do my 12-Step facilitation.

JAIME: What?

GLORIA: There are several different ways we can approach the implementation. We may decide that MI works better with some client populations than others. A place to begin would be for us to learn more about how MI can be implemented in the program. I know you've been to the MI training. That's a great start. MI has some good strategies that are congruent with a variety of client populations.

LARRY: What I heard you just say is that it doesn't matter whether we're on board or not.

GLORIA: That's a dilemma. The State's said, “You have to do it.” What they haven't said is how you have to do it. They said we have to do “something.” We have something to say about how we're planning this, how we'll implement an EBP. I want to be sure that we hear and use your experience.

[image] Master Supervisor Note: It is helpful to watch how Gloria handles the polarizing confrontation. A Level 1 supervisor might either come down hard on Larry for his suggestion, saying “No, we're not doing that.” A Level 2 might argue about it. Note the Level 3 approach, not to confront the statement by Larry but to find a working alternative.

A master supervisor is able to manage staff confrontation and avoid becoming defensive. To do this, it is important for the supervisor to understand that struggle is a sign of staff ambivalence to change. Resistance and ambivalence are normal in any situation involving change. A master supervisor works with the resistance, using its energy to promote change, not taking it “head-on.”

LARRY: I like the idea that we can implement the strategies that work best for our agency because that allows us to stay close to our roots of 12 Steps.

GLORIA: So you see the value of implementing an EBP approach such as MI as long as it stays close to our 12-Step roots. Moving ahead, I recognize that this is going to change some of our approaches, how we think about treatment, how clients experience us.

LARRY: How are we going to do this implementation anyway? Who's going to do the implementation, train us in MI?

GLORIA: Perhaps I can show a videotape of a counseling session I conduct when I think I am doing effective MI. What do you think of that idea? Would that help us all feel more comfortable with an EBP? I'm willing to stick my neck out if you're willing to give me feedback on what you see on the videotape.

[image] Master Supervisor Note: A basic rule of supervision is “do not ask a supervisee to do something you're not willing to do first.” A second rule is that “leaders bear pain, they don't inflict it.” Master supervisors are willing to take a risk by demonstrating their skills first before asking staff to do so. Effective supervisors are able to establish trust by serving as a team leader, inspiring staff by encouragement and motivation, communicating enthusiasm and capability, and taking appropriate risks to initiate change. Leaders also demonstrate vision, drive, poise under pressure, and maturity of character. They inspire rather than command staff. Since leadership entails teaching, mentoring, and coaching, having the title “supervisor” does not necessarily make a person a leader. To earn respect, the supervisor should display qualities of honesty, responsibility, fairness, and understanding. In this vignette, Gloria provides direction and leadership by showing staff how they can implement MI together and how the training will work. She also gives them a say in the process and allows them to keep to their roots, learn new tools, and do so over time.

GLORIA: That's a good question about implementation. Any approach we use needs to be respectful and build on the counselor–client relationship. So let's start there. First, we want to implement MI over time. It's not something that we'll become instant experts at. I want to make sure that we're well prepared and understand what we're doing.

[Larry and Jaime nod in agreement.]

GLORIA: Again, let's be clear. We need to implement EBP for State funding. Remember when the agency went smoke free: How difficult that was, how much resistance some staff expressed? But, it was something we just needed to do, and in the end, being smoke free has had significant health benefits to staff and clients, and has reduced the health care premiums for all personnel. I'm interested whether you see the similarity to such changes.

LARRY: Yes, I do. The smoke-free campus has been a real benefit to all. I hope implementing an EBP is also.

GLORIA: I agree. Maybe we can return to the training issue you raised earlier. Larry and Jaime, with your help and support, I'd like to establish a year-long training plan. First, I'd like to have an advanced trainer come in and provide several days more of training that particularly addresses the needs and concerns of the staff. We'd also like to contract with the trainer to establish an MI coding system that will be part of what we do in our clinical supervision. Over the year, we'd continue our direct observation for supervision. Only now we'd look at the interactions through the MI lens. The coding system will help us in doing so.

JAIME: I remember hearing about coding in the basic MI course I attended. Can you tell me more about that?

GLORIA: Here is a coding sheet that the trainer of that course recommended. I like the form and find it simple and easy to use. I also think it's consistent with what we do as counselors, and it reinforces our efforts to listen better to clients. As in 12-Step facilitation, it helps to build an alliance with the client.

LARRY: So you're convinced this is a good thing? You're not just doing this to get State money?

GLORIA: From what I know about MI and have read about it, I think MI is a very useful tool for us. We're concerned about our funding, of course. But, client welfare always comes first. No, we would not be doing this simply for money. I believe this will help our clients, and that's the bottom line, isn't it? So, perhaps we can discuss the skills we have as a team and how to proceed.

JAIME: I think we work well together and we seem to have good stable funding that allows us to maintain the quality of care we offer to our clients.

LARRY: Yes, we have good teamwork and support each other. Jaime and I work well together. We've got a lot of respect for each other. We've had the basic MI training. That's a good start.

GLORIA: Teamwork is important.

LARRY: We do good treatment. Our clients respect us. We have good credibility out there. That's a plus.

GLORIA: I'd also add that we have experience at successfully implementing changes.

JAIME: Three years ago we had few Latino clients and no Latino program.

GLORIA: Implementing a Latino program was a major positive step forward. The other thing I like is that we have a good supervision system which helps us assess how we're doing when we implement any new practice or program, like the Latino program. It gives us a way of assessing quality.

LARRY: So, what's going to change here?

GLORIA: We do have time for more training. It's difficult jumping into a new approach if we don't feel like we're adequately prepared for the change. One solution would be for us to devote more time in our normal clinical supervision sessions (individually and in group) to MI practices, to use videotapes and role plays to continue our learning and practice our skills. We can phase in MI over time. I'm committed to supporting you in whatever you need to do your job effectively. More than 150 studies have shown that MI is effective; this will enhance our skills and give us better client outcomes. It might be helpful for us to talk to an agency that uses MI and ask how they did it. We need to do training, as I said earlier, so we can be consistent with our core approach. I want to integrate this in a way that makes sense for all of us. Perhaps between now and our next meeting you'd think about two things you can do to help us write the implementation plan that will show how we're going to do this. We have an excellent team and do good work. I value and trust the work that we do. Learning a new strategy requires training, mentoring, and coaching. Our relationships with the clients and each other are the most important because that's how we serve the clients.

[A discussion follows when they discuss the training system, who might serve as a consultant for the advanced training, and how the coding system works and can be incorporated into the clinical supervision system. The session ends with a mutual commitment to move to the next stage of implementation.]

## Vignette 5—Maintaining Focus on Job Performance

### Overview

In this supervisory session, a counselor with marital problems carries this stress into the workplace. She feels overwhelmed by the complexity of her caseload, misses work, and cancels patient appointments. Observe how the supervisor must address the counselor's job performance, provide emotional support for the counselor, and, at the same time, not get involved in the counselor's personal life.

### Background

Juanita has worked as a counselor at the agency for over a year and brings a number of valuable attributes to her job. She is bilingual, understands the stresses and cultural dynamics faced by recent Central American immigrants living in the United States, works well with female clients, and gets along well with other staff. Her husband is a recovering alcoholic, and Juanita has been active in Spanish-speaking Al-Anon. She recently received her addiction counselor credential.

Since receiving her license as a substance abuse counselor, Juanita has been given new job assignments that involve working with more complex and difficult clients. She now conducts educational and support groups by herself, does intake interviews, provides individual counseling to her caseload, and has recently increased her caseload to accommodate the increased number of clients at the agency. She is also seeing several clients with co-occurring disorders.

While she is friendly and outgoing with others, her natural response to stress is to withdraw and isolate herself, rather than ask for help. To Melissa, her supervisor, Juanita seems more tentative and less energetic in their supervision sessions. She seems to be meeting most of her work performance goals established in the supervision, but the quality of discussion about her cases and her lack of vitality in the meetings concerns Melissa.

In the past month, Juanita has come late to work on a number of occasions and missed several client appointments. She has called in sick three times in the last 3 weeks. In supervision, she seems distracted, which is a change from her prior behavior. Melissa, in her concern, asked in supervision “is everything OK?” Juanita replied, “No, Jorge has been laid off his construction job, and he has been drinking.” She explains that she is quite distressed, having trouble sleeping, and feeling overwhelmed. Though clearly worried, Juanita did not elaborate, and Melissa did not pursue the questioning. Juanita did ask if she could talk to Melissa at another time to discuss her personal problems and to seek Melissa's advice on how to handle her current situation at home. Melissa was uncomfortable agreeing to this but also was uncomfortable not responding to Juanita's distress. She hesitatingly said that they could discuss this at the next supervisory meeting.

In the upcoming supervisory session, Melissa feels it is important to clarify the differences between providing help for personal problems and maintaining supervision goals. Melissa also thinks it is important to address Juanita's job performance issues in the next meeting.

### Learning Goals

1. To illustrate how work-related stresses and personal problems can interact and affect one another.
2. To demonstrate the boundary between clinical supervision and personal counseling.
3. To demonstrate how to help an employee get the help necessary to address personal (non–work-related) life problems that affect the work environment.
4. To illustrate how to monitor and maintain adequate clinical performance when an employee is facing difficult personal dilemmas that affect job performance.
5. To demonstrate awareness of and sensitivity to cultural issues that arise in the context of personal issues that affect job performance.

[The vignette picks up with the beginning of the next clinical supervisory session.]

MELISSA: Juanita, hi! Come on in. Before we start talking cases today, I would really like to go over some of what we discussed last week and see where things stand.

JUANITA: That's fine, but I think I owe you an apology about our last session. I really want to apologize for saying all those things to you about my family and how that is affecting me and all that, and I just want to apologize. I know it had nothing to do with anything work related. We were doing supervision and should just have talked about cases, and I just want to assure you that that will never happen again.

MELISSA: Well, Juanita, I'm sorry you have to cope with all that's going on, but I don't feel you need to apologize for anything last week. I know that what's happening is stressful to you. I hope we can work out a plan to help you get the help you need and also be sure that the pressures you are experiencing don't spill over into your work with clients.

How To Address Personal Issues That Affect Job Performance

[image] Consider the following points when you need to confront a supervisee in clinical supervision with problems of job performance that are exacerbated by personal difficulties, such as emotional, familial, interpersonal, financial, health, or legal concerns:

1. You can help your supervisees see the relationship between their personal difficulties and work-related problems. The key question you need to return to is “How is this personal issue affecting your job performance?” This prevents you from becoming the counselor's counselor and turning supervision into therapy.
2. You can clarify the boundaries of what constitutes acceptable job performance, as some counselors may be uncertain where the boundaries lie.
3. You should continually focus on approaches to improve job performance, providing useful suggestions and recommendations for improvement. It is also helpful to provide measurable benchmarks by which counselors can assess their own improvement.
4. You and your supervisee should develop a written work plan for how the employee will take the necessary steps to improve job performance.
5. You can help the counselor examine how personal stressors might affect interactions with coworkers or clients.
6. Finally, you and your supervisee can explore how you and the agency can support the employee in confronting and resolving personal issues that are affecting job performance, such as a referral to the EAP, use of personal or sick time, rescheduling of the counselor's time, and the like.

JUANITA: I appreciate that. I just want you to know that that's not me. That's not me.

MELISSA: And I appreciate that, and I want you to know that I value your work. You've worked hard. You've really worked hard in learning not only your job, but also as a professional counselor and you've made a valuable contribution to working with our clients.

JUANITA: I love my job. I love it.

MELISSA: Juanita, I want to be really clear with you that I am concerned about what is going on in your personal life, and I want to work with you to get help for that. I don't feel that it's something that we should address in supervision though, except to the extent that it affects your job performance. The goal of our supervision time is to help you to be the best counselor possible. When personal issues come up, those may keep you from being the best person you can be. These are important issues for you to address in your own personal counseling and therapy. I hope that distinction is clear for you. But I really want you to hear my concern for you.

[image] Master Supervisor Note: Although the distinction between personal counseling and supervision may be contingent on the supervisor's theoretical orientation, and both are interpersonal relationships, there are differences between the two, as summarized in the table below.

Personal Counseling | Supervision
1. The goal is personal growth and development, self-exploration, becoming a better person. | 1. The goal is to make the counselor a better counselor.
2. Requires exploration of personal issues. | 2. Requires monitoring of client care and facilitating professional training.
3. The focus of exploration is on the origins and manifestations of cognitions, affects, and behaviors associated with life issues and how these issues can be resolved. | 3. The focus is on how issues may affect client care, the conceptualization of the client problems and counseling process, and accomplishment of client goals.
To help the counselor and the supervisor differentiate between therapy and supervision, the supervisor needs to continually ask him- or herself, “What does this have to do with your counseling functions? How is this affecting your relationship with clients?”

JUANITA: I'm still kind of worried that I told you about my personal life, but I do want to be the best counselor I can be.

MELISSA: I'm concerned about the time you have been missing from work and especially the times you have had to cancel patient appointments as a result of your situation at home.

JUANITA: I know I've missed a couple of sessions, but I called. The clients were okay with me rescheduling, and I've continued to meet with them. I don't think there's any problem. It was the first time I ever had to reschedule those clients, and we caught up on their visits later in the week.

MELISSA: I hear that you were concerned about missing some sessions so you made a strong effort to reconnect with your clients later. I really appreciate your effort. I had a chance to review a videotape of a session you did last week. I'm pleased with the skills you've developed in group counseling. In the middle of the session we videotaped, there were some issues that came up about men that I thought might be a concern and might illustrate what we're talking about. Can we view that section of the tape and discuss what was happening for you at that point?

JUANITA: Sure, if you have the tape there.

[Together, Juanita and Melissa watch the tape, cued to the segment about clients actively drinking while in treatment. Juanita appears surprised to see her response to the client on tape and notes the impact she might be having on clients. For example, there was an interaction between Juanita and a male client in group where she saw herself being judgmental and overly critical. Melissa and Juanita continue to discuss the tape and the meaning of counter-transference in the counseling relationship. From the discussion of being angry at clients who continue to drink, Juanita becomes aware that the sessions she has cancelled with clients were all with drinking men.]

MELISSA: I'm glad you can stand back objectively and see the relationship between your personal issues and your clinical functioning. So, what do you think you need to do now?

JUANITA: Well, first maybe I shouldn't see any more male patients?

MELISSA: That is an option. But I think we can find a better resolution. For right now, let's focus on what else needs to change.

JUANITA: Well, I just won't cancel any more appointments. I didn't realize rescheduling was such a problem. But I just won't do it anymore. And about the missed days, I think that is beyond me now. If I need a day off for personal reasons, I'll schedule them in advance from now on.

MELISSA: OK. I think I would like you to go through me for the next few months if you need either time off or if you have to cancel patient appointments. I know emergencies happen, but just let me know if you need time off and we'll see where we go from there.

JUANITA: I understand. I am so sorry that my personal life is intruding on my counseling. I never thought that would happen. And I'm going to get back to my work. I'm going to make sure I get the paperwork and everything done, and I will be on time tomorrow.

MELISSA: Let's put the paperwork aside and talk about your work with the clients and what you need to do to maintain your high level of work performance. Let's get back to the countertransference. I'd like to hear more about the clients you work with. Let's go back to the videotape and discuss what else is happening in the session.

JUANITA: Basically, I've moved into working with some of the more difficult clients in the last several months. It's been very challenging developing plans with them and encouraging their attendance and working with their treatment plans on a more active level because I'm definitely sensing the resistance.

MELISSA: So, not only are you working with more complex clients but you also have a higher caseload than you had not so long ago. So your job responsibility has increased significantly recently. I think you'll see some different features of supervision as you continue to see clients with more complex problems and as you begin to work in other treatment modalities, such as group. Let's discuss how you're dealing with the more complex clients.

[A discussion follows, using the videotape, about how Juanita has been working with these clients, some of her concerns about working with clients with more difficult co-occurring disorders, some specific points about counseling interventions and her countertransferential reactions to men who are drinking. She acknowledges that her reaction to the client who has relapsed is in part a response to her current life situation with her husband. Now that Juanita recognizes where her work is being impacted by her personal issues, Melissa returns to the issue of the EAP and re-introduces the possibility of a referral.]

[image] Master Supervisor Note: It is important for the supervisor and counselor to understand the impact of countertransference in a counseling relationship, including:

1. It can distract from the therapeutic relationship.
2. A counselor's personal issues may contaminate how he or she sees the client's issues.
3. The counselor may distance him- or herself or avoid discussion when the client's issues come too close to home, or conversely, the counselor may focus on client issues that resemble her own.
4. The counselor may have negative reactions to the client, based on the counselor's current life issues, as Juanita did with the men in her group who were actively drinking.

MELISSA: Juanita, you may remember that, as part of your professional development plan, we talked about a personal care plan: knowing when you need support and where you could get it. Your Al-Anon program has been a strong support for you, and you've used it in a very effective way. I'm wondering if you have used or would consider using our EAP to help you address the crisis you are experiencing now. I think it would be helpful if you had the opportunity to sit down with someone and assess how things are going and what could help. I hope you'll use our EAP for that. As you know, using the EAP is optional. I'm not mandating that you go. But if you think it would help, I hope you'll take advantage of it. This booklet has some information about the EAP and how to access their services. As you know, the EAP is strictly confidential, and nothing is reported back to the agency. I'm also wondering how I can be of support to you.

JUANITA: Just be there for these sessions. Just be there as the supervisor when I come and have questions. I'll call the EAP this afternoon. Do you think they would also be willing to help Jorge if he is willing to come with me?

MELISSA: The EAP is for the whole family, and I'm sure they would be available to see Jorge too, either with you or separately. I'm glad you are going to follow up on that.

[image] Master Supervisor Note: Note that Melissa doesn't ask Juanita to report back to her about using the EAP. The EAP referral is to address personal life issues that are not the concern of her employer. It is Melissa's role to monitor job performance and to use all of the resources that are available to help Juanita improve her job performance. In most organizations, an employee's use of the EAP is not the concern of the supervisor. The focus of the supervisor needs to be on improving job performance. Statements such as “Let me know if you use the EAP” are not within the supervisor's scope. Remember, the goal of clinical supervision is not necessarily to make the supervisee a better person, but a better worker. It is tempting for clinical supervisors to focus on the personal issues of staff—after all that's what they do for a living. However, personal issues are a part of clinical supervision only insofar as they affect the counselor's interactions with clients.

[Melissa and Juanita continue to discuss some of her cases and her efforts to work with more challenging clients. At the end of the supervision session, Melissa and Juanita schedule two sessions in the coming week for Melissa to sit in on Juanita's sessions again. Melissa reaffirmed that she hoped Juanita would consider using the EAP to address some of the issues in her personal life.]

## Vignette 6—Promoting a Counselor From Within

### Overview

In this vignette, a counselor has been promoted from within a work group to a supervisor position over the counselors she worked with as a peer. Issues addressed include how the new supervisor handles staff resistance and works to build a new relationship with the counselors she will now be supervising.

### Background

Kate has been a counselor at the agency for 3 years. She, Maggie, and Kevin have worked together as outpatient counselors, supervised by Gene, who left the agency last month to take another position. Kate has a master's degree in counseling, is licensed as a drug and alcohol counselor and, for the past year, has been taking continuing education courses to develop her supervisory skills, hoping that a supervisory position would open up in this or another agency. But the courses only gave brief reference as to how to work with and supervise counselors who last week were her peers.

Maggie has worked at the agency 2 years longer than Kate, is a licensed drug and alcohol counselor, recently completed her bachelor's degree and has started working on her master's degree. She understands that Kate got the promotion partly because of her advanced degree but still feels she was treated unfairly in the selection process because she has been with the agency longer.

Kevin, also a counselor, is in process of becoming licensed. He has a bachelor's degree and has worked in the field for about a year. He has concerns that someone who was a counselor and his peer last week can be an effective supervisor for him now. He likes Kate and has turned to her numerous times for advice and support, but wonders about her competence as a supervisor.

The agency director announced the promotion yesterday afternoon and suggested to Kate that she meet with Maggie and Kevin soon. The director offered to sit in on the meeting, but Kate declined, feeling that she would rather discuss the promotion and changes alone with Maggie and Kevin first. Since everyone had appointments already scheduled for the morning, lunchtime was the first available opportunity for the meeting.

### Learning goals

1. To demonstrate how a new supervisor can establish a leadership position and demonstrate a leadership style with former peers.
2. To show how a new supervisor handles the potential conflict of her promotion over others with whom she has worked.
3. To give some guidance to recently promoted supervisors to clarify their roles, develop opportunities to learn new supervisory skills, and establish rapport with supervisees.

[Kate, Maggie, and Kevin meet over lunch to discuss Kate's new position.]

KATE: Thanks for being willing to sit down with me and discuss how we are going to proceed in face of the changes that were announced yesterday. I'm pleased with the promotion and excited about getting my feet wet in this new role. I hope we can work together to continue doing the good job we have been doing.

[Long pause while Kevin and Maggie wait for Kate to proceed.]

KATE: I hope you see this as an opportunity for all of us.

[Another pause while Kate waits expectantly.]

KEVIN: Well, Kate, it's going to be strange having you as a supervisor. Gene and I had a good relationship. He was my boss the entire time I've been here, and I learned a lot from him. I knew there were going to be changes. I guess I'd rather see you or Maggie get the promotion rather than having someone new come in from the outside. This is quite a shift. Two weeks ago, when Gene announced he was leaving, all three of us were in group supervision together. Now you're our boss.

[Another pause.]

KATE: Yes, Kevin, it seems strange for me too, I have to admit. I've enjoyed our collegial relationship. I've learned from you and appreciated your input too. I've even enjoyed our “grousing sessions” when we've felt overworked and underpaid. [Laughter.] And I know there is going to be a shift in our relationship, but I still want us to see ourselves, as well as new staff, as a team, focused on the best patient care we can offer.

[image] Master Supervisor Note: It is important for new supervisors who are promoted from inside not to try to be something they're not. Everyone knows you don't know the job. Don't try to fake it. Instead, acknowledge to staff that this is new, that you have things to learn, and that, with their assistance, you can work as a team. The worst mistake you can make as a new supervisor promoted from within is to try to take the reins of leadership abruptly and without consideration of staff reaction to your promotion.

KEVIN: I'd like to hear about any changes you are planning or how things might be different now that you are running the show.

KATE: Great question, Kevin. In the past, we've all sat around in the lunchroom and spoken of what needs to be different in the agency. Now, together, perhaps we have an opportunity to make some of those changes. For example, we've spoken before about how we'd like to streamline the paperwork process. I know we're all buried in forms. How can we reduce the strain of administrative tasks we all face? How do we deal with our burnout? So much is asked of us, and that places great strain on us. We've spoken about that together, how tired we can become. How can we take better care of ourselves and of the team?

But, I want that process to unfold together. I need your help and input. Also, I want a few weeks or a month of breaking in time before any changes are made. So, perhaps we can sit together as a group and think about what needs to be different. I will then “run those changes up the flagpole” with the director and do what needs to be done to bring about the changes we deem necessary. How does that sound to you?

How To Demonstrate Leadership

[image] It is important for a new supervisor to demonstrate leadership without being controlling or condescending, especially if promoted from within. Perceptions of quality leadership have shifted from the traditional hierarchical, command-and-control model to a networked, team-based approach that values participative leadership and staff empowerment, bottom-up management, team input, and collaboration. Qualities of this leadership style include:

1. Taking responsibility for decisions made, never blaming others for something you've done, and giving credit to others when things succeed.
2. Always putting the well-being of supervisees above personal accomplishments.
3. Not being afraid of taking appropriate risks that are in the best interests of the organization, staff, and clients.
4. Protecting and advocating for supervisees, defending them to senior administrators and buffering them from rapid changes.
5. Not playing favorites. Most important, not giving orders just to prove who's boss. If you have to prove who is the boss, you are not.

MAGGIE: I have to say that I'm not very happy about this. I met with Gene and Susan [the agency director] about ten days ago and expressed an interest in applying for the position. I didn't hear a word until I found out yesterday that you got the job. I want to be clear that I'm not upset with you. I'm glad for you, but I'm not happy about the way this was handled, especially how Susan made the announcement. It makes me wonder how decisions are really made around here.

KATE: I think if I were in your situation I'd be unhappy too. It doesn't feel very good when there's no communication. I understand that you were interested in the position. I am sorry about how the communication was handled.

MAGGIE: Like I said, I'm not upset with you, but with Gene and Susan. I felt disrespected after my years of service to the agency. That really doesn't feel very good, like not being valued.

KATE: Yes, it feels like you should have had some communication at the least, and not have been surprised by the decision.

MAGGIE: Yeah, it feels lousy. I wonder what my future is with the agency: if I'll be passed over for other promotions. And, quite honestly, I regret that I didn't go back to school and finish my degree years ago, if that's required for a supervisory job. It makes me angry though, because they never told me that education would be a deciding factor. I don't even know what the criteria were for the decision.

KATE: Maggie, I can sure understand your feeling that way. And to be honest with you, I think I would have felt much the same as you do if the decision had gone the other way. I'm sorry that's the way this happened. If it would be helpful to discuss your concerns with Susan, either together or alone, I'd be willing to help you with that.

[image] Master Supervisor Note: It would be easy for Kate at this point to triangulate the communication, making Gene and Susan “the bad guys.” However, Kate skillfully identifies Maggie's feelings, provides self-reflection on how she'd feel if in a similar situation, without polarizing the process and the others involved.

KATE: In the future, perhaps we can make suggestions to administrators on how we'd prefer the process and communication to flow. How could this situation have been handled differently? What would have been more helpful to you, Maggie?

[A healthy discussion follows between Kate, Kevin, and Maggie about how to improve the communication process in the future. Maggie feels like she has a voice in the process and feels listened to and understood. Kate asks Maggie what she needs now.]

MAGGIE: Thanks for this conversation and for your concern. Let me think about what I want to do now and what I need. Can I get back to you on that?

KATE: Sure, we can discuss it when you're ready.

KEVIN: I'd still like to maintain our friendship. I understand it is going to be a little different, for instance, calling you “boss.” But the three of us have had a good thing going here. It's been fun for this last year. I want to keep that.

MAGGIE: Our friendship has been fun: something I've treasured, too. As you say, things aren't going to be the same. Kate is the supervisor now. And when we hire a new counselor, you are no longer the new guy on the block. More is going to be expected of you.

KATE: I am going to miss some of what we have had together too. It would be hard to act as if we're peers and then have any objectivity when it comes to management decisions. We'd risk claims by others of favoritism. So, as hard as that will be for me, I'll need to stop doing as much socializing as I did before. I don't understand fully what I mean by that, but I know things will be different. I also will experience a sense of loss of some of my clinical duties. I'm giving up some of the real satisfaction that I found in counseling, working with clients. And I'm swapping that for new tasks. So I likely will also go through some grieving as well.

KEVIN: Thanks for your honesty, Kate. This means changes in a number of ways, for all of us. Kate, I have confidence you'll do a good job. Although you'll have to get a new wardrobe and dress more like a manager. [Laughter.]

KATE: Thank you so much for your patience and understanding. I was nervous coming into this meeting, given how this all unfolded. I feel like we're heading in the right direction. How do you feel we're doing so far?

MAGGIE: I appreciate your listening to my venting and I think you understand how I'm feeling.

KEVIN: I am cautiously optimistic, which, for me, is saying something positive. After all, you know what a cynic I am. [Laughter.]

KATE: You, a cynic, Kevin? No way! [Laughter.] There's one more thing I would like to address before we stop today: how we proceed. Gene had a really good system in place for clinical supervision. I would like to return to that system and schedule that includes the efforts Gene was making to improve our supervision process. What do you think?

[The discussion continues about what to do in clinical supervision, returning to the effective system formerly in place.]

[image] Master Supervisor Note: It is important to move forward, saving what was working before, not seeking to make radical, hasty, drastic changes. Also, this is an opportunity for Kate to demonstrate leadership by not languishing in the present situation, not “badmouthing” administrators for how this decision was made, while also acknowledging the emotional and professional concerns of staff.

[The session ends with a group decision to move forward in their clinical supervision.]

## Vignette 7—Mentoring a Successor

### Overview

This vignette illustrates the process of mentorship as a supervisor faces retirement and needs to mentor a successor from within the agency. Mentorship is an urgently needed process in the substance abuse field as a significant number of current leaders in the field face retirement in the near future.

### Background

Margie is a certified clinical supervisor with 25 years' experience in the field. She is in her early 60s, has worked at the agency her entire career, and is, in fact, the longest term employee at the agency. She is approaching retirement in the next 2 years. It is agency policy to promote from within whenever possible.

Betty has been in the field for 10 years and has been employed by this agency for 3 years. She is an excellent counselor and is well respected by colleagues in the agency. She has the potential to be promoted to Margie's position as clinical supervisor. However, she has professional development issues that need to be addressed before she could be promoted. For example, she would need training in clinical supervision skills and eventually will need to get her certification as a supervisor. She also has a managerial style that needs to soften a bit. She sometimes comes off as too authoritarian and abrupt. Previous attempts by other supervisors to address this style have not been successful in changing the behavior. Margie has worked with Betty for 3 years as her clinical supervisor but without a mentorship training plan.

The vignette focuses on how Margie can mentor her successor and the next generation of personnel so they could be promoted upon her retirement. The vignette addresses the necessary systems of mentorship that can be involved, what ought to be in Betty's IDP, and the coaching Margie will provide to Betty.

The dialog begins with a discussion about current and future personnel issues and Margie's pending retirement. Margie's goals in this session are to begin to define Betty's learning needs, to establish a mentoring relationship, and to pave the way for Betty to be accepted as a supervisor by others in the agency. Margie's approach is to be a positive, supportive coach and to encourage Betty to begin the professional development and training required to be a supervisor.

### Learning Goals

1. To illustrate how to design a mentorship program for personnel, including the writing of mutually agreed upon IDPs for potential successors and all clinical staff.
2. To illustrate the process of establishing a supervisory alliance that incorporates principles of mentorship and training.
3. To suggest how to develop and maintain a strong collaborative and professional supervisor–supervisee relationship.

MARGIE: Betty, as you know, I'm beginning to wind down my career and am looking forward to retirement in 2 years. Our agency strongly believes in the idea of fostering our own leaders and promoting people from within. You and I have had a great relationship over these past few years. I've seen your skills and feel you have great potential to grow professionally and as an important professional in this agency. Your clinical skills are excellent, you always complete your paperwork on time, and you're a joy to supervise.

[image] Master Supervisor Note: It takes a Level 3 supervisor to be able to mentor someone else. Level 1 and 2 supervisors might find it difficult to let go of the reins, to essentially work themselves out of a job, and might feel threatened by helping others develop to their own level of competence. A Level 3 supervisor needs superior vision: the ability to look ahead and see what's needed for the sake of the agency and staff. This requires maturity, serenity, and wisdom.

BETTY: Thanks so much, Margie. That really feels good. I really like my job and would like to continue working here.

MARGIE: I hope you continue working here. You're a great asset to the agency. You've just implemented some innovative ideas, and you're enthusiastic about the work. Whenever I ask you to take on an assignment, you're always the first to complete it. I like that. You've worked hard to become an excellent counselor. So, I'd like to have an idea where you want to be in 5 years. Would you be willing to discuss that with me?

BETTY: Sure. I hope I'm still here. I like the clients, my colleagues, and this agency. I like that I get to try new things. You've been supportive of that. This is a place where I'm able to make a contribution to my community.

MARGIE: So this is “home” for you: That is so evident. It's working really well for you. Perhaps we can discuss what's ahead for you. What would you like to be doing differently here in the future?

BETTY: I don't know. I'd like to continue to improve my counseling skills, maybe even advance up the ladder a bit. I think I have good individual and group counseling skills, but I also know administration involves another whole set of competencies.

MARGIE: You're right, there are different skills in administration and that's important to recognize. And I'm excited that you want to move up.

BETTY: Oh, that scares me a bit. I like seeing clients and wouldn't want to become a paper-pusher, not that that's all you do. [Laughter.]

MARGIE: I like that you want to stay anchored in clinical work. I think that is important and I appreciate your concern for clients. That's one reason you're so good at counseling. You have a real caring and compassionate nature for the people you work with.

[A discussion follows about Margie's job and what it means to be in a supervisory position at that agency. Margie outlines the roles and requirements of being a supervisor.]

MARGIE: Another way to look at your contribution to clients and legacy in counseling might be in the fancy word used by Erik Ericson, who spoke of “generativity”: getting to a stage of life when you want to give something over to the next generation of people to follow you. You're having a great impact now on your clients. As you progress into a supervisory role, you have the potential of affecting even more clients and staff, as you train and supervise counselors.

BETTY: What do you mean?

MARGIE: Remember years ago in school? Can you recall any teachers that left their mark on you, people that helped you become the professional you are today?

BETTY: Yes, there were many.

[A discussion follows about these mentors and how Betty benefited from their teaching.]

MARGIE: As you supervise, you have the opportunity to touch more people's lives. Yes, there is more dreaded paperwork. But, at the end of my day, I go home with a rich sense of legacy that I've had the chance to touch even more people's lives as a result of being a supervisor, even more than I might have as a counselor alone.

BETTY: Yes, I see that in you. You've had a profound impact on my life and that of so many counselors here.

[image] Master Supervisor Note: One of the most effective ways to lead is by example. Mentorship should include something of attraction; people should see something in you that they want. “Whatever she has, whatever she does, I want to have and do that.” People are imitative; they find role models they want to be like. So, when mentoring, use personal examples for the potential to grow and impact on others. It is important to identify the qualities and characteristics of a positive mentor and role model for staff, such as eliciting, rather than imposing, their judgment; drawing ideas from the supervisee, and being positive and affirming.

Mentorship is a special kind of professional growth opportunity, differing from other supervisory models. In mentorship, the mentee asks questions, shares concerns, and observes a more experienced professional in a safe learning environment. Through reflection and collaboration, the mentee can become more self-confident and competent in his or her integration and application of the knowledge and skills gained. Mentorship addresses the unique needs, personality, learning styles, expectations, and experiences of each person. Mentorship can be defined in numerous ways. One definition is a working alliance offering regular opportunities for discussion, training, and learning to occur between less experienced and more experienced people in various settings, addressing practical, hands-on work experience to enhance the knowledge, skills, attitudes, and competencies of everyone.

MARGIE: So, perhaps we can discuss how you can increase your skills, both clinically and in supervision. This is the beginning of our developing and updating your IDP. One place to start would be for you to attend clinical supervision training. There are online courses, self-study programs, and classroom programs. I have a list of upcoming training events. I'd encourage you to take a look at these options and see whether you'd be interested in one of them.

BETTY: Sure, of course. I'm always open to training, especially if it's held on the beach, in a nice location. [Laughter.] Will the agency pay for the training? You know a counselor's salary will only stretch so far.

MARGIE: Yes, it would be part of your IDP. We fund professional development as much as possible.

BETTY: Thanks for the vote of confidence.

MARGIE: Further, I'd like you to start doing more staff training, using your clinical experience and conducting sessions for other staff.

BETTY: You mean like some of the presentations I do in the community, to staff here? That's a little intimidating, presenting to my peers.

MARGIE: It can be intimidating, presenting to people you work with.

BETTY: I assume you'll help me with that?

MARGIE: Yes. I also think you have the potential to present at State and national conferences. This would expand your repertoire of material, hone your speaking skills, build your confidence, and help you become better known outside the agency. We know you're good. It's time for others outside to see in you what we see.

BETTY: Really?

MARGIE: Really. I have a call for papers for a counselors' conference in Cincinnati this fall. I think you should submit a proposal. The conference's theme is PTSD and substance use disorders. I've heard you present here at the agency on this topic. The people attending the conference will be your peers. That's a good place for us to take another step in the mentorship process, and you can begin with an area where we know you're especially strong. I'll attend the conference, too, and we can discuss afterward how it went for you. I'm interested if you've ever thought of being acknowledged outside of the agency for what we all know you know.

BETTY: If I'm really honest with you, yes. I've gone to conferences and thought “I can talk on that subject.” But it's always seemed immodest to say that out loud.

MARGIE: Yes, it's difficult stepping forward, not wanting to seem arrogant, but also acknowledging that you might have something others would benefit from hearing. So, how about putting your thoughts together for a proposal? It's due in 3 weeks. You and I can review the proposal together. I'm confident it will be accepted for presentation. When it comes to your actual presentation, you can do the outline and slides and we can discuss your ideas.

BETTY: So is this what you meant by mentorship?

MARGIE: It's a good place to start. I'll never forget my mentor, Todd. He saw in me something I couldn't see in myself at the time. He believed in me when I was feeling uncertain and insecure about my abilities, when I wasn't even sure I wanted to stay in counseling for the rest of my life. He got me to do things I didn't think I could do. He made me really stretch and taught me some invaluable lessons I still remember. Perhaps I can discuss what I mean by mentorship. Would that be okay with you?

BETTY: Sure, I want to hear.

MARGIE: Well, this is my own view and from my own experience, but it seems to me that mentorship is when someone with more experience and professional maturity helps someone coming along to want to reach out for more and develop new skills. There are lots of new opportunities for mentorship that weren't available just a few years ago. Mentorship is different from our supervision relationship. Together we can identify areas of growth for you, and then we'll meet to discuss what we need to do so you can achieve your goals.

BETTY: I am honored (and a wee bit embarrassed) that you see that potential in me, and want to invest in my professional growth. I'm not sure anyone else has expressed that interest to me before. I'm really flattered.

MARGIE: It has been an honor for me to work with you these last 3 years. It also gives me great joy to see you grow professionally, and perhaps advance into supervisory and administrative positions here in the future. Speaking nationally will give you better exposure. We'll start with that, if that's okay. Then we'll move on into other areas that we identify together on your IDP.

BETTY: Okay, if you really think I can do this.

[image] Master Supervisor Note: One of the four foci of supervision is supportive, which includes at times cheerleading and encouragement. Often counselors may lack the confidence in themselves to step forward. Supervision should build on strengths, nurture assets, and support and encourage all personnel to grow. Identifying staff with high potential for advancement is a key function of a supervisor. Through mentorship, personnel can grow professionally, and leadership succession can become a key aspect of the organization and field.

MARGIE: You can help our agency. We will see the scope and the focus of how you want to shape your career as it moves on.

BETTY: And you would be willing to make that kind of investment in me, Margie?

MARGIE: I sure am. The agency surely is.

BETTY: You know how exciting this is? I am fluttering inside.

MARGIE: It's exciting for me too. I enjoy seeing staff use their potential to the fullest. It's something I can leave behind when I retire that will last far beyond my years of service. It's like looking into the eyes of children and seeing the future in them that I will never realize myself. If I can help mentor you and others, that will be the icing on the cake of my career.

BETTY: If I can grow to become a representative of the agency and to work more closely with you and learn from your experience and your wisdom, I'd love that.

MARGIE: Here are some other ideas where you might consider growing professionally: learning about leadership, creating a vision, business and financial management, continuous quality improvement, organizational development, conflict resolution, and on and on. I know that might all sound rather intimidating at this point, but there are many areas we can address. I'll be there with you throughout the learning and mentorship process.

[Discussion continues about the next steps for Betty. First, they arrange to begin to revise and update her IDP and the strategies to reach her learning goals. The supervision session then turns to the future needs of the agency and how Margie and Betty can be part of the evolving future. The session ends with an agreement to begin writing an IDP and decide on the next steps for their mentorship.]

Resources on Mentorship

ATTC Leadership Institute (http://www.nattc.org/leaderInst/index.htm). After an assessment of leadership and management interests, values, and skills, participants attend a 5-day training session designed to present the necessary body of information. With their mentors, participants develop an individualized training plan and individualized project. They then return to their organizations for 6 months of mentoring and working on their projects.

Michael E. Townsend Leadership Academy (http://kentuckyoar.net/about_us.htm). A 3-day onsite workshop continues in followup sessions throughout the year in this program sponsored by the Kentucky Division of Mental Health and Substance Abuse.

South Carolina Addiction Fellows Program (http://academicdepartments.musc.edu/psychiatry/education/res_fell/addict/addict.htm). Participants meet in six 3-day sessions during the year.

North Carolina Addiction Fellows Program (http://www.fellowshiphall.com/training.php). Twenty participants meet to create a group of leaders for the field in North Carolina.

## Vignette 8—Making the Case for Clinical Supervision to Administrators

### Overview

This vignette illustrates how a clinical supervisor can justify a system of supervision, along with time and resource allocations, to agency administrators in the light of recent pressures from the administration to increase billable hours. (Clinical supervision is not a billable expense at this agency.)

### Background

Ella, a Level 2 supervisor, was recently hired to be the clinical supervisor of this agency, overseeing the work of six counselors. Jonathan is the agency's CEO and Ella's immediate boss. Jonathan has directed Ella to maintain supervisory functions “the way your predecessor did.” Jonathan does not want to introduce any significant tasks into the workload, especially those that are not billable or revenue generating.

Ella, on the other hand, recently attended a 30-hour class on clinical supervision and is seeking her certification as a clinical supervisor. During the class she learned the importance of “making a reasonable effort to supervise,” and the legal and ethical obligations of the agency to supervise. She learned about her and the agency's vicarious liability for the actions of the clinical staff. In the class, Ella was given the 20-to-1 guideline: for every 20 hours of client contact, staff should receive a minimum of 1 hour of clinical supervision.

Until now, staff has received primarily consultation and support with case management. To justify more in-depth clinical supervision, Ella needs the support and endorsement from Jonathan of the new supervision system. Given his emphasis on billable hours and reducing nonreimbursable activities, Ella knows that introducing these changes in the agency will not be easy, but she comes to Jonathan with her plan for supervision, asking for his endorsement.

### Learning Goals

1. To describe the benefits and rationale of clinical supervision.
2. To design a system of supervision that is efficient and effective, without greatly increasing staff and supervisory time and resources.
3. To explore a system in which the supervisor can balance management and administrative duties, maintain a clinical caseload, conduct training, and perform other duties as assigned.

[The vignette begins with a meeting between Jonathan and Ella to discuss her supervisory tasks and her plan. After a short introduction in which Ella discusses her feeling of being overwhelmed by her tasks, the dialog continues.]

JONATHAN: The last time we met you were to look at how to improve the quality of our counseling and design a new plan for supervision. What did you come up with?

ELLA: Well, first I looked at what makes us a quality agency: our strengths and skills and our weaknesses and liabilities. We want to be the best agency possible. There are four issues that came to me. First, after the client suicide last year, concerns were raised about our liability as an agency. Even though we took the right action, we need to be mindful of our vicarious liability for what our staff does. I think we're both concerned about that issue.

Second, we're now required by the State to eventually have all counseling staff be certified addiction counselors. Our accrediting body is pushing us to provide better quality assurance systems with more clinical supervision.

Third, I know our organizational development plan calls for us to expand services in the near future. We need to attract high-quality counselors. That's difficult in a highly competitive market, with many agencies vying for good staff. We've had significant staff turnover in recent years for several reasons. I found that the average tenure of a counselor in our agency is 2 years, which, by the way, is consistent with the national average. We know from the exit interviews that the majority of staff who leave complain that we didn't provide as many good training and supervision opportunities as other agencies do to support their learning and self-care needs. It's costing us a lot of money to have such high staff turnover.

Finally, we need to increase our billable hours. Research tells us that the better the supervision, the better staff morale and in turn, the better the client services. This has a direct impact on our bottom line if we retain clients in treatment longer.

[Ella gives Jonathan copies of various studies she's compiled from her training on the cost of staff turnover, the CSAT Manpower Study (CSAT, 2003), and a synopsis on staff development issues from the agency's development plan.]

[image] Master Supervisor Note: Notice how Ella is well prepared for her presentation to Jonathan, providing a rationale in language and terms that appeal to administrators: concerns about liability, credentialing of personnel as mandated by the State, staffing needs and turnover, and billable hours. When presenting a proposal for a clinical supervision system to senior administrators, it is wise to:

1. Use terms and language that apply and appeal to administrators
2. Be prepared with facts and figures (e.g., the CSAT Manpower Study)
3. Be clear, direct, and succinct; most administrators value clarity, directness, and results-oriented presentations
4. State clearly the goals, objectives, timelines, and costs for the system and have the data to support them

JONATHAN: Wow, I'm impressed. You've done your homework. So, what is it you're suggesting? You know money is a key issue right now.

ELLA: Money is an important issue. I'm suggesting that we look at our current supervision system and that we design and offer a new system that will help counselors become credentialed, meet the requirements of our accreditation body, reduce our high turnover rates, protect our liability concerns, improve morale, and in turn, bring more money into the agency.

JONATHAN: That's a tall order. And you're going to do this without spending any money? [Laughing.] Let me go back to what you said. I thought after last year's suicide that we beefed up our oversight.

ELLA: Yes, we trained staff on how to deal with suicidal ideation and what actions to take. We were really sensitive to suicidal symptoms and documentation of issues. We have done a good job addressing that issue. However, I have concerns about our liabilities in general. What is going on right now that we don't know about? What are our counselors actually doing behind closed doors? Is there another legal issue waiting for us that we don't know about? That's what I mean by our vicarious liability. Without a sound, consistent system of supervision, it will feel like we're constantly putting our fingers in the dike.

[image] Master Supervisor Note: When conceptualizing, justifying, and implementing a new comprehensive supervision program each level of staff—agency administration, supervisory staff, counselors providing direct services, and support staff—have unique concerns about the needs and effects of clinical supervision. Administrative staff are most likely to be concerned about some of the issues noted below:

1. Legal and ethical requirements for supervision, such as vicarious liability, scope of competence and practice requirements, and recent court rulings requiring clinical supervision. It is useful to stress the agency's fiduciary responsibility to ensure the quality of services provided.
2. Relevant Federal, State, and credentialing or accreditation requirements for supervision.
3. Staffing costs, such as personnel retention and turnover rates, hiring costs and expenses associated with retraining of personnel, and impact on staff morale. It is useful to provide any research data available in the field or from your agency.
4. Costs associated with implementing a supervision system, such as material and time costs and the impact on billable hours.
5. The cost benefit for implementing a supervision system, addressing: “What's in it for the agency? Why should we do this? What are the ramifications and costs if we don't?”
6. A timeline for implementation, with dates and deliverables, including benchmarks to measure success.

It is important that support in the form of data or relevant resource materials supplement these points.

JONATHAN: I agree. Are you telling me we're not doing our job? That our supervisors are not supervising?

ELLA: Our counselors are working very hard. We have fine staff here. Yet, we've got to give them more tools to do a better job, to continue to enhance their skills, and to ensure they recognize what they don't know. And, as we grow, the skills needed by staff will also grow.

JONATHAN: We're not doing that now? We have money in the budget for training. We send people to summer institutes every year. We have weekly training sessions. Isn't that supposed to address those issues?

ELLA: It does, but only partly. Much of what we do in these sessions is administratively oriented, addressing new policies, procedures, and paperwork, compliance issues, and personnel concerns. We're not doing clinical supervision.

JONATHAN: I'm confused. Maybe I don't have a good understanding of what clinical supervision is. I thought that's what we were doing. Are we better off than we were a year ago? I need to assure the board of directors that we're doing a better job, that the legal concerns of last year have been addressed.

[Ella presents a brief and clear description of what clinical supervision is and how it differs from what they have been doing, which is primarily case management.]

ELLA: We've made significant progress. You can assure the board of that. We've minimized some of our legal risk. We've addressed compliance issues. That's good! When you asked me to look at a quality assurance plan, it was clear our weekly staff meetings and training sessions only address some of the needs. We must increase our clinical oversight of staff. That's not just administrative in nature. In the course on clinical supervision you sent me to, I found a definition that I think really makes my point. First, clinical supervision is a process where counseling principles are transformed into practical skills. Second, there are four focuses in clinical supervision: administrative, evaluative, supportive, and clinical/educational. We've addressed the administrative aspects of supervision well. We now need to increase the amount of evaluation we give staff, support them in their clinical duties, and train them by watching them work with our clients more closely.

[image] Master Supervisor Note: In many agencies, administrators may not have a clinical background and thus may not understand the differences between case management and clinical supervision. A skillful supervisor patiently educates administrators about the distinction and stresses clinical concerns.

JONATHAN: I think I understand the difference. I'm not a clinician so I am not always familiar with terminology. So what are you proposing we do?

ELLA: I need your endorsement and support for a system of supervision involving direct observation of counseling staff, so we shift the balance of our supervision from mostly administrative to include a clinical focus, too. The supervision will address each counselor's skills, what competencies they need to develop further, and how each can best address the needs of the clients.

How To Demonstrate the Importance of Administrative Support for Clinical Supervision

[image] An individual developing a clinical supervision program for an agency clearly needs to explain to an administrator what is being asked of the organization. It is essential that administrators understand and support the supervision system. Without that endorsement, supervision systems will not be successful. Critical steps in this process include:

1. The endorsement of supervision to all staff should be both verbal and in writing.
2. Clinical supervision systems need the support of staff at all levels of management and in a manner they will understand: how it will benefit them, the agency, and the clients.
3. Staff should hear a consistent message about supervision over time, lest they see the supervision system as the current “flavor of the month,” and believe “this will pass as soon as another priority comes along.” Staff need to hear that administrators have a long-term commitment to a consistent program of quality assurance in their supervision program.
4. It is essential that administrators understand that systemic change takes time. Although some immediate results will be seen, long-term results can best be measured over the long term. Many staff have settled into their ways of doing counseling and might take time to adjust to receiving clinical supervision and make noticeable improvements in their skills.

JONATHAN: This is making me nervous. It's sounding like money. [Laughing.] You know the pressure we're under to increase billable hours and decrease activities that don't generate revenue. Now you seem to be adding more activities and expenses. Where's the time coming from to do this?

ELLA: I understand the concern about increasing expenses. There are two answers. Remember the oil commercial years ago, that went something like: “Pay me now or pay me later, but you're eventually going to pay me.” We're paying a lot for staff turnover and decreased productivity because people are feeling unsupported by administrators. Staff morale is lower, too. If we can provide better training and supervision, we can save the agency considerable expense. Second, if we can train our staff better, we can perhaps increase both the quality of our care and the number of clients we can serve. That goes right to the bottom line.

JONATHAN: Are you sure you didn't get an M.B.A. somewhere along the way? You sound like a business person. Are you saying we're not as productive as we might be? Isn't that an administrative issue if people are not doing their jobs?

ELLA: If we support them further, they could do an even better job. Our counselors are excellent at what they do. They work very hard and for long hours. Often that leads to burnout and eventually staff turnover. If we reduced that burnout through supervision, we'd keep them here longer, and their treatment of clients would improve. That would help our credibility in the community and eventually lead to more services and revenue. “Pay me now or pay me later.” The choice is up to you.

JONATHAN: Okay. So what are you proposing, and what will it cost?

ELLA: For an agency our size, with only a few counselors, two clinical supervisors can do the job. At the same time, they can attend to some administrative issues too, in addition to their own clinical work. At the training, I learned of a system where a supervisor would spend about 3 hours a week supervising her counselors. Some of the time is observation, and the rest is individual and group supervision. I can show you the matrix we'd use to do this. Each counselor would be observed in action with a client at least once a month. The supervisor would meet with the team every week and review the case presented by the counselor of the week. We'd use videotape of counseling sessions to demonstrate the counselor's skills and actions. The group would view sections of the videotape, and we'd have an hour-long discussion of the tape. In some cases, instead of videotaping (it may not be appropriate to videotape some clients), the supervisor would sit in on the actual session and observe. They'd then follow the same individual in small group supervision discussion. To do this, I need you to provide funds to purchase video cameras, tripods, and DVDs. We need $1,000 for this purchase. That will ensure we're making a reasonable effort to supervise and will significantly increase our clinical supervision system here. What do you think?

How To Implement a Clinical Supervision System

[image] To clarify the above statement by Ella, if a supervisor oversees the work of one to five counselors, it typically requires 2–3 hours per week (see Figure 3 on p. 11). This entails relying on group clinical supervision and direct observation through audio- or videotaping or live supervision. Supervisors might need to provide additional time for close supervision of trainees, interns, or counselors needing specific attention. The critical aspects in rolling out a clinical supervision system include:

1. Administrative support. This should be in the form of both written and oral communication to all personnel showing administrators' support for clinical supervision.
2. Training of supervisors. Credentialing organizations require a certain number of hours of training to be certified as clinical supervisors. Simply because a person is a good counselor does not qualify them to be a supervisor. It requires another body of knowledge and skills to be a supervisor.
3. Educating staff about what quality supervision is and what to expect in the new system. A session for clinical staff should be held (1–2 hours duration), explaining the rationale for supervision, the policies, procedures, techniques, and expectations of supervision.
4. A system of supervision of supervision, monitoring the progress of supervisors in implementing the system, and providing feedback on how they are doing. This is sorely lacking for most supervisors, at least initially. This can be done through internal supervisors overseeing other supervisors, peer supervision of supervisors, or externally by contracting with a master supervisor to oversee the work of supervisors.
5. Consistency of the message that supervision is here to stay and that clinical supervision is a requirement of the agency.
6. Time to implement the system, acknowledging and working through staff resistance to change. Attitudes and behaviors about supervision change slowly. Thus, administrators need to understand that it takes time to work with personnel, to be clear about what's expected of them, and to overcome staff resistance.

JONATHAN: We can do that. That's a modest expense we can afford. How do I sell this to the board?

ELLA: What did the potential law suit cost us last year in legal fees? Surely more than the cost of three cameras. What does it cost us to train a new counselor when someone leaves? Surely more than the time we're investing in their training. Perhaps you could tell that board that if we can retain a staff member for 6–12 months longer, we'll save the agency far more than you've invested in supervision. By being careful, by providing quality supervision, in the long run, it will in fact save us money by being preventive.

JONATHAN: What else can I tell the board about this supervision system?

ELLA: You can tell them that when a counselor leaves, clients react and the quality of their care decreases. The board is interested in client satisfaction and treatment outcome. This supervision system will help with that.

JONATHAN: Okay, I'm sold. What's next?

ELLA: First, I want to submit to you this plan I've developed for the supervision system. I'd ask that you read it and next time we meet, if we concur, I'd like a written statement from you endorsing the plan. I'd also like you to introduce the program at our next all-staff meeting. How does that sound so far?

JONATHAN: That's fair. Then what?

ELLA: Second, we need funding for the equipment. Third, we need to identify potential supervisory candidates from within the organization. If none can be found, we will have to look outside the agency to recruit a qualified supervisor. Fourth, we will begin to train our supervisors in this model of supervision. This can be done through a number of low-cost media. Fifth, we will provide an in-service training for all staff on the supervision system. We need to be clear with staff that we're going to be observing them with videotape and/or direct observation. Some won't like that. Some staff will be quite resistant to the change. This will take time—likely about a year for everybody to be on board. You and I have to be consistent over time, reinforcing the message that this is how we're doing clinical supervision here, regardless of staff's credentials or years of experience. There's going to be a learning curve.

[image] Master Supervisor Note: Again, it is important to be prepared for this presentation with a clear statement of funding requirements, training needs, mechanisms of how these needs will be met, and benchmarks for success. Further, it is essential to get a firm commitment to the plan from administrators before the supervisor proceeds. The supervisor should also stress the barriers and obstacles to be overcome and how those will be addressed.

JONATHAN: Some of the distinction between case management and clinical supervision will hopefully become clearer to me and staff as we implement the system. You're going to have to continue to educate me about it. I'd like to meet regularly with you, perhaps once a week during the roll-out, to discuss how we're doing. Since the State now requires our counselors to eventually be certified, will this help in that process?

ELLA: Absolutely. As you might recall, to be certified as an addiction counselor, the person must be supervised by a certified supervisor. This system will meet that requirement. It will help our counselors to be certified.

[Jonathan and Ella summarize the advantages of a model for clinical supervision that includes workforce development and a means to implement evidence-based practices, address risk-management issues and vicarious liability, create consistency within the agency, minimize reactivity, address accreditation issues, and support counselor wellness.]

JONATHAN: Can you bring me a budget for what this will cost in person hours and hardware by next week? Talk to our accountant if you need costing data. How are we going to train our supervisors? What will that cost? What's the most cost-effective way of conducting the staff and supervisor training? I'd like to see a 3-, 6-, and 12-month implementation and financial plan for this. Can you provide projections as to potential cost offsets and savings on the other end? Can you have that for me by next week?

ELLA: Yes, I can do that by next week. I'll also give ideas as to how supervisors can balance management and administrative duties, maintain a caseload, and perform other duties as assigned.