# Appendix F—Acknowledgments

Numerous people contributed to the development of this TIP, including the TIP Consensus Panel (see page v), the Knowledge Application Program (KAP) Advisory Meeting Panel (see Appendix C), the SAMHSA Stakeholders Meeting attendees, (see Appendix D), and TIP Field Reviewers (see Appendix E).

This publication was produced under KAP, a Joint Venture of The CDM Group, Inc. (CDM), and JBS International, Inc. (JBS), for the Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment.

CDM KAP personnel included Rose M. Urban, M.S.W., J.D., LCSW, LCAS, KAP Executive Deputy Project Director; Susan Kimner, Managing Project Co-Director; Bruce Carruth, Ph.D., Expert Content Director; Janet Humphrey, M.A., former Editor; Virgie D. Paul, M.L.S., Librarian; Lee Ann Knapp, Quality Assurance Editor.