# Appendix E: Field Reviewers

Note that information given indicates each participant's affiliation as of 2008, when the review was conducted, and may no longer reflect the individual's current affiliation.

L. DiAnne Borders, Ph.D.
Excellence Professor
University of North Carolina at Greensboro
Greensboro, NC

Donny Brock
Treatment Director, Outpatient Division Head
Charleston Center
Charleston, SC

Patricia A Burke, M.S.W., LCSW
Private Practice
West Baldwin, ME

Charlotte M. Chapman
Director of Training
Mid-Atlantic Addiction Technology Transfer Center
Richmond, VA

Thomas G. Durham, Ph.D.
Executive Director, The Danya Institute
Silver Spring, MD

Janet E. Falvey, Ph.D., NCC, ACS
Professor
University of New Hampshire
Durham, NH

Steven L. Gallon, Ph.D.
Northwest Frontier Addiction Technology Transfer Center
Salem, OR

John Hamilton LMFT, LADC
Regional Network of Programs, Inc.
Fairfield, CT

Ted Judson, M.Ed., ADC2, CCS
Assistant Department Head
Navy Drug and Alcohol Counselor School
San Diego, CA

Hunter McQuisition, M.D.
Director, Division of Integrated Psychiatric Services, Department of Psychiatry
The St. Luke's–Roosevelt Hospitals
New York, NY

Thomas A. Peltz, LMHC, CADAC I, CAS
Private Practice
Beverly Farms, MA

Annie Ramniceanu
Clinical Director
Spectrum Youth and Family Services
Burlington, VT

Sandra A. Rigazio-DiGilio, Ph.D.
Professor
Marriage and Family Therapy Program
University of Connecticut
Storrs, CT

John (Jack) M. Schibik, Ph.D., LPC, LCADC, CCS, CPS
Kairos Counseling, Consulting Coaching Services
Naples, Florida

Diane Shea, Ph.D.
Adjunct Professor
Holy Family University
Newtown, PA

Ernestine Winfrey
Executive Director
Good News Home for Women
Flemington, NJ