# Appendix D: Stakeholders Meeting Participants

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

H. Westley Clark, M.D., J.D., M.P.H., CAS, FASAM
Director
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Mirean Coleman, M.S.W., LICSW, CT
Senior Policy Associate
National Association of Social Workers (NASW)
Washington, DC

Tom Durham, Ph.D.
Executive Director
The Danya Institute
Silver Spring, Maryland

Anne M. Herron, M.S.W.
Director, Division of State and Community Assistance
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Ted Judson, M.Ed., ADC2, CCS
Certification and Contracts Officer
Navy Drug and Alcohol Counselor School
San Diego, California

Linda Kaplan
Special Expert
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Peter J. Martieau
Public Health Analyst
Center for Substance Abuse Prevention
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Jack Stein, M.S.W., Ph.D.
Director, Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Bill Trefzger
Lead, Communication Services Team
Office of Communication
Substance Abuse and Mental Health Services Administration
Rockville, Maryland