# Appendix A: Bibliography

Addiction Technology Transfer Center. (2004). The Change Book: A Blueprint for Technology Transfer. (2nd ed.) Kansas City, MO: Author.
American Psychological Association. (2007). Record keeping guidelines. American Psychologist, 62, 993–1004.
Anderson, C. E. (2000). Supervision of substance abuse counselors using the integrated developmental model. Clinical Supervisor, 19, 185–195.
Beauchamp, T. L. & Childress, J. F. (2001). Principles of Biomedical Ethics. (5th ed.) New York: Oxford University Press.
Bernard, J. M. & Goodyear, R. K. (2004). Fundamentals of Clinical Supervision. Boston, MA: Pearson Education.
Borders, L. D., & Brown, L. L. (2005). The New Handbook of Counseling Supervision. Mahwah, NJ: Lawrence Erlbaum Associates.
Bradley, L. J. & Ladany, N. (Eds.) (2001). Counselor Supervision: Principles, Process, and Practice. (3rd ed.) Philadelphia: Brunner-Routledge.
Burke, P. A., Carruth, B., & Prichard, D. (2006). Counselor self-care in work with traumatized, addicted people. In Carruth, B. (Ed.). Psychological Trauma and Addiction Treatment (pp. 283–301). New York: Haworth Press.
Campbell, J. M. (2000). Becoming an Effective Supervisor: A Workbook for Counselors and Psychotherapists. Philadelphia: Accelerated Development.
Carroll, K. M., Ball, S. A., Nich, C., Martino, S., Frankforter, T. L., Farentinos, C. et al. (2006). Motivational interviewing to improve treatment engagement and outcome in individuals seeking treatment for substance abuse: A multisite effectiveness study. Drug and Alcohol Dependence, 81, 301–312.16169159
Center for Substance Abuse Treatment. (1993a). Improving Treatment for Drug-Exposed Infants. Treatment Improvement Protocol (TIP) Series 5. (HHS Publication No. (SMA) 95-3057. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1993b). Pregnant, Substance-Using Women. Treatment Improvement Protocol (TIP) Series 2. (HHS Publication No. (SMA) 93-1998. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1993c). Screening for Infectious Diseases Among Substance Abusers. Treatment Improvement Protocol (TIP) Series 6. (HHS Publication No. (SMA) 95-3060. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1994). Simple Screening Instruments for Outreach for Alcohol and Other Drug Abuse and Infectious Diseases. Treatment Improvement Protocol (TIP) Series 11. (HHS Publication No. (SMA) 94-2094. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995a). Alcohol and Other Drug Screening of Hospitalized Trauma Patients. Treatment Improvement Protocol (TIP) Series 16. (HHS Publication No. (SMA) 95-3041. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995b). Combining Alcohol and Other Drug Treatment With Diversion for Juveniles in the Justice System. Treatment Improvement Protocol (TIP) Series 21. (HHS Publication No. (SMA) 95-3051. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995c). Developing State Outcomes Monitoring Systems for Alcohol and Other Drug Abuse Treatment. Treatment Improvement Protocol (TIP) Series 14. (HHS Publication No. (SMA) 95-3031. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995d). The Role and Current Status of Patient Placement Criteria in the Treatment of Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 13. (HHS Publication No. (SMA) 95-3021. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995e). The Tuberculosis Epidemic: Legal and Ethical Issues for Alcohol and Other Drug Abuse Treatment Providers. Treatment Improvement Protocol (TIP) Series 18. (HHS Publication No. (SMA) 95-3047. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1996). Treatment Drug Courts: Integrating Substance Abuse Treatment with Legal Case Processing. Treatment Improvement Protocol (TIP) Series 23. (HHS Publication No. (SMA) 96-3113. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1997a). A Guide to Substance Abuse Services for Primary Care Clinicians. Treatment Improvement Protocol (TIP) Series 24. (HHS Publication No. (SMA) 97-3139. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1997b). Substance Abuse Treatment and Domestic Violence. Treatment Improvement Protocol (TIP) Series 25. (HHS Publication No. (SMA) 97-3163. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998a). Comprehensive Case Management for Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 27. (HHS Publication No. (SMA) 98-3222. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998b). Continuity of Offender Treatment for Substance Use Disorders from Institution to Community. Treatment Improvement Protocol (TIP) Series 30. (HHS Publication No. (SMA) 98-3245. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998c). Naltrexone and Alcoholism Treatment. Treatment Improvement Protocol (TIP) Series 28. (HHS Publication No. (SMA) 98-3206. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998d). Substance Abuse Among Older Adults. Treatment Improvement Protocol (TIP) Series 26. (HHS Publication No. (SMA) 98-3179. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998e). Substance Use Disorder Treatment for People With Physical and Cognitive Disabilities. Treatment Improvement Protocol (TIP) Series 29. (HHS Publication No. (SMA) 98-3249. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999a). Brief Interventions and Brief Therapies for Substance Abuse. Treatment Improvement Protocol (TIP) Series 34. (HHS Publication No. (SMA) 99-3353. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999b). Enhancing Motivation for Change in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 35. (HHS Publication No. (SMA) 99-3354. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999c). Screening and Assessing Adolescents for Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 31. (HHS Publication No. (SMA) 99-3282. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999d). Treatment of Adolescents With Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 32. (HHS Publication No. (SMA) 99-3283. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999e). Treatment for Stimulant Use Disorders. Treatment Improvement Protocol (TIP) Series 33. (HHS Publication No. (SMA) 99-3296. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2000a). Integrating Substance Abuse Treatment and Vocational Services. Treatment Improvement Protocol (TIP) Series 38. (HHS Publication No. (SMA) 00-3470. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2000b). Substance Abuse Treatment for Persons With Child Abuse and Neglect Issues. Treatment Improvement Protocol (TIP) Series 36. (HHS Publication No. (SMA) 00-3357. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2000c). Substance Abuse Treatment for Persons With HIV/AIDS. Treatment Improvement Protocol (TIP) Series 37. (HHS Publication No. (SMA) 00-3459. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2003). Manpower Development Study. Bethesda, MD: Department of Health and Human Services.
Center for Substance Abuse Treatment. (2004a). Clinical Guidelines for the Use of Buprenorphine in the Treatment of Opioid Addiction. Treatment Improvement Protocol (TIP) Series 40. (HHS Publication No. (SMA) 04-3939. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2004b). Substance Abuse Treatment and Family Therapy. Treatment Improvement Protocol (TIP) Series 39. (HHS Publication No. (SMA) 04-3957. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005a). Medication-Assisted Treatment for Opioid Addiction. Treatment Improvement Protocol (TIP) Series 43. (HHS Publication No. SMA 05-4048. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005b). Substance Abuse Treatment for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series 44. (HHS Publication No. (SMA) 05-4056. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005c). Substance Abuse Treatment: Group Therapy. Treatment Improvement Protocol (TIP) Series 41. (HHS Publication No. SMA 05-4056. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005d). Substance Abuse Treatment for Persons With Co-Occurring Disorders. Treatment Improvement Protocol (TIP) Series 42. (HHS Publication No. SMA 05-3992. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006). Addiction Counseling Competencies: The Knowledge, Skills, and Attitudes of Professional Practice. Technical Assistance Publication (TAP) Series 21 (Rep. No. HHS Publication No. (SMA) 07-4243. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006a). Detoxification and Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 45. (HHS Publication No. SMA 06-4131. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006b). Substance Abuse: Administrative Issues in Intensive Outpatient Treatment. Treatment Improvement Protocol (TIP) Series 46. (HHS Publication No. SMA 06-4151. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006c). Substance Abuse: Clinical Issues in Intensive Outpatient Treatment. Treatment Improvement Protocol (TIP) Series 47. (HHS Publication No. 06-4182. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2007). Competencies for Substance Abuse Treatment Clinical Supervisors. Technical Assistance Publication (TAP) Series 21-A (Rep. No. HHS Publication No. (SMA) 07-4243. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2008). Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery. Treatment Improvement Protocol (TIP) Series 48. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2009). Addressing Suicidal Thoughts and Behaviors in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 50. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2009). Incorporating Alcohol Pharmacotherapies Into Medical Practice. Treatment Improvement Protocol (TIP) Series 49. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2009). Substance Abuse Treatment: Addressing the Specific Needs of Women. Treatment Improvement Protocol (TIP) Series 51. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development a). Addressing Viral Hepatitis in People With Substance Use Disorders. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development b). Improving Cultural Competence in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development c). Management of Chronic Pain in People With or in Recovery From Substance Use Disorders. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development d). Relapse Prevention and Recovery Promotion. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development e). Substance Abuse Treatment for Native Americans and Alaska Natives. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development f). Substance Abuse Treatment: Men's Issues. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development g). Substance Abuse Treatment for People Who Are Homeless. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development h). Substance Abuse and Trauma. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Constantine, M. G. (2003). Multicultural competence in supervision: Issues, processes, and outcomes. In Pope-Davis, D. B., Coleman, H. L. K., Liu, W. M., & Toporek, R. L. (Eds.), Handbook of Multicultural Competencies: In Counseling & Psychology (pp. 383–391). Thousand Oaks, CA: Sage Publications.
Cross, T. L., Bazron, B. J., Dennis, K. W., and Isaacs, M. R. (1989). Towards a Culturally Competent System of Care: A Monograph on Effective Services for Minority Children Who Are Severely Emotionally Disturbed. Volume 1. Washington, DC: Georgetown University Child Development Center.
Delaney, D. J. (1972). A behavioral model for the supervision of counselor candidates. Counselor Education and Supervision 12, 46–50.
Dixon, G. D. (2004). Clinical Supervision: A Key to Treatment Success. Southern Coast Beacon Tallahassee, FL: Southern Coast ATTC.
Falender, C. A., & Shafranske, E. P. (2004). Clinical supervision: A Competency-Based Approach. Washington, DC: American Psychological Association.
Falvey, J. E. (2002a). Documentation in Supervision: The Focused Risk Management Supervision System (FoRMSS). Pacific Grove, CA: Brooks/Cole.
Falvey, J. E. (2002b). Managing Clinical Supervision: Ethical Practice and Legal Risk Management. Pacific Grove, CA: Brooks/Cole-Thomson Learning.
Fong, M. L., & Lease, S. H. (1997). Cross-cultural supervision: Issues for the white supervisor. In D. B. Pope-Davis & H. L. K. Coleman (Eds.), Multicultural Counseling Competencies: Assessment, Education and Training and Supervision (pp. 387–405). Thousand Oaks, CA: Sage.
Glenn, E., & Serovich, J. M. (1994). Documentation of family therapy supervision: A rationale and method. American Journal of Family Therapy, 22, 345–355.
Herman, K. C. (1993). Reassessing predictors of therapist competence. Journal of Counseling & Development, 72, 29–32.
Hogan, R. A. (1964). Issues and approaches in supervision. Psychotherapy: Theory, Research, Practice, Training, 1, 139–141.
Holloway, E. (1995). Clinical Supervision: A Systems Approach. Thousand Oaks, CA: Sage Publications.
Hubble, M. A., Duncan, B. L., and Miller, S. D. (Eds.). (1999). The Heart and Soul of Change: What Works in Therapy. Washington, DC: American Psychological Association.
International Certification & Reciprocity Consortium. (2000). Clinical Supervisor of Alcohol and Other Drug Abuse Counselors Role Delineation Study. Research Triangle Park, NC: CASTLE Worldwide, Inc.
Kadushin A. (1976). Supervision in Social Work. New York: Columbia University Press.
Lambie, G. (2006). Burnout prevention: A humanistic perspective and structured group supervision activity. Journal of Humanistic Counseling, Education & Development, 45, 32–44.
Lindbloom, G., Ten Eyck, T. G., & Gallon, S. L. (2004). Clinical Supervision I: Building Chemical Dependency Counselor Skills: Instructor Guide. Salem, Oregon: Northwest Frontier Addiction Technology Transfer Center.
Loganbill, C., Hardy, E., & Delworth, U. (1982). Supervision: A conceptual model. Counseling Psychologist, 10, 3–42.
Mattel, P. (2007). Designing and implementing clinical supervision. Unpublished manuscript.
Munson, C. E. (1979). Social Work Supervision. New York: Free Press.
Munson, C. E. (1993). Clinical Social Work Supervision. (2nd ed.) New York: Haworth Press.
NAADAC, The Association for Addiction Professionals (2003). NAADAC, The Association for Addiction Professionals Practitioner Services Network Year 2 Final Report: A Survey of Early Career Substance Abuse Counselors. Washington, DC: NAADAC, The Association for Addiction Professionals.
Nichols, W. C., Nichols, D. P., & Hardy, K. V. (1990). Supervision in family therapy: A decade restudy. Journal of Marital & Family Therapy, 16, 275–285.
Pope, K. S., Sonne, J. L., & Greene, B. (2006). What Therapists Don't Talk About and Why: Understanding Taboos That Hurt Us and Our Clients. (2d ed.). Washington, DC: American Psychological Association.
Pope-Davis, D. B. & Coleman, H. L. K. (Eds.) Multicultural Counseling Competencies: Assessment, Education and Training, and Supervision (1997). Thousand Oaks, CA: Sage Publications.
Porter, J. & Gallon, S. L. (2006). Clinical Supervision II: Addressing Supervisory Problems in Addictions Treatment. Salem, OR: Northwest Frontier Addiction Technology Transfer Center.
Powell, D. J., & Brodsky, A. (2004). Clinical Supervision in Alcohol and Drug Abuse Counseling: Principles, Models, Methods. (Rev. ed.). San Francisco: Jossey-Bass.
Reamer, F. G. (2006). Social Work Values and Ethics. (3rd ed.) New York: Columbia University Press.
Remley, T. P., & Herlihy, B. (2007). Ethical, Legal, and Professional Issues in Counseling. (Updated 2nd ed.). Upper Saddle River, NJ: Pearson Merrill Prentice Hall.
Rigazio-DiGilio, S. A. (1997). Integrative supervision: Approaches to tailoring the supervisory process. In T. Todd and C. Storm (Eds.) The Complete Systemic Supervisor: Context, Philosophy, and Methods (pp. 195–217). Needham Heights, MA: Allyn and Bacon.
Roche, A. M., Todd, C. L., & O'Connor, J. (2007). Clinical supervision in the alcohol and other drugs field: An imperative or an option? Drug and Alcohol Review, 26, 241–249.17454013
Shoptaw, S., Stein, J., & Rawson, R. (2000). Burnout in substance abuse counselors: Impact of environment, attitudes, and clients with HIV. Journal of Substance Abuse Treatment, 19, 117–126.10963923
Skovholt, T. M., & Ronnestad, M. H. (1992). The Evolving Professional Self: Stages and Theories in Therapist and Counselor Development. New York: Wiley.
Spice, C. G., Jr. & Spice, W. H. (1976). A triadic method of supervision in the training counselors and counseling supervisors. Counselor Education and Supervision, 15, 251–258
Stoltenberg, C. D. & Delworth, U. (1987). Supervising Counselors and Therapists: A Developmental Approach. San Francisco: Jossey-Bass.
Stoltenberg, C. D., McNeill, B., & Delworth, U. (1998). IDM Supervision: An Integrated Developmental Model for Supervising Counselors and Therapists. (1st ed.) San Francisco: Jossey-Bass Publishers.
Swenson, L. C. (1997). Psychology and Law for the Helping Professions (2nd ed.). Pacific Grove, CA: Brooks/Cole Pub. Co.
Tromski-Klingshirn, D. (2006). Should the clinical supervisor be the administrative supervisor? The ethics versus the reality, The Clinical Supervisor, 25, 53–67.
U.S. Department of Health and Human Services (2003). Developing Cultural Competence in Disaster Mental Health Programs: Guiding Principles and Recommendations. (Rep. No. HHS Pub. No. SMA 3828). Rockville, MD: Center for Mental Health Services, Substance Abuse and Mental Health Services Administration.
White, W. L. & Popovits, R. M. (2001). Critical incidents: Ethical Issues in the Prevention and Treatment of Addiction. (2nd ed.). Bloomington, IL: Chestnut Health Systems.
Williams, L. (1994). A tool for training supervisors: Using the supervision feedback form (SFF). Journal of Marital and Family Therapy, 20, 311–315.