# Editorial Board

Gene Burkett, M.D., B.S., FRCOG, FACOG, Diplomate American Board, OB/GYN
Professor
Obstetrics and Gynecology
University of Miami School of Medicine

Jacqueline Butler, M.S.W., LISW, LPCC, CCDC III, CJS
Professor of Clinical Psychiatry (Social Work)
University of Cincinnati, College of Medicine
Executive Director
The Crossroads Center

Grace Chang, M.D., M.P.H.
Associate Professor of Psychiatry, Harvard Medical School
Brigham and Women's Hospital

Elena Flores, Ph.D.
Associate Professor
Counseling Psychology Department
School of Education
University of San Francisco

Jacki McKinney
Executive Director
National People of Color Consumer Survivor Network

Lisa Najavits, Ph.D.
Associate Professor of Psychology
Harvard Medical School

Dace Svikis, Ph.D.
Associate Professor
Virginia Commonwealth University

William White, M.A.
Senior Research Consultant
Chestnut Health Systems/Lighthouse Institute