# Consensus Panel

## Chair

Norma B. Finkelstein, Ph.D., M.S.W.
Executive Director
Institute for Health & Recovery
Cambridge, Massachusetts

## Co-Chair

Juana Mora, Ph.D.
Professor
Northridge Chicano/a Studies Department
California State University, Northridge
Northridge, California

## Workgroup Leaders

Karen Allen, Ph.D., R.N., FAAN
Professor/Chair
Department of Nursing
Andrews University
Berrien Springs, Michigan

Hortensia Amaro, Ph.D.
Distinguished Professor
Center on Health and Social Science Research Director
Institute on Urban Health Research
Northeastern University
Boston, Massachusetts

Stephanie S. Covington, Ph.D., LCSW
Co-Director
Center for Gender and Justice
Institute for Relational Development
La Jolla, California

Francine Feinberg, Psy.D., CISCW
Executive Director
Meta House
Whitefish Bay, Wisconsin

Beth Glover Reed, Ph.D.
Associate Professor
Social Work and Women's Studies
School of Social Work
University of Michigan
Ann Arbor, Michigan

Brenda L. Underhill, M.S., CAC
President
Underhill and Associates
El Cerrito, California

## Panelists

Belinda Biscoe, Ph.D.
Assistant Vice President for Public and Community Services
Director, Region VII Comprehensive Assistance Center
Director, Education, Training, Evaluation, Assessment and Measurement Department (E-TEAM)
University of Oklahoma
Norman, Oklahoma

Vivian B. Brown, Ph.D.
Founder, Board Member Emeritus
PROTOTYPES
Culver City, California

Margaret A. Cramer, Ph.D.
Clinical Psychologist/Instructor
Massachusetts General Hospital
Boston, Massachusetts

Gloria Grijalva-Gonzales
Certified Sr. Substance Abuse Case Manager/Counselor
Allies Project
San Joaquin County
Stockton, California

Tonda L. Hughes, Ph.D., R.N.
Professor
Department of Health Systems Science
University of Illinois at Chicago
Chicago, Illinois

Marty A. Jessup, Ph.D., R.N., M.S.
Associate Adjunct Professor
Department of Family Health Care Nursing
Institute for Health and Aging
University of California, San Francisco
San Francisco, California

Karol A. Kaltenbach, Ph.D.
Clinical Associate Professor of Pediatrics, Psychiatry and Human Behavior
Director, Maternal Addiction Treatment Education and Research
Department of Pediatrics
Jefferson Medical College
Thomas Jefferson University
Philadelphia, Pennsylvania

Robin A. LaDue, Ph.D.
Clinical Psychologist
Department of Psychiatry and Behavioral Sciences
University of Washington
Renton, Washington

LaVerne R. Saunders, B.S.N., R.N., M.S.
Founder/Partner
Dorrington & Saunders and Associates
Framingham, Massachusetts

Starleen Scott-Robbins, M.S.W., LCSW
Women's Treatment Coordinator
Best Practice Consultant
Developmental Disabilities and Substance Abuse Services
Division of Mental Health
North Carolina Department of Health and Human Services
Raleigh, North Carolina

Sally J. Stevens, Ph.D.
Executive Director
Southwest Institute for Research on Women
University of Arizona
Tucson, Arizona

Sharon Wilsnack, Ph.D.
Professor
Department of Clinical Neuroscience
Medical School for the Public
School of Medicine & Health Sciences
University of North Dakota
Grand Forks, North Dakota

Rita Zimmer, M.P.H.
Founder
Women in Need, Inc.
New York, New York