# 8 Recovery Management and Administrative Considerations

In This Chapter

Continuing Care

Treatment Outcome

Support Systems for Women

Administrative Considerations

## Overview

The first part of this chapter, aimed at the substance abuse treatment counselor, examines the most critical aspects of recovery management including continuing care services, outcome and relapse variables, and support services. The second part is directed toward substance abuse treatment program administrators and supervisors. This segment looks at the benefits of consumer participation in programming, the characteristics of a healing environment for treatment, and the main components of staff development including staffing, training, and clinical supervision specific to women's programming. Organizational change strategies that focus on how an organization can become gender responsive follow.

## Continuing Care

Continuing care services, often referred to as aftercare, are substance abuse services that occur after initial treatment. Continuing care is designed to provide less intensive services as the client progresses in treatment and establishes greater duration of abstinence. The dearth of research on continuing care is particularly evident surrounding gender differences. Several studies are available that show potential patterns, but caution is needed in interpreting the findings due to methodological issues and sample size.

Although women appear more likely to attend aftercare, any transition from one service to the next can be challenging for the client and treatment provider (Carter et al. 2008). In general, clients are more likely to discontinue treatment during these periods. Women often express feelings of disconnection with the new treatment provider and experience additional struggles in managing the added demands and expectations of child care while attending less intensive treatment. Relapse is more prevalent during these periods, especially when there is little compliance or support from family to follow aftercare plans. The initial risk factors that served as a direct or indirect path to substance use often are the same risk factors that reappear in early recovery and sabotage involvement in continuing care, recovery activities, and abstinence. As an example, women who have a history of substance use that involves a significant relationship appear more likely to leave care prematurely due to the influence of a boyfriend, spouse, or significant other.

In one study that gained information from program case managers, it was reported that the women who had prior inadequate drug treatment services were most likely to drop out of continuing services (Coughey et al. 1998). Those women who completed aftercare had two times the amount of prior residential alcohol/drug treatment and longer sobriety time at admission. Equally important, women appear more likely to engage in continuing care if the primary treatment they received involved specialized programming for women (Claus et al. 2007).

## Treatment Outcome

Historically, researchers have used posttreatment abstinence rates as the focal point of measuring success. Debate has ensued regarding how to measure treatment outcome and whether or not posttreatment abstinence rates are myopic in that they fail to account for the physical, psychological, and social conditions that improve in the treatment process. Other commentaries have suggested that using abstinence rates as the only benchmark to measure outcome falls short of recognizing the chronic nature of substance dependence disorders—that relapse is not inevitable but a likely event that can provide a client with a learning opportunity to strengthen recovery skills. Overall, most outcome studies have targeted more immediate responses to treatment, often measuring and following outcome variables no longer than 12 months beyond discharge (Grella et al. 2005). This section examines the many factors that contribute to treatment outcome and includes numerous studies that expand the definition of treatment outcome beyond abstinence rates, including quality of life and other biopsychosocial benefits. The segment ends with a discussion on relapse and prevention for women, and specifically for postpartum women.

Gender is not a significant predictor of treatment outcome. Once in treatment, women are as likely as men to complete treatment and have good treatment outcomes, although outcome differences are noted when evaluating individual and program characteristics (for a comprehensive literature review, see Greenfield et al. 2007a). Women are also as likely to have similar abstinence rates and overall quality of life 1 year after discharge from treatment (Slaymaker and Owen 2006). As shown by previous research (Timko et al. 2002), women show greater increases than men in employment, recovery-oriented social support systems, and participation in self-help groups (Grella et al. 2005). Grella's study found that women have greater reduction in levels of distress, although their levels of distress appear to remain consistently higher than those of their male counterparts at each period of outcome evaluation. For women with posttraumatic stress reactions, literature supports the relationship between the receipt of integrated trauma treatment services and positive treatment outcome (Cohen and Hien 2006; Cocozza et al. 2005). In a posttreatment outcome study measuring factors that predicted 5-year abstinence, 12-Step participation and involvement in social networks that support recovery were among the essential ingredients (Weisner et al. 2003a, b).

Although further evaluation is needed, there appears to be a stronger association between treatment participation and posttreatment outcome among women (Fiorentine et al. 1997; Hser et al. 2004). Literature suggests that treatment completion and length of stay in residential treatment are important factors in establishing positive posttreatment outcomes among women (Greenfield et al. 2004). Specific posttreatment outcome analysis comparing length of treatment to posttreatment outcome in residential treatment for pregnant and parenting women and their children shows an association between longer lengths of stay and abstinence, improvements in employment and income, decreases in arrests and depressive symptoms, and more positive attitudes toward parenting (Conners et al. 2006). Although studies have begun to shed light on gender differences in posttreatment outcome, future research should continue to examine the specific underlying factors that influence treatment outcomes and how these factors differ between men and women.

### Relapse

Gender alone does not predict substance abuse treatment outcomes. Instead, client characteristics are more likely to predict relapse, and these characteristics often influence the risk of relapse differently in men and women (Greenfield et al. 2007b). Women who complete treatment for substance use disorders show no significant differences in relapse rates or only slightly better outcomes compared with men (for review, see Walitzer and Dearing 2006). However, gender differences do emerge across qualitative and quantitative studies that evaluate antecedents or risk factors associated with relapse and the clients' psychological and behavioral reactions to the relapse. Relapse characteristics and reactions specific to women are highlighted in Figure 8-1 (p. 184).

Figure 8-1 Women-Specific Predictors of Relapse and Reactions to Relapse

Relapse Risks Unique to Women

Women are more likely to relapse if they report or display:

• Interpersonal problems and conflicts.
• Low self-worth that is connected to intimate relationships.
• Severe untreated childhood trauma.
• Strong negative affect.
• More symptoms of depression.
• Greater difficulty in severing ties with other people who use.
• Failure to establish a new network of friends.
• Lack of relapse prevention coping skills.

Women's Reactions to Relapse

Women are more likely than men to exhibit the following behaviors during or after relapse:

• Relapsing in the company of others and particularly with female friends or a significant other.
• Escalating use after initial relapse that is positively associated with severity of childhood trauma.
• Seeking help.
• Experiencing slightly shorter relapse episodes.
• Reporting depressed mood.

Women are less likely than men to be affected by the same relapse risks across multiple relapse episodes.

Source: Coyne et al. 2006; Hyman et al. 2007; McKay et al. 1996; Project MATCH 1997; Rubin et al. 1996; Sun 2007; Zywiak et al. 2006.

Women are as likely as men to experience positive treatment outcomes including similar abstinence rates and overall improvement in quality of life.

Currently, many relapse prevention programs do not delineate specific strategies and therapeutic approaches for women. Thus, research is needed to develop and evaluate relapse prevention programs and intervention strategies for women. One randomized study is available that evaluates a manual-based, women-only, women-oriented relapse prevention therapy group called Women's Recovery Group (WRG). In this study, WRG produced better outcomes in the 6 months following treatment than a mix-gender group using a standard manual-based program (Greenfield et al. 2007b). A forthcoming book by Greenfield, to be published by Guildford Press, will provide the protocol for this women-specific relapse prevention group. Figure 8-2 provides examples of topics discussed in WRG.

Figure 8-2 Women's Recovery Group: Manual-Based Relapse Prevention

Group Format: 90-minute sessions

• Brief check-in
• Review of past week's skill practice
• Presentation on session topic
• Open discussion of topic and other recovery-related issues
• Review of session's “take-home message” and upcoming week's skill practice
• Check-out

Content Areas:

• The effect of drugs and alcohol on women's health
• What are the obstacles to seeking treatment and getting into recovery?
• Managing mood, anxiety, and eating problems without using substances
• Violence and abuse: Getting help
• Women and their partners: The effect on the recovery process
• Women as caretakers: Can you care for yourself while taking care of others?
• Women's use of substances through the life cycle
• Substance use and women's reproductive health
• The issue of disclosure: To tell or not to tell
• How to manage triggers and high risk situations
• Using self-help groups to help yourself
• Can I have fun and not use drugs or alcohol?
• Coping with stress
• Achieving balance in your life

Source: Greenfield et al. 2007b

Note to Clinicians: Family Reunification

The ability to regain custody of children can significantly motivate mothers to not only enter and pursue treatment but also to maintain motivation for ongoing recovery after treatment. Mothers in early recovery can face numerous challenges and stressors associated with reunification, including time pressures in establishing recovery to avoid termination of parental rights, the maintenance of recovery activities while assuming the parenting role, the management of affect associated with the impact of their past drug and alcohol use on their children's physical and mental health, effective implementation of parenting skills, and others (for review, see Carlson et al. 2006). As a provider, it is important to not only acknowledge the mother's initial enthusiasm and motivation for reunification, but also incorporate preparatory skills, including parenting, stress and anger management, and problemsolving to help fortify personal resources in anticipation of future parenting and childcare issues and challenges.

#### Postpartum relapse prevention

It is not uncommon for women who abstained from alcohol, drugs, and tobacco during pregnancy to return to use after childbirth (Mullen 2004). The stresses of parenting a newborn and the resumption of activities curtailed during pregnancy can involve a host of triggers. The postpartum period presents numerous triggers for relapse in recovering women who are drug dependent, including:

• Pain and other common discomforts of the postpartum period.
• Fatigue and sleep deprivation.
• Other chronic health problems.
• The stress of role adaptation and caring for a newborn (along with other children for some women).
• Shifts in relationships with partners and family members.
• Interactions with child welfare agencies, courts, and criminal justice agencies.
• Ambivalence about parenting.
• Temporary or permanent loss of custody, whether voluntary or involuntary.
• Reunification after temporary loss of infant custody.
• Guilt and grief related to infant illness or death.
• Other stressors of daily living.

Relapse prevention education with emphasis on postpartum triggers will help women anticipate and plan for such triggers. Relapse prevention techniques are often taught in groups using structured curricula that include strategies for maintenance of abstinence and recovery, such as identifying high risk situations; learning refusal skills that can be practiced with peers and staff in advance of “real life” challenges; and recognizing triggers that lead to relapse thinking, drug craving, and eventual use. Although there are multiple new demands placed on recovering postpartum women, using the tools for relapse prevention in the context of a full program of recovery activities is essential for continued abstinence.

During treatment, triggers for drug use should be identified and explored with recovering women prior to program discharge in concert with individualized treatment planning. Many of the services and resources used by the client prenatally should be continued, if not intensified, in the postpartum period. Alumnae groups and in-home visitation programs have assisted women with relapse prevention and family preservation (French et al. 2007; Gruber et al. 2001). Drug-specific research on postpartum women and relapse has primarily examined relapse to smoking after childbirth. In one study, correlates of postpartum relapse to smoking included high maternal weight gain, late or no prenatal care, and stressful life events (Carmichael and Ahluwalia 2000). Other research suggests that postpartum women relapsed to smoking in order to manage emotions, stress, and weight, and because they did not initially quit for themselves (Bottorff et al. 2000; Levine and Marcus 2004). Relapse prevention programs for postpartum women who smoke can decrease future smoking in some of these women (Ratner et al. 2000).

Advice to Clinicians: Postpartum Relapse Prevention

• Pregnancy issues must always be fully addressed within a set of comprehensive treatment plans, including postpartum relapse prevention.
• Relapse prevention following delivery is especially critical as many clients “quit for the baby” and not themselves and thus are susceptible to resume use.
• The postpartum period is saturated with stresses and triggers for relapse, and each must be addressed in the client's relapse prevention plan.

For many perinatal women who are monitored by drug courts, probation, parole, and child welfare agencies, the consequences of relapse can be devastating in terms of the potential for loss of child custody. Perinatal programs, in acknowledgment of the importance of parenting roles and relationships to women, recognize the possibility of relapse and acknowledge that this is the time when assistance to the client and her child should be intensified, not eliminated.

## Support Systems for Women

Twelve-Step recovery groups have been a vital resource for over 50 years, and as time has evolved, more women have participated in these recovery support groups. Originally, the Alcoholics Anonymous (AA) program was written by men and primarily for men, and the content and language reflected this bias—a bias that was steeped in the culture of the time period in which it was written. The AA literature has since been revised and updated, yet issues regarding sensitivity to language and the limited focus on cultural and social issues pertinent to women's dependence and recovery remain a potential roadblock for some women (Covington 1994). Nonetheless, 12-Step support groups have been the most steadfast peer-facilitated program, providing women a viable avenue of support in establishing abstinence, in developing recovery skills, and in maintaining recovery.

Most research on the effectiveness of 12-Step groups has been conducted with men, but some studies have examined gender differences. To date, research results reflect inconsistencies regarding differences in attendance and abstinence rates between men and women. Moos, Moos, and Timko (2006) found that women appeared to gain even greater benefits from AA than men, and women were more likely to attend AA and to attend more frequently. Compared with men, women showed less avoidance coping and greater reduction in depression with continued AA participation. Another study reported no gender differences in 12-Step attendance over a 24-month period, including frequency of participation and dropout rates (Hillhouse and Fiorentine 2001). For women, availability of support and sponsorship appear to be the main ingredients in perceived social support in 12-Step recovery groups (Rush 2002).

Like men, women have other options for support group involvement. Women for Sobriety is the only self-help program designed specifically for women who are alcohol-dependent. Although women can benefit from participation in groups and from the supporting women-centered literature, availability of support groups is limited. To date, gender-specific outcome research on recovery groups outside of 12-Step programs is minimal.

## Administrative Considerations

### Consumer Direction, Participation, and Empowerment

The field of substance abuse treatment has a tradition of integrating consumers into service delivery as counselors and case managers, particularly at the direct service level. However, the field is only beginning to learn about and apply the enormous benefits received when these individuals are integrated into the entire fabric of service delivery, from program design to implementation and evaluation. For example, the SAMHSA-funded Women, Co-Occurring Disorders and Violence Study demonstrated a priority on including consumers in all aspects of study design and implementation throughout the 5 years of the study.

Prescott (2001) identifies the important contributions made to service systems and research when consumers are actively involved. When hiring people in recovery as mentors, case managers, counselors, and board members, characteristics to consider include significant time in recovery, ability to handle the expected range of tasks, and considerable training in issues related to recovery in the specific treatment areas (Moses et al. 2004).

Service system benefits include:

• Improving quality of services and systems.
• Contributing to systems knowledge.
• Improving customer orientation.
• Positively affecting policy development.
• Adding diversity.
• Reducing stigma.
• Providing positive role models.
• Promoting increased awareness and education among coworkers.
• Providing knowledge about and linkages to community and alternative resources.
• Increasing client engagement and retention.

Research benefits include:

• Enhancing research design.
• Promoting engagement of research subjects.
• Broadening interpretations and perspectives of research findings.
• Increasing research relevance (Prescott 2001, p. 6).

Active involvement of consumers in all aspects of treatment planning significantly contributes to both recovery and empowerment, and is essential if meaningful, effective services for women and children are to be developed (Schauer et al. 2007). The consensus panel believes consumers should have input into program design as well as management and research evaluation protocols. In addition, training in leadership and advocacy for consumers contributes to their feeling of being part of a group, effecting changes in their lives and communities, learning skills, changing others' perception of their competencies, increasing their positive self-images, and overcoming stigma. These elements are critical components of empowerment (Chamberlin and Schene 1997).

Prescott (2001) lists the benefits to recovering women involved in programs:

• Positive role model. Consumers are positive role models when they serve in capacities ranging from chief executive officer to support staff. Women who volunteer at the treatment program or in the community can be positive role models for clients new to treatment.
• Promotion of specific skills. As staff members in a treatment program, consumers learn skills to help themselves communicate with community agencies and social service groups and learn how organizations change and ideas are implemented, thereby gaining a sense of control over the environment.
• Promotion of recovery and well-being. Being a part of the treatment milieu, having responsibility for an aspect of the program, and working with colleagues whose mission is to promote wellness can help a woman focus her life on maintaining her health and recovery.
• Increased sense of hope. The increased security of having employment and perhaps income helps consumers envision their future in a more promising light.
• Cultivation of self-efficacy. As consumers acquire the skills they need to make positive contributions to the work of the treatment program, their belief grows in their abilities to handle problems on a broad scale.
• Decreased stigma. When consumers play a role in a treatment program, they give evidence that substance abuse is not a character flaw or moral defect but an illness that can be overcome. Their presence sends that message to others and mitigates any internalized stigma of consumers.

Consumer-centered programs incorporate the views of women in recovery in all stages of program design, management, and evaluation. In this way, the quality of services and systems integration improves, coworkers become better educated about the process of recovery, and the stigma of substance abuse is reduced.

### Creating a Healing Environment

The primary characteristic of a healing environment is safety. The environment should also be holistic, seamless, and centered on a woman's needs. To promote healing, the therapeutic environment must be inviting and welcoming, with culturally appropriate decorations and pictures. Surroundings should be multicultural, highlighting heroines from many cultures. A connection to women's history and female heroes plays an important role in bolstering women's self-efficacy.

In both residential and outpatient programs, the physical layout must provide privacy and space where women can be quiet and meditative. Private time is needed in their schedules; treatment programs can offer an array of services that pack a daily schedule, but women need time for contemplation and to pursue personal interests. Music and recreational activities should be available. Space dedicated to child care and equipment for children's activities is essential if children are included in the program.

In women's treatment programs, sensitivity to trauma-related issues is critical to a healing environment. A calm atmosphere that respects privacy and maximizes client choices promotes healing. Staff should be trained to recognize the effects of trauma, and women should have a clear understanding of the rules and policies of the residence. A trauma-informed environment must consider:

• Attention to safety.
• Attention to boundaries between staff and participants, among participants, and between participants and visitors (e.g., giving women permission to say no to hugging; hugging can be a common expression of positive emotion for some women, but for those who have been traumatized it could represent an undesired intrusion into their personal space).
• Mutuality in staff–staff and staff–client relationships.
• A nonpunitive atmosphere in which conflict is addressed by negotiation to the extent possible.
• An organizational structure that allows participants access to several layers of staff and administrators.
• Encouragement of assertiveness and leadership.
• Self-care.

### Staffing

A woman-centered staff member is an active participant in treatment and considers the specific needs of women in general and of each particular client and how they can be addressed. She weighs the realities and complexities of women's lives and their social and gender roles with a nonjudgmental attitude. Although programs are not always able to hire a woman for each staff position, a program still can adhere to a woman-centered philosophy. A key rationale for having female staff work with female clients is role modeling; people watch more than they listen. A woman-run program shows clients how women can exercise power effectively. Women need to be seen in leadership roles in the program.

This goal does not, however, exclude men as treatment providers for female clients; men who are respectful of women's experiences can help women. They must have a woman-centered perspective and be knowledgeable about women's issues, particularly trauma and domestic violence. In residential programs or other programs with children's services, male staff members can play a valuable role by being healthy male role models for women and their children. Women report that working with a male counselor who is compassionate and respectful can be a healing experience, particularly if they endured negative relationships with men. Ideally, a woman should have the option to choose either a man or a woman as her primary counselor.

Men can serve in a variety of roles in nonresidential programs, including case manager, housing coordinator, couples' or children's counselor, and general equivalency diploma teacher. They can provide a male point of view about parenting and assist in exploring the attitudes and behavior of the clients' partners.

### Training

Treatment providers and staff members at all entry points in systems that serve women need to be able to screen, triage, and refer for substance abuse treatment using an approach that supports and encourages women to receive treatment. Because of a lack of knowledge about substance use generally and about women particularly, as well as the tremendous stigma attached to women who abuse substances, it is important that all staff training include a process that identifies, acknowledges, and brings to awareness the biases, judgments, and anger toward women who use and abuse substances. The pervasiveness of substance use and abuse and the negative effect it has on the lives of so many people make it difficult to remain objective as a helping professional. If women are to be identified and referred when in need of treatment for their substance use, those in a position to help must be able to interact in a manner that assists and causes no harm.

#### Training for point-of-entry providers

Point-of-entry providers see women with a variety of complaints and have the potential to identify and refer women for assessment and treatment. These point-of-entry providers include those in healthcare, domestic violence, social service, child protection, mental health systems; schools and daycare centers; the criminal justice system; TANF (Temporary Assistance for Needy Families) workers, judges, and clergy. The consensus panel recommends that because these providers are in the position to identify women in need of substance abuse treatment, a minimum standard of cross-training among systems and within interdisciplinary groups is needed. With a heightened focus on cultural and linguistic competency, along with substance abuse education, training can help practitioners avoid creating barriers to treatment when clients are from cultures, ethnicities, or sexual orientations different from their own (Goode et al. 2006). Figure 8-3 defines the attitudes, skills, and knowledge that should be the goals for training an audience of point-of-entry staff.

Figure 8-3 Goals and Training Guidelines for Point-of-Entry Staff (Non–Substance-Abuse Treatment Providers)

Goals | Guidelines
Attitudes | • To be nonjudgmental, supportive, and respectful; • To be culturally responsive and appropriate
Skills | • To actively listen and express concern; • To treat all women with respect and dignity; • To engage women in nonthreatening discussions; • To routinely screen for alcohol and substance use and abuse (e.g., complete a behavioral checklist, identify behavioral signs); • To recognize signs of intoxication and symptoms of mental disorders; • To facilitate appropriate referrals for women who abuse substances
Knowledge | • To understand women's lives in sociocultural, psychological, economic, and political contexts; • To learn about the etiology, symptoms, consequences, and course of substance use disorders among women; • To know the available treatment and support resources for women who abuse substances and how to make a referral; • To continue to learn drug language and culture; • To understand the diverse experiences of women from different cultural groups, sexual orientations, and gender identities

#### Training for substance abuse treatment counselors

Although it is widely assumed that clinical staff members who provide substance abuse treatment are prepared to serve both men and women, the training received by clinicians does not always specifically include women-centered treatment. The consensus panel believes that training for clinicians should include information on the psychological growth and development of women, cultural competence, sexual orientation and gender identity issues, the role of relationships in women's development of a sense of self, the importance of children in the treatment process, children's importance in the lives of mothers, and the sense of adequacy in parenting that is vital to self-esteem. Training should include information on the etiology of use and abuse of substances in women and the physiological effects that are unique to women. Counselors also need to be able to disseminate accurate information about the bodily changes and potential effects of substance use on both a pregnant woman and her fetus.

In addition, social roles and status in society strongly influence the patterns, consequences, and context of use, as well as the treatment experience. Some clients need to feel empowered to assume new roles, make decisions and a new life, and remain substance free. Treatment staff can help clients find acceptance, understand their conflicts, and reach comfortable roles. Figure 8-4 defines the attitudes, skills, and knowledge that training should instill in an audience of substance abuse treatment counselors.

Figure 8-4 Goals and Training Guidelines for Substance Abuse Treatment Counselors

Goals | Guidelines
Attitudes | • To main tain a nonjudgmental, supportive, and respectful manner; • To understand the diverse experience of women from different cultural groups, abilities, sexual orientations, and gender identities (e.g., be aware of attitudes toward race, sex, and disability); • To be committed to women's issues; • To uphold a sense of hope; • To demonstrate unconditional acceptance of and positive regard for the client
Skills | • To engage women with empathy, warmth, and sincerity; • To develop a treatment alliance with female clients that is mutual and collaborative, individualized, and continually negotiated; • To have clear professional boundaries (neither distant nor abandoning) and maintain confidentiality; • To remain consistent in caring and availability and possess the ability to set limits in a calm and supportive manner; • To conduct assessments that are thorough and trauma informed; • To develop individually focused and outcome-oriented treatment plans; • To work with multidisciplinary teams; • To perform crisis intervention; • To apply trauma coping skills; • To tolerate one's own distress in hearing trauma information; • To deliver client-led treatment (e.g., help the client learn how to manage her distress without shutting down or becoming overwhelmed—a central focus of treatment); • To maintain and ensure self-care; • To support clients' cultural and racial identities and sexual orientations; • To ask for and participate in supervision, in part to explore personal biases in ongoing processes, and to be invested in ongoing training; • To be a visible advocate for women who use/abuse substances for stigma reduction and for treatment (within treatment teams, the community, and the system); • To be an appropriate role model for women, including on the topic of parenting; • To develop professional, respectful, mutually supportive, and collaborative relationships with coworkers
Knowledge | • To be culturally informed and knowledgeable; • To be trauma informed, including awareness of the prevalence and impact of trauma on women's lives; • To understand the psychological growth and development of women; • To recognize the centrality of relationships for women, particularly parenting and social roles and the socialization process; • To be knowledgeable about the physiology of women as it relates to substance use and abuse; • To understand the etiology of substance abuse in women; • To be familiar with the co-occurring disorders that commonly occur in women; • To understand the context of abuse and patterns of use for women; • To identify the consequences of substance abuse (e.g., legal, general health, infectious diseases, family and relationships, psychological); • To understand the treatment and recovery experience of women; • To identify family dynamics (e.g., family of origin, parenting, child development); • To be familiar with a woman's process of recovery; • To be knowledgeable about relapse prevention for women; relapse triggers such as family reunification; recovery resources; maintaining a safe place for the client; and loss, grief, and mourning; • To understand issues related to sexuality, sexual orientation, and gender identity for women and their relationship to substance abuse; • To know confidentiality rules and guidelines

### Supervision

The consensus panel recommends that staff supervision be built into an agency's procedures on two levels: administrative supervision (timesheets, policies, etc.) and clinical supervision. Clinical supervision provides a method to address countertransference issues or other problems when a staff member's values, attitudes, and/or expectations might interfere with the therapeutic process. Clinical supervisors can help counselors foster therapeutic alliances and help providers learn to use the therapeutic relationship to model and foster mutuality, respect, and connection for women (Finkelstein 1996; Finkelstein et al. 1997). Literature from cross-cultural psychology and social work shows that therapeutic relationships with those who have substance use problems are stronger and more effective if the counselor understands the client's historical, cultural, and economic background (Pedersen et al. 1989; Sue and Sue 2003). Research in psychology shows that counselors' gender and ethnicity can affect the diagnoses they assign (Loring and Powell 1988). This speaks to the need for ongoing clinical supervision of counselors and to the need for training individuals to be effective supervisors (Cramer 2002). Supervisors also can support staff members who are in recovery and working as volunteers or mentors.

#### Clinical supervision for trauma

The management of the powerful effect associated with trauma presents challenges for counselors. As a result of their intense daily contact with trauma survivors, counselors are vulnerable to many symptoms and conditions including:

Vicarious traumatization. The experiences of trauma frequently are overwhelming for clients. As counselors listen to the life experiences of their clients, they too are at risk of becoming overwhelmed. Counselors can develop symptoms of depression, such as sleep disturbance, loss of appetite, or loss of pleasure in usually enjoyable activities. Programs can take various steps to lessen the effect of vicarious traumatization:

• Training. Staff training on trauma issues (including vicarious traumatization) and on the connections between trauma, substance abuse, and mental illness, help staff address trauma experiences.
• Supervision. Regular clinical supervision helps counselors unburden themselves. The sooner a counselor's distress is addressed, the easier it is to manage. Understanding the counselor's emotional vulnerabilities when she works with women who were traumatized is essential to providing effective treatment and allowing staff to work well, safely, and consistently.
• Debriefing. Managers and supervisors need to ensure that counselors debrief after hearing painful and intense histories from their clients and to watch for signs of counselors becoming overwhelmed.
• Self-care. Agency support should include awareness and education about signs of burnout, breaks from work, vacations, and varied schedules (i.e., with periods of less exposure to trauma histories).
• Employee services. Through peer support groups, an agency can acknowledge that vicarious traumatization is taking place and that its employees' ability to do their jobs well is important.
• Staff appreciation. Program managers and supervisors should be aware that staff members perform an important function as role models; they need to let staff members know they are valued. Counselors need to be examples of assertive, appropriate, high-functioning adults.

Supervision for counselors can be understood in a rock-climbing metaphor. The client has survived a terrible experience; it is as if she were on a high and windy ledge, still alive, but unable to find her way back to safety. To help her, the counselor must go out on the ledge; calling to her from safe ground will not do. To manage the task, the counselor must be tied to a supervisor, much as a rock climber is tied to another climber, to keep from falling (Cramer 2002).

### Strategies for Organizational Change

A program seeking to become woman-centered cannot limit the transformation process to simply adopting superficial elements of the treatment culture (Markoff et al. 2005), such as creating a female-only program without changing program structure, integrating services, or building collaborative relationships across community agencies. Rather, it must use numerous strategies and endorse a change model to ensure organizational change is deep, pervasive, and across systems. The consensus panel recommends the following:

• Training and education. Staff members need help in identifying their biases and assumptions. Such training does not have to be intensive or expensive to be effective. For example, agencies can trade speakers.
• Policies and procedures. It is critical that programs have clear policies and procedures, and that women are informed of these policies and procedures at the beginning of their treatment. Programs must be consistent in how they implement policies and procedures. This is important from both a program management perspective and a clinical treatment perspective. Having clear, reasonable standards that are implemented uniformly creates a safe and predictable environment for clients.
  Drug and alcohol testing and searches for contraband must be done respectfully, letting the client know it is part of treatment and seeking her cooperation. It is necessary to spend time building a relationship with the client and to give her an opportunity to admit to a relapse or to remove items that are not permitted in a residential community.
  Staff must reinforce policies and rules uniformly and without preferential treatment. Fairness and justice are critical for women in treatment, and they must be modeled by the staff.
  Rules and punitive restrictions must be germane to treatment. For example, some programs do not allow women to talk to their children for the first 30 days of treatment. Such a blanket rule is inappropriate for children and shows disrespect for the importance of the mother–child relationship. Arbitrary rules are disempowering for women and not part of a collaborative relationship. The treatment milieu is a model for parent–child relationships, in which the use of arbitrary rules is discouraged. Following rules and procedures should not result in acts that retraumatize women. For example, it could be frightening for some women to have counselors check rooms at night while the women are sleeping.
• Top-down support for change. Advocacy for the program's philosophy of treatment is essential. It must be top down and explicit.
• Hiring, retention, and promotion. Programs must reflect women's needs, possibly including onsite daycare for staff, sick-child care, support (both financial and technical) for staff to become certified as addiction counselors, onsite training, and a good health benefits package. The programs should consider ways in which male staff members can contribute to woman-centered programming. Staff members are more likely to support staffing policies and procedures when they are involved in their development.
• Consumer input. The development of consumer advisory boards allows clients to share their input and lets them know their opinions are valued and respected.
• Relationships. Positive relationships are of immeasurable value to women. How staff members relate to one another is part of the treatment milieu. Administrators need to model respectful relationships with clients and staff and incorporate support services for staff issues, such as mediation for staff conflicts and peer support groups for handling job stress.
• The environment is a message. Women recover best in a homelike atmosphere that is warm and welcoming for them and their children. The program environment needs to reflect the diverse cultures of the staff and clients; all groups can participate in designing, arranging, and furnishing the facility.
• Adopt a change model. Administrators and supervisors need to develop a change plan to maintain a steadfast course in adopting new policies and procedures and in integrating services. Anticipation of roadblocks, methods for creating buy-in with staff, and strategies for building interagency relationships are a few issues that need consideration. Relevant resources to help support and guide change include the Relational Systems Change Model (Markoff et al. 2005a) and The Change Book: A Blueprint of Technology Transfer (Addiction Technology Transfer Center [ATTC] 2004).
• Collaborative relationships. Establishing a collaborative relationship with the client provides the woman with an experience of mutuality and shared power in a relationship, which in itself is part of healing. At all times, staff members should work respectfully and in partnership with the client, and should:
  Set a positive tone for the treatment relationship. Counselors get a good start by showing respect for the clients' personal needs and comfort. For example, one treatment agency keeps a book that highlights the stories of women who have successfully completed treatment. Another offers clients food and drink. During a long client-assessment session, a counselor can offer a client a break instead of waiting for the client to ask for one. If possible, during the break the counselor should interact with the client so that she does not feel alone. However, if she requests it, the client should have private time.
  Treat substance abuse as a health issue, not a moral one. A client who feels judged is more likely to leave treatment. Let clients know how they can be involved in their treatment, explain the process to them, explain the roles of the treatment staff members, and explain when clients will make decisions with staff about their treatment (i.e., during treatment planning, reassessments, discharge).
  Allow time to hear the client's stories. Too often, a client's low self-esteem is made even lower by cues that there is not enough time to listen to her.
  Do what is necessary to ensure that the client understands the assessment and treatment processes. For a client with cognitive impairment, this can involve breaking down the process into short sessions, repeating or explaining questions, proceeding more slowly, using less abstract language, or presenting information in an alternative format.
  Seek feedback from the client on how her treatment plan is working. Inquire where she is in relation to her goals for treatment, her life, and her feelings about her progress. Implement formal strategies to obtain client feedback on a regular basis instead of gathering this data at the termination of treatment.
  When addressing noncompliance with clients, involve them in identifying the problem and its solution. Use policies that are educational rather than punitive. For example, encourage clients to examine the behaviors they need to change, how staff can help them in this process, an agreeable timeframe for doing so, and so on.

#### State substance abuse treatment standards for women

To provide general guidance in establishing and providing services for women, administrators and clinical staff benefit from reviewing available State standards or protocols for women, pregnant women, and women and children programs for substance abuse treatment (for review, see CSAT 2007). Figure 8-5 provides examples of State standards of gender-specific treatment across the continuum of care.

Figure 8-5 State Standard Examples of Gender-Specific Treatment

Gender-Specific Women Services | State Standard Examples
Treatment Approach | • A relational or cultural approach that focuses on the relevance and centrality of relationships for women must be a vital ingredient in treatment; • Selected treatment approaches shall be grounded in evidence-based or best practices for women
Screening/Assessment | • Screening and assessments shall involve the use of tools, including the Addiction Severity Index and Stages of Change/Readiness Assessment; • Assessments shall evaluate barriers to treatment and related services; • Assessment and documentation of a client's need for prenatal care shall be included in the assessment process; • History and assessment of interpersonal violence shall be evaluated; • Sensitivity to retraumatization must be taken into consideration in the assessment process; • Assessment shall be a collaborative process across agencies
Treatment Planning | • Planning shall include participation of significant others and other agencies; i.e., child welfare, correction, and other social service agencies
Treatment Programs | • Emotional and physical safety of women shall take precedence over all other considerations in the delivery of services; • Women-only therapeutic environments shall be made available; • Treatment shall include psychoeducation on the impact of gender on development and functioning in society; • Treatment must be strength-based
Treatment Services | • Services must provide prenatal and childcare services; • Treatment shall include smoking cessation strategies and programs; • Services shall include child safety, parenting, and nutrition services; • Wrap-around and integrated interagency and intra-agency services must be an integral part of treatment delivery services
Trauma-Informed and Integrated Trauma Services | • Treatment considerations shall incorporate an understanding of the way symptoms of trauma affect treatment, progress in treatment, and the relationship among counselor, program, and client
Co-Occurring Disorders | • Treatment must include symptom management strategies; • Services for mental health and substance abuse treatment shall be integrated and coordinated
Staffing | • The program must provide gender-specific staff; • Treatment services shall involve a majority of women as staff members
Support Systems | • The program shall make use of peer supports; • Referrals shall be made to female-dominated support groups where available
Staff Training | • Formal staff training in women's treatment needs must include family counseling, trauma-informed services, prenatal education, etc.
Program Evaluation | • Program must measure short- and long-term impact of interventions, including educational attainment, employment, housing, parenting and reunification with children, and physical and mental health

Source: Adapted from Connecticut Treatment Guidelines 2007; Colorado Alcohol and Drug Abuse Division Substance Use Disorder Treatment Rules 2006; Oklahoma Department of Mental Health and Substance Abuse Services Standards and Criteria for Alcohol and Drug Treatment Programs 2008; and Oregon Department of Human Services Standards for Outpatient and Residential Alcohol and Drug Treatment Programs 2008.

Guidance to States: Treatment Standards for Women with Substance Use Disorders

This document serves as a comprehensive guide to assist States in creating their own treatment standards for women with substance use disorders. It provides a summary of existing State standards and incorporates other relevant resources pertinent to women's treatment needs across multiple service systems. Specific concerns for special populations are addressed, such as pregnant women, women with children, and women involved in the criminal justice system (The National Association of State Alcohol and Drug Abuse Directors 2008; see http://www.nasadad.org/resource.php?base_id=1482).