# Appendix A: Bibliography

Abs, R., Verhelst, J., Maeyaert, J., Van Buyten, J.P., Opsomer, F., Adriaensen, H., Verlooy, J., Van Havenbergh, T., Smet, M., and Van Acker, K. Endocrine consequences of long-term intrathecal administration of opioids. Journal of Clinical Endocrinology and Metabolism 85(6):2215–2222, 2000.10852454
Ackard, D.M., and Neumark-Sztainer, D. Multiple sexual victimizations among adolescent boys and girls: Prevalence and associations with eating behaviors and psychological health. Journal of Child Sexual Abuse 12(1):17–37, 2003.
Acker, C. Neuropsychological deficits in alcoholics: the relative contributions of gender and drinking history. British Journal of Addiction 81(3):395–403, 1986.3461848
Adams, H., and Phillips, L. Experiences of two-spirit lesbian and gay Native Americans: An argument for standpoint theory in identity research. Identity 6(3):273–291, 2006.
Addiction Technology Transfer Center. The Change Book: A Blueprint for Technology Transfer. 2nd ed. Kansas City, MO: Addiction Technology Transfer Center, 2004.
Adler, N.E., and Coriell, M. Socioeconomic status and women's health. In: Gallant, S.J., Keita, G.P., and Royak-Schaler, R., eds. Health Care for Women: Psychological, Social, and Behavioral Influences. Washington, DC: American Psychological Association Press, 1997. pp. 11–23.
Agrawal, A., Gardner, C.O., Prescott, C.A., and Kendler, K.S. The differential impact of risk factors on illicit drug involvement in females. Social Psychiatry and Psychiatric Epidemiology 40(6):454–466, 2005.16003595
Aguirre-Molina, M., Molina, C.W., and Zambrana, R.E. Health Issues in the Latino Community. San Francisco: Jossey-Bass, 2001.
Alati, R., Al, M.A., Williams, G.M., O'Callaghan, M., Najman, J.M., and Bor, W. In utero alcohol exposure and prediction of alcohol disorders in early adulthood: a birth cohort study. Archives of General Psychiatry 63(9):1009–1016, 2006.16953003
Alegria, M., Canino, G., Rios, R., Vera, M., Calderon, J., Rusch, D., and Ortega, A.N. Mental health care for Latinos: Inequalities in use of specialty mental health services among Latinos, African Americans, and Non-Latino Whites. Psychiatric Services 53(12):1547–1555, 2002.12461214
Alexander, M.J. Women with co-occurring addictive and mental disorders: An emerging profile of vulnerability. American Journal of Orthopsychiatry 66(1):61–70, 1996.
Allen, D.N., Frantom, L.V., Forrest, T.J., and Strauss, G.P. Neuropsychology of substance use disorders. In: Snyder, P.J., Nussbaum, P.D., and Robins, D.L., eds. Clinical Neuropsychology: A Pocket Handbook for Assessment, 2nd ed. 1-59147-283-0 (paperback). American Psychological Association: Washington, 2006. pp. 649–673.
Allen, J.P. The interrelationship of alcoholism assessment and treatment. Alcohol Health and Research World 15:178–185, 1991.
Allen, K. Barriers to treatment for addicted African-American women. Journal of the National Medical Association 87(10):751–756, 1995.7473850
Altarriba, J., and Bauer, L.M. Counseling the Hispanic client: Cuban Americans, Mexican Americans, and Puerto Ricans. Journal of Counseling & Development 76(4):389–396, 1998.
Alvarez, L.R., and Ruiz, P. Substance abuse in the Mexican American population. In: Straussner, S.L.A., ed. Ethnocultural Factors in Substance Abuse Treatment. New York: Guilford Press, 2001. pp. 111–136.
Amaro, H., and Aguiar, M. Programa Mama / Mom's Project: A community-based outreach model for addicted women. In: Szapocznik, J., Orlandi, M.A., and Epstein, L.G., eds. A Hispanic/Latino Family Approach to Substance Abuse Prevention. CSAP Cultural Competence Series 2. HHS Publication No. (SMA) 95–3034. Rockville, MD: Center for Substance Abuse Prevention, 1995. pp. 125–153.
Amaro, H., and de la Torre, A. Public health needs and scientific opportunities in research on Latinas. American Journal of Public Health 92(4):525–529, 2002.11919044
Amaro, H., and Hardy-Fanta, C. Gender relations in addiction and recovery. Journal of Psychoactive Drugs 27(4):325–337, 1995.8788689
Amaro, H., Chernoff, M., Brown, V., Arevalo, S., and Gatz, M. Does integrated trauma-informed substance abuse treatment increase treatment retention? Journal of Community Psychology 35(7):845–862, 2008.
Amaro, H., Larson, M.J., Gampel, J., Richardson, E., Savage, A., and Wagler, D. Racial/ethnic differences in social vulnerability among women with co-occurring mental health and substance abuse disorders: Implications for treatment services. Journal of Community Psychology 33(4):495–511, 2005.
Amaro, H., Larson, M.J., Zhang, A., Acevedo, A., Dai, J., and Matsumoto, A. Effects of trauma intervention on HIV sexual risk behaviors among women with co-occurring disorders in substance abuse treatment. Journal of Community Psychology 35(7):895–908, 2007.
Amaro, H., Nieves, R., Johannes, S.W., and Labault Cabeza, N.M. Substance abuse treatment: Critical issues and challenges in the treatment of Latina women. Hispanic Journal of Behavioral Sciences 21(3):266–282, 1999.
Amaro, H., Whitaker, R., Coffman, G., and Heeren, T. Acculturation and marijuana and cocaine use: Findings from HHANES 1982–84. American Journal of Public Health 80(Supplement):54–60, 1990.
American Association of Community Psychiatrists. LOCUS - Level of Care Utilization System, Psychiatric and Addiction Services. Adult Version, 2000.
American Psychiatric Association. Diagnostic and Statistical Manual of Mental Disorders. 4th ed. Washington, DC: American Psychiatric Association, 1994.
American Psychiatric Association. Diagnostic and Statistical Manual of Mental Disorders. 4th Text Revision ed. Washington, DC: American Psychiatric Association, 2000a.
American Psychiatric Association. Position Statement on Therapies Focused on Memories of Childhood Physical and Sexual Abuse. Washington, DC: American Psychiatric Association, 2000b.
American Psychological Association - Presidential Task Force on Violence and the Family. Violence and the Family: Report of the American Psychological Association Presidential Task Force on Violence and the Family. Washington, DC: American Psychological Association, 1996.
American Society of Addiction Medicine. Patient Placement Criteria for the Treatment of Substance-Related Disorders: ASAM PPC-2. 2d ed. Chevy Chase, MD: American Society of Addiction Medicine, 1996.
American Society of Addiction Medicine. Patient Placement Criteria for the Treatment of Substance-Related Disorders: ASAM PPC-2R. 2d - Revised ed. Chevy Chase, MD: American Society of Addiction Medicine, 2001.
Ames, G., and Mora, J. Alcohol problem prevention in Mexican American populations. In: Gilbert, M.J., ed. Alcohol Consumption Among Mexicans and Mexican Americans: A Binational Perspective. Los Angeles: University of California, 1988. pp. 253–281.
Ammendola, A., Gemini, D., Iannaccone, S., Argenzio, F., Ciccone, G., Ammendola, E., Serio, L., Ugolini, G., and Bravaccio, F. Gender and peripheral neuropathy in chronic alcoholism: Clinical-electroneurographic study. Alcohol and Alcoholism 35(4):368–371, 2000.10906002
Amodeo, M., and Jones, L.K. Viewing alcohol and other drug use cross culturally: A cultural framework for clinical practice. Families in Society 78(3):240–254, 1997.
Anda, R.F., Whitfield, C.L., Felitti, V.J., Chapman, D., Edwards, V.J., Dube, S.R., and Williamson, D.F. Adverse childhood experiences, alcoholic parents, and later risk of alcoholism and depression. Psychiatric Services 53(8):1001–1009, 2002.12161676
Andersen, A., Due, P., Holstein, B.E., and Iversen, L. Tracking drinking behaviour from age 15–19 years. Addiction 98(11):1505–1511, 2003.14616176
Andersen, M. Health needs of drug dependent clients: Focus on women. Women and Health 5(1):23–33, 1980.
Anderson, F., Paluzzi, P., Lee, J., Huggins, G., and Huggins, G. Illicit use of clonidine in opiate-abusing pregnant women. Obstetrics and Gynecology 90(5):790–794, 1997.9351766
Anderson, S.C. Substance abuse and dependency in gay men and lesbians. In: Peterson, K.J., ed. Health Care for Lesbians and Gay Men: Confronting Homophobia and Heterosexism. Binghamton, NY: Haworth Press, 1996. pp. 59–77.
Andrykowski, M.A., Cordova, M.J., Studts, J.L., and Miller, T.W. Posttraumatic stress disorder after treatment for breast cancer: Prevalence of diagnosis and use of the PTSD Checklist–Civilian Version (PCL–C) as a screening instrument. Journal of Consulting and Clinical Psychology 66(3):586–590, 1998.9642900
Antai-Otong, D. Women and alcoholism: Gender-related medical complications: Treatment considerations. Journal of Addictions Nursing 17(1):33–45, 2006.
Appel, P.W., Ellison, A.A., Jansky, H.K., and Oldak, R. Barriers to enrollment in drug abuse treatment and suggestions for reducing them: opinions of drug injecting street outreach clients and other system stakeholders. American Journal of Drug and Alcohol Abuse 30(1):129–153, 2004.
Aquilino, W.S. Interview mode effects in surveys of drug and alcohol use: A field experiment. Public Opinion Quarterly 58(2):210–240, 1994.
Arborelius, E., and Damstrom, T.K. Why is it so difficult for general practitioners to discuss alcohol with patients? Family Practice 12(4):419–422, 1995.8826058
Archie, C. Methadone in the management of narcotic addiction in pregnancy. Current Opinion in Obstetrics and Gynecology 10(6):435–440, 1998.9866009
Arfken, C.L., Klein, C., di Menza, S., and Schuster, C.R. Gender differences in problem severity at assessment and treatment retention. Journal of Substance Abuse Treatment 20(1):53–57, 2001.11239728
Arnett, J.J. The developmental context of substance use in emerging adulthood. Journal of Drug Issues 35(2):235–254, 2005.
Ashley, O.S., Sverdlov, L., and Brady, T.M. Length of stay among female clients in substance abuse treatment. Health Services Utilization by Individuals With Substance Abuse and Mental Disorders Council, C. L. (HHS Publication No. SMA 04-3949, Analytic Series A-25) Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004.
Augustyn, M., Parker, S., Groves, B., and Zuckerman, B. Silent victims: Children who witness violence. Contemporary Pediatrics 12(8):35–37, 1995.
Ayala, J., and Coleman, H. Predictors of depression among lesbian women. Journal of Lesbian Studies 4(3):71–86, 2000.24802684
Babor, T.F., and Grant M. From clinical research to secondary prevention: International collaboration in the development of the Alcohol Use Disorders Identification Test (AUDIT). Alcoholism and Health Research World 13:371–374, 1989.
Babor, T.F., McRee, B.G., Kassebaum, P.A., Grimaldi, P.L., Ahmed, K., and Bray, J. Screening, Brief Intervention, and Referral to Treatment (SBIRT): Toward a public health approach to the management of substance abuse. Substance Abuse 28(3):7–30, 2007.18077300
Baca, C.T., Alverson, D.C., Manuel, J.K., and Blackwell, G.L. Telecounseling in rural areas for alcohol problems. Alcoholism Treatment Quarterly 25(4):31–45, 2007.
Bachu, A., and O'Connell, M. Fertility of American Women: June 2000. Current Population Reports. P20-543RV Washington, DC: U.S. Census Bureau, 2001.
Bagnardi, V., Blangiardo, M., La Vecchia, C., and Corrao, G. Alcohol consumption and the risk of cancer: A meta-analysis. Alcohol Research and Health 25(4):263–270, 2001.11910703
Balcazar, H., and Qian, Z. Immigrant families and sources of stress. In: McKenry, P.C., and Price, S.J., eds. Families and Change: Coping with Stressful Events and Transitions. 2d ed. Thousand Oaks, CA: Sage Publications, 2000. pp. 359–377.
Balsam, K.F., Huang, B., Fieland, K.C., Simoni, J.M., and Walters, K.L. Culture, trauma, and wellness: a comparison of heterosexual and lesbian, gay, bisexual, and two-spirit Native Americans. Cultural Diversity & Ethnic Minority Psychology 10(3):287–301, 2004.15311980
Barnes, J.S., and Bennett, C.E. The Asian Population: 2000. Census 2000 Brief Washington, DC: U.S. Census Bureau, 2002.
Barnes-Josiah, D.L. Undoing racism in public health: A blueprint for action in urban MCH. CityMatCH at the University of Nebraska Medical Center. Omaha, NE, 2004.
Baron, M. Addiction treatment for Mexican American families. In: Krestan, J.A., ed. Bridges to Recovery: Addiction, Family Therapy, and Multicultural Treatment. New York: The Free Press, 2000. pp. 219–252.
Barsky, A.J., Peekna, H.M., and Borus, J.F. Somatic symptom reporting in women and men. Journal of General Internal Medicine 16(4):266–275, 2001.11318929
Bassuk, E.L., Melnick, S., and Browne, A. Responding to the needs of low-income and homeless women who are survivors of family violence. Journal of the American Medical Women's Association 53(2):57–64, 1998.
Bateman, D.A., and Chiriboga, C.A. Dose-response effect of cocaine on newborn head circumference. Pediatrics 106(3):E33, 2000.
Battle, C.L., Zlotnick, C., Najavits, L.M., Gutierrez, M., and Winsor, C. Posttraumatic stress disorder and substance use disorder among incarcerated women. In: Ouimette, P., and Brown, P.J., eds. Trauma and Substance Abuse: Causes, Consequences, and Treatment of Comorbid Disorders. Washington, DC: American Psychological Association, 2003. pp. 209–225.
Bauer, C.R., Langer, J.C., Shankaran, S., Bada, H.S., Lester, B., Wright, L.L., Krause-Steinrauf, H., Smeriglio, V.L., Finnegan, L.P., Maza, P.L., and Verter, J. Acute neonatal effects of cocaine exposure during pregnancy. Archives of Pediatrics & Adolescent Medicine 159(9):824–834, 2005.16143741
Beatty, L.A. Substance abuse, disabilities, and black women: An issue worth exploring. Women & Therapy 26(3-4):223–236, 2003.
Beauvais, F., Wayman, J.C., Jumper Thurman, P., Plested, B., and Helm, H. Inhalant abuse among American Indian, Mexican American, and non-Latino white adolescents. American Journal of Drug and Alcohol Abuse 28(1):171–187, 2002.
Beck, A.J. Prisoners in 1999. NCJ 183476 Washington, DC: Bureau of Justice Statistics, 2000.
Beck, A.J., and Harrison, P.M. Prisoners in 2000. Bureau of Justice Statistics Bulletin Washington, DC: Bureau of Justice Statistics, 2001.
Beck, A.J., Karberg, J.C., and Harrison, P.M. Prison and Jail Inmates at Midyear 2001. NCJ 191702 Washington, DC: Bureau of Justice Statistics, 2002.
Beck, A.T. Beck Anxiety Inventory. San Antonio, TX: The Psychological Corporation, 1993.
Beck, A.T., Steer, R.A., and Brown, G.K. Beck Depression Inventory - II Manual. San Antonio, TX: The Psychological Corporation, 1996a.
Beck, R.W., Jijon, C.R., and Edwards, J.B. The relationships among gender, perceived financial barriers to care, and health status in a rural population. Journal of Rural Health 12(3):188–189, 1996b.
Becker, U., Deis, A., Sorensen, T.I., Gronbaek, M., Borch-Johnsen, K., Muller, C.F., Schnohr, P., and Jensen, G. Prediction of risk of liver disease by alcohol intake, sex, and age: A prospective population study. Hepatology 23(5):1025–1029, 1996.8621128
Becker, M.A., and Gatz, M. Introduction to the impact of co-occurring disorders and violence on women: Findings from the SAMHSA Women, Co-occurring Disorders and Violence Study. Journal of Behavior Health Services & Research 32(2):111–112, 2005.
Beckman, L.J. Treatment needs of women with alcohol problems. Alcohol Health and Research World 18(3):206–211, 1994.31798108
Beckman, L.J., and Amaro, H. Personal and social difficulties faced by women and men entering alcoholism treatment. Journal of Studies on Alcohol 47(2):135–145, 1986.3713175
Bell, B.P., Mast, E.E., Terrault, N., and Hutin, Y.J. Prevention of hepatitis C in women. Emerging Infectious Diseases 10(11):2035–2036, 2004.16010740
Bell, E.C., Baker, G.B., Poag, C., Bellavance, F., Khudabux, J., and Le Melledo, J.M. Response to flumazenil in the late luteal phase and follicular phase of the menstrual cycle in healthy control females. Psychopharmacology (Berl) 172(3):248–254, 2004.14712334
Bell, G.L., and Lau, K. Perinatal and neonatal issues of substance abuse. Pediatric Clinics of North America 42(2):261–281, 1995.7536914
Bell, P. Chemical Dependency and the African-American: Counseling Strategies and Community Issues. 2nd ed. Center City, MN: Hazelden, 2002.
Benshoff, J.J., Harrawood, L.K., and Koch, D.S. Substance abuse and the elderly: Unique issues and concerns. Journal of Rehabilitation 69(2): 2003.
Bergmark, K.H. Drinking in the Swedish gay and lesbian community. Drug and Alcohol Dependence 56(2):133–143, 1999.10482404
Berkowitz, G., Peterson, S., Smith, E.M., Taylor, T., and Brindis, C. Community and treatment program challenges for chemically dependent American Indian and Alaska Native women. Contemporary Drug Problems 25(2):347–371, 1998.
Bernstein, D.P. Childhood trauma and drug addiction: Assessment, diagnosis, and treatment. Alcoholism Treatment Quarterly 18(3):19–30, 2000.
Besharov, D.J., and Hanson, K.W. When Drug Addicts Have Children: Reorienting Child Welfare's Response. Washington, DC: Child Welfare League of America, 1994.
Beutler, L.E., Machado, P.P., and Neufeldt, S.A. Therapist variables. In: Bergin, A.E., and Garfield, S.L., eds. Handbook of Psychotherapy and Behavior Change. 4th ed. Oxford: John Wiley and Sons, 1994. pp. 229–269.
Bickelhaupt, E.E. Alcoholism and drug abuse in gay and lesbian persons: A review of incidence studies. Journal of Gay and Lesbian Social Services 2(1):5–14, 1995.
Black, S.A., and Markides, K.S. Acculturation and alcohol consumption in Puerto Rican, Cuban-American, and Mexican-American women in the United States. American Journal of Public Health 83(6):890–893, 1993.8498630
Blanchard, E.B., Jones-Alexander, J., Buckley, T.C., and Forneris, C.A. Psychometric properties of the PTSD Checklist (PCL). Behaviour Research & Therapy 34(8):669–673, 1996.8870294
Block, R.I., Farinpour, R., and Schlechte, J.A. Effects of chronic marijuana use on testosterone, luteinizing hormone, follicle stimulating hormone, prolactin and cortisol in men and women. Drug and Alcohol Dependence 28(2):121–128, 1991.1935564
Bloom, B., Owen, B., and Covington, S. Gender-Responsive Strategies: Research, Practice, and Guiding Principles for Women Offenders. Washington, DC: National Institute of Corrections, 2003.
Blow, F.C., and Barry, K.L. Use and misuse of alcohol among older women. Alcohol Research and Health 26(4):308–315, 2002.12875042
Blum, L.N., Nielsen, N.H., and Riggs, J.A. Alcoholism and alcohol abuse among women: Report of the Council on Scientific Affairs. American Medical Association. Journal of Women's Health 7(7):861–871, 1998.
Blume, S. Sexuality and stigma. Alcohol Health and Research World 15(2):139–146, 1991.
Blume, S.B. Women and alcohol: Issues in social policy. In: Wilsnack, R.W., and Wilsnack, S.C., eds. Gender And Alcohol: Individual And Social Perspectives. New Brunswick, NJ: Rutgers Center of Alcohol Studies, 1997. pp. 462–489.
Blumenthal, S.J. Women and substance abuse: A new national focus. In: Wetherington, C.L., and Roman, A.B., eds. Drug Addiction Research and the Health of Women. NIH Publication No. 98–4290. Rockville, MD: National Institute on Drug Abuse, 1998. pp. 13–32.
Bobo, J.K., Schilling, R.F., Gilchrist, L.D., and Schinke, S.P. The double triumph: Sustained sobriety and successful cigarette smoking cessation. Journal of Substance Abuse Treatment 3(1):21–25, 1986.3735474
Bolnick, J.M., and Rayburn, W.F. Substance use disorders in women: special considerations during pregnancy. Obstetrics and Gynecology Clinics of North America 30(3):545–58, vii, 2003.14664326
Borrelli, B., Papandonatos, G., Spring, B., Hitsman, B., and Niaura, R. Experimenter-defined quit dates for smoking cessation: adherence improves outcomes for women but not for men. Addiction 99(3):378–385, 2004.14982551
Bottorff, J.L., Johnson, J.L., Irwin, L.G., and Ratner, P.A. Narratives of smoking relapse: The stories of postpartum women. Research in Nursing and Health 23(2):126–134, 2000.10782871
Boyd, M.B., Mackey, M.C., Phillips, K.D., and Tavakoli, A. Alcohol and other drug disorders, comorbidity and violence in rural African American women. Issues in Mental Health Nursing 27(10):1017–1036, 2006.17050336
Boyd, M.R. Substance abuse in rural women. Nursing Connections 11(2):33–45, 1998.
Boyd, M.R. Vulnerability to alcohol and other drug disorders in rural women. Archives of Psychiatric Nursing 17(1):33–41, 2003.12642886
Boyd, M.R., and Mackey, M.C. Alienation from self and others: The psychosocial problem of rural alcoholic women. Archives of Psychiatric Nursing 14(3):134–141, 2000a.10870251
Boyd, M.R., and Mackey, M.C. Running away to nowhere: Rural women's experiences of becoming alcohol dependent. Archives of Psychiatric Nursing 14(3):142–149, 2000b.10870252
Boyd-Franklin, N. Black Families In Therapy: A Multisystems Approach. New York: Guilford Press, 1989.
Boyd-Franklin, N., and Lockwood, T.W. Spirituality and religion: Implications for psychotherapy with African American families. In: Walsh, F., ed. Spiritual Resources In Family Therapy (2nd ed.). 978-1-60623-022-0 (hardcover). Guilford Press: New York, 2009. pp. 141–155.
Bradley, K.A., Badrinath, S., Bush, K., Boyd-Wickizer, J., and Anawalt, B. Medical risks for women who drink alcohol. Journal of General Internal Medicine 13(9):627–639, 1998a.9754520
Bradley, K.A., Boyd-Wickizer, J., Powell, S.H., and Burman, M.L. Alcohol screening questionnaires in women: A critical review. JAMA 280(2):166–171, 1998b.9669791
Bradley, K.A., Bush, K.R., McDonell, M.B., Malone, T., and Fihn, S.D. Screening for problem drinking: Comparison of CAGE and AUDIT. Ambulatory Care Quality Improvement Project (ACQUIP). Alcohol Use Disorders Identification Test. Journal of General Internal Medicine 13(6):379–388, 1998c.
Brady, K. Anxiety and Substance Abuse. 154th Annual Meeting of the American Psychiatric Association May 5 – 10, 2001, New Orleans, Louisiana, 2001a.
Brady, K.T. Comorbid posttraumatic stress disorder and substance use disorders. Psychiatric Annals 31(5):313–319, 2001b.
Brady, K.T., and Randall, C.L. Gender differences in substance use disorders. Psychiatric Clinics of North America 22(2):241–252, 1999.
Brady, K.T., Dansky, B.S., Back, S.E., Foa, E.B., and Carroll, K.M. Exposure therapy in the treatment of PTSD among cocaine-dependent individuals: Preliminary findings. Journal of Substance Abuse Treatment 21(1):47–54, 2001.11516926
Brady, K.T., Killeen, T.K., Brewerton, T., and Lucerini, S. Comorbidity of psychiatric disorders and posttraumatic stress disorder. Journal of Clinical Psychiatry 61(Suppl 7):22–32, 2000.
Brady, T.M., and Ashley, O.S. Women In Substance Abuse Treatment: Results from the Alcohol and Drug Services Study (ADSS). (HHS Publication No. SMA 04-3968, Analytic Series A-26). Rockville, MD: Substance Abuse and Mental Health Services Administration, Office of Applied Studies, 2005.
Brecht, M.L., O'Brien, A., Mayrhauser, C.V., and Anglin, M.D. Methamphetamine use behaviors and gender differences. Addictive Behaviors 29(1):89–106, 2004.14667423
Brems, C. Substance use, mental health, and health in Alaska: Emphasis on Alaska Native peoples. Arctic Medical Research 55(3):135–147, 1996.8885436
Brennan, P.L., Moos, R.H., and Kim, J.Y. Gender differences in the individual characteristics and life contexts of late-middle-aged and older problem drinkers. Addiction 88(6):781–790, 1993.8329969
Breslau, N., Davis, G.C., Andreski, P., and Peterson, E. Traumatic events and posttraumatic stress disorder in an urban population of young adults. Archives of General Psychiatry 48(3):216–222, 1991.1996917
Breslau, N., Davis, G.C., Andreski, P., Peterson, E.L., and Schultz, L.R. Sex differences in posttraumatic stress disorder. Archives of General Psychiatry 54(11):1044–1048, 1997.9366662
Bride, B.E. Single-gender treatment of substance abuse: Effect on treatment retention and completion. Social Work Research 25(4):223–232, 2001.
Brindis, C.D., and Theidon, K.S. The role of case management in substance abuse treatment services for women and their children. Journal of Psychoactive Drugs 29(1):79–88, 1997.9110268
Brome, D.R., Ownes, M.D., Allen, K., and Vevaina, T. An examination of spirituality among African American women in recovery from substance abuse. Journal of Black Psychology 26(4):470–486, 2000.
Bronfenbrenner, U. Ecological systems theory. Annals of Child Development 6:187–249, 1989.
Brook, D.W., Brook, J.S., Richter, L., Masci, J.R., and Roberto, J. Needle sharing: a longitudinal study of female injection drug users. American Journal of Drug and Alcohol Abuse 26(2):263–281, 2000.
Brook, J., Whiteman, M., Balka, E., Win, P., and Gursen, M. Similar and different precursors to drug use and delinquency among African Americans and Puerto Ricans. Journal of Genetic Psychology 159(1):13–29, 1998.
Brown, E., Frank, D., and Friedman, A. Supplementary Administration Manual for the Expanded Female Version of the Addiction Severity Index (ASI) Instrument The ASI-F. HHS Publication Number 96-8056. U.S. Department of Health and Human Services, Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment, 1997.
Brown, E.R., Ponce, N., and Rice, T. The State of Health Insurance in California: Recent Trends, Future Prospects. Los Angeles: UCLA Center for Health Policy Research, 2001.
Brown, P.J., Recupero, P.R., and Stout, R. PTSD substance abuse comorbidity and treatment utilization. Addictive Behaviors 20(2):251–254, 1995.7484319
Brown, P.J., Stout, R.L., and Mueller, T. Posttraumatic stress disorder and substance abuse relapse among women: A pilot study. Psychology of Addictive Behaviors 10(2):124–128, 1996.
Brown, S.P., Lipford-Sanders, J., and Shaw, M. Kujichagulia: Uncovering the secrets of the heart: Group work with African American women on predominantly white campuses. Journal for Specialists in Group Work 20(3):151–158, 1995a.
Brown, T.G., Kokin, M., Seraganian, P., and Shields, N. The role of spouses of substance abusers in treatment: Gender differences. Journal of Psychoactive Drugs 27(3):223–229, 1995b.8594165
Brown, V.B. Changing And Improving Services For Women And Children: Strategies Used And Lessons Learned. Los Angeles, CA: Prototypes Systems Change Center, 2000.
Brown, V.B., Najavits, L.M., Cadiz, S., Finkelstein, N., Heckman, J.P., and Rechberger, E. Implementing an evidence-based practice: Seeking Safety Group. Journal of Psychoactive Drugs 39(3):231–240, 2007.18159776
Brownridge, D.A. Partner violence against women with disabilities: Prevalence, risk, and explanations. Violence Against Women 12(9):805–822, 2006.16905674
Brudenell, I. Parenting an infant during alcohol recovery. Journal of Pediatric Nursing 15(2):82–88, 2000.10808623
Bryant, J., and Treloar, C. The gendered context of initiation to injecting drug use: evidence for women as active initiates. Drug And Alcohol Review 26(3):287–293, 2007.17454018
Buchsbaum, D.G., Buchanan, R.G., Lawton, M.J., Elswick, R.K., Jr., and Schnoll, S.H. A program of screening and prompting improves short-term physician counseling of dependent and nondependent harmful drinkers. Archives of Internal Medicine 153(13):1573–1577, 1993.8323420
Bulik, C., and Sullivan, P. Comorbidity of eating disorders and substance-related disorders. In: Kranzler, H.R., and Rounsaville, B., eds. Dual Diagnosis and Treatment: Substance Abuse and Cormorbid Medical and Psychiatric Disorders. New York: Marcel Dekker, 1998. pp. 365–392.
Bulik, C.M., Klump, K.L., Thornton, L., Kaplan, A.S., Devlin, B., Fichter, M.M., Halmi, K.A., Strober, M., Woodside, D.B., Crow, S., Mitchell, J.E., Rotondo, A., Mauri, M., Cassano, G.B., Keel, P.K., Berrettini, W.H., and Kaye, W.H. Alcohol use disorder comorbidity in eating disorders: A multi-center study. Journal of Clinical Psychiatry 65(7):1000–1006, 2004.
Bureau of Justice Statistics. Compendium of Federal Justice Statistics, 2004. Washington, DC: U.S. Department of Justice, 2006.
Bureau of the Census (Current Population Survey, March 2002, Ethnic and Hispanic Statistics Branch, Population Division). Table 15.1 Poverty status of families in 2001 by family type and by Hispanic origin and race of householder: March 2002 http://www.census.gov/population/socdemo/hispanic/ppl-165/tab15-1.pdf [Accessed September 17, 2008].
Burkett, G., Gomez-Marin, O., Yasin, S.Y., and Martinez, M. Prenatal care in cocaine-exposed pregnancies. Obstetrics and Gynecology 92(2):193–200, 1998.9699750
Burkett, G., Yasin, S.Y., Palow, D., LaVoie, L., and Martinez, M. Patterns of cocaine binging: Effect on pregnancy. American Journal of Obstetrics and Gynecology 171(2):372–379, 1994.8059815
Burling, T.A., Burling, A.S., and Latini, D. A controlled smoking cessation trial for substance-dependent inpatients. Journal of Consulting & Clinical Psychology 69(2):295–304, 2001.11393606
Burns, L., Mattick, R.P., Lim, K., and Wallace, C. Methadone in pregnancy: treatment retention and neonatal outcomes. Addiction 102(2):264–270, 2007.17222281
Burt, V.K., and Stein, K. Epidemiology of depression throughout the female life cycle. Journal of Clinical Psychiatry 63(Suppl7):9–15, 2002.
Bushy, A. Mental health and substance abuse: Challenges in providing services to rural clients. In: Center for Substance Abuse Treatment, ed. Bringing Excellence To Substance Abuse Services In Rural And Frontier America. Technical Assistance Publication Series 20. Rockville, MD: Center for Substance Abuse Treatment, 1997. pp. 45–53.
Butler, A.C., Chapman, J.E., Forman, E.M., and Beck, A.T. The empirical status of cognitive-behavioral therapy: a review of meta-analyses. Clinical Psychology Review 26(1):17–31, 2006.16199119
Caetano, R. Alcohol use among Hispanic groups in the United States. American Journal of Drug and Alcohol Abuse 14(3):293–308, 1988.
Caetano, R. Drinking patterns and alcohol problems in a national sample of U.S. Hispanics. In: Spiegler, D., Tate, D., Aitken, S., and Christian, C., eds. Alcohol Use Among U.S. Ethnic Minorities: Proceedings Of A Conference On The Epidemiology Of Alcohol Use And Abuse Among Ethnic Minority Groups, September 1985. NIAAA Research Monograph No. 18. HHS Publication No. (ADM) 89–1435. Rockville, MD: National Institute on Alcohol Abuse and Alcoholism, 1989. pp. 147–162.
Caetano, R. Drinking and alcohol-related problems among minority women. Alcohol Health and Research World 18(3):233–241, 1994.31798124
Caetano, R., Ramisetty-Mikler, S., Vaeth, P.A.C., and Harris, T.R. Acculturation stress, drinking, and intimate partner violence among Hispanic couples in the U.S. Journal of Interpersonal Violence 22(11):1431–1447, 2007.17925291
Caetano, R., Ramisetty-Mikler, S., Wallisch, L.S., McGrath, C., and Spence, R.T. Acculturation, drinking, and alcohol abuse and dependence among Hispanics in the Texas-Mexico border. Alcoholism: Clinical & Experimental Research 32(2):314–321, 2008.
Caldwell, T.M., Rodgers, B., Jorm, A.F., Christensen, H., Jacomb, P.A., Korten, A.E., and Lynskey, M.T. Patterns of association between alcohol consumption and symptoms of depression and anxiety in young adults. Addiction 97(5):583–594, 2002.12033659
Camp, J.M., and Finkelstein, N. Parenting training for women in residential substance abuse treatment: Results of a demonstration project. Journal of Substance Abuse Treatment 14(5):411–422, 1997.9437610
Canino, G. Alcohol use and misuse among Hispanic women: Selected factors, processes, and studies. International Journal of the Addictions 29(9):1083–1100, 1994.
Canino, G., Vega, W.A., Sribney, W.M., Warner, L.A., and Alegria, M. Social Relationships, social assimilation, and substance use disorders among adult Latinos in the U.S. Journal of Drug Issues 38(1):69–101, 2008.20011228
Carlson, B.E., Matto, H., Smith, C.A., and Eversman, M. A pilot study of reunification following drug abuse treatment: Recovering the mother role. Journal of Drug Issues 36(4):877–902, 2006.
Carmen, E.H. Inner city community mental health: The interplay of abuse and race in chronic mentally ill women. In: Willie, C.V., Rieker, P.P., Kramer, B.M., and Brown, B.S., eds. Mental Health: Racism and Sexism. Pittsburgh, PA: University of Pittsburgh Press, 1995. pp. 217–236.
Carmichael, S.L., and Ahluwalia, I.B. Correlates of postpartum smoking relapse: Results from the pregnancy risk assessment monitoring system (PRAMS). American Journal of Preventive Medicine 19(3):193–196, 2000.11020597
Carney, C.P., and Jones, L.E. The influence of type and severity of mental illness on receipt of screening mammography. Journal of General Internal Medicine 21(10):1097–1104, 2006.16970559
Carr, A., and McNulty, M. Eating disorders. In: Carr, A., and McNulty, M., eds. The Handbook Of Adult Clinical Psychology: An Evidence-Based Practice Approach. 978-1-58391-854-8 (paperback); 978-1-58391-853-1 (hardcover). Routledge/Taylor & Francis Group: New York, 2006. pp. 724–765.
Carroll, J.F.X., and McGinley, J.J. A screening form for identifying mental health problems in alcohol/other drug dependent persons. Alcoholism Treatment Quarterly 19(4):33–47, 2001.
Carter, R.E., Haynes, L.F., Back, S.E., Herrin, A.E., Brady, K.T., Leimberger, J.D., Sonne, S.C., Hubbard, R.L., and Liepman, M.R. Improving the transition from residential to outpatient addiction treatment: Gender differences in response to supportive telephone calls. American Journal of Drug and Alcohol Abuse 34(1):47–59, 2008.
Case, P., Austin, S.B., Hunter, D.J., Manson, J.E., Malspeis, S., Willett, W.C., and Spiegelman, D. Sexual orientation, health risk factors, and physical functioning in the Nurses' Health Study II. Journal of Women's Health (Larchmt.) 13(9):1033–1047, 2004.
Catalano, S. Intimate partner violence in the United States. Bureau of Justice Statistics Washington, DC: U.S. Department of Justice, 2007.
Center for Substance Abuse Prevention. Maternal Substance Use Assessment Methods Reference Manual: A Review Of Screening And Clinical Assessment Instruments For Examining Maternal Use Of Alcohol, Tobacco, And Other Drugs. CSAP Special Report 13. HHS Publication No. (SMA)93–2059. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1993.
Center for Substance Abuse Prevention. Substance Abuse Resource Guide: Lesbian, Gay, Bisexual, And Transgender Populations. Revised 2000 ed. Rockville, MD: Center for Substance Abuse Prevention, 2000.
Center for Substance Abuse Treatment. Improving Treatment for Drug-Exposed Infants. Treatment Improvement Protocol (TIP) Series 5. HHS Publication No. (SMA) 95–3057. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1993a.
Center for Substance Abuse Treatment. Pregnant, Substance-Using Women. Treatment Improvement Protocol (TIP) Series 2. HHS Publication No. (SMA) 93–1998. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1993b.
Center for Substance Abuse Treatment. Screening for Infectious Diseases Among Substance Abusers. Treatment Improvement Protocol (TIP) Series 6. HHS Publication No. (SMA) 95–3060. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1993c.
Center for Substance Abuse Treatment. Practical Approaches in the Treatment of Women Who Abuse Alcohol and Other Drugs. HHS Publication No. (SMA) 94–3006. Washington, DC: U.S. Government Printing Office, 1994a.
Center for Substance Abuse Treatment. Simple Screening Instruments for Outreach for Alcohol and Other Drug Abuse and Infectious Diseases. Treatment Improvement Protocol (TIP) Series 11. HHS Publication No. (SMA) 94–2094. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994b.
Center for Substance Abuse Treatment. Alcohol and Other Drug Screening of Hospitalized Trauma Patients. Treatment Improvement Protocol (TIP) Series 16. HHS Publication No. (SMA) 95–3041. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1995a.
Center for Substance Abuse Treatment. Combining Alcohol and Other Drug Treatment with Diversion for Juveniles in the Justice System. Treatment Improvement Protocol (TIP) Series 21. HHS Publication No. (SMA) 95–3051. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1995b.
Center for Substance Abuse Treatment. Developing State Outcomes Monitoring Systems for Alcohol and Other Drug Abuse Treatment. Treatment Improvement Protocol (TIP) Series 14. HHS Publication No. (SMA) 95–3031. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1995c.
Center for Substance Abuse Treatment. The Role and Current Status of Patient Placement Criteria in the Treatment of Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 13. HHS Publication No. (SMA) 95–3021. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1995d.
Center for Substance Abuse Treatment. The Tuberculosis Epidemic: Legal and Ethical Issues for Alcohol and Other Drug Abuse Treatment Providers. Treatment Improvement Protocol (TIP) Series 18. HHS Publication No. (SMA) 95–3047. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1995e.
Center for Substance Abuse Treatment. Treatment Drug Courts: Integrating Substance Abuse Treatment With Legal Case Processing. Treatment Improvement Protocol (TIP) Series 23. HHS Publication No. (SMA) 96–3113. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1996.
Center for Substance Abuse Treatment. A Guide to Substance Abuse Services for Primary Care Clinicians. Treatment Improvement Protocol (TIP) Series 24. HHS Publication No. (SMA) 97–3139. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997a.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Domestic Violence. Treatment Improvement Protocol (TIP) Series 25. HHS Publication No. (SMA) 97–3163. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997b.
Center for Substance Abuse Treatment. Supplementary Administration Manual For The Expanded Female Version Of The Addiction Severity Index (ASI) Instrument. HHS Publication No. (SMA) 96–8056. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997c.
Center for Substance Abuse Treatment. Comprehensive Case Management for Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 27. HHS Publication No. (SMA) 98–3222. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998a.
Center for Substance Abuse Treatment. Continuity of Offender Treatment for Substance Use Disorders From Institution to Community. Treatment Improvement Protocol (TIP) Series 30. HHS Publication No. (SMA) 98–3245. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998b.
Center for Substance Abuse Treatment. Naltrexone and Alcoholism Treatment. Treatment Improvement Protocol (TIP) Series 28. HHS Publication No. (SMA) 98–3206. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998c.
Center for Substance Abuse Treatment. Substance Abuse Among Older Adults. Treatment Improvement Protocol (TIP) Series 26. HHS Publication No. (SMA) 98–3179. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998d.
Center for Substance Abuse Treatment. Substance Use Disorder Treatment for People With Physical and Cognitive Disabilities. Treatment Improvement Protocol (TIP) Series 29. HHS Publication No. (SMA) 98–3249. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998e.
Center for Substance Abuse Treatment. Brief Interventions and Brief Therapies for Substance Abuse. Treatment Improvement Protocol (TIP) Series 34. HHS Publication No. (SMA) 99–3353. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999a.
Center for Substance Abuse Treatment. Enhancing Motivation for Change in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 35. HHS Publication No. (SMA) 99–3354. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999b.
Center for Substance Abuse Treatment. Screening and Assessing Adolescents for Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 31. HHS Publication No. (SMA) 99–3282. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999c.
Center for Substance Abuse Treatment. Treatment of Adolescents With Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 32. HHS Publication No. (SMA) 99–3283. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999d.
Center for Substance Abuse Treatment. Treatment for Stimulant Use Disorders. Treatment Improvement Protocol (TIP) Series 33. HHS Publication No. (SMA) 99–3296. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999e.
Center for Substance Abuse Treatment. Integrating Substance Abuse Treatment and Vocational Services. Treatment Improvement Protocol (TIP) Series 38. HHS Publication No. (SMA) 00–3470. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000a.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Persons With Child Abuse and Neglect Issues. Treatment Improvement Protocol (TIP) Series 36. HHS Publication No. (SMA) 00–3357. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000b.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Persons With HIV/AIDS. Treatment Improvement Protocol (TIP) Series 37. HHS Publication No. (SMA) 00–3459. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000c.
Center for Substance Abuse Treatment. Benefits of Residential Substance Abuse Treatment for Pregnant and Parenting Women: Highlights from a Study of 50 Demonstration Programs of the Center for Substance Abuse Treatment. Rockville, MD: Center for Substance Abuse Treatment 2001a.
Center for Substance Abuse Treatment. A Provider's Introduction To Substance Abuse Treatment For Lesbian, Gay, Bisexual, And Transgender Individuals. HHS Publication No. (SMA) 01–3498. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2001b.
Center for Substance Abuse Treatment. Telling Their Stories: Reflections Of The 11 Original Grantees That Piloted Residential Treatment For Women And Children For CSAT. HHS Publication No. (SMA) 01–3529. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2001c.
Center for Substance Abuse Treatment. Helping Yourself Heal: A Recovering Woman's Guide To Coping With Childhood Abuse Issues. HHS Publication No. (SMA) 03–3789. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2003a.
Center for Substance Abuse Treatment. Lessons Learned: Residential Substance Abuse Treatment For Women And Their Children. HHS Publication No. (SMA) 03–3787. Rockville, MD: U.S. Department of Health and Human Services, Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment, 2003b.
Center for Substance Abuse Treatment. Clinical Guidelines for the Use of Buprenorphine in the Treatment of Opioid Addiction. Treatment Improvement Protocol (TIP) Series 40. HHS Publication No. (SMA) 04–3939. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004a.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Family Therapy. Treatment Improvement Protocol (TIP) Series 39. HHS Publication No. (SMA) 04–3957. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004b.
Center for Substance Abuse Treatment. Medication-Assisted Treatment For Opioid Addiction In Opioid Treatment Programs. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005a.
Center for Substance Abuse Treatment. Medication-Assisted Treatment for Opioid Addiction. Treatment Improvement Protocol (TIP) Series 43. HHS Publication No. SMA 05–4048. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005b.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series 44. HHS Publication No. (SMA) 05–4056. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005c.
Center for Substance Abuse Treatment. Substance Abuse Treatment: Group Therapy. Treatment Improvement Protocol (TIP) Series 41. HHS Publication No. SMA 05–4056. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005d.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Persons with Co-Occurring Disorders. Treatment Improvement Protocol (TIP) Series 42. HHS Publication No. SMA 05–3992. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005e.
Center for Substance Abuse Treatment. Detoxification and Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 45. HHS Publication No. SMA 06–4131. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2006a.
Center for Substance Abuse Treatment. Substance Abuse: Administrative Issues in Intensive Outpatient Treatment. Treatment Improvement Protocol (TIP) Series 46. HHS Publication No. SMA 06–4151. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2006b.
Center for Substance Abuse Treatment. Substance Abuse: Clinical Issues in Intensive Outpatient Treatment. Treatment Improvement Protocol (TIP) Series 47. HHS Publication No. 06–4182. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2006c.
Center for Substance Abuse Treatment. State substance abuse treatment standards for women: A review of the current landscape. Prepared for Discussion at the NASADADWTC 2007 Annual Meeting June 6, 2007, Burlington, Vermont. 2007.
Center for Substance Abuse Treatment. Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery. Treatment Improvement Protocol (TIP) Series 48. HHS Publication No. SMA 08-4353 Rockville, MD: Substance Abuse and Mental Health Services Administration, 2008.
Center for Substance Abuse Treatment. Addressing Suicidal Thoughts and Behaviors With Clients in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 50. HHS Publication No. SMA 09–4381. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2009a.
Center for Substance Abuse Treatment. Incorporating Alcohol Pharmacotherapies Into Medical Practice. Treatment Improvement Protocol (TIP) Series 49. HHS Publication No. SMA 09–4380. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2009b.
Center for Substance Abuse Treatment. Improving Cultural Competence in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development a.
Center for Substance Abuse Treatment. Management of Chronic Pain in People With Substance Use Disorders. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development b.
Center for Substance Abuse Treatment. Relapse Prevention and Recovery in Substance Abuse Treatment Settings. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development c
Center for Substance Abuse Treatment. Substance Abuse Treatment: Addressing the Specific Needs of Women. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development d.
Center for Substance Abuse Treatment. Substance Abuse Treatment with American Indians and Alaska Natives. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration. In development e.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Men's Issues. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development f.
Center for Substance Abuse Treatment. Substance Abuse Treatment With People Who Are Homeless. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development g.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Trauma. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development h.
Center for Substance Abuse Treatment. Supervision and the Professional Development of the Substance Abuse Counselor. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development i.
Center for Substance Abuse Treatment. Viral Hepatitis and Substance Abuse. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development j.
Center on Alcoholism. Substance Abuse and Addictions. Religious Practice and Beliefs Instrument. Albuquerque, NM: University of New Mexico, 2004.
Centers for Disease Control and Prevention. Public Health Service task force recommendations for the use of antiretroviral drugs in pregnant women infected with HIV-1 for maternal health and for reducing perinatal HIV-1 transmission in the United States. Morbidity and Mortality Weekly Report 47(RR-2):1–30, 1998.9450721
Centers for Disease Control & Prevention. Women and Smoking: A Report of the Surgeon General, 2001. Pattern of Tobacco Use Among Women and Girls - Fact Sheet Atlanta, GA: Center for Disease Control & Prevention, Office of Smoking and Health 2001.
Centers for Disease Control and Prevention. Drug-Associated HIV Transmission Continues in the United States. Atlanta, GA: 2002.
Centers for Disease Control and Prevention. Cigarette smoking among adults - United States, 2002. MMWR 53(20):427–446. Washington, D.C.: Centers for Disease Control and Prevention, 2004.15163928
Centers for Disease Control and Prevention. HIV/AIDS among African Americans. Fact Sheet - HIV/AIDS Among African Americans. Atlanta, GA: Centers for Disease Control and Prevention (CDC) 2005.
Centers for Disease Control and Prevention. HIV/AIDS among Women. Atlanta, GA: Centers for Disease Control and Prevention, 2007a.
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Report, 2005: Cases of HIV infection and AIDS in the United States and Dependent Areas, 2005. Volume 17 Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, 2007b.
Centers for Disease Control and Prevention. Hepatitis C fact sheet. 2008. http://cdc.gov/hepatitis/hcv/pdfs/hepcgeneralfactsheet.pdf [Accessed October 2, 2008].
Chabrol, H., Teissedre, F., Saint-Jean, M., Teisseyre, N., Roge, B., and Mullet, E. Prevention and treatment of post-partum depression: A controlled randomized study on women at risk. Psychological Medicine 32(6):1039–1047, 2002.12214785
Chamberlin, J., and Schene, A.H. A working definition of empowerment. Psychiatric Rehabilitation Journal 20(4):43–46, 1997.
Chan, A.W., Pristach, E.A., Welte, J.W., and Russell, M. Use of the TWEAK test in screening for alcoholism/heavy drinking in three populations. Alcoholism: Clinical & Experimental Research 17(6):1188–1192, 1993.
Chan, C.S. Issues of identity development among Asian-American lesbians and gay men. Journal of Counseling and Development 68(1):16–20, 1989.
Chan, C.S. Don't ask, don't tell, don't know: The formation of a homosexual identity and sexual expression among Asian American lesbians. In: Greene, B., ed. Ethnic And Cultural Diversity Among Lesbians And Gay Men. Thousand Oaks, CA: Sage Publications, 1997. pp. 240–248.
Chang, G. Brief interventions for problem drinking and women. Journal of Substance Abuse Treatment 23(1):1–7, 2002.12127463
Chang, G., Goetz, M.A., Wilkins-Haug, L., and Berman, S. A brief intervention for prenatal alcohol use: An in-depth look. Journal of Substance Abuse Treatment 18(4):365–369, 2000.10812310
Chang, G., McNamara, T.K., Haimovici, F., and Hornstein, M.D. Problem drinking in women evaluated for infertility. American Journal of Addiction 15(2):174–179, 2006.
Chang, G., Wilkins-Haug, L., Berman, S., and Goetz, M.A. The TWEAK: Application in a prenatal setting. Journal of Studies on Alcohol 60(3):306–309, 1999.10371256
Chang, G., Wilkins-Haug, L., Berman, S., Goetz, M.A., Behr, H., and Hiley, A. Alcohol use and pregnancy: Improving identification. Obstetrics and Gynecology 91(6):892–898, 1998.9610992
Chang, P. Treating Asian/Pacific American addicts and their families. In: Krestan, J.-A., ed. Bridges To Recovery: Addiction, Family Therapy, And Multicultural Treatment. New York: Free Press, 2000. pp. 192–218.
Chang, Y.-Y.J. Comorbidity of depression and substance use disorders: The role of depression as a risk factor for post-treatment relapse, 1997.
Chasnoff, I.J., McGourty, R.F., Bailey, G.W., Hutchins, E., Lightfoot, S.O., Pawson, L.L., Fahey, C., May, B., Brodie, P., McCulley, L., and Campbell, J. The 4P's Plus screen for substance use in pregnancy: clinical application and outcomes. Journal of Perinatology 25(6):368–374, 2005.15703775
Chasnoff, I.J., Neuman, K., Thornton, C., and Callaghan, M.A. Screening for substance use in pregnancy: A practical approach for the primary care physician. American Journal of Obstetrics and Gynecology 184(4):752–758, 2001.11262483
Chatham, L.R., Hiller, M.L., Rowan-Szal, G.A., Joe, G.W., and Simpson, D.D. Gender differences at admission and follow-up in a sample of methadone maintenance clients. Substance Use & Misuse 34(8):1137–1165, 1999.10359226
Chavkin, W., and Breitbart, V. Substance abuse and maternity: The United States as a case study. Addiction 92(9):1201–1205, 1997.9374021
Chen, H., Guarnaccia, P.J., and Chung, H. Self-attention as a mediator of cultural influences on depression. International Journal of Social Psychiatry 49(3):192–203, 2003.
Chen, X., Burgdorf, K., Dowell, K., Roberts, T., Porowski, A., and Herrell, J.M. Factors associated with retention of drug abusing women in long-term residential treatment. Evaluation and Program Planning 27(2):205–212, 2004.
Chen, C.M., Yoon, Y.H., Yi, H.y., and Lucas, D.L. Alcohol and hepatitis C mortality among males and females in the United States: A life table analysis. Alcoholism: Clinical and Experimental Research 31(2):285–292, 2007.
Cherry, D.K., and Woodwell, D.A. National Ambulatory Medical Care Survey: 2000 Summary. Advance Data From Vital and Health Statistics, No.328 Hyattsville, MD: National Center for Health Statistics 2002.
Chilcoat, H.D., and Breslau, N. Alcohol disorders in young adulthood: Effects of transitions into adult roles. Journal of Health and Social Behavior 37(4):339–349, 1996.8997889
Child Welfare League of America. Crack And Other Addictions: Old Realities And New Challenge For Child Welfare. Washington, DC: Child Welfare League of America, 1990.
Child Welfare League of America. Children at the Front: A Different View of the War on Alcohol and Drugs. Washington, DC: Child Welfare League of America, 1992.
Chisholm, D., Rehm, J., Van, O.M., and Monteiro, M. Reducing the global burden of hazardous alcohol use: a comparative cost-effectiveness analysis. Journal of Studies on Alcohol 65(6):782–793, 2004.15700517
Choi, S., and Ryan, J.P. Co-occurring problems for substance abusing mothers in child welfare: Matching services to improve family reunification. Children and Youth Services Review 29(11):1395–1410, 2007.
Chou, S.P., Grant, B.F., and Dawson, D.A. Medical consequences of alcohol consumption–United States, 1992. Alcoholism: Clinical and Experimental Research 20(8):1423–1429, 1996.
Chung, R.H., Kim, B.S., and Abreu, J.M. Asian American multidimensional acculturation scale: development, factor analysis, reliability, and validity. Cultural Diversity and Ethnic Minority Psychology 10(1):66–80, 2004.14992631
Clark, J.J., Leukefeld, C., Godlaski, T., Brown, C., Garrity, J., and Hays, L. Developing, implementing, and evaluating a treatment protocol for rural substance abusers. Journal of Rural Health 18(3):396–406, 2002.
Claus, R.E., Orwin, R.G., Kissin, W., Krupski, A., Campbell, K., and Stark, K. Does gender-specific substance abuse treatment for women promote continuity of care? Journal of Substance Abuse Treatment 32(1):27–39, 2007.17175396
Cochran, S.D., Ackerman, D., Mays, V.M., and Ross, M.W. Prevalence of non-medical drug use and dependence among homosexually active men and women in the US population. Addiction 99(8):989–998, 2004.15265096
Cochran, S.D., and Mays, V.M. Relation between psychiatric syndromes and behaviorally defined sexual orientation in a sample of the US population. American Journal of Epidemiology 151(5):516–523, 2000.10707921
Cochran, S.D., Keenan, C., Schober, C., and Mays, V.M. Estimates of alcohol use and clinical treatment needs among homosexually active men and women in the U.S. population. Journal of Consulting and Clinical Psychology 68(6):1062–1071, 2000.11142540
Cochran, S.D., Mays, V.M., Alegria, M., Ortega, A.N., and Takeuchi, D. Mental health and substance use disorders among Latino and Asian American lesbian, gay, and bisexual adults. Journal of Consulting and Clinical Psychology 75(5):785–794, 2007.17907860
Cochran, S.D., Mays, V.M., Bowen, D., Gage, S., Bybee, D., Roberts, S.J., Goldstein, R.S., Robison, A., Rankow, E.J., and White, J. Cancer-related risk indicators and preventive screening behaviors among lesbians and bisexual women. American Journal of Public Health 91(4):591–597, 2001.11291371
Cocozza, J.J., Jackson, E.W., Hennigan, K., Morrissey, J.P., Reed, B.G., Fallot, R., and Banks, S. Outcomes for women with co-occurring disorders and trauma: program-level effects. Journal of Substance Abuse Treatment 28(2):109–119, 2005.15780540
Cohen, J.B., Dickow, A., Horner, K., Zweben, J.E., Balabis, J., Vandersloot, D., and Reiber, C. Abuse and violence history of men and women in treatment for methamphetamine dependence. American Journal of Addiction 12(5):377–385, 2003.
Cohen, L.R., and Hien, D.A. Treatment outcomes for women with substance abuse and PTSD who have experienced complex trauma. Psychiatric Services 57(1):100–106, 2006.16399969
Cohen, L.S., Viguera, A.C., Bouffard, S.M., Nonacs, R.M., Morabito, C., Collins, M.H., and Ablon, J.S. Venlafaxine in the treatment of postpartum depression. Journal of Clinical Psychology 62(8):592–596, 2001.
Cohen, M. Counseling Addicted Women. Thousand Oaks, CA: Sage Publications, 2000.
Cohen, R.A., Hao, C., and Coriaty-Nelson, Z. Health insurance coverage: Estimates from the National Health Interview Survey, January - June 2004. Atlanta, GA: Centers for Disease Control and Prevention, 2004.
Cohen-Smith, D., and Severson, H.H. A comparison of male and female smokeless tobacco use. Nicotine & Tobacco Research 1(3):211–218, 1999.11072417
Cohn, J.A. HIV-1 infection in injection drug users. Infectious Disease Clinics of North America 16(3):745–770, 2002.12371125
Coleman, V.E. Lesbian battering: The relationship between personality and the perpetration of violence. Violence and Victims 9(2):139–152, 1994.7696194
Collins, R.L., and McNair, L.D. Minority women and alcohol use. Alcohol Research & Health 26(4):251–256, 2002.12875034
Colorado Department of Human Services, and Alcohol and Drug Abuse Division (ADAD). Substance use disorder treatment rules. Denver, CO: Colorado Department of Human Services, Alcohol and Drug Abuse Division (ADAD), 2006.
Comfort, M., and Kaltenbach, K. The psychosocial history: An interview for pregnant and parenting women in substance abuse treatment and research. In: Rahdert, E.R., ed. Treatment For Drug-Exposed Women And Their Children: Advances In Research Methodology. NIDA Research Monograph 166. NIH Publication No. 96–3632. Rockville, MD: National Institute on Drug Abuse, 1996. pp. 133–142.
Comfort, M., and Kaltenbach, K.A. Predictors of treatment outcomes for substance-abusing women: A retrospective study. Substance Abuse 21(1):33–45, 2000.12466646
Comfort, M., Hagan, T., and Kaltenbach, K. Psychosocial History. Philadelphia, PA: Thomas Jefferson University, Jefferson Medical Center, Family Center, 1996.
Comfort, M., Loverro, J., and Kaltenbach, K. A search for strategies to engage women in substance abuse treatment. Social Work in Health Care 31(4):59–70, 2000.
Comfort, M., Zanis, D.A., Whiteley, M.J., Kelly-Tyler, A., and Kaltenbach, K.A. Assessing the needs of substance abusing women: Psychometric data on the psychosocial history. Journal of Substance Abuse Treatment 17(1–2):79–83, 1999.10435254
Connecticut Department of Mental Health and Addiction Services, Women's Services Practice Improvement Collaborative, compiled by David J. Berkowitz. Treatment Guidelines: Gender Responsive Treatment Of Women With Substance Use Disorders. January 23, 2007 Revision Hartford, CT: Connecticut Department of Mental Health and Addiction Services, 2007.
Conners, N.A., Bradley, R.H., Mansell, L.W., Liu, J.Y., Roberts, T.J., Burgdorf, K., and Herrell, J.M. Children of mothers with serious substance abuse problems: An accumulation of risks. American Journal of Drug and Alcohol Abuse 30(1):85–100, 2004.
Conners, N.A., Grant, A., Crone, C.C., and Whiteside-Mansell, L. Substance abuse treatment for mothers: Treatment outcomes and the impact of length of stay. Journal of Substance Abuse Treatment 31(4):447–456, 2006.17084800
Conway, K.P., and Montoya, I.D. Symposium: What is the directionality of the onset of comorbid substance use and other psychiatric disorders? Bethesda, MD: National Institute on Drug Abuse, 2007.
Cooley, M.E., Blood, E., Hoskinson, R., and Garvey, A. Gender differences in smoking relapse. Oncology Nursing Forum 33(2):401–402, 2006.
Corcos, M., Nezelof, S., Speranza, M., Topa, S., Girardon, N., Guilbaud, O., TaÇeb, O., Bizouard, P., Halfon, O., Venisse, J.L., Perez-Diaz, F., Flament, M., and Jeammet, P. Psychoactive substance consumption in eating disorders. Eating Behaviors 2(1):27–38, 2001.15001048
Corliss, H.L., Grella, C.E., Mays, V.M., and Cochran, S.D. Drug use, drug severity, and help-seeking behaviors of lesbian and bisexual women. Journal of Women's Health (Larchmt.) 15(5):556–568, 2006.
Corse, S.J., McHugh, M.K., and Gordon, S.M. Enhancing provider effectiveness in treating pregnant women with addictions. Journal of Substance Abuse Treatment 12(1):3–12, 1995.7752295
Cottrell, B.H. Vaginal douching. Journal of Obstetric, Gynecologic, and Neonatal Nursing 32(1):12–18, 2003.
Coughey, K., Feighan, K., Cheney, R., and Klein, G. Retention in an aftercare program for recovering women. Substance Use and Misuse 33(4):917–933, 1998.9548630
Cournoyer, L.G., Brochu, S., Landry, M., and Bergeron, J. Therapeutic alliance, patient behaviour and dropout in a drug rehabilitation programme: the moderating effect of clinical subpopulations. Addiction 102(12):1960–1970, 2007.18031431
Covington, S. A case for gender-responsive drug treatment. Clinical Psychiatry News 35(8):15, 2007.
Covington, S.S. A Woman's Way through the Twelve Steps. Center City, MN: Hazelden, 1994.
Covington, S.S. Women, addiction, and sexuality. In: Straussner, S.L.A., and Zelvin, E., eds. Gender and Addictions: Men and Women in Treatment. Northvale, NJ: Jason Aronson, 1997. pp. 71–95.
Covington, S.S. Women in prison: Approaches in the treatment of our most invisible population. Women & Therapy 21(1):141–155, 1998.
Covington, S.S. Helping Women Recover: A Program for Treating Addiction. San Francisco: Jossey-Bass, 1999a.
Covington, S.S. Helping Women Recover: A Program for Treating Addiction. Special Edition for Use in Correctional Settings. San Francisco: Jossey-Bass, 1999b.
Covington, S.S. Awakening Your Sexuality: A Guide for Recovering Women. Center City, MN: Hazelden, 2000.
Covington, S.S. A Woman's Journey Home: Challenges for Female Offenders and Their Children. Washington, DC: Urban Institute 2002a.
Covington, S.S. Helping women recover: Creating gender-responsive treatment. In: Straussner, S.L.A., and Brown, S., eds. Handbook of Women's Addiction Treatment: Theory and Practice. San Francisco: Jossey-Bass, 2002b. pp. 52–72.
Covington, S.S. Beyond Trauma: A Healing Journey for Women: Facilitator's Guide. Center City, Minnesota: Hazelden, 2003a.
Covington, S.S. Beyond Trauma: A Healing Journey for Women: Participant's Workbook. Center City, Minnesota: Hazelden, 2003b.
Covington, S. S. Women and Addiction: A Gender-Responsive Approach. Clinical Innovators Series. Center City, MN: Hazelden, 2007.
Covington, S.S. Helping Women Recover: A Program for Treating Addiction. (Rev. ed.) San Francisco: Jossey-Bass, 2008a.
Covington, S.S. Helping Women Recover: A Program for Treating Addiction. Special Edition for Use in Correctional Settings. (Rev. ed.) San Francisco: Jossey-Bass, 2008b.
Covington, S.S., and Bloom, B.E. Gendered justice: Women in the criminal justice system. In: Bloom, B.E., ed. Gendered Justice: Addressing the Female Offender. Durham, NC: Carolina Academic Press, 2003. pp. 3–24.
Covington, S.S., and Surrey, J.L. The relational model of women's psychological development: Implications for substance abuse. In: Wilsnack, R.W., and Wilsnack, S.C., eds. Gender and Alcohol: Individual and Social Perspectives. New Brunswick, NJ: Rutgers Center of Alcohol Studies, 1997. pp. 335–351.
Cowan, G., and Ullman, J.B. Ingroup rejection among women: The role of personal inadequacy. Psychology of Women Quarterly 30(4):399–409, 2006.
Coyhis, D. Culturally specific addiction recovery for Native Americans. In: Krestan, J., ed. Bridges To Recovery: Addiction, Family Therapy, And Multicultural Treatment. New York: The Free Press, 2000. pp. 77–114.
Coyne, C.M., Jarrett, M.E., Burr, R.L., and Murphy, S.A. Women's physical and psychological symptoms during early phase recovery from alcoholism: A longitudinal study. Journal of Addictions Nursing 17(2):83–93, 2006.
Cramer, M. Issues in the treatment of dual diagnosis: PTSD and substance abuse in women. Presentation to DATA of Rhode Island, Providence, RI, October, 2000.
Cramer, M. Under the influence of unconscious process: Countertransference in the treatment of PTSD and substance abuse in women. American Journal of Psychotherapy 56(2):194–210, 2002.12125297
Crits-Christoph, P., Baranackie, K., Kurcias, J.S., and Beck, A.T. Meta-analysis of therapist effects in psychotherapy outcome studies. Psychotherapy Research 1(2):81–91, 1991.
Cuellar, I., Harris, L.C., and Jasso, R. An acculturation scale for Mexican American normal and clinical populations. Hispanic Journal of Behavioral Sciences. 2(3):199–217, 1980.
Cuijpers, P., van Straten, A., and Warmerdam, L. Behavioral activation treatments of depression: A meta-analysis. Clinical Psychology Review 27(3):318–326, 2007.17184887
Cunningham, J.A., Sobell, L.C., Gavin, D.R., Sobell, M.B., and Breslin, F.C. Assessing motivation for change: Preliminary development and evaluation of a scale measuring the costs and benefits of changing alcohol or drug use. Psychology of Addictive Behaviors 11(2):107–114, 1997.
Curtis, C.E., Jason, L.A., Olson, B.D., and Ferrari, J.R. Disordered eating, trauma, and sense of community: Examining women in substance abuse recovery homes. Women & Health 41(4):87–100, 2005.
Cutrona, C.E., Cadoret, R.J., Suhr, J.A., Richards, C.C., Troughton, E., Schutte, K., and Woodworth, G. Interpersonal variables in the prediction of alcoholism among adoptees: evidence for gene-environment interactions. Comprehensive Psychiatry 35(3):171–179, 1994.8045106
Daley, M., Argeriou, M., and McCarty, D. Substance abuse treatment for pregnant women: A window of opportunity? Addictive Behaviors 23(2):239–249, 1998.9573427
Dallam, S.J. The identification and management of self-mutilating patients in primary care. Nurse Practitioner 22(5):151–165, 1997.
Dansky, B.S., Brewerton, T.D., and Kilpatrick, D.G. Comorbidity of bulimia nervosa and alcohol use disorders: Results from the National Women's Study. International Journal of Eating Disorders 27(2):180–190, 2000.
Dashe, J.S., Jackson, G.L., Olscher, D.A., Zane, E.H., and Wendel, G.D., Jr. Opioid detoxification in pregnancy. Obstetrics and Gynecology 92(5):854–858, 1998.9794682
D'Avanzo, C., Dunn, P., Murdock, J., and Naegle, M. Developing culturally informed strategies for substance-related interventions. In: Naegle, M.A., and D'Avanzo, C.E., eds. Addictions And Substance Abuse: Strategies For Advanced Practice Nursing. Upper Saddle River, NJ: Prentice Hall Health, 2001. pp. 59–74.
D'Avanzo, C.E., Frye, B., and Froman, R. Culture, stress and substance use in Cambodian refugee women. Journal of Studies on Alcohol 55(4):420–426, 1994.7934049
Davidson, P.R., and Parker, K.C. Eye movement desensitization and reprocessing (EMDR): A meta-analysis. Journal of Consulting and Clinical Psychology 69(2):305–316, 2001.11393607
Davis, T.M., Bush, K.R., Kivlahan, D.R., Dobie, D.J., and Bradley, K. Screening for substance abuse and psychiatric disorders among women patients in a VA Health Care System. Psychiatric Services 54:214–218, 2003.12556603
Dawson, D.A., Grant, B.F., Chou, S.P., and Stinson, F.S. The impact of partner alcohol problems on women's physical and mental health. Journal of Studies on Alcohol and Drugs 68(1):66–75, 2007.17149519
Day, N., Cornelius, M., Goldschmidt, L., Richardson, G., Robles, N., and Taylor, P. The effects of prenatal tobacco and marijuana use on offspring growth from birth through 3 years of age. Neurotoxicology and Teratology 14(6):407–414, 1992.1488035
Dayton, T. Trauma and Addiction: Ending the Cycle of Pain Through Emotional Literacy. Deerfield Beach, FL: Health Communications, 2000.
de Mello, M.F., de Jesus Mari, J., Bacaltchuk, J., Verdeli, H., and Neugebauer, R. A systematic review of research findings on the efficacy of interpersonal therapy for depressive disorders. European Archives of Psychiatry and Clinical Neuroscience 255(2):75–82, 2005.15812600
Dean, L., Meyer, I.H., Robinson, K., Sell, R.L., Sember, R., Silenzio, V.M.B., Bowen, D.J., Bradford, J., Rothblum, E., Scout, White J., Dunn, P., Lawrence, A., Wolfe, D., and Xavier, J. Lesbian, gay, bisexual, and transgender health: Findings and concerns. Journal of the Gay and Lesbian Medical Association 4(3):101–151, 2000.
Dempsey, P., Bird, D.C., and Hartley, D. Rural mental health and substance abuse. In: Ricketts, T.C., ed. Rural Health in the United States. New York: Oxford University Press, 1999. pp. 159–178.
DeNavas-Walt, C., Proctor, B.D., and Mills, R.J. Income, Poverty, and Health Insurance Coverage in the United States: 2003. U.S. Census Bureau, Current Population Reports, P60-226, Washington, D.C.: U.S. Government Printing Office, 2004.
Dennerstein, L. Factors associated with the experience of menopause and related therapy. Presented at First World Congress on Women's Mental Health, Berlin, Germany, March 27–31, 2001a.
Dennerstein, L. How does women's mental health differ from that of men? Plenary speech presented at First World Congress on Women's Mental Health, Berlin, Germany, March 27–31, 2001b.
Derauf, C., LaGasse, L.L., Smith, L.M., Grant, P., Shah, R., Arria, A., Huestis, M., Haning, W., Strauss, A., Grotta, S.D., Liu, J., and Lester, B.M. Demographic and psychosocial characteristics of mothers using methamphetamine during pregnancy: Preliminary results of the infant development, environment, and lifestyle study (IDEAL). American Journal of Drug and Alcohol Abuse 33(2):281–289, 2007.
Derogatis, L.R., and Melisaratos, N. The Brief Symptom Inventory: An introductory report. Psychological Medicine 13(3):595–605, 1983.6622612
Devaud, L.L., Risinger, F.O., and Selvage, D. Impact of the Hormonal Milieu on the Neurobiology of Alcohol Dependence and Withdrawal. Journal of General Psychology 133(4):337–356, 2006.
DeVoe, D. Feminist and nonsexist counseling: Implications for the male counselor. Journal of Counseling & Development 69(1):33–36, 1990.
Diamant, A.L., Wold, C., Spritzer, K., and Gelberg, L. Health behaviors, health status, and access to and use of health care: A population-based study of lesbian, bisexual, and heterosexual women. Archives of Family Medicine 9(10):1043–1051, 2000.11115206
Dick, D.M., Pagan, J.L., Holliday, C., Viken, R., Pulkkinen, L., Kaprio, J., and Rose, R.J. Gender differences in friends' influences on adolescent drinking: a genetic epidemiological study. Alcoholism: Clinical & Experimental Research 31(12):2012–2019, 2007.
DiNitto, D.M., and Crisp, C. Addictions and women with major psychiatric disorders. In: Straussner, S.L.A., and Brown, S., eds. The Handbook of Addiction Treatment for Women: Theory and Practice. San Francisco: Jossey-Bass, 2002. pp. 423–450.
Dixit, A.R., and Crum, R.M. Prospective study of depression and the risk of heavy alcohol use in women. American Journal of Psychiatry 157(5):751–758, 2000.
Dobie, D.J., Kivlahan, D.R., Maynard, C., Bush, K.R., Davis, T.M., and Bradley, K.A. Posttraumatic stress disorder in female veterans: association with self-reported health problems and functional impairment. Archives of Internal Medicine 164(4):394–400, 2004.14980990
Dole, V.P., and Nyswander, M.E. Rehabilitation of heroin addicts after blockade with methadone. New York State Journal of Medicine 66(15):2011–2017, 1966a.5220498
Dole, V.P., Nyswander, M.E., and Kreek, M.J. Narcotic blockade. Archives of Internal Medicine 118(4):304–309, 1966b.4162686
Donaldson, P.L. Perinatal drug and alcohol addiction: The role of the primary care provider. Lippincotts Primary Care Practice 4(3):349–358, 2000.
Dorgan, J.F., Baer, D.J., Albert, P.S., Judd, J.T., Brown, E.D., Corle, D.K., Campbell, W.S., Hartman, J.J., Tejpar, A.A., Clevidence, Beverly a., Giffen, C.A., Chandler, D.W., Stanczyk, F.Z., and Taylor, P.R. Serum hormones and the alcohol-breast cancer association in postmenopausal women. Journal of the National Cancer Institute 93(9):710–715, 2001.11333294
Drabble, L. Elements of effective services for women in recovery: Implications for clinicians and program supervisors. In: Underhill, B.L., and Finnegan, D.G., eds. Chemical Dependency: Women At Risk. New York: Harrington Park Press/Haworth Press, 1996. pp. 1–21.
Drabble, L., and Underhill, B. Elements of effective intervention and treatment for lesbians. In: Straussner, S.L.A., and Brown, S., eds. The Handbook of Addiction Treatment for Women: Theory and Practice. San Francisco: Jossey-Bass, 2002. pp. 399–422.
Drake, R.E., Mercer-McFadden, C., Mueser, K.T., McHugo, G.J., and Bond, G.R. Review of integrated mental health and substance abuse treatment for patients with dual disorders. Schizophrenia Bulletin 24(4):589–608, 1998.9853791
Dube, S.R., Miller, J.W., Brown, D.W., Giles, W.H., Felitti, V.J., Dong, M., and Anda, R.F. Adverse childhood experiences and the association with ever using alcohol and initiating alcohol use during adolescence. Journal of Adolescent Health 38(4):444–10, 2006.
Duszynski, K.R., Nieto, F.J., and Valente, C.M. Reported practices, attitudes, and confidence levels of primary care physicians regarding patients who abuse alcohol and other drugs. Maryland Medical Journal 44(6):439–446, 1995.7596237
Eaton, D.K., Kann, L., Kinchen, S., Shanklin, S., Ross, J., Hawkins, J., Harris, W.A., Lowry, R., McManus, T., Chyen, D., Lim, C., Brener, N.D., and Wechsler, H. Youth Risk Behavior Surveillance–United States, 2007. 57: No. SS-4:1–133. Atlanta, GA: Centers for Disease Control and Prevention, 2008.
Eggert, J., Theobald, H., and Engfeldt, P. Effects of alcohol consumption on female fertility during an 18-year period. Fertility and Sterility 81(2):379–383, 2004.14967377
Ehrmin, J.T. Unresolved feelings of guilt and shame in the maternal role with substance-dependent African American women. Journal of Nursing Scholarship 33(1):47–52, 2001.11253579
El-Bassel, N., Gilbert, L., Frye, V., Wu, E., Go, H., Hill, J., and Richman, B.L. Physical and Sexual Intimate Partner Violence Among Women in Methadone Maintenance Treatment. Source. Psychology of Addictive Behaviors. 18(2):180–183, 2004.15238060
El-Bassel, N., Gilbert, L., Wu, E., Go, H., and Hill, J. Relationship Between Drug Abuse and Intimate Partner Violence: A Longitudinal Study Among Women Receiving Methadone. American Journal of Public Health 95(3):465–470, 2005.15727978
Eliason, M.J., and Skinstad, A.H. Drug and alcohol intervention for older women: A pilot study. Journal of Gerontological Nursing 27(12):18–24, 2001.11820530
Ellickson, P.L., Hays, R.D., and Bell, R.M. Stepping through the drug use sequence: Longitudinal scalogram analysis of initiation and regular use. Journal of Abnormal Psychology 101(3):441–451, 1992.1500601
Elliott, D.E., Bjelajac, P., Fallot, R.D., Markoff, L.S., and Reed, B.G. Trauma-informed or trauma-denied: Principles and implementation of trauma-informed services for women. Journal of Community Psychology 33(4):461–477, 2005.
El-Mohandes, A., Herman, A.A., Nabil El-Khorazaty, M., Katta, P.S., White, D., and Grylack, L. Prenatal care reduces the impact of illicit drug use on perinatal outcomes. Journal of Perinatology 23(5):354–360, 2003.12847528
Epstein, E.E., Fischer-Elber, K., and Al-Otaiba, Z. Women, aging, and alcohol use disorders. Journal of Women and Aging 19(1–2):31–48, 2007.17588878
Evans, J., Hahn, J., Page-Shafer, K., Lum, P., Stein, E., Davidson, P., and Moss, A. Gender differences in sexual and injection risk behavior among active young injection drug users in San Francisco (the UFO study). Journal of Urban Health 80(1):137–146, 2003.12612103
Evans, K., and Sullivan, J.M. Treating Addicted Survivors of Trauma. New York: Guilford Press, 1995.
Evans, S.M. The role of estradiol and progesterone in modulating the subjective effects of stimulants in humans. Experimental and Clinical Psychopharmacology 15(5):418–426, 2007.17924776
Evans, S.M., and Foltin, R.W. Exogenous progesterone attenuates the subjective effects of smoked cocaine in women, but not in men. Neuropsychopharmacology 31(3):659–674, 2006.16160708
Evans, S.M., Haney, M., and Foltin, R.W. The effects of smoked cocaine during the follicular and luteal phases of the menstrual cycle in women. Psychopharmacology 159(4):397–406, 2002.11823892
Evans-Campbell, T. Historical trauma in American Indian/Native Alaska communities: A multilevel framework for exploring impacts on individuals, families, and communities. Journal of Interpersonal Violence 23(3):316–338, 2008.18245571
Evans-Campbell, T., Fredriksen-Goldsen, K.I., Walters, K.L., and Stately, A. Caregiving experiences among American Indian two-spirit men and women: Contemporary and historical roles. Journal of Gay & Lesbian Social Services: Issues in Practice, Policy & Research 18(3–4):75–92, 2005.
Ewing, H. A Practical Guide to Intervention in Health and Social Services with Pregnant and Postpartum Addicts and Alcoholics: Theoretical Framework, Brief Screening Tool, Key Interview Questions, and Strategies for Referral to Recovery Resources. State of California Grant for Training and Cross-Training in Health, Social Services, and Alcohol/Drug Services, 1990.
Ewing, J.A. Detecting alcoholism. The CAGE questionnaire. JAMA: The Journal of the American Medical Association 252(14):1905–1907, 1984.6471323
Eyler, F.D., and Behnke, M. Early development of infants exposed to drugs prenatally. Clinics in Perinatology 26(1):107–150, vii, 1999.10214546
Eyler, F.D., Behnke, M., Garvan, C.W., Woods, N.S., Wobie, K., and Conlon, M. Newborn evaluations of toxicity and withdrawal related to prenatal cocaine exposure. Neurotoxicology and Teratology 23(5):399–411, 2001.11711242
Fals-Stewart, W., Birchler, G.R., and O'Farrell, T.J. Drug-abusing patients and their intimate partners: Dyadic adjustment, relationship stability, and substance use. Journal of Abnormal Psychology 108(1):11–23, 1999.10066989
Fals-Stewart, W., O'Farrell, T.J., Birchler, G.R., Cordova, J., and Kelley, M.L. Behavioral couples therapy for alcoholism and drug abuse: Where we've been, where we are, and where we're going. Journal of Cognitive Psychotherapy 19(3):229–246, 2005.
Federal Interagency Forum on Aging-Related Statistics. Older Americans 2004: Key Indicators of Well-being. November. Federal Interagency Forum on Aging-Related Statistics. Washington, D.C.: U.S. Government Printing Office, 2004.
Feinberg, F. Substance-abusing mothers and their children: Treatment for the family. In: Combrinck-Graham, L., ed. Children in Families at Risk: Maintaining the Connections. New York: Guilford Press, 1995. pp. 228–247.
Felitti, V.J., Anda, R.F., Nordenberg, D., Williamson, D.F., Spitz, A.M., Edwards, V., Koss, M.P., and Marks, J.S. Relationship of childhood abuse and household dysfunction to many of the leading causes of death in adults. The Adverse Childhood Experiences (ACE) Study. American Journal of Preventive Medicine 14(4):245–258, 1998.9635069
Fernandez-Sola, J., and Nicolas-Arfelis, J.M. Gender differences in alcoholic cardiomyopathy. The Journal of Gender-Specific Medicine: JGSM: The Official Journal of the Partnership for Women's Health at Columbia. 5(1):41–47, 2002.
Ferreyra, N. Substance abuse and women with disabilities. Barker, L. T., Magill, K., MacKinnon, J. Dougal., Ridley, B., and Freeman, A. Cupolo. Practitioner's Guide To Primary Care For Women With Physical Disabilities. Oakland, CA: Berkeley Policy Associates and Alta Bates Summit Medical Center, 2005.
Fetzer Institute/National Institute on Aging Workgroup. Multidimensional Measurement Of Religiousness/Spirituality For Use In Health Research: A Report Of The Fetzer Institute/National Institute On Aging Workgroup. Kalamazoo, MI: Fetzer Institute, 1999.
Fetzer Institute/National Institute on Aging Workgroup. Multidimensional Measurement Of Religiousness/Spirituality For Use In Health Research: A Report of the Fetzer Institute/National Institute on Aging Workgroup. Kalamazoo, MI: Fetzer Institute, 2003.
Fields, J., and Casper, L.M. America's Families and Living Arrangements. Current Population Reports March 2000. P20-537 Washington, DC: U.S. Census Bureau, 2000.
Fillmore, K.M., Leino, E.V., Motoyoshi, M., Shoemaker, C., Terry, H., Ager, C.R., and Ferrer, H.P. Patterns and trends in women's and men's drinking. In: Wilsnack, R.W., and Wilsnack, S.C., eds. Gender and Alcohol: Individual and Social Perspectives. New Brunswick, NJ: Rutgers Center of Alcohol Studies, 1997. pp. 21–48.
Finch, B.K., Kolody, B., and Vega, W.A. Perceived discrimination and depression among Mexican-origin adults in California. Journal of Health and Social Behavior 41(3):295–313, 2000.11011506
Finkelhor, D., Hotaling, G., Lewis, I.A., and Smith, C. Sexual abuse in a national survey of adult men and women: Prevalence, characteristics, and risk factors. Child Abuse and Neglect 14(1):19–28, 1990.2310970
Finkelstein, N. The relational model. In: Pregnancy and Exposure to Alcohol and Other Drug Use. CSAP Technical Report 7. Rockville, MD: Center for Substance Abuse Prevention, 1993a. pp. 47–59.
Finkelstein, N. Treatment programming for alcohol and drug-dependent pregnant women. International Journal of the Addictions 28(13):1275–1309, 1993b.
Finkelstein, N. Treatment issues for alcohol- and drug-dependent pregnant and parenting women. Health & Social Work 19(1):7–15, 1994.8168782
Finkelstein, N. Using the relational model as a context for treating pregnant and parenting chemically dependent women. In: Underhill, B.L., and Finnegan, D.G., eds. Chemical Dependency: Women at Risk. New York: Harrington Park Press/Haworth Press, 1996. pp. 23–44.
Finkelstein, N., Brown, K.N., and Laham, C.Q. Alcoholic mothers and guilt: Issues for caregivers. Alcohol Health and Research World 6(1):45–49, 1981.
Finkelstein, N., Kennedy, C., Thomas, K., and Kearns, M. Gender-Specific Substance Abuse Treatment. Rockville, MD: Center for Substance Abuse Prevention, 1997.
Finkelstein, N., VandeMark, N., Fallot, R., Brown, V., Cadiz, S., and Heckman, S. Enhancing substance abuse recovery through integrated trauma treatment. Sarasota, FL: National Trauma Consortium, 2004.
Fiorentine, R., and Anglin, M.D. Does increasing the opportunity for counseling increase the effectiveness of outpatient drug treatment? American Journal of Drug and Alcohol Abuse 23(3):369–382, 1997.
Fiorentine, R., Anglin, M.D., Gil-Rivas, V., and Taylor, E. Drug treatment: Explaining the gender paradox. Substance Use and Misuse 32(6):653–678, 1997.9178435
Fischer, G., Ortner, R., Rohrmeister, K., Jagsch, R., Baewert, A., Langer, M., and Aschauer, H. Methadone versus buprenorphine in pregnant addicts: A double-blind, double-dummy comparison study. Addiction 101(2):275–281, 2006.16445556
Fitzgerald, L.F., and Harmon, L.W. Women's career development: A postmodern update. In: Leong, F.T.L., and Barak, A., eds. Contemporary Models In Vocational Psychology: A Volume In Honor Of Samuel H. Osipow. 0-8058-2666-1 (hardcover); 0-8058-2667-X (paperback). Lawrence Erlbaum Associates Publishers: Mahwah, 2001. pp. 207–230.
Fitzgerald, L.F., Fassinger, R.E., and Betz, N.E. Theoretical advances in the study of women's career development. In: Walsh, W.B., and Osipow, S.H., eds. Handbook Of Vocational Psychology: Theory, Research, And Practice (2nd ed.). Contemporary topics in vocational psychology. 0-8058-1374-8 (hardcover). Lawrence Erlbaum Associates, 1995. pp. 67–109.
Fitzsimons, H.E., Tuten, M., Vaidya, V., and Jones, H.E. Mood disorders affect drug treatment success of drug-dependent pregnant women. Journal of Substance Abuse Treatment 32(1):19–25, 2007.17175395
Flannery, B., Fishbein, D., Krupitsky, E., Langevin, D., Verbitskaya, E., Bland, C., Bolla, K., Egorova, V., Bushara, N., Tsoy, M., and Zvartau, E. Gender differences in neurocognitive functioning among alcohol-dependent Russian patients. Alcoholism: Clinical & Experimental Research 31(5):745–754, 2007.
Flensborg-Madsen, T., Knop, J., Mortensen, E.L., Becker, U., and Gronbaek, M. Amount of alcohol consumption and risk of developing alcoholism in men and women. Alcohol and Alcoholism 42(5):442–447, 2007.17491106
Flores, E., Tschann, J.M., Dimas, J.M., Bachen, E.A., Pasch, L.A., and de Groat, C.L. Perceived discrimination, perceived stress, and mental and physical health among Mexican-origin adults. Hispanic Journal of Behavioral Sciences 30(4):401–424, 2008.
Foa, E.B., and Rothbaum, B.O. Treating the Trauma of Rape: Cognitive-Behavioral Therapy for PTSD. New York: Guilford Press, 1998.
Foa, E.B., Hembree, E.A., and Rothbaum, B.O. Prolonged Exposure Therapy For PTSD: Emotional Processing Of Traumatic Experiences: Therapist Guide. Treatments that work. Oxford University Press: New York, 2007.
Ford, J., Kasimer, N., MacDonald, M., and Savill, G. Trauma Adaptive Recovery Group Education and Therapy (TARGET): Participant Guidebook and Leader Manual. Farmington, CT: University of Connecticut Health Center, 2000.
Fortenberry, J.D., McFarlane, M., Bleakley, A., Bull, S., Fishbein, M., Grimley, D.M., Malotte, C.K., and Stoner, B.P. Relationships of stigma and shame to gonorrhea and HIV screening. American Journal of Public Health 92(3):378–381, 2002.11867314
Frajzyngier, V., Neaigus, A., Gyarmathy, V.A., Miller, M., and Friedman, S.R. Gender differences in injection risk behaviors at the first injection episode. Drug and Alcohol Dependence 89(2–3):145–152, 2007.17276623
Frank, D.A., Augustyn, M., Knight, W.G., Pell, T., and Zuckerman, B. Growth, development, and behavior in early childhood following prenatal cocaine exposure. Journal of the American Medical Association 285(12):1613–1625, 2001.11268270
Frank, J.B., Weihs, K., Minerva, E., and Lieberman, D.Z. Women's mental health in primary care: Depression, anxiety, somatization, eating disorders, and substance abuse. Medical Clinics of North America 82(2):359–389, 1998.
Franklin, T.R., Ehrman, R., Lynch, K.G., Harper, D., Sciortino, N., O'Brien, C.P., and Childress, A.R. Menstrual cycle phase at quit date predicts smoking status in an NRT treatment trial: A retrospective analysis. Journal of Women's Health (15409996) 17(2):287–292, 2008.
Franko, D.L., Dorer, D.J., Keel, P.K., Jackson, S., Manzo, M.P., and Herzog, D.B. How do eating disorders and alcohol use disorder influence each other? International Journal of Eating Disorders 38(3):200–207, 2005.
French, G.M., Groner, J.A., Wewers, M.E., and Ahijevych, K. Staying smoke free: An intervention to prevent postpartum relapse. Nicotine & Tobacco Research 9(6):663–670, 2007.17558823
Frezza, M., di Padova, C., Pozzato, G., Terpin, M., Baraona, E., and Lieber, C.S. High blood alcohol levels in women: The role of decreased gastric alcohol dehydrogenase activity and first-pass metabolism. New England Journal of Medicine 322(2):95–99, 1990.
Fried, P.A., and Smith, A.M. A literature review of the consequences of prenatal marihuana exposure: An emerging theme of a deficiency in aspects of executive function. Neurotoxicology and Teratology 23(1):1–11, 2001.11274871
Fullilove, M.T., Fullilove, R.E., Smith, M., and Winkler, K. Violence, trauma, and posttraumatic stress disorder among women drug users. Journal of Traumatic Stress 6(4):533–543, 1993.
Funkhouser, E., Pulley, L., Lueschen, G., Costello, C., Hook, E., III, and Vermund, S.H. Douching beliefs and practices among black and white women. Journal of Women's Health and Gender-Based Medicine 11(1):29–37, 2002.
Galbraith, S. And So I Began to Listen to Their Stories: Working with Women in the Criminal Justice System. Delmar, NY: National Gains Center, 1998.
Gale, T.C., White, J.A., and Welty, T.K. Differences in detection of alcohol use in a prenatal population (on a Northern Plains Indian Reservation) using various methods of ascertainment. South Dakota Journal of Medicine 51(7):235–240, 1998.9676158
Galea, S., and Vlahov, D. Social determinants and the health of drug users: Socioeconomic status, homelessness, and incarceration. Public Health Reports 117 Suppl 1:S135–S145, 2002.12435837
Galen, L.W., Brower, K.J., Gillespie, B.W., and Zucker, R.A. Sociopathy, gender, and treatment outcome among outpatient substance abusers. Drug and Alcohol Dependence 61(1):23–33, 2000.11064181
Garner, D.M., Olmstead, M.P., Bohr, Y., and Garfinkel, P.E. The Eating Attitudes Test: Psychometric features and clinical correlates. Psychological Medicine 12:871–878, 1982.6961471
Garner, D.M., Rosen, L.W., and Barry, D. Eating disorders among athletes: Research and recommendations. Child and Adolescent Psychiatric Clinics of North America 7(4):839–857, 1998.9894045
Gary, L.E., and Littlefield, M.B. The protective factor model: Strengths-oriented prevention for African-American families. In: Brisbane, F.L., Epstein, L.G., Pacheco, G., and Quinlan, J.W., eds. Cultural Competence for Health Care Professionals Working with African-American Communities: Theory and Practice. CSAP Cultural Competence Series 7. HHS Publication No. (SMA) 98–3238. Rockville, MD: Center for Substance Abuse Prevention, 1998. pp. 81–105.
Gavaler, J.S., and Arria, A.M. Increased susceptibility of women to alcoholic liver disease: Artifactual or real? In: Hall, P.M., ed. Alcoholic Liver Disease: Pathology and Pathogenesis. 2nd ed. London, UK: Edward Arnold, 1995. pp. 123–133.
Gear, R.W., Gordon, N.C., Heller, P.H., Paul, S., Miaskowski, C., and Levine, J.D. Gender difference in analgesic response to the kappaopioid pentazocine. Neuroscience Letters 205(3):207–209, 1996.8852594
Gee, G.C. A Multilevel Analysis of the Relationship Between Institutional and Individual Racial Discrimination and Health Status. American Journal of Public Health 92(4):615–623, 2002.11919062
Gehart, D.R., and Lyle, R.R. Client experience of gender in therapeutic relationships: an interpretive ethnography. Family Process 40(4):443–458, 2001.11802490
George, W.H., Gournic, S.J., and McAfee, M.P. Perceptions of postdrinking female sexuality: Effects of gender, beverage choice, and drink payment. Journal of Applied Social Psychology 18(15, Pt 1):1295–1317, 1988.
Giglia, R., and Binns, C. Alcohol and lactation: A systematic review. Nutrition & Dietetics 63:103–116, 2006.
Gilbert, M.J. Acculturation and changes in drinking patterns among Mexican-American women: Implications for prevention. Alcohol Health and Research World 15(3):234–238, 1991.
Gilbert, M.J., and Collins, R.L. Ethnic variation in women's and men's drinking. In: Wilsnack, R.W., and Wilsnack, S.C., eds. Gender and Alcohol: Individual and Social Perspectives. New Brunswick, NJ: Rutgers Center of Alcohol Studies, 1997. pp. 357–378.
Gilligan, C. In a Different Voice: Psychological Theory and Women's Development. Cambridge, MA: Harvard University Press, 1982.
Gilligan, C., Lyons, N., Hanmer, T.J., and Emma Willard School. Making Connections: The Relational Worlds of Adolescent Girls at Emma Willard School. Cambridge, Mass: Harvard University Press, 1990.
Gilman, S.E., Cochran, S.D., Mays, V.M., Hughes, M., Ostrow, D., and Kessler, R.C. Risk of psychiatric disorders among individuals reporting same-sex sexual partners in the National Comorbidity Survey. American Journal of Public Health 91(6):933–939, 2001.11392937
Gil-Rivas, V., Fiorentine, R., and Anglin, M.D. Sexual abuse, physical abuse, and posttraumatic stress disorder among women participating in outpatient drug abuse treatment. Journal of Psychoactive Drugs 28(1):95–102, 1996.8714338
Gil-Rivas, V., Fiorentine, R., Anglin, M.D., and Taylor, E. Sexual and physical abuse: Do they compromise drug treatment outcomes? Journal of Substance Abuse Treatment 14(4):351–358, 1997.9368211
Gim Chung, R.H., Kim, B.S.K., and Abreu, J.M. Asian American Multidimensional Acculturation Scale: Development, Factor Analysis, Reliability, and Validity. Cultural Diversity and Ethnic Minority Psychology 10(1):66–80, 2004.14992631
Gloria, A.M., and Peregoy, J.J. Counseling Latino alcohol and other substance users/abusers: Cultural considerations for counselors. Journal of Substance Abuse Treatment 13(2):119–126, 1996.8880669
Goldberg, B. A Framework for Systems Change: Evaluation of the Milwaukee Family Services Coordination Initiative. Madison, WI: Wisconsin Department of Health and Family Services, Division of Supportive Living, Bureau of Substance Abuse Services, 2000.
Goldschmidt, L., Day, N.L., and Richardson, G.A. Effects of prenatal marijuana exposure on child behavior problems at age 10. Neurotoxicology and Teratology 22(3):325–336, 2000.10840176
Goode, T.D., Dunne, C., and Bronheim, S.M. The Evidence Base for Cultural and Linguistic Competency in Health Care. October New York, NY: The Commonwealth Fund 2006.
Gopaul-McNicol, S.A., and Brice-Baker, J. Cross-Cultural Practice: Assessment, Treatment, and Training. New York: John Wiley & Sons, 1998.
Gordon, M.T., and Riger, S. The Female Fear. New York: The Free Press, 1989.
Gottheil, E., Sterling, R.C., and Weinstein, S.P. Outreach engagement efforts: Are they worth the effort? American Journal of Drug and Alcohol Abuse 23(1):61–66, 1997.
Graham, K., Massak, A., Demers, A., and Rehm, J. Does the association between alcohol consumption and depression depend on how they are measured? Alcoholism: Clinical & Experimental Research 31(1):78–88, 2007.
Grant, B.F., Dawson, D.A., Stinson, F.S., Chou, S.P., Dufour, M.C., and Pickering, R.P. The 12-Month prevalence and trends in DSM-TR-IV alcohol abuse and dependence. Alcohol Research & Health 29(2):79–91, 2006.
Grant, B.F., Stinson, F.S., Hasin, D.S., Dawson, D.A., Chou, S.P., and Anderson, K. Immigration and lifetime prevalence of DSM-IV Psychiatric disorders among Mexican Americans and Non-Hispanic Whites in the United States: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. Archives of General Psychiatry 61(12):1226–1233, 2004.15583114
Gray, M., and Littlefield, M.B. Black women and addiction. In: Straussner, S.L.A., and Brown, S., eds. The Handbook of Addiction Treatment for Women: Theory and Practice. San Francisco: Jossey-Bass, 2002. pp. 301–322.
Grayson, C.E., and Nolen-Hoeksema, S. Motives to drink as mediators between childhood sexual assault and alcohol problems in adult women. Journal of Traumatic Stress 18(2):137–145, 2005.16281206
Green, C.A., Polen, M.R., Dickinson, D.M., Lynch, F.L., and Bennett, M.D. Gender differences in predictors of initiation, retention, and completion in an HMO-based substance abuse treatment program. Journal of Substance Abuse Treatment 23(4):285–295, 2002.12495790
Green, C.A., Polen, M.R., Lynch, F.L., Dickinson, D.M., and Bennett, M.D. Gender differences in outcomes in an HMO-based substance abuse treatment program. Journal of Addictive Diseases. 23(2):47–70, 2004.15132342
Green, J.H. Fetal Alcohol Spectrum Disorders: understanding the effects of prenatal alcohol exposure and supporting students. J Sch Health 77(3):103–108, 2007.17302851
Greene, B. Ethnic minority lesbians and gay men: Mental health and treatment issues. In: Greene, B., ed. Ethnic and Cultural Diversity Among Lesbians and Gay Men. Thousand Oaks, CA: Sage Publications, 1997. pp. 216–239.
Greenfeld, L.A., and Snell, T.L. Women Offenders. Bureau of Justice Statistics Special Report. NCJ 175688. Washington, DC: Bureau of Justice Statistics, 1999.
Greenfield, L., Burgdorf, K., Chen, X., Porowski, A., Roberts, T., and Herrell, J. Effectiveness of long-term residential substance abuse treatment for women: findings from three national studies. American Journal of Drug and Alcohol Abuse 30(3):537–550, 2004.
Greenfield, S.F. Women and substance use disorders. In: Jensvold, M.F., and Halbreich, U., eds. Psychopharmacology and Women: Sex, Gender, and Hormones. Washington, DC: American Psychiatric Press, 1996. pp. 299–321.
Greenfield, S.F., and O'Leary, G. Sex differences in substance use disorders. In: Lewis-Hall, F., and Williams, T.S., eds. Psychiatric Illness in Women: Emerging Treatments and Research. Washington, DC: American Psychiatric Publishing, Inc, 2002. pp. 467–533.
Greenfield, S.F., Brooks, A.J., Gordon, S.M., Green, C.A., Kropp, F., McHugh, R.K., Lincoln, M., Hien, D., and Miele, G.M. Substance abuse treatment entry, retention, and outcome in women: A review of the literature. Drug and Alcohol Dependence 86(1):1–21, 2007a.16759822
Greenfield, S.F., Trucco, E.M., McHugh, R.K., Lincoln, M., and Gallop, R.J. The Women's Recovery Group Study: a Stage I trial of women-focused group therapy for substance use disorders versus mixed-gender group drug counseling. Drug and Alcohol Dependence 90(1):39–47, 2007b.17446014
Grella, C.E. Background and overview of mental health and substance abuse treatment systems: Meeting the needs of women who are pregnant or parenting. Journal of Psychoactive Drugs 28(4):319–343, 1996.9017555
Grella, C.E. Services for perinatal women with substance abuse and mental health disorders: The unmet need. Journal of Psychoactive Drugs 29(1):67–78, 1997.9110267
Grella, C.E. Women in residential drug treatment: Differences by program type and pregnancy. Journal of Health Care for the Poor and Underserved 10(2):216–229, 1999.10224827
Grella, C.E., and Joshi, V. Gender differences in drug treatment careers among clients in the national Drug Abuse Treatment Outcome Study. American Journal of Drug and Alcohol Abuse 25(3):385–406, 1999.
Grella, C.E., Annon, J.J., and Anglin, M.D. Ethnic differences in HIV risk behaviors, self-perceptions, and treatment outcomes among women in methadone maintenance treatment. Journal of Psychoactive Drugs 27(4):421–433, 1995.8788697
Grella, C.E., Joshi, V., and Hser, Y.I. Program variation in treatment outcomes among women in residential drug treatment. Evaluation Review 24(4):364–383, 2000.11009864
Grella, C.E., Scott, C.K., and Foss, M.A. Gender differences in long-term drug treatment outcomes in Chicago PETS. Journal of Substance Abuse Treatment 28(Suppl1):S3–S12, 2005.15797637
Grice, D.E., Brady, K.T., Dustan, L.R., Malcolm, R., and Kilpatrick, D.G. Sexual and physical assault history and posttraumatic stress disorder in substance-dependent individuals. American Journal on Addictions 4(4):297–305, 1995.
Grieco, E.M. The Native Hawaiian and Other Pacific Islander Population: 2000. Census 2000 Brief Washington, DC: U.S. Census Bureau 2001.
Griffin, M.L., Mendelson, J.H., Mello, N.K., and Lex, B.W. Marihuana use across the menstrual cycle. Drug and Alcohol Dependence 18(2):213–224, 1986.3780416
Griffiths, E.J., Lorenz, R.P., Baxter, S., and Talon, N.S. Acute neurohumoral response to electroconvulsive therapy during pregnancy: A case report. Journal of Reproductive Medicine 34(11):907–911, 1989.
Grosenick, J.K., and Hatmaker, C.M. Perceptions of the importance of physical setting in substance abuse treatment. Journal of Substance Abuse Treatment 18(1):29–39, 2000.10636604
Gross, M., and Brown, V. Outreach to injection drug-using women. In: Brown, B.S., and Beschner, G.M., eds. Handbook on Risk of AIDS: Injection Drug Users and Sexual Partners. Westport, CT: Greenwood Press, 1993. pp. 445–463.
Gruber, K., Fleetwood, T., and Herring, M. In-home continuing care services for substance affected families: The Bridges Program. Social Work 46(3):267–277, 2001.11495371
Grucza, R.A., Bucholz, K.K., Rice, J.P., and Bierut, L.J. Secular trends in the lifetime prevalence of alcohol dependence in the United States: a re-evaluation. Alcoholism: Clinical & Experimental Research 32(5):763–770, 2008.
Gutierres, S.E., and Todd, M. The impact of childhood abuse on treatment outcomes of substance users. Professional Psychology: Research and Practice 28(4):348–354, 1997.
Hagedorn, H., Dieperink, E., Dingmann, D., Durfee, J., Ho, S.B., Isenhart, C., Rettmann, N., and Willenbring, M. Integrating hepatitis prevention services into a substance use disorder clinic. Journal of Substance Abuse Treatment 32(4):391–398, 2007.17481462
Hall, J.M. Lesbians in alcohol recovery surviving childhood sexual abuse and parental substance misuse. International Journal of Psychiatric Nursing Research 5(1):507–515, 1999.
Hall, J.M. Core issues for female child abuse survivors in recovery from substance misuse. Qualitative Health Research 10(5):612–631, 2000.11066868
Hall, P.M. Pathological spectrum of alcoholic liver disease. In: Hall, P.M., ed. Alcoholic Liver Disease: Pathology and Pathogenesis. 2nd ed. London, UK: Edward Arnold, 1995. pp. 41–68.
Haller, D.L., and Miles, D.R. Psychopathology is associated with completion of residential treatment in drug dependent women. Journal of Addictive Diseases 23(1):17–28, 2004.15077837
Haller, D.L., Miles, D.R., and Dawson, K.S. Psychopathology influences treatment retention among drug-dependent women. Journal of Substance Abuse Treatment 23(4):431–436, 2002.12495807
Hamajima, N., Hirose, K., Tajima, K., Rohan, T., Calle, E.E., Heath, C.W., et al. Alcohol, tobacco and breast cancer: Collaborative reanalysis of individual data from 53 epidemiological studies, including 58,515 women with breast cancer and 95,067 women without the disease. British Journal of Cancer 87(11):1234–1245, 2002.12439712
Handmaker, N.S., and Wilbourne, P. Motivational interventions in prenatal clinics. Alcohol Research and Health 25(3):219–229, 2001.11810961
Hankin, J., McCaul, M.E., and Heussner, J. Pregnant, alcohol-abusing women. Alcoholism: Clinical and Experimental Research 24(8):1276–1286, 2000.
Hanlon, J.T., Fillenbaum, G.G., Ruby, C.M., Gray, S., and Bohannon, A. Epidemiology of over-the-counter drug use in community dwelling elderly: United States perspective. Drugs and Aging 18(2):123–131, 2001.11346126
Hanna, E., Dufour, M.C., Elliott, S., and Stinson, F. Dying to be equal: Women, alcohol, and cardiovascular disease. British Journal of Addiction 87(11):1593–1597, 1992.1458038
Harned, M.S., Najavits, L.M., and Weiss, R.D. Self-harm and suicidal behavior in women with comorbid PTSD and substance dependence. American Journal of Addiction 15(5):392–395, 2006.
Harris, B., Lovett, L., Newcombe, R.G., Read, G.F., Walker, R., and Riad-Fahmy, D. Maternity blues and major endocrine changes: Cardiff puerperal mood and hormone study II. British Medical Journal 308(6934):949–953, 1994.8173402
Harris, M. Modifications in service delivery and clinical treatment for women diagnosed with severe mental illness who are also the survivors of sexual abuse trauma. Journal of Mental Health Administration 21(4):397–406, 1994.10138013
Harris, M., and Community Connections Trauma Work Group. Trauma Recovery and Empowerment: A Clinician's Guide for Working with Women in Groups. New York: Simon & Schuster, 1998.
Harris, M., and Fallot, R.D. Designing trauma-informed addictions services. In: Harris, M., and Fallot, R.D., eds. Using Trauma Theory to Design Service Systems. New Directions for Mental Health Services, No. 89. San Francisco: Jossey-Bass, 2001a. pp. 57–73.
Harris, M., and Fallot, R.D. Envisioning a trauma-informed service system: A vital paradigm shift. In: Harris, M., and Fallot, R.D., eds. Using Trauma Theory to Design Service Systems. New Directions for Mental Health Services, No. 89. San Francisco: Jossey-Bass, 2001b. pp. 3–22.
Harrison, P.M., and Beck, A.J. Prisoners in 2001. Bureau of Justice Statistics Bulletin Washington, DC: Bureau of Justice Statistics, 2002.
Harrison, P.M., and Karberg, J.C. Prison and Jail Inmates at Midyear 2002. Washington, DC: Bureau of Justice Statistics, 2003.
Haskett, M.E., Miller, J.W., Whitworth, J.M., and Huffman, J.M. Intervention with cocaine-abusing mothers. Families in Society 73(8):451–461, 1992.
Haswell, D.E., and Graham, M. Self-inflicted injuries: Challenging knowledge, skill, and compassion. Canadian Family Physician 42:1756–1758, 1761–1764, 1996.8828878
Havens, J.R., Cornelius, L.J., Ricketts, E.P., Latkin, C.A., Bishai, D., Lloyd, J.J., Huettner, S., and Strathdee, S.A. The effect of a case management intervention on drug treatment entry among treatment-seeking injection drug users with and without comorbid antisocial personality disorder. Journal of Urban Health 84(2):267–271, 2007.17334939
Hawke, J.M., Jainchill, N., and De Leon, G. The prevalence of sexual abuse and its impact on the onset of drug use among adolescents in therapeutic community drug treatment. Journal of Child & Adolescent Substance Abuse 9(3):35–49, 2000.
Heath, A.C., Slutske, W.S., and Madden, P.A.F. Gender differences in the genetic contribution to alcoholism risk and to alcohol consumption patterns. In: Wilsnack, R.W., and Wilsnack, S.C., eds. Gender and Alcohol: Individual and Social Perspectives. New Brunswick, NJ: Rutgers Center of Alcohol Studies, 1997. pp. 114–149.
Heffernan, K. The nature and predictors of substance use among lesbians. Addictive Behaviors 23(4):517–528, 1998.9698980
Heflin, C.M. Dynamics of Material Hardship in the Women's Employment Survey. Paper presented at the annual meeting of the American Sociological Association, Montreal Convention Center, Montreal, Quebec, Canada, 2006.
Heintges, T., and Wands, J.R. Hepatitis C virus: epidemiology and transmission. Hepatology 26(3):521–526, 1997.9303478
Henderson, D.J. Drug abuse and incarcerated women: A research review. Journal of Substance Abuse Treatment 15(6):579–587, 1998.9845871
Henderson, D.J., Boyd, C., and Mieczkowski, T. Gender, relationships, and crack cocaine: A content analysis. Research in Nursing and Health 17(4):265–272, 1994.8036274
Herman, J.L. Trauma and Recovery. Rev. ed. New York: Basic Books, 1997.
Hernandez-Avila, C.A., Rounsaville, B.J., and Kranzler, H.R. Opioid-, cannabis- and alcohol-dependent women show more rapid progression to substance abuse treatment. Drug and Alcohol Dependence 74(3):265–272, 2004.15194204
Herzog, D.B., Franko, D.L., Dorer, D.J., Keel, P.K., Jackson, S., and Manzo, M.P. Drug abuse in women with eating disorders. International Journal of Eating Disorders 39(5):364–368, 2006.
Hewitt, P.L., and Norton, G.R. The Beck Anxiety Inventory: A psychometric analysis. Psychological Assessment 5(4):408–412, 1993.
Hiebert-Murphy, D., and Woytkiw, L. A model for working with women dealing with child sexual abuse and addictions: The Laurel Centre, Winnipeg, Manitoba, Canada. Journal of Substance Abuse Treatment 18(4):387–394, 2000.10812313
Hien, D.A., Cohen, L.R., Miele, G.M., Litt, L.C., and Capstick, C. Promising treatments for women with comorbid PTSD and substance use disorders. American Journal of Psychiatry 161(8):1426–1432, 2004.
Highleyman, L. Women and HCV. HCV Advocate San Francisco, CA: Hepatitis C Support Project 2005.
Hill, R.B. The Strengths of Black Families. New York: Emerson Hall Publishers, 1972.
Hillhouse, M.P., and Fiorentine, R. 12–Step program participation and effectiveness: Do gender and ethnic differences exist? Journal of Drug Issues 31(3):767–780, 2001.
Hoek, H. The distribution of eating disorders. In: Brownell, K.D., and Fairburn, C.G., eds. Eating Disorders and Obesity: A Comprehensive Handbook. New York: Guilford Press, 1995. pp. 207–211.
Hoek, H.W., and van Hoeken, D. Review of the prevalence and incidence of eating disorders. International Journal of Eating Disorders 34(4):383–396, 2003.
Hoffman, E.H., Blackburn, C., and Cullari, S. Brief residential treatment for nicotine addiction: a five-year follow-up study. Psychological Reports 89(1):99–105, 2001.11729559
Hofmann, S.G., and Smits, J.A. Cognitive–behavioral therapy for adult anxiety disorders: a meta-analysis of randomized placebo-controlled trials. Journal of Clinical Psychiatry 69(4):621–632, 2008.
Holcomb-McCoy, C. Group mentoring with urban African American female adolescents. E-Journal of Teaching and Learning in Diverse Settings 2(1):161–176. Baton Rouge, LA: Southern University and A&M College 2004.
Holdcraft, L.C., and Comtois, K.A. Description of and preliminary data from a women's dual diagnosis community mental health program. Canadian Journal of Community Mental Health 21(2):91–109, 2002.
Holderness, C.C., Brooks-Gunn, J., and Warren, M.P. Co-morbidity of eating disorders and substance abuse: Review of the literature. International Journal of Eating Disorders 16(1):1–34, 1994.
Holman, C.D.J., English, D.R., Milne, E., and Winter, M.G. Meta-analysis of alcohol and all-cause mortality: A validation of NHMRC recommendations. Medical Journal of Australia 164(3):141–145, 1996.
Hommer, D., Momenan, R., Rawlings, R., Ragan, P., Williams, W., Rio, D., and Eckardt, M. Decreased corpus callosum size among alcoholic women. Archives of Neurology 53(4):359–363, 1996.8929159
Hommer, D.W., Momenan, R., Kaiser, E., and Rawlings, R.R. Evidence for a gender-related effect of alcoholism on brain volumes. American Journal of Psychiatry 158(2):198–204, 2001.
Hope, S., Rodgers, B., and Power, C. Marital status transitions and psychological distress: Longitudinal evidence from a national population sample. Psychological Medicine 29(2):381–389, 1999.10218928
Horrell, S.C.V. Effectiveness of cognitive–behavioral therapy with adult ethnic minority clients: A review. Professional Psychology: Research and Practice 39(2):160–168, 2008.
Horwitz, A.V., White, H.R., and Howell-White, S. The use of multiple outcomes in stress research: A case study of gender differences in responses to marital dissolution. Journal of Health and Social Behavior 37(3):278–291, 1996.8898498
Howell, E.M., and Chasnoff, I.J. Perinatal substance abuse treatment: Findings from focus groups with clients and providers. Journal of Substance Abuse Treatment 17(1–2):139–148, 1999.10435262
Howland, R.H. The treatment of persons with dual diagnoses in a rural community. Psychiatric Quarterly 66(1):33–49, 1995.
Hser, Y.I., Anglin, M.D., and Booth, M.W. Sex differences in addict careers: 3. Addiction. American Journal of Drug and Alcohol Abuse 13(3):231–251, 1987.
Hser, Y.I., Evans, E., Huang, D., and Anglin, D.M. Relationship between drug treatment services, retention, and outcomes. Psychiatric Services 55(7):767–774, 2004.15232015
Hser, Y.I., Polinsky, M.L., Maglione, M., and Anglin, M.D. Matching clients' needs with drug treatment services. Journal of Substance Abuse Treatment 16(4):299–305, 1999.10349602
Hudson, J.I., Hiripi, E., Pope, H.G., Jr., and Kessler, R.C. The prevalence and correlates of eating disorders in the National Comorbidity Survey Replication. Biological Psychiatry 61(3):348–358, 2007.16815322
Hudson, J.I., Weiss, R.D., Pope, H.G., Jr., McElroy, S.K., and Mirin, S.M. Eating disorders in hospitalized substance abusers. American Journal of Drug and Alcohol Abuse 18(1):75–85, 1992.
Hughes, P.H., Coletti, S.D., Neri, R.L., Urmann, C.F., Stahl, S., Sicilian, D.M., and Anthony, J.C. Retaining cocaine-abusing women in a therapeutic community: The effect of a child live-in program. American Journal of Public Health 85(8 Pt 1):1149–1152, 1995.7625517
Hughes, T.L., and Eliason, M. Substance use and abuse in lesbian, gay, bisexual and transgender populations. Journal of Primary Prevention 22(3):263–298, 2002.
Hughes, T.L., and Jacobson, K.M. Sexual orientation and women's smoking. Current Women's Health Report 3(3):254–261, 2003.
Hughes, T.L., and Norris, J. Sexuality, sexual orientation, and violence: Pieces in the puzzle of women's use and abuse of alcohol. In: McElmurry, F.J., and Parker, R.S., eds. Annual Review of Women's Health: Vol. II. New York: National League for Nursing Press, 1995. pp. 285–317.
Hughes, T.L., and Wilsnack, S.C. Use of alcohol among lesbians: Research and clinical implications. American Journal of Orthopsychiatry 67(1):20–36, 1997.
Hughes, T.L., Haas, A.P., Razzano, L., Cassidy, R., and Matthews, A. Comparing lesbians' and heterosexual women's mental health: Findings from a multi-site study. Journal of Gay and Lesbian Social Services 11(1):57–76, 2000.
Hughes, T.L., Johnson, T.P., Wilsnack, S.C., and Szalacha, L.A. Childhood risk factors for alcohol abuse and psychological distress among adult lesbians. Child Abuse and Neglect 31(7):769–789, 2007.17628667
Hurd, Y.L., Wang, X., Anderson, V., Beck, O., Minkoff, H., and Dow-Edwards, D. Marijuana impairs growth in mid-gestation fetuses. Neurotoxicology and Teratology 27(2):221–229, 2005.15734273
Hurt, H., Brodsky, N.L., Betancourt, L., Braitman, L.E., Malmud, E., and Giannetta, J. Cocaine-exposed children: Follow-up through 30 months. Journal of Developmental and Behavioral Pediatrics 16(1):29–35, 1995.7730454
Hurt, H., Malmud, E., Betancourt, L.M., Brodsky, N.L., and Giannetta, J.M. A prospective comparison of developmental outcome of children with in utero cocaine exposure and controls using the Battelle Developmental Inventory. Journal of Developmental and Behavioral Pediatrics 22(1):27–34, 2001.11265920
Hussong, R.G., Bird, K., and Murphy, C.V. Substance abuse among American Indian women of childbearing age. IHS Primary Care Provider 19(12):196–199, 1994.
Hyman, S.M., Paliwal, P., and Sinha, R. Childhood maltreatment, perceived stress, and stress-related coping in recently abstinent cocaine dependent adults. Psychology of Addictive Behaviors 21(2):233–238, 2007.17563143
Hyman, S.M., Paliwal, P., Chaplin, T.M., Mazure, C.M., Rounsaville, B.J., and Sinha, R. Severity of childhood trauma is predictive of cocaine relapse outcomes in women but not men. Drug and Alcohol Dependence 92(1–3):208–216, 2008.17900822
Hymbaugh, K., Miller, L.A., Druschel, C.M., Podvin, D.W., Meaney, F.J., and Boyle, C.A. A multiple source methodology for the surveillance of fetal alcohol syndrome–The Fetal Alcohol Syndrome Surveillance Network (FASSNet). Teratology 66 Suppl 1:S41–S49, 2002.12239744
Indian Health Service. Demographic statistics section of regional differences in Indian health 2000–2001: Tables only. Rockville, MD: Indian Health Service, 2002.
International Longevity Center-USA. Caregiving in America. New York, NY: 2006.
Jacobson, J.O., Robinson, P.L., and Bluthenthal, R.N. Racial disparities in completion rates from publicly funded alcohol treatment: economic resources explain more than demographics and addiction severity. Health Services Research 42(2):773–794, 2007.17362217
Janes, J. Their own worst enemy? Management and prevention of self-harm. Professional Nurse 9(12):838–841, 1994.
Janoff-Bulman, R. Shattered Assumptions: Towards a New Psychology of Trauma. New York: Free Press, 1992.
Jansson, L.M., Svikis, D.S., Breon, D., and Cieslak, R. Intensity of Case Management Services: Does More Equal Better for Drug-Dependent Women and Their Children? Social Work in Mental Health 3(4):63–78, 2005.
Jarvis, M.A., and Schnoll, S.H. Methadone use during pregnancy. In: Chiang, C.N., and Finnegan, L.P., eds. Medications Development for the Treatment of Pregnant Addicts and Their Infants. NIDA Research Monograph 149. NIH Publication No. 95–3891. Rockville, MD: National Institute on Drug Abuse, 1995. pp. 58–77.
Jarvis, T.J., Copeland, J., and Walton, L. Exploring the nature of the relationship between child sexual abuse and substance use among women. Addiction 93(6):865–875, 1998.9744122
Jennison, K.M., and Johnson, K.A. Alcohol dependence in adult children of alcoholics: Longitudinal evidence of early risk. Journal of Drug Education 28(1):19–37, 1998.9567578
Jennison, K.M., and Johnson, K.A. Parental alcoholism as a risk factor for DSM-IV defined alcohol abuse and dependence in American women: The protective benefits of dyadic cohesion in marital communication. American Journal of Drug and Alcohol Abuse 27(2):349–374, 2001.
Jessup, M. Addiction in women: Prevalence, profiles, and meaning. Journal of Obstetric, Gynecologic, and Neonatal Nursing 26(4):449–458, 1997.
Jessup, M., Humphreys, J., Brindis, C., and Lee, K. Extrinsic barriers to substance abuse treatment among pregnant drug dependent women. Journal of Drug Issues 23(2):285–304, 2003.
Joe, G.W., Rowan-Szal, G.A., Greener, J.M., and Simpson, D.D. The TCU Brief Intake and Client Problem Index (CPI). Poster presented at the American Methadone Treatment Association conference, San Francisco, April 2000.
Joe, G.W., Simpson, D.D., and Broome, K.M. Retention and patient engagement models for different treatment modalities in DATOS. Drug and Alcohol Dependence 57(2):113–125, 1999.10617096
Joe, G.W., Simpson, D.D., Dansereau, D.F., and Rowan-Szal, G.A. Relationships between counseling rapport and drug abuse treatment outcomes. Psychiatric Services 52(9):1223–1229, 2001.11533397
Joe, K.A. “Ice is strong enough for a man but made for a woman:” A social cultural analysis of crystal methamphetamine use among Asian Pacific Americans. Crime, Law, and Social Change 22:269–289, 1995.
Joe, K.A. Lives and times of Asian-Pacific American women drug users: An ethnographic study of their methamphetamine use. Journal of Drug Issues 26(1):199–218, 1996.
Joe, S., Baser, R.E., Breeden, G., Neighbors, H.W., and Jackson, J.S. Prevalence of and risk factors for lifetime suicide attempts among blacks in the United States. JAMA 296(17):2112–2123, 2006.17077376
John, U., Meyer, C., Rumpf, H.J., and Hapke, U. Psychiatric comorbidity including nicotine dependence among individuals with eating disorder criteria in an adult general population sample. Psychiatry Research 141(1):71–79, 2006.16364452
Johnson, H.L., Glassman, M.B., Fiks, K.B., and Rosen, T.S. Path analysis of variables affecting 36-month outcome in a population of multi-risk children. Infant Behavior and Development 10(4):451–465, 1987.
Johnson, J.L., and Leff, M. Children of substance abusers: Overview of research findings. Pediatrics 103(5 Pt 2):1085–1099, 1999.10224196
Johnson, P.B., Richter, L., Kleber, H.D., McLellan, A.T., and Carise, D. Telescoping of drinking-related behaviors: Gender, racial/ethnic, and age comparisons. Substance Use & Misuse 40(8):1139–1151, 2005.16040374
Johnson, T.P., and Hughes, T.L. Reliability and concurrent validity of the cage screening questions: A Comparison of lesbians and heterosexual women. Substance Use & Misuse 40(5):657–669, 2005.15887596
Jones, H.E., and Johnson, R.E. Pregnancy and substance abuse. Current Opinion in Psychiatry 14:187–193, 2001.
Jones, H.E., Haug, N., Silverman, K., Stitzer, M., and Svikis, D. The effectiveness of incentives in enhancing treatment attendance and drug abstinence in methadone-maintained pregnant women. Drug and Alcohol Dependence 61(3):297–306, 2001.11164694
Jones, H. E., Johnson, R. E., Jasinski, D. R., O'Grady, K. E., Chisholm, C. A., Choo, R. E. et al. Buprenorphine versus methadone in the treatment of pregnant opioid-dependent patients: Effects on the neonatal abstinence syndrome. Drug and Alcohol Dependence, 79, 2005. pp. 1–10.15943939
Jones, K.L., and Smith, D.W. Recognition of the fetal alcohol syndrome in early infancy. Lancet 2(7836):999–1001, 1973.
Jones-Webb, R.J., Hsiao, C.Y., and Hannan, P. Relationships between socioeconomic status and drinking problems among black and white men. Alcoholism: Clinical and Experimental Research 19(3):623–627, 1995.
Jonker, J., De Jong, C.A., de Weert-van Oene, G.H., and Gijs, L. Gender-role stereotypes and interpersonal behavior: How addicted inpatients view their ideal male and female therapist. Journal of Substance Abuse Treatment 19(3):307–312, 2000.11027903
Jordan, J.V., and Hartling, L.M. New developments in relational-cultural theory. In: Ballou, M., and Brown, L.S., eds. Rethinking Mental Health and Disorders: Feminists Perspectives. New York: Guilford Publications, 2002. pp. 48–70.
Jordan, K.M., and Deluty, R.H. Coming out for lesbian women: Its relation to anxiety, positive affectivity, self-esteem and social support. Journal of Homosexuality 35(2):41–63, 1998.9524921
Jumper Thurman, P., and Plested, B. Health needs of American Indian women. Drug Addiction Research and the Health of Women. (eds.) Wetherington, Cora Lee and Roman, Adele B. 553–562. Bethesda, MD: National Institute on Drug Abuse, 1998.
Kail, B.L., and Elberth, M. Moving the Latina substance abuser toward treatment: The role of gender and culture. Journal of Ethnicity in Substance Abuse 1(3):3–16, 2002.
Kalarchian, M.A., Marcus, M.D., Levine, M.D., Courcoulas, A.P., Pilkonis, P.A., Ringham, R.M., Soulakova, J.N., Weissfeld, L.A., and Rofey, D.L. Psychiatric disorders among bariatric surgery candidates: Relationship to obesity and functional health status. American Journal of Psychiatry 164(2):328–334, 2007.
Kaltenbach, K. The effects of maternal cocaine abuse on mothers and newborns. Current Psychiatry Reports 2(6):514–518, 2000.11123004
Kaltenbach, K., Berghella, V., and Finnegan, L. Opioid dependence during pregnancy: Effects and management. Obstetrics and Gynecology 25(1):139–151, 1998.9547764
Kaltenbach, K.A. Effects of in-utero opiate exposure: New paradigms for old questions. Drug and Alcohol Dependence 36(2):83–87, 1994.7851284
Kaltenbach, K.A. Exposure to opiates: Behavioral outcomes in preschool and school-age children. In: Wetherington, C.L., Smeriglio, V.L., and Finnegan, L.P., eds. Behavioral Studies of Drug-Exposed Offspring: Methodological Issues in Human and Animal Research. NIDA Research Monograph 164. NIH Publication No. 96–4105. Rockville, MD: National Institute on Drug Abuse, 1996. pp. 230–241.
Kamimori, G.H., Sirisuth, N., Greenblatt, D.J., and Eddington, N.D. The influence of the menstrual cycle on triazolam and indocyanine green pharmacokinetics. Journal of Clinical Pharmacology 40(7):739–744, 2000.10883415
Karberg, J.C., and James, D.J. Substance Dependence, Abuse, and Treatment of Jail Inmates, 2002. Bureau of Justice Statistics: Special Report JulyNCJ209588 Washington, DC: U. S. Department of Justice, 2005.
Karenga, M. Kwanzaa; A Celebration of Family, Community, and Culture. Los Angeles: University of Sankore Press, 1998.
Kaskutas, L.A., Zhang, L., French, M.T., and Witbrodt, J. Women's programs versus mixed-gender day treatment: Results from a randomized study. Addiction 100(1):60–69, 2005.15598193
Kasl, C.D. Many Roads, One Journey: Moving Beyond the Twelve Steps. New York: Harper Perennial, 1992.
Katz, E.C., Chutuape, M.A., Jones, H., Jasinski, D., Fingerhood, M., and Stitzer, M. Abstinence incentive effects in a short-term outpatient detoxification program. Experimental and Clinical Psychopharmacology 12(4):262–268, 2004.15571443
Kauffman, E., Dore, M.M., and Nelson-Zlupko, L. The role of women's therapy groups in the treatment of chemical dependence. American Journal of Orthopsychiatry 65(3):355–363, 1995.
Kayemba-Kay's, S., and Laclyde, J.P. Buprenorphine withdrawal syndrome in newborns: a report of 13 cases. Addiction 98(11):1599–1604, 2003.14616186
Kaysen, D., Dillworth, T.M., Simpson, T., Waldrop, A., Larimer, M.E., and Resick, P.A. Domestic violence and alcohol use: Trauma-related symptoms and motives for drinking. Addictive Behaviors 32(6):1272–1283, 2007.17098370
Keefe, S.E., and Padilla, A.M. Chicano Ethnicity. Albuquerque, NM: University of New Mexico Press, 1987.
Kelly, B.C., and Parsons, J.T. Prescription drug misuse among club drug-using young adults. American Journal of Drug and Alcohol Abuse 33(6):875–884, 2007.
Kelly, P.J., Blacksin, B., and Mason, E. Factors affecting substance abuse treatment completion for women. Issues in Mental Health Nursing 22(3):287–304, 2001a.11885213
Kelly, R., Zatzick, D., and Anders, T. The detection and treatment of psychiatric disorders and substance use among pregnant women cared for in obstetrics. American Journal of Psychiatry 158(2):213–219, 2001b.
Kelly, S. Cognitive–behavioral therapy with African Americans. In: Hays, P.A., and Iwamasa, G.Y., eds. Culturally Responsive Cognitive–Behavioral Therapy: Assessment, Practice, and Supervision. Washington, DC: American Psychological Association, 2006. pp. 97–116.
Kendler, K.S., and Prescott, C.A. Cannabis use, abuse, and dependence in a population-based sample of female twins. American Journal of Psychiatry 155(8):1016–1022, 1998.
Kendler, K.S., Bulik, C.M., Silberg, J., Hettema, J.M., Myers, J., and Prescott, C.A. Childhood sexual abuse and adult psychiatric and substance use disorders in women: An epidemiological and co twin control analysis. Archives of General Psychiatry 57(10):953–959, 2000.11015813
Kendler, K.S., Gardner, C.O., and Prescott, C.A. Religion, psychopathology, and substance use and abuse; A multimeasure, genetic-epidemiologic study. American Journal of Psychiatry 154(3):322–329, 1997.
Kendler, K.S., Heath, A.C., Neale, M.C., Kessler, R.C., and Eaves, L.J. A population-based twin study of alcoholism in women. JAMA 268(14):1877–1882, 1992.1404711
Kendler, K.S., Liu, X.Q., Gardner, C.O., McCullough, M.E., Larson, D., and Prescott, C.A. Dimensions of religiosity and their relationship to lifetime psychiatric and substance use disorders. American Journal of Psychiatry 160(3):496–503, 2003.
Kendler, K.S., Thornton, L.M., and Prescott, C.A. Gender differences in the rates of exposure to stressful life events and sensitivity to their depressogenic effects. American Journal of Psychiatry 158(4):587–593, 2001.
Kennedy, C., Finkelstein, N., Hutchins, E., and Mahoney, J. Improving screening for alcohol use during pregnancy: the Massachusetts ASAP program. Maternal & Child Health Journal 8(3):137–147, 2004.15503394
Kesmodel, U., Wisborg, K., Olsen, S.F., Henriksen, T.B., and Secher, N.J. Moderate alcohol intake during pregnancy and the risk of stillbirth and death in the first year of life. American Journal of Epidemiology 155(4):305–312, 2002.11836194
Kessler, R.C., Borges, G., and Walters, E.E. Prevalence of and risk factors for lifetime suicide attempts in the National Comorbidity Survey. Archives of General Psychiatry 56(7):617–626, 1999.10401507
Kessler, R.C., Crum, R.M., Warner, L.A., Nelson, C.B., Schulenberg, J., and Anthony, J.C. Lifetime co-occurrence of DSM-III-R alcohol abuse and dependence with other psychiatric disorders in the National Comorbidity Survey. Archives of General Psychiatry 54(4):313–321, 1997a.9107147
Kessler, R.C., McGonagle, K.A., Zhao, S., Nelson, C.B., Hughes, M., Eshleman, S., Wittchen, H.U., and Kendler, K.S. Lifetime and 12-month prevalence of DSM-III-R psychiatric disorders in the United States. Archives of General Psychiatry 51(1):8–19, 1994.8279933
Kessler, R.C., Sonnega, A., Bromet, E., Hughes, M., and Nelson, C.B. Posttraumatic stress disorder in the National Comorbidity Survey. Archives of General Psychiatry 52(12):1048–1060, 1995.7492257
Kessler, R.C., Zhao, S., Blazer, D.G., and Swartz, M. Prevalence, correlates, and course of minor depression and major depression in the national comorbidity survey. Journal of Affective Disorders 45(1-2):19–30, 1997b.9268772
Key, J., Hodgson, S., Omar, R.Z., Jensen, T.K., Thompson, S.G., Boobis, A.R., Davies, D.S., and Elliott, P. Meta-analysis of studies of alcohol and breast cancer with consideration of the methodological issues. Cancer Causes and Control 17(6):759–770, 2006.16783604
Killeen, T., Hien, D., Campbell, A., Brown, C., Hansen, C., Jiang, H., Kristman-Valente, A., Neuenfeldt, C., Rocz-de la, L.N., Sampson, R., Suarez-Morales, L., Wells, E., Brigham, G., and Nunes, E. Adverse events in an integrated trauma-focused intervention for women in community substance abuse treatment. Journal of Substance Abuse Treatment, 2008.
Kilpatrick, D.G., Acierno, R., Resnick, H.S., Saunders, B.E., and Best, C.L. A 2-year longitudinal analysis of the relationships between violent assault and substance use in women. Journal of Consulting and Clinical Psychology 65(5):834–847, 1997.9337502
Kitano, K.J., and Louie, L.J. Asian and Pacific Islander women and addiction. In: Straussner, S.L.A., and Brown, S., eds. The Handbook Of Addiction Treatment For Women: Theory And Practice. San Francisco: Jossey-Bass, 2002. pp. 348–373.
Klein, H., Elifson, K.W., and Sterk, C.E. Perceived temptation to use drugs and actual drug use among women. Journal of Drug Issues 33(1):161–192, 2003.
Kleiner, K.D., Gold, M.S., Frost-Pineda, K., Lenz-Brunsman, B., Perri, M.G., and Jacobs, W.S. Body Mass Index and Alcohol Use. Journal of Addictive Diseases 23(3):105–118, 2004.15256347
Klitzner, M., Fisher, D., Stewart, K., and Gilbert, S. Substance Abuse: Early Intervention for Adolescents. Princeton, NJ: The Robert Wood Johnson Foundation, 1992.
Knight, D.K., and Simpson, D.D. Influences of family and friends on client progress during drug abuse treatment. Journal of Substance Abuse 8(4):417–429, 1996.9058354
Knight, D.K., Logan, S., and Simpson, D.D. Predictors of program completion for women in residential substance abuse treatment. American Journal of Drug and Alcohol Abuse 27(1):1–18, 2001a.
Knight, D.K., Wallace, G.L., Joe, G.W., and Logan, S.M. Change in psychosocial functioning and social relations among women in residential substance abuse treatment. Journal of Substance Abuse 13(4):533–547, 2001b.11775081
Knight, K. TCU Drug Screen II. Fort Worth, TX: Texas Christian University, Institute of Behavioral Research, 2002.
Knight, K., Simpson, D.D., and Hiller, M.L. Screening and referral for substance abuse treatment in the criminal justice system. In: Leukefeld, C.G., Tims, F.M., and Farabee, D., eds. Treatment of Drug Offenders: Policies and Issues. New York: Springer Publishing Company, 2002. pp. 259–272.
Koegel, P., Sullivan, G., Burnam, A., Morton, S.C., and Wenzel, S. Utilization of mental health and substance abuse services among homeless adults in Los Angeles. Medical Care 37(3):306–317, 1999.10098574
Koh, A.S. Use of preventive health behaviors by lesbian, bisexual, and heterosexual women: Questionnaire survey. Western Journal of Medicine 172(6):379–384, 2000.
Kohn, L.P., Oden, T., Munoz, R.F., Robinson, A., and Leavitt, D. Adapted cognitive behavioral group therapy for depressed low-income African American women. Community Mental Health Journal 38(6):497–504, 2002.12474937
Kornstein, S.G., Schatzberg, A.F., Thase, M.E., Yonkers, K.A., McCullough, J.P., Keitner, G.I., Gelenberg, A.J., Ryan, C.E., Hess, A.L., Harrison, W., Davis, S.M., and Keller, M.B. Gender differences in chronic major and double depression. Journal of Affective Disorders 60(1):1–11, 2000.10940442
Kovalesky, A. Factors affecting mother–child visiting identified by women with histories of substance abuse and child custody loss. Child Welfare 80(6):749–768, 2001.11817660
Kreek, M.J. Opiate-ethanol interactions: Implications for the biological basis and treatment of combined addictive diseases. In: Harris, L.S., ed. Problems of Drug Dependence, 1987: Proceedings of the 49th Annual Scientific Meeting, the Committee on Problems of Drug Dependence, Inc. NIDA Research Monograph Series 81. Rockville, MD: National Institute on Drug Abuse, 1988. pp. 428–439.
Krieger, N. Embodying inequality: A review of concepts, measures, and methods for studying health consequences of discrimination. International Journal of Health Services 29(2):295–352, 1999.10379455
Kuba, S.A., and Hanchey, S.G. Reclaiming women's bodies: A feminist perspective on eating disorders. In: Van Den Bergh, N., ed. Feminist Perspectives on Addictions. New York: Springer Publishing, 1991. pp. 125–137.
Kuehn, B.M. Despite benefit, physicians slow to offer brief advice on harmful alcohol use. JAMA 299(7):751–753, 2008.18285582
Kumar, C., McIvor, R.J., Davies, T., Brown, N., Papadopoulos, A., Wieck, A., Checkley, S.A., Campbell, I.C., and Marks, M.N. Estrogen administration does not reduce the rate of recurrence of affective psychosis after childbirth. Journal of Clinical Psychiatry 64(2):112–118, 2003.
Kurdek, L.A., and Schmitt, J.P. Relationship quality of partners in heterosexual married, heterosexual cohabiting, and gay and lesbian relationships. Journal of Personality and Social Psychology 51(4):711–720, 1986.3783422
Kuyken, W., Dalgleish, T., and Holden, E.R. Advances in cognitive–behavioural therapy for unipolar depression. The Canadian Journal of Psychiatry / La Revue Canadienne De Psychiatrie 52(1):5–13, 2007.
LaFromboise, T.D., Trimble, J.E., and Mohatt, G.V. Counseling intervention and American Indian tradition: An integrative approach. In: Atkinson, D.R., and Morten, G., eds. Counseling American minorities. 5th ed. New York: McGraw-Hill, 1998. pp. 159–182.
Lai, S., Lai, H., Page, J.B., and McCoy, C.B. The association between cigarette smoking and drug abuse in the United States. Journal of Addictive Diseases 19(4):11–24, 2000.
Lando, H.A., Pirie, P.L., Hellerstedt, W.L., and McGovern, P.G. Survey of smoking patterns, attitudes, and interest in quitting. American Journal of Preventive Medicine 7(1):18–23, 1991.1867896
Larson, M.J., Miller, L., Becker, M., Richardson, E., Kammerer, N., Thom, J., Gampel, J., and Savage, A. Physical health burdens of women with trauma histories and co-occurring substance abuse and mental disorders. Journal of Behavior Health Services & Research 32(2):128–140, 2005.
Larsson, S.C., Giovannucci, E., and Wolk, A. Alcoholic beverage consumption and gastric cancer risk: A prospective population-based study in women. International Journal of Cancer 120(2):373–377, 2007.17066442
Laudet, A., Magura, S., Furst, R.T., Kumar, N., and Whitney, S. Male partners of substance-abusing women in treatment: An exploratory study. American Journal of Drug and Alcohol Abuse 25(4):607–627, 1999.
Laumann, E.O., Gagnon, J.H., Michael, R.T., and Michaels, S. The social organization of sexuality: Sexual practices in the United States. Chicago: University of Chicago Press, 1994.
Leech, S.L., Richardson, G.A., Goldschmidt, L., and Day, N.L. Prenatal substance exposure: Effects on attention and impulsivity of 6-year-olds. Neurotoxicology and Teratology 21(2):109–118, 1999.10192271
Legal Action Center. Steps to Success: Helping Women with Alcohol and Drug Problems Move from Welfare to Work. Washington, DC: Legal Action Center, 1999.
Lehmann, E.R., Kass, P.H., Drake, C.M., and Nichols, S.B. Risk factors for first-time homelessness in low-income women. American Journal of Orthopsychiatry 77(1):20–28, 2007.
Leigh, W.A. Women of color health data book: Adolescents to seniors. (3rd): Bethesda, MD: Office of Research on Women's Health, Office of the Director, National Institutes of Health 2006.
Lenz, S.K., Goldberg, M.S., Labreche, F., Parent, M.E., and Valois, M.F. Association between alcohol consumption and postmenopausal breast cancer: Results of a case-control study in Montreal, Quebec, Canada. Cancer Causes and Control 13(8):701–710, 2002.12420948
Leong, F.T., and Lee, S.H. A cultural accommodation model for cross-cultural psychotherapy: Illustrated with the case of Asian Americans. Psychotherapy: Theory, Research, Practice, Training 43(4):410–423, 2006.
Leong, F.T.L. Cultural accommodation as method and metaphor. American Psychologist 62(8):916–927, 2007.
Leong, F.T.L., Leach, M.M., Yeh, C., and Chou, E. Suicide among Asian Americans: What do we know? What do we need to know? Death Studies 31(5):417–434, 2007.17554837
Leong, P. Religion, flesh, and blood: Re-creating religious culture in the context of HIV/AIDS. Sociology of Religion: A Quarterly Review 67(3): 2006.
Leserman, J. Sexual Abuse History: Prevalence, Health Effects, Mediators, and Psychological Treatment. Psychosomatic Medicine 67(6):906–915, 2005.16314595
Lessler, J.T., and O'Reilly, J.M. Mode of interview and reporting of sensitive issues: Design and implementation of audio computer-assisted self-interviewing. In: Harrison, L., and Hughes, A., eds. The Validity of Self-Reported Drug Use: Improving the Accuracy of Survey Estimates. NIDA Research Monograph 167. Rockville, MD: National Institute on Drug Abuse, 1997. pp. 366–382.
Leukefeld, C., Godlaski, T., Clark, J., Brown, C., and Hays, L. Behavioral Therapy for Rural Substance Abusers: A Treatment Intervention for Substance Abusers. Lexington, KY: University Press of Kentucky, 2000.
Levin, R., McKean, L., and Raphael, J. Pathways to and from homelessness: Women and children in Chicago shelters. Chicago: Center for Impact Research 2004.
Levine, M.D., and Marcus, M.D. Do changes in mood and concerns about weight relate to smoking relapse in the postpartum period? Archives of Women's Mental Health 7(3):155–166, 2004.
Lewis, L.M. Culturally appropriate substance abuse treatment for parenting African American women. Issues in Mental Health Nursing 25(5):451–472, 2004a.15204890
Lewis, M.W., Misra, S., Johnson, H.L., and Rosen, T.S. Neurological and developmental outcomes of prenatally cocaine-exposed offspring from 12 to 36 months. American Journal of Drug & Alcohol Abuse 30(2):299–320, 2004b.
Lewis, R.A., Haller, D.L., Branch, D., and Ingersoll, K.S. Retention issues involving drug-abusing women in treatment research. In: Rahdert, E.R., ed. Treatment for Drug-Exposed Women and Their Children: Advances in Research Methodology. NIDA Research Monograph 166. NIH Publication No. 96–3632. Rockville, MD: National Institute on Drug Abuse, 1996. pp. 110–122.
Lex, B. Gender differences and substance abuse. Advances in Substance Abuse 4:225–296, 1991.
Lex, B.W. Alcohol and other psychoactive substance dependence in women and men. In: Seeman, M.V., ed. Gender and Psychopathology. Washington, DC: American Psychiatric Press, 1995. pp. 311–358.
Lex, B.W., Mendelson, J.H., Bavli, S., Harvey, K., and Mello, N.K. Effects of acute marijuana smoking on pulse rate and mood states in women. Psychopharmacology (Berl) 84(2):178–187, 1984.6438677
Li, C.I., Malone, K.E., Porter, P.L., Weiss, N.S., Tang, M.T., and Daling, J.R. The relationship between alcohol use and risk of breast cancer by histology and hormone receptor status among women 65–79 years of age. Cancer Epidemiology Biomarkers Prevention 12(10):1061–1066, 2003.
Li, L., and Ford, J.A. Illicit drug use by women with disabilities. American Journal of Drug and Alcohol Abuse 24(3):405–418, 1998.
Lieber, C. S. (2000). Ethnic and gender differences in ethanol metabolism. Alcoholism: Clinical & Experimental Research 24, 417–418.
Liechti, M.E., Gamma, A., and Vollenweider, F.X. Gender differences in the subjective effects of MDMA. Psychopharmacology 154(2):161–168, 2001.11314678
Liepman, M., Goldman, R., Monroe, A., Green, K., Sattler, A., Broadhurst, J., and Gomberg, E. Substance abuse by special populations of women. In: Gomberg, E., and Nirenberg, T., eds. Women and Substance Abuse. Norwood, NJ: Ablex Press, 1993.
Lifschitz, M.H., Wilson, G.S., Smith, E.O., and Desmond, M.M. Factors affecting head growth and intellectual function in children of drug addicts. Pediatrics 75(2):269–274, 1985.3969327
Lincoln, A.K., Liebschutz, J.M., Chernoff, M., Nguyen, D., and Amaro, H. Brief screening for co-occurring disorders among women entering substance abuse treatment. Substance Abuse Treatment, Prevention and Policy 1:26, 2006.
Longshore, D., Grills, C., Annon, K., and Grady, R. Promoting recovery from drug abuse: An Afrocentric intervention. Journal of Black Studies 28(3):319–332, 1998.
Longshore, D., Hsieh, S.C., Anglin, M.D., and Annon, T.A. Ethnic patterns in drug abuse treatment utilization. Journal of Mental Health Administration 19(3):268–277, 1992.10171332
Lopez, F. Confidentiality of Patient Records for Alcohol and Other Drug Treatment. Technical Assistance Publication Series 13. HHS Publication No. (SMA) 99–3321. Rockville, MD: Center for Substance Abuse Treatment, 1994.
Loring, M., and Powell, B. Gender, race, and DSM-III: A study of the objectivity of psychiatric diagnostic behavior. Journal of Health and Social Behavior 29(1):1–22, 1988.3367027
Louisiana Department of Health and Hospitals. News Release: New Screening Project Assists Pregnant Women Seeking to Quit Using Alcohol, Tobacco, Other Drugs. Baton Rouge, LA, 2007.
Lucas, G.M., Griswold, M., Gebo, K.A., Keruly, J., Chaisson, R.E., and Moore, R.D. Illicit drug use and HIV-1 disease progression: a longitudinal study in the era of highly active antiretroviral therapy. American Journal of Epidemiology 163(5):412–420, 2006.16394200
Lundgren, L.M., Amaro, H., and Ben-Ami, L. Factors associated with drug treatment entry patterns among hispanic women injection drug users seeking treatment. Journal of Social Work Practice in the Addictions 5(1-2):157–174, 2005.
Lundgren, L.M., Schilling, R.F., Fitzgerald, T., Davis, K., and Amodeo, M. Parental Status of Women Injection Drug Users and Entry to Methadone Maintenance. Substance Use & Misuse 38(8):1109–1131, 2003.12901451
Luty, S.E., Carter, J.D., McKenzie, J.M., Rae, A.M., Frampton, C.M.A., Mulder, R.T., and Joyce, P.R. Randomised controlled trial of interpersonal psychotherapy and cognitive–behavioural therapy for depression. British Journal of Psychiatry 190:496–502, 2007.
Lynch, W.J., Roth, M.E., and Carroll, M.E. Biological basis of sex differences in drug abuse: preclinical and clinical studies. Psychopharmacology (Berl) 164(2):121–137, 2002.12404074
Maguire, K., and Pastore, A.L. Sourcebook of Criminal Justice Statistics [Online]. Albany, NY: University at Albany 2001.
Maharaj, R.G., Rampersad, J., Henry, J., Khan, K.V., Koonj-Beharry, B., Mohammed, J., Rajhbeharrysingh, U., Ramkissoon, F., Sriranganathan, M., Brathwaite, B., and Barclay, S. Critical incidents contributing to the initiation of substance use and abuse among women attending drug rehabilitation centres in Trinidad and Tobago. West Indian Medical Journal 54(1):51–58, 2005.
Malcolm, B.P., Hesselbrock, M.N., and Segal, B. Multiple substance dependence and course of alcoholism among Alaska native men and women. Substance Use & Misuse 41(5):729–741, 2006.16603457
Mangrum, L.F., Spence, R.T., and Steinley-Bumgarner, M.D. Gender differences in substance-abuse treatment clients with co-occurring psychiatric and substance-use disorders. Brief Treatment and Crisis Intervention 6(3):255–267, 2006.
Mann, K., Ackermann, K., Croissant, B., Mundle, G., Nakovics, H., and Diehl, A. Neuroimaging of gender differences in alcohol dependence: Are women more vulnerable? Alcoholism: Clinical and Experimental Research 29(5):896–901, 2005.
Marcus, R.N., and Katz, J.L. Inpatient care of the substance-abusing patient with a concomitant eating disorder. Hospital and Community Psychiatry 41(1):59–63, 1990.2295478
Marin, G., and Marin, B.V. Research with Hispanic Populations. Newbury Park, CA: Sage Publications, 1991.
Marin, G., Otero-Sabogal, R., and Perez-Stable, E. MARIN Short Scale. Hispanic Journal of Behavioral Sciences 9:183–205, 1987.
Markides, K.S., Krause, N., and Mendes de Leon, C.F. Acculturation and alcohol consumption among Mexican Americans: A three-generation study. American Journal of Public Health 78(9):1178–1181, 1988.3407815
Markides, K.S., Ray, L.A., Stroup-Benham, C.A., and Trevino, F.M. Acculturation and alcohol consumption in the Mexican American population of the southwestern United States: Findings from HHANES 1982–84. American Journal of Public Health 80(Supplement):42–46, 1990.9187581
Markoff, L.S., Finkelstein, N., Kammerer, N., Kreiner, P.e., and Prost, C.A. Relational systems change: Implementaing a model of change in integrating services for women with substance abuse and mental health disorders and histories of trauma. Journal of Behavior Health Services & Research 32(2):227–240, 2005a.
Markoff, L.S., Reed, B.G., Fallot, R.D., Elliott, D.E., and Bjelajac, P. Implementing trauma-informed alcohol and other drug and mental health services for women: lessons learned in a multisite demonstration project. American Journal of Orthopsychiatry 75(4):525–539, 2005b.
Markowitz, J.C. Interpersonal psychotherapy. In: Hales, R.E., and Yudofsky, S.C., eds. The American Psychiatric Publishing Textbook of Clinical Psychiatry (4th ed.). 1-58562-032-7 (hardcover). American Psychiatric Publishing, 2003. pp. 1207–1223.
Marks, M.N., Wieck, A., Checkley, S.A., and Kumar, R. Life stress and post-partum psychosis: A preliminary report. British Journal of Psychiatry Supplement May (10):45–49, 1991.
Marlatt, G.A., Baer, J.S., Donovan, D.M., and Kivlahan, D.R. Addictive behaviors: Etiology and treatment. Annual Review of Psychology 39:223–252, 1988.
Marr, D.D., and Wenner, A. Gender specific treatment for chemically dependent women: A rationale for inclusion of vocational services. Alcoholism Treatment Quarterly 14(1):21–31, 1996.
Martin, V., Cayla, J.A., Bolea, A., and Castilla, J. Mycobacterium tuberculosis and human immunodeficiency virus co-infection in intravenous drug users on admission to prison. International Journal of Tuberculosis and Lung Disease 4(1):41–46, 2000.
Matthews, A.K., and Hughes, T.L. Mental health service use by African American women: Exploration of subpopulation differences. Cultural Diversity and Ethnic Minority Psychology 7(1):75–87, 2001.11244906
Matthews, D.A., McCullough, M.E., Larson, D.B., Koenig, H.G., Swyers, J.P., and Milano, M.G. Religious Commitment and Health Status: A Review of the Research and Implications for Family Medicine. Archives of Family Medicine 7(2):118–124, 1998.9519914
Mayes, L.C., Grillon, C., Granger, R., and Schottenfeld, R. Regulation of arousal and attention in preschool children exposed to cocaine prenatally. Annals of the New York Academy of Sciences 846:126–143, 1998.
Mayfield, D., McLeod, G., and Hall, P. The CAGE questionnaire: Validation of a new alcoholism screening instrument. American Journal of Psychiatry 131(10):1121–1123, 1974.
Mays, V.M., Beckman, L.J., Oranchak, E., and Harper, B. Perceived social support for help-seeking behaviors of Black heterosexual and homosexually active women alcoholics. Psychology of Addictive Behaviors 8(4):235–242, 1994.
Mays, V.M., Cochran, S.D., and Barnes, N.W. Race, race-based discrimination, and health outcomes among African Americans. Annual Review of Psychology 58(1):201–225, 2007.
Mazure, C.M., Keita, G.P., and Blehar, M.C. Summit on Women and Depression: Proceedings and Recommendations. Washington, DC: American Psychological Association 2002.
McCance-Katz, E.F., Hart, C.L., Boyarsky, B., Kosten, T., and Jatlow, P. Gender effects following repeated administration of cocaine and alcohol in humans. Substance Use & Misuse 40(4):511–528, 2005.15830733
McCoy, C.B., Comerford, M., and Metsch, L.R. Employment among chronic drug users at baseline and 6-month follow-up. Substance Use and Misuse 42(7):1055–1067, 2007.17668325
McCrady, B.S., and Raytek, H.S. Women and substance abuse: Treatment modalities and outcomes. In: Gomberg, E.S., and Nirenberg, T.D., eds. Women and Substance Abuse. Stamford, CT: Ablex Publishing, 1993. pp. 314–338.
McCusker, J., Bigelow, C., Servigon, C., and Zorn, M. Test–retest reliability of the Addiction Severity Index composite scores among clients in residential treatment. American Journal on Addictions 3:254–262, 1994.
McElhatton, P.R. Heart and circulatory system drugs. In: Schaefer, C.H., ed. Drugs During Pregnancy and Lactation: Handbook of Prescription Drugs and Comparative Risk Assessment: With Updated Information on Recreational Drugs. Amsterdam: Elsevier, 2001. pp. 116–131.
McGee, G., Johnson, L., and Bell, P. Black, Beautiful, and Recovering. Center City, MN: Hazelden, 1985.
McGoldrick, M., Giordano, J., and Pearce, J.K. Families of African origin: An overview. In: Ethnicity and Family Therapy. 2nd ed. New York: Guilford Press, 1996. pp. 57–84.
McKay, J.R., Rutherford, M.J., Cacciola, J.S., Kabasakalian-McKay, R., and Alterman, A.I. Gender differences in the relapse experiences of cocaine patients. Journal of Nervous and Mental Disease 184(10):616–622, 1996.
McKirnan, D.J., and Peterson, P.L. Psychosocial and cultural factors in alcohol and drug abuse: An analysis of a homosexual community. Addictive Behaviors 14(5):555–563, 1989.2589134
McKirnan, D.J., and Peterson, P.L. Gay and lesbian alcohol use: Epidemiological and psychosocial perspectives. In: Kelly, J., ed. The Research Symposium on Alcohol and Other Drug Problem Prevention Among Lesbians and Gay Men. Sacramento, CA: EMT Group, Inc., 1992. pp. 61–84.
McLellan, A.T., Grissom, G.R., Zanis, D., Randall, M., Brill, P., and O'Brien, C.P. Problem-service ‘matching’ in addiction treatment: A prospective study in 4 programs. Archives of General Psychiatry 54(8):730–735, 1997.9283508
McLellan, A.T., Gutman, M., Lynch, K., McKay, J.R., Ketterlinus, R., Morgenstern, J., and Woolis, D. One-year outcomes from the CASAWORKS for families intervention for substance-abusing women on welfare. Evaluation Review 27(6):656–680, 2003.14650279
McLellan, A.T., Luborsky, L., Cacciola, J., Griffith, J., Evans, F., Barr, H.L., and O'Brien, C.P. New data from the Addiction Severity Index: Reliability and validity in three centers. Journal of Nervous and Mental Disease 173(7):412–423, 1985.
McLellan, A.T., Luborsky, L., Woody, G.E., and O'Brien, C.P. An improved diagnostic evaluation instrument for substance abuse patients: The Addiction Severity Index. Journal of Nervous and Mental Disease 168(1):26–33, 1980.
McMahon, T.J., and Luthar, S.S. Bridging the gap for children as their parents enter substance abuse treatment. In: Hampton, R.L., Senatore, V., and Gullotta, T.P., eds. Substance Abuse, Family Violence, and Child Welfare: Bridging Perspectives. Issues in children's and families' lives, Vol. 10. 0-7619-1457-9 (hardcover); 0-7619-1458-7 (paperback). Sage Publications, 1998. pp. 143–187.
McMurtrie, C., Rosenberg, K.D., Kerker, B.D., Kan, J., and Graham, E.H. A unique drug treatment program for pregnant and postpartum substance-using women in New York City: Results of a pilot project, 1990–1995. American Journal of Drug and Alcohol Abuse 25(4):701–713, 1999.
McNeece, C.A., and DiNitto, D.M. Chemical Dependency: A Systems Approach. Englewood Cliffs, N.J: Prentice Hall, 1994.
Meara, E. Welfare reform, employment, and drug and alcohol use among low-income women. Harvard Review of Psychiatry 14(4):223–232, 2006.16912008
Medina, C. Toward an understanding of Puerto Rican ethnicity and substance abuse. In: Straussner, S.L.A., ed. Ethnocultural Factors in Substance Abuse Treatment. New York: Guilford Press, 2001. pp. 137–163.
Mejta, C.L., and Lavin, R. Facilitating healthy parenting among mothers with substance abuse or dependence problems: Some considerations. Alcoholism Treatment Quarterly 14(1):33–46, 1996.
Melchior, L.A., Huba, G.J., Brown, V.B., and Slaughter, R. Evaluation of the effects of outreach to women with multiple vulnerabilities on entry into substance abuse treatment. Evaluation & Program Planning 22(3):269–277, 1999.24011447
Mello, N.K., Mendelson, J.H., and Teoh, S.K. Overview of the effects of alcohol on the neuroendocrine function in women. In: Zakhari, S., ed. Alcohol and the Endocrine System. NIAAA Research Monograph No. 23. Bethesda, MD: National Institute on Alcohol Abuse and Alcoholism, 1993. pp. 139–169.
Melnick, S.M., and Bassuk, E.L. Identifying and responding to violence among poor and homeless women. Nashville, TN: National Health Care for the Homeless Council 2000.
Menninger, J.A. Assessment and treatment of alcoholism and substance-related disorders in the elderly. Bulletin of the Menninger Clinic 66(2):166–183, 2002.12141383
Merikangas, K.R., and Stevens, D.E. Substance abuse among women: Familial factors and comorbidity. In: Wetherington, C.L., and Roman, A.B., eds. Drug Addiction Research and the Health of Women. NIH Publication No. 98–4290. Rockville, MD: National Institute on Drug Abuse, 1998. pp. 245–269.
Messinger, D.S., Bauer, C.R., Das, A., Seifer, R., Lester, B.M., LaGasse, L.L., Wright, L.L., Shankaran, S., Bada, H.S., Smeriglio, V.L., Langer, J.C., Beeghly, M., and Poole, W.K. The maternal lifestyle study: Cognitive, motor, and behavioral outcomes of cocaine-exposed and opiate-exposed infants through three years of age. Pediatrics 113(6):1677–1685, 2004.15173491
Metsch, L.R., McCoy, C.B., Miller, M., McAnany, H., and Pereyra, M. Moving substance-abusing women from welfare to work. Journal of Public Health Policy 20(1):36–55, 1999.10874397
Metsch, L.R., Pereyra, M., Miles, C.C., and McCoy, C.B. Welfare and work outcomes after substance abuse treatment. Social Service Review. 77(2):237–254, 2003.
Metsch, L.R., Rivers, J.E., Miller, M., Bohs, R., McCoy, C.B., Morrow, C.J., Bandstra, E.S., Jackson, V., and Gissen, M. Implementation of a family-centered treatment program for substance-abusing women and their children: Barriers and resolutions. Journal of Psychoactive Drugs 27(1):73–83, 1995.7602443
Metsch, L.R., Wolfe, H.P., Fewell, R., McCoy, C.B., Elwood, W.N., Wohler-Torres, B., Petersen-Baston, P., and Haskins, H.V. Treating substance-using women and their children in public housing: Preliminary evaluation findings. Child Welfare Journal 80(2):199–220, 2001.
Michaels, S. The prevalence of homosexuality in the United States. In: Cabaj, R.P., and Stein, T.S., eds. Textbook of Homosexuality and Mental Health. Washington, DC: American Psychiatric Press, 1996. pp. 43–63.
Midanik, L.T., Zahnd, E.G., and Klein, D. Alcohol and drug CAGE screeners for pregnant, low-income women: The California perinatal needs assessment. Alcoholism: Clinical and Experimental Research 22(1):121–125, 1998.
Miller, B.A., Downs, W.R., and Testa, M. Interrelationships between victimization experiences and women's alcohol use. Journal of Studies on Alcohol Supplement 11(9):109–117, 1993.8410952
Miller, D. Women Who Hurt Themselves: A Book of Hope and Understanding. New York: Basic Books, 1994.
Miller, D., and Guidry, L. Addictions and Trauma Recovery: Healing the Body, Mind, and Spirit. New York: W.W. Norton, 2001.
Miller, J.B. Toward a New Psychology of Women. Boston: Beacon Press, 1976.
Miller, J.B. The Development of Women's Sense of Self. Work in Progress No. 12. Wellesley, MA: Stone Center for Developmental Services and Studies, 1984.
Miller, S.D., Duncan, B.L., and Hubble, M.A. Escape from Babel: Toward a Unifying Language for Psychotherapy Practice. W W Norton & Co: New York, 1997.
Miller, W.R. Rediscovering fire: Small interventions, large effects. Psychology of Addictive Behaviors 14(1):6–18, 2000.10822741
Miller, W.R., and Rollnick, S. Motivational Interviewing: Preparing People to Change Addictive Behavior. New York: Guilford Press, 1991.
Miller, W.R., and Rollnick, S. Motivational Interviewing: Preparing People for Change. 2nd ed. New York: Guilford Press, 2002.
Miller, W.R., Tonigan, J.S., and Longabaugh, R. The Drinker Inventory of Consequences (DrInC): An Instrument For Assessing Adverse Consequences of Alcohol Abuse. Project MATCH Monograph Series Vol. 4. Rockville, MD: National Institute on Alcohol Abuse and Alcoholism, 1995.
Minino, A.M., Arias, E., Kochanek, K.D., Murphy, S.L., and Smith, B.L. Deaths: Final Data for 2000. National Vital Statistics Reports: Vol. 50, No. 15. Hyattsville, MD: National Center for Health Statistics, 2002.
Mokuau, N. Health and well-being for Pacific Islanders: Status, barriers, and resolutions. In: Mokuau, N., Epstein, L.G., Pacheco, G., and Quinlan, J.W., eds. Responding to Pacific Islanders: Culturally Competent Perspectives For Substance Abuse Prevention. CSAP Cultural Competence Series 8. HHS Publication No. (SMA)98-3195. Rockville, MD: Center for Substance Abuse Prevention, 1998a. pp. 1–24.
Mokuau, N. Reality and vision: A cultural perspective in addressing alcohol and drug abuse among Pacific Islanders. In: Mokuau, N., Epstein, L.G., Pacheco, G., and Quinlan, J.W., eds. Responding to Pacific Islanders: Culturally Competent Perspectives For Substance Abuse Prevention. CSAP Cultural Competence Series 8. HHS Publication No. (SMA)98-3195. Rockville, MD: Center for Substance Abuse Prevention, 1998b. pp. 25–47.
Moncrieff, J., and Farmer, R. Sexual abuse and the subsequent development of alcohol problems. Alcohol and Alcoholism 33(6):592–601, 1998.9872346
Mondanaro, J. Medical services for drug dependent women. In: Beschner, G.M., Reed, B.G., and Mondanaro, J., eds. Treatment Services for Drug Dependent Women: Vol. 1. HHS Publication No. (ADM) 81–1177. Rockville, MD: National Institute on Drug Abuse, 1981. pp. 208–257.
Moore, J., and Finkelstein, N. Parenting services for families affected by substance abuse. Child Welfare 80(2):221–238, 2001.11291902
Moore, R.D., Bone, L.R., Geller, G., Mamon, J.A., Stokes, E.J., and Levine, D.M. Prevalence, detection, and treatment of alcoholism in hospitalized patients. JAMA 261(3):403–407, 1989.2909780
Moos, R.H., Moos, B.S., and Timko, C. Gender, treatment and self-help in remission from alcohol use disorders. Clinical Medicine & Research 4(3):163–174, 2006.16988095
Moos, R.H., Schutte, K., Brennan, P., and Moos, B.S. Ten-year patterns of alcohol consumption and drinking problems among older women and men. Addiction 99(7):829–838, 2004.15200578
Mora, J. The treatment of alcohol dependency among Latinas: A feminist, cultural and community perspective. Alcoholism Treatment Quarterly 16(1-2):163–177, 1998.
Mora, J. Latinas in cultural transition: Addiction, treatment and recovery. In: Straussner, S.L.A., and Brown, S., eds. The Handbook of Addiction Treatment for Women: Theory and Practice. San Francisco: Jossey Bass, 2002. pp. 323–347.
Morgen, C.S., Bove, K.B., Larsen, K.S., Kjaer, S.K., and Gronbaek, M. Association Between Smoking and the Risk of Heavy Drinking Among Young Women: A Prospective Study. Alcohol and Alcoholism, 2008.
Morgenstern, J., Blanchard, K.A., McCrady, B.S., McVeigh, K.H., Morgan, T.J., and Pandina, R.J. Effectiveness of intensive case management for substance-dependent women receiving temporary assistance for needy families. American Journal of Public Health 96(11):2016–2023, 2006.17018819
Morgenstern, J., McCrady, B.S., Blanchard, K.A., McVeigh, K.H., Riordan, A., and Irwin, T.W. Barriers to employability among substance dependent and nonsubstance-affected women on federal welfare: implications for program design. Journal of Studies on Alcohol 64(2):239–246, 2003.12713198
Morrissey, J.P., Ellis, A.R., Gatz, M., Amaro, H., Reed, B.G., Savage, A., Finkelstein, N., Mazelis, R., Brown, V., Jackson, E.W., and Banks, S. Outcomes for women with co-occurring disorders and trauma: program and person-level effects. Journal of Substance Abuse Treatment 28(2):121–133, 2005a.15780541
Morrissey, J.P., Jackson, E.W., Ellis, A.R., Amaro, H., Brown, V.B., and Najavits, L.M. Twelve-month outcomes of trauma-informed interventions for women with co-occurring disorders. Psychiatric Services 56(10):1213–1222, 2005b.16215186
Morse, B., Gehshan, S., and Hutchins, E. Screening for Substance Abuse During Pregnancy: Improving Care, Improving Health. Arlington, VA: National Center for Education in Maternal and Child Health, 1997.
Moscato, B.S., Russell, M., Zielezny, M., Bromet, E., Egri, G., Mudar, P., and Marshall, J.R. Gender differences in the relation between depressive symptoms and alcohol problems: A longitudinal perspective. American Journal of Epidemiology 146(11):966–974, 1997.9400339
Moses, D.J., Huntington, N., and D'Ambrosio, B. Developing Integrated Services for Women with Co-Occurring Disorders and Trauma Histories: Lessons from the SAMHSA Women with Alcohol, Drug Abuse and Mental Health Disorders Who Have Histories of Violence Study. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004.
Moses, D.J., Reed, B.G., Mazelis, R., and D'Ambrosio, B. Creating Trauma Services for Women With Co-Occurring Disorders: Experiences from the SAMHSA Women with Alcohol, Drug Abuse and Mental Health Disorders Who Have Histories of Violence Study. Women, Co-Occurring Disorders & Violence Study. Rockville, MD: Substance Abuse And Mental Health Services Administration, 2003.
Mrazek, P.B., Haggerty, R.J., Institute of Medicine, Committee on Prevention of Mental Disorders, United States, and Congress. Reducing Risks For Mental Disorders: Frontiers For Preventive Intervention Research. Washington, D.C: National Academy Press, 1994.
Mucha, L., Stephenson, J., Morandi, N., and Dirani, R. Meta-analysis of disease risk associated with smoking, by gender and intensity of smoking. Gender Medicine 3(4):279–291, 2006.17582369
Mullen, P.D. How can more smoking suspension during pregnancy become lifelong abstinence? Lessons learned about predictors, interventions, and gaps in our accumulated knowledge. Nicotine & Tobacco Research 6(Suppl2):S217–S238, 2004.15203823
Mumenthaler, M.S., Taylor, J.L., O'Hara, R., and Yesavage, J.A. Gender differences in moderate drinking effects. Alcohol Research and Health 23(1):55–64, 1999.10890798
Mumola, C.J. Incarcerated Parents and Their Children. Bureau of Justice Statistics Special Report Washington, DC: Bureau of Justice Statistics, 2000.
Mumola, C.J., and Karberg, J.C. Drug use and dependence, State and Federal prisoners, 2004. Bureau of Justice Statistics Special Report Washington, DC: U.S. Department of Justice, 2007.
Musgrave, C.F., Allen, C.E., and Allen, G.J. Spirituality and health for women of color. American Journal of Public Health 92(4):557–560, 2002.11919051
Najavits, L.M. Training clinicians in the Seeking Safety treatment protocol for posttraumatic stress disorder and substance abuse. Alcoholism Treatment Quarterly 18(3):83–98, 2000.
Najavits, L.M. A woman's addiction workbook: Your guide to in-depth healing. Oakland, CA: New Harbinger, 2002a.
Najavits, L.M. Seeking safety: A treatment manual for PTSD and substance abuse. New York: Guilford Press, 2002b.
Najavits, L.M. Treatment of posttraumatic stress disorder and substance abuse: clinical guidelines for implementing “Seeking Safety” therapy. Alcoholism Treatment Quarterly 22(1):43–62, 2004.
Najavits, L.M. Managing trauma reactions in intensive addiction treatment environments. Journal of Chemical Dependency Treatment 8:153–161, 2006.
Najavits, L.M. Seeking safety: An evidence-based model for substance abuse and trauma/PTSD. In: Witkiewitz, K.A., and Marlatt, G.A., eds. Therapist's Guide to Evidence-Based Relapse Prevention. Practical Resources for the Mental Health Professional. Boston, MA: Elsevier Academic Press, 2007. pp. 141–168.
Najavits, L.M., Gallop, R.J., and Weiss, R.D. Seeking safety therapy for adolescent girls with PTSD and substance use disorder: a randomized controlled trial. Journal of Behavior Health Services Research 33(4):453–463, 2006.
Najavits, L.M., Runkel, R., Neuner, C., Frank, A.F., Thase, M.E., Crits-Christoph, P., and Elaine, J. Rates and Symptoms of PTSD among cocaine-dependent patients. Journal of Studies on Alcohol 64(5):601–606, 2003.14572180
Najavits, L.M., Schmitz, M., Gotthardt, S., and Weiss, R.D. Seeking safety plus exposure therapy: An outcome study on dual diagnosis men. Journal of Psychoactive Drugs 37(4):425–435, 2005.16480170
Najavits, L.M., Weiss, R.D., and Liese, B. Group cognitive–behavioral therapy for women with PTSD and substance use disorder. Journal of Substance Abuse Treatment 13(1):13–22, 1996.8699538
Najavits, L.M., Weiss, R.D., and Shaw, S.R. The link between substance abuse and posttraumatic stress disorder in women: A research review. American Journal on Addictions 6(4):273–283, 1997.
Najavits, L.M., Weiss, R.D., Shaw, S.R., and Muenz, L.R. “Seeking Safety”: Outcome of a new cognitive–behavioral psychotherapy for women with posttraumatic stress disorder and substance dependence. Journal of Traumatic Stress 11(3):437–456, 1998.9690186
Nanchahal, K., Ashton, W.D., and Wood, D.A. Alcohol consumption, metabolic cardiovascular risk factors and hypertension in women. International Journal of Epidemiology 29(1):57–64, 2000.10750604
Nardi, D. Addiction recovery for low-income pregnant and parenting women: A process of becoming. Archives of Psychiatric Nursing 12(2):81–89, 1998.9573635
National Alliance for Caregiving and AARP, Caregiving in the U.S. Bethesda, MD: National Alliance for Caregiving 2004.
National Association for Children of Alcoholics. Celebrating Families Model. 2007. Available on-line at: http://www.celebratingfamilies.net/CFmodel.htm
National Center on Addiction and Substance Abuse. Substance abuse and the American woman. New York: National Center on Addiction and Substance Abuse, 1996.
National Center on Addiction and Substance Abuse. Depression, Substance Abuse and College Student Engagement: A Review of the Literature Report to the Charles Engelhard Foundation and the Bringing Theory to Practice Planning Group. New York, NY: National Center on Addiction and Substance Abuse at Columbia University 2003.
National Coalition of Anti-Violence Programs. Lesbian, Gay, Bisexual and Transgender Domestic Violence in the United States in 2006: A Report Of The National Coalition Of Anti-Violence Programs. New York, NY: National Coalition of Anti-Violence Programs, 2007.
National Institute of Diabetes and Digestive and Kidney Diseases. Binge Eating Disorders. Bethesda, MD: National Institute of Diabetes and Digestive and Kidney Diseases, 2001.
National Institute of Mental Health. Anxiety Disorders. NIH Publication No. 06-3879 Bethesda, MD: National Institutes of Health, 2007.
National Institute on Drug Abuse. Principles Of Drug Addiction Treatment: A Research-Based Guide. NIH Publication No. 00–4180. Bethesda, MD: National Institutes of Health, 1999.
National Institute on Drug Abuse. Heroin: Abuse and Addiction. National Institute on Drug Abuse Research Report Series Rockville, MD: National Institute on Drug Abuse, 2000.
National Institute on Drug Abuse. Prescription drugs: Abuse and addiction. National Institute on Drug Abuse Research Report Series Rockville, MD: National Institute on Drug Abuse 2001.
National Institute on Drug Abuse. Behavioral problems related to maternal smoking during pregnancy manifest early in childhood. NIDA Notes 21(6):7–8, 2008.
National Institutes of Health - Office of Research on Women's Health. Women of Color Health Data Book: Adolescents to Seniors. Bethesda, MD: National Institutes of Health, Office of Research on Women's Health, 1999.
National Poverty Center. Poverty in the United States: Frequently Asked Questions. Ann Arbor, MI: University of Michigan 2006.
Neff, J.A., and Mantz, R.J. Marital status transition, alcohol consumption, and number of sex partners over time in a tri-ethnic sample. Journal of Divorce and Remarriage 29(1-2):19–42, 1998.
Nelson-Zlupko, L., Kauffman, E., and Dore, M.M. Gender differences in drug addiction and treatment: implications for social work intervention with substance-abusing women. Soc Work 40(1):45–54, 1995.7863372
Nelson-Zlupko, L., Dore, M.M., Kauffman, E., and Kaltenbach, K. Women in recovery: Their perceptions of treatment effectiveness. Journal of Substance Abuse Treatment 13(1):51–59, 1996.8699543
Neumarker, K.J. Mortality and sudden death in anorexia nervosa. International Journal of Eating Disorders 21(3):205–212, 1997.
Neuspiel, D.R. Racism and perinatal addiction. Ethnicity and Disease 6(1-2):47–55, 1996.8882835
New York State Education Department – Office of Bilingual Education. Directory of Languages. Albany, NY: New York State Education Department, Office of Bilingual Education, 1997.
Newmann, J.P., and Sallmann, J. Women, trauma histories, and co-occurring disorders: Assessing the scope of the problem. Social Service Review 78(3):446–499, 2004.
Niccols, A., and Sword, W. “New Choices” for substance-using mothers and their children: Preliminary evaluation. Journal of Substance Use 10(4):239–251, 2005.
Nicoloff, L.K., and Stiglitz, E.A. Lesbian alcoholism: Etiology, treatment, and recovery. In: Boston Lesbian Psychologies Collective, ed. Lesbian psychologies: Explorations and challenges. Urbana, IL: University of Illinois Press, 1987. pp. 283–293.
Nielsen Forman, D., Videbech, P., Hedegaard, M., Dalby, S.J., and Secher, N.J. Postpartum depression: Identification of women at risk. BJOG: An International Journal of Obstetrics and Gynaecology 107(10):1210–1217, 2000.11028570
Nikolopoulou, G.B., Nowicki, M.J., Du, W., Homans, J., Stek, A., Kramer, F., and Kovacs, A. HCV viremia is associated with drug use in young HIV-1 and HCV coinfected pregnant and non-pregnant women. Addiction 100(5):626–635, 2005.15847620
Nishimoto, R.H., and Roberts, A.C. Coercion and drug treatment for postpartum women. American Journal of Drug Alcohol Abuse 27(1):161–181, 2001.
Nishith, P., Resick, P.A., and Mueser, K.T. Sleep difficulties and alcohol use motives in female rape victims with posttraumatic stress disorder. Journal of Traumatic Stress 14(3):469–479, 2001.11534879
Niv, N., and Hser, Y.I. Women-only and mixed-gender drug abuse treatment programs: service needs, utilization and outcomes. Drug and Alcohol Dependence 87(2-3):194–201, 2007.16996232
Niv, N., Wong, E.C., and Hser, Y.I. Asian Americans in community-based substance abuse treatment: service needs, utilization, and outcomes. Journal of Substance Abuse Treatment 33(3):313–319, 2007.17376635
Norris, J., and Hughes, T.L. Alcohol consumption and female sexuality: A review. In: Howard, J.M., Martin, S.E., Mail, P.D., Hilton, M.E., and Taylor, E.D., eds. Women and Alcohol: Issues for Prevention Research. NIAAA Research Monograph No. 32. Bethesda, MD: National Institute on Alcohol Abuse and Alcoholism, 1996. pp. 315–345.
North, C.S., Eyrich, K.M., Pollio, D.E., and Spitznagel, E.L. Are rates of psychiatric disorders in the homeless population changing? American Journal of Public Health 94(1):103–108, 2004a.14713706
North, C.S., Eyrich, K.M., Pollio, D.E., Foster, D.A., Cottler, L.B., and Spitznagel, E.L. The Homeless Supplement to the Diagnostic Interview Schedule: test-retest analyses. International Journal of Methods in Psychiatric Research 13(3):184–191, 2004b.15297902
Oates, M. Management of major mental illness in pregnancy and the puerperium. Baillieres Best Practice and Research: Clinical Obstetrics and Gynaecology 3(4):905–920, 1989.
Oetjen, H., and Rothblum, E.D. When lesbians aren't gay: Factors affecting depression among lesbians. Journal of Homosexuality 39(1):49–73, 2000.10864377
Oetzel, J., Duran, B., Jiang, Y., and Lucero, J. Social support and social undermining as correlates for alcohol, drug, and mental disorders in American Indian women presenting for primary care at an Indian Health Service hospital. Journal of Health Communication 12(2):187–206, 2007.17365359
Office of Applied Studies. Results from the 2001 National Household Survey on Drug Abuse: Vol.1. Summary of National Findings. National Household Survey on Drug Abuse Series: H-17. HHS Publication No. (SMA) 02-3758. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2002a.
Office of Applied Studies. Results from the 2001 National Household Survey on Drug Abuse: Volume III. Detailed Tables. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2002b.
Office of Applied Studies. Characteristics of homeless female admissions to substance abuse treatment: 2002. The DASIS Report (October 8, 2004): Rockville, M.D.: Substance Abuse and Mental Health Services Administration 2004a.
Office of Applied Studies. Gender differences in substance dependence and abuse. The NSDUH Report (October 29, 2004): Rockville, MD: Substance Abuse and Mental Health Services Administration 2004b.
Office of Applied Studies. Women with co-occurring serious mental illness and a substance use disorder. The NSDUH Report (August 20, 2004):1–3. Rockville, MD: Substance Abuse and Mental Health Services Administration 2004c.
Office of Applied Studies. Results from the 2004 National Survey on Drug Use and Health: National Findings. HHS Publication No. SMA 05-4062 Rockville, MD: Substance Abuse and Mental Health Services Administration 2005.
Office of Applied Studies. Facilities offering special programs or groups for women: 2005. The DASIS Report Issue 35 Rockville, MD: Substance Abuse and Mental Health Services Administration, 2006.
Office of Management and Budget. Recommendations from the Interagency Committee for the review of the racial and ethnic standards to the Office of Management and Budget Concerning Changes to the Standards for the Classification of Federal Data on Race and Ethnicity. Federal Register 62(13):36873–36946, 1997.
Office of National Drug Control Policy. National Drug Control Strategy. Washington, DC: Office of National Drug Control Policy, 2007.
Office of the Surgeon General. Fact Sheets: Asian Americans/Pacific Islanders. Mental Health: Culture, Race, and Ethnicity A Supplement to Mental Health: A Report of the Surgeon General Rockville, MD: U.S. Public Health Service 2001a.
Office of the Surgeon General. Women and Smoking: A Report of the Surgeon General. Atlanta, GA: Centers for Disease Control and Prevention, Office on Smoking and Health 2001b.
O'Hara, M.W., Stuart, S., Gorman, L.L., and Wenzel, A. Efficacy of interpersonal psychotherapy for postpartum depression. Archives of General Psychiatry 57(11):1039–1045, 2000.11074869
Okazaki, S. Psychological assessment of Asian Americans: Research agenda for cultural competency. Journal of Personality Assessment 70(1):54–70, 1998.
Oklahoma Department of Mental Health and Substance Abuse Services. Title 450. Department of Mental Health and Substance Abuse Services. chapter 18. Standards and Criteria for Alcohol and Drug Treatment Programs. Oklahoma City, OK: Oklahoma Department of Mental Health and Substance Abuse Services, 2008.
Oncology Nursing Society 31st Annual Congress Podium and Poster Abstracts. Oncology Nursing Forum 33(2):394–491, 2006.
Onland-Moret, N.C., Peeters, P.H., Van Der Schouw, Y.T., Grobbee, D.E., and van Gils, C.H. Alcohol and endogenous sex steroid levels in postmenopausal women: a cross-sectional study. Journal of Clinical Endocrinology and Metabolism 90(3):1414–1419, 2005.15572431
Oregon Secretary of State, and Department of Human Services, A.S. Standards for Outpatient and Residential Alcohol and Drug Treatment Programs. Salem, OR: Oregon Secretary of State, 2008.
Orenstein, R., and Tsogas, N. Hepatitis C virus and human immunodeficiency virus co-infection in women. Journal of the American Osteopathic Association 101(12 Suppl Pt 2):S1–S6, 2001.
Ouimette, P.C., Kimerling, R., Shaw, J., and Moos, R.H. Physical and sexual abuse among women and men with substance use disorders. Alcoholism Treatment Quarterly 18(3):7–17, 2000.
Page, R.M. Perceived physical attractiveness and frequency of substance use among male and female adolescents. Journal of Alcohol and Drug Education 38(2):81–91, 1993.
Paniagua, F.A. Assessing and Treating Culturally Diverse Clients: A Practical Guide. 2d ed. Thousand Oaks, CA: Sage Publications, 1998.
Paranjape, A., and Liebschutz, J. STaT: a three-question screen for intimate partner violence. Journal of Women's Health (Larchment) 12(3):233–239, 2003.
Parelman, A. Emotional Intimacy in Marriage: A Sex-Roles Perspective. Research in Clinical Psychology. Ann Arbor, Mich: UMI Research Press, 1983.
Parks, C.A. Lesbian identity development: An examination of differences across generations. American Journal of Orthopsychiatry 69(3):347–361, 1999a.
Parks, C.A. Lesbian social drinking: The role of alcohol in growing up and living as a lesbian. Contemporary Drug Problems 26(1):75–129, 1999b.
Parks, C.A., and Hughes, T.L. Alcohol use and alcohol-related problems in self-identified lesbians: age and racial/ethnic comparisons. Journal of Lesbian Studies 9(3):31–44, 2005.
Parks, C.A., Hesselbrock, M.N., Hesselbrock, V.M., and Segal, B. Factors affecting entry into substance abuse treatment: Gender differences among alcohol-dependent Alaska Natives. Social Work Research 27(3):151–161, 2003.
Passaro, K.T., and Little, R.E. Childbearing and alcohol use. In: Wilsnack, R.W., and Wilsnack, S.C., eds. Gender and Alcohol: Individual and Social Perspectives. New Brunswick, NJ: Rutgers Center of Alcohol Studies, 1997. pp. 90–113.
Patkar, A.A., Sterling, R.C., Gottheil, E., and Weinstein, S.P. A comparison of medical symptoms reported by cocaine-, opiate-, and alcohol-dependent patients. Substance Abuse 20(4):227–235, 1999.12511830
Pedersen, P.B., Fukuyama, M., and Heath, A. Client, counselor, and contextual variables in multicultural counseling. In: Pedersen, P.B., Draguns, J.G., Lonner, W.J., and Trimble, J.E., eds. Counseling Across Cultures. 3d ed. Honolulu, HI: University of Hawaii Press, 1989. pp. 23–52.
Pelissier, B. Gender differences in substance use treatment entry and retention among prisoners with substance use histories. American Journal of Public Health 94(8):1418–1424, 2004.15284053
Peluso, E., and Peluso, L.S. Women and Drugs: Getting Hooked, Getting Clean. Minneapolis, MN: CompCare Publishers, 1988.
Penn, P.E., Brooks, A.J., and Worsham, B.D. Treatment concerns of women with co-occurring serious mental illness and substance abuse disorders. Journal of Psychoactive Drugs 34(4):355–362, 2002.12562103
Peters, T.J., Millward, L.M., and Foster, J. Quality of life in alcohol misuse: Comparison of men and women. Archives of Women's Mental Health 6(4):239–243, 2003.
Pettinati, H.M., Rukstalis, M.R., Luck, G.J., Volpicelli, J.R., and O'Brien, C.P. Gender and psychiatric comorbidity: Impact on clinical presentation of alcohol dependence. American Journal on Addictions 9(3):242–252, 2000.
Piazza, N.J., Vrbka, J.L., and Yeager, R.D. Telescoping of alcoholism in women alcoholics. International Journal of the Addictions 24(1):19–28, 1989.
Pickens, R.W., Svikis, D.S., McGue, M., Lykken, D.T., Heston, L.L., and Clayton, P.J. Heterogeneity in the inheritance of alcoholism: A study of male and female twins. Archives of General Psychiatry 48(1):19–28, 1991.1984758
Piran, N., and Robinson, S.R. Associations between disordered eating behaviors and licit and illicit substance use and abuse in a university sample. Addictive Behaviors 31(10):1761–1775, 2006.16448780
Pomerleau, C.S., Zucker, A.N., and Stewart, A.J. Characterizing concerns about post-cessation weight gain: results from a national survey of women smokers. Nicotine and Tobacco Research 3(1):51–60, 2001.11260811
Poole, N., and Dell, C.A. Girls, Women and Substance Use. 1–16. Ottawa, ON: Canadian Centre on Substance Abuse 2005.
Porter, L. Women and HCV: Treatment. HCSP Factsheet June version 1.0 San Francisco, CA: Hepatitis C Support Project, 2005.
Porter, L.K. Women and Hepatitis C: An HCSP Guide. San Francisco, CA: Hepatits C Support Project, 2008.
Poundstone, K.E., Chaisson, R.E., and Moore, R.D. Differences in HIV disease progression by injection drug use and by sex in the era of highly active antiretroviral therapy. AIDS 15(9):1115–1123, 2001.11416713
Power, C., Rodgers, B., and Hope, S. Heavy alcohol consumption and marital status: Disentangling the relationship in a national study of young adults. Addiction 94(10):1477–1487, 1999.10790900
Prescott, C.A. Sex differences in the genetic risk for alcoholism. Alcohol Research & Health 26(4):264–273, 2002.12875036
Prescott, L. Consumer/Survivor/Recovering Women: A Guide for Partnerships in Collaboration. Delmar, NY: Policy Research Associates, 2001.
Price, A., and Simmel, C. Partners' Influence on Women's Addiction and Recovery: The Connection Between Substance Abuse, Trauma, and Intimate Relationships. Berkeley, CA: University of California at Berkeley, School of Social Welfare, National Abandoned Infants Assistance Resource Center, 2002.
Prochaska, J.J., Delucchi, K., and Hall, S.M. A meta-analysis of smoking cessation interventions with individuals in substance abuse treatment or recovery. Journal of Consulting & Clinical Psychology 72(6):1144–1156, 2004.15612860
Project MATCH Research Group. Project MATCH secondary a priori hypotheses. Addiction 92(12):1671–1698, 1997.9581001
Pugatch, D., Ramratmanm M., Strong, L., Feller, A., and Levesque, B. Gender differences in HIV risk behaviors among young adults and adolescents entering a Massachusetts detoxification center. Substance Abuse 21(2):79–86, 2000.12466648
Quinlivan, J.A., and Evans, S.F. The impact of continuing illegal drug use on teenage pregnancy outcomes–a prospective cohort study. BJOG: An International Journal of Obstetrics and Gynaecology 109(10):1148–1153, 2002.12387469
Radloff, L.S. The CES-D Scale: A self-report depression scale for research in the general population. Applied Psychological Measurement 1(3):385–401, 1977.
Raeburn, S.D. Women and eating disorders. In: Straussner, S.L.A., and Brown, S., eds. The Handbook of Addiction Treatment for Women: Theory and Practice. San Francisco: Jossey-Bass, 2002. pp. 127–153.
Randall, C.L. Alcohol and pregnancy: Highlights from three decades of research. Journal of Studies on Alcohol 62(5):554–561, 2001.11702794
Randolph, W.M., Stroup-Benham, C., Black, S.A., and Markides, K.S. Alcohol use among Cuban-Americans, Mexican-Americans, and Puerto Ricans. Alcohol Health and Research World 22(4):265–269, 1998.15706753
Ratner, P.A., Johnson, J.L., Bottorff, J.L., Dahinten, S., and Hall, W. Twelve-month follow-up of a smoking relapse prevention intervention for postpartum women. Addictive Behaviors 25(1):81–92, 2000.10708321
Ravndal, E., and Vaglum, P. Treatment of female addicts: the importance of relationships to parents, partners, and peers for the outcome. International Journal of Addictions 29(1):115–125, 1994.
Rayburn, W.F., and Bogenschutz, M.P. Pharmacotherapy for pregnant women with addictions. American Journal of Obstetrics and Gynecology 191(6):1885–1897, 2004.15592269
Reed, B.G., and Mowbray, C.T. Mental illness and substance abuse: Implications for women's health and health care access. Journal of the American Medical Women's Association 54(2):71–78, 1999.
Reeves, T., and Bennett, C. The Asian and Pacific Islander population in the United States: March 2002. Current Psychiatry Reports Washington, DC: U. S. Census Bureau 2003.
Register, T.C., Cline, J.M., and Shively, C.A. Health issues in postmenopausal women who drink. Alcohol Research & Health 26(4):299–307, 2002.12875041
Register, T.C., Cline, J.M., and Shively, C.A. Health Issues in Postmenopausal Women Who Drink. Bethesda, MD: National Institute on Alcohol Abuse and Alcoholism, 2003.
Reid, D.J. Addiction, African Americans, and a Christian recovery. In: Krestan, J.A., ed. Bridges to Recovery: Addiction, Family Therapy, and Multicultural Treatment. New York: The Free Press, 2000. pp. 145–172.
Renzetti, C.M. Violence in lesbian relationships. In: Hansen, M., and Harway, M., eds. Battering and Family Therapy: A Feminist Perspective. Thousand Oaks, CA: Sage Publications, 1993. pp. 188–199.
Renzetti, C.M. On dancing with a bear: Reflections on some of the current debates among domestic violence theorists. Violence and Victims 9(2):195–200, 1994.7696198
Reyes, M. Latina lesbians and alcohol and other drugs: Social work implications. Alcoholism Treatment Quarterly 16(1/2):179–192, 1998.
Reynolds, E.W., and Bada, H.S. Pharmacology of drugs of abuse. Obstetrics and Gynecology Clinics of North America 30(3):501–522, 2003.14664324
Rhoades, J.A., and Chu, M.C. Health insurance status of the civilian noninstitutionalized population: 1999. Rockville, MD: Agency for Healthcare Research and Quality 2000.
Rhodes, R., and Johnson, A. A feminist approach to treating alcohol and drug-addicted African-American women. Women & Therapy 20(3):23–37, 1997.
Rice, C., Mohr, C.D., Del Boca, F.K., Mattson, M.E., Young, L., Brady, K., and Nickless, C. Self-reports of physical, sexual and emotional abuse in an alcoholism treatment sample. Journal of Studies on Alcohol 62(1):114–123, 2001.11271959
Richardson, G.A., Goldschmidt, L., and Larkby, C. Effects of prenatal cocaine exposure on growth: a longitudinal analysis. Pediatrics 120(4):e1017–e1027, 2007.17893189
Ridenour, T.A., Maldonado-Molina, M., Compton, W.M., Spitznagel, E.L., and Cottler, L.B. Factors associated with the transition from abuse to dependence among substance abusers: implications for a measure of addictive liability. Drug and Alcohol Dependence 80(1):1–14, 2005.16157227
Riehman, K.S., Hser, Y.I., and Zeller, M. Gender differences in how intimate partners influence drug treatment motivation. Journal of Drug Issues 30(4):823–838, 2000.
Riehman, K.S., Iguchi, M.Y., Zeller, M., and Morral, A.R. The influence of partner drug use and relationship power on treatment engagement. Drug and Alcohol Dependence 70(1):1–10, 2003.12681520
Rinehart, D.J., Becker, M.A., Buckley, P.R., Dailey, K., Reichardt, c.S., Graeber, C., VanDeMark, N.R., and Brown, E. The relationship between mothers' child abuse potential and current metal health symptoms: Implications for screening and referral. Journal of Behavior Health Services & Research 32(2):155–166, 2005.
Roberts, A., Jackson, M.S., and Carlton-LaNey, I. Revisiting the need for feminism and afrocentric theory when treating African-American female substance abusers. Journal of Drug Issues 30(4):901–918, 2000.
Roberts, A.C., and Nishimoto, R. Barriers to engaging and retaining African American post-partum women in drug treatment. Journal of Drug Issues 36(1):53–76, 2006.
Roberts, A.C., and Nishimoto, R.H. Predicting treatment retention of women dependent on cocaine. American Journal of Drug and Alcohol Abuse 22(3):313–333, 1996.
Robertson, M.J., Zlotnick, C., and Westerfelt, A. Drug use disorders and treatment contact among homeless adults in Alameda County, California. American Journal of Public Health 87(2):221–228, 1997.9103101
Robin, R.W., Chester, B., Rasmussen, J.K., and Jaranson, J.M. Factors influencing utilization of mental health and substance abuse services by American Indian men and women. Psychiatric Services 48(6):826–832, 1997.9175194
Rodriguez-Andrew, S. Alcohol use and abuse among Latinos: Issues and examples of culturally competent services. Alcoholism Treatment Quarterly 16(1-2):55–70, 1998.
Rogers, C. Older women and poverty in rural America. Rural Population and Migration: Trend 6-Challenges From an Aging Population Washington, DC: U.S. Department of Agriculture, 2005.
Rohan, T.E., Jain, M., Howe, G.R., and Miller, A.B. Alcohol consumption and risk of breast cancer: A cohort study. Cancer Causes and Control 11(3):239–247, 2000.10782658
Romach, M.K., and Sellers, E.M. Alcohol dependence: Women, biology, and pharmacotherapy. In: McCance-Katz, E.F., and Kosten, T.R., eds. New Treatments for Chemical Addictions. Washington, DC: American Psychiatric Press, 1998. pp. 35–73.
Rome, E.S. Eating disorders. Obstetrics and Gynecology Clinics of North America 30(2):353–377, 2003.12836725
Root, M.P. Treatment failures: The role of sexual victimization in women's addictive behavior. American Journal of Orthopsychiatry 59(4):542–549, 1989.
Rosenberg, L., Palmer, J.R., Rao, R.S., and Adams-Campbell, L.L. Patterns and correlates of alcohol consumption among African-American women. Ethnicity and Disease 12(4):548–554, 2002.12477142
Ross, J. Food addiction: A new look at the nature of craving. Addiction and Recovery 13(5):17–19, 1993.
Ross-Durow, P.L., and Boyd, C.J. Sexual abuse, depression, and eating disorders in African American women who smoke cocaine. Journal of Substance Abuse Treatment 18(1):79–81, 2000.10636611
Rotgers, F. Clinically useful, research validated assessment of persons with alcohol problems. Behaviour Research and Therapy 40(12):1425–1441, 2002.12457637
Rotter, J.C., and Casado, M. Promoting strengths and celebrating culture: Working with Hispanic families. Family Journal 6(2):132–137, 1998.
Rouse, B.A., Carter, J.H., and Rodriguez-Andrew, S. Race/ethnicity and other sociocultural influences on alcoholism treatment for women. In: Galanter, M., ed. Recent Developments in Alcoholism, Vol. 12: Alcoholism and Women. New York: Plenum Press, 1995. pp. 343–367.
Rubin, A., Stout, R.L., and Longabaugh, R. Gender differences in relapse situations. Addiction 91(Suppl):S111–S120, 1996.8997785
Rush, M.M. Perceived social support: Dimensions of social interaction among sober female participants in Alcoholics Anonymous. Journal of the American Psychiatric Nurses Association 8(4):114–119, 2002.
Russell, M. New assessment tools for risk drinking during pregnancy: T-ACE, TWEAK, and others. Alcohol Health and Research World 18(1):55–61, 1994.31798157
Russell, M., Czarnecki, D.M., Cowan, R., McPherson, E., and Mudar, P.J. Measures of maternal alcohol use as predictors of development in early childhood. Alcoholism: Clinical & Experimental Research 15(6):991–1000, 1991.
Russell, M., Martier, S.S., Sokol, R.J., Mudar, P., Jacobson, S., and Jacobson, J. Detecting risk drinking during pregnancy: A comparison of four screening questionnaires. American Journal of Public Health 86(10):1435–1439, 1996.8876514
Russell, P.L. Trauma and the cognitive function of affects. In: Teicholz, J.G., and Kriegman, D., eds. Trauma, Repetition, and Affect Regulation: The Work of Paul Russell. New York: The Other Press, 1998. pp. 23–47.
Ryland, S.A., and Lucas, L. A rural collaborative model of treatment and recovery services for pregnant and parenting women with dual disorders. Journal of Psychoactive Drugs 28(4):389–395, 1996.9017559
Sabol, W.J., Couture, H., and Harrison, P.M. Prisoners in 2006. Bureau of Justice Statistics Bulletin Washington, DC: U.S. Department of Justice 2007.
Safer, D.L., Telch, C.F., and Agras, W.S. Dialectical behavior therapy adapted for bulimia: A case report. International Journal of Eating Disorders 30(1):101–106, 2001.
Salasin, S.E. Evolution of women's trauma-integrated services at the Substance Abuse and Mental Health Services Administration. Journal of Community Psychology 33(4):379–393, 2005.
Sale, E., Sambrano, S., Springer, J.F., Pena, C., Pan, W., and Kasim, R. Family protection and prevention of alcohol use among Hispanic youth at high risk. American Journal of Community Psychology 36(3-4):195–205, 2005.16389495
Salmon, M.M., Joseph, B.M., Saylor, C., and Mann, R.J. Women's perception of provider, social, and program support in an outpatient drug treatment program. Journal of Substance Abuse Treatment 19(3):239–246, 2000.11027893
Sampson, H.W. Alcohol's harmful effects on bone. Alcohol Health and Research World 22(3):190–194, 1998.15706795
Sampson, H.W. Alcohol and other factors affecting osteoporosis risk in women. Alcohol Research & Health 26(4):292–298, 2002.12875040
Sandfort, T.G., de Graaf, R., Bijl, R.V., and Schnabel, P. Same-sex sexual behavior and psychiatric disorders: Findings from the Netherlands Mental Health Survey and Incidence Study (NEMESIS). Archives of General Psychiatry 58(1):85–91, 2001.11146762
Santen, F.J., Sofsky, J., Bilic, N., and Lippert, R. Mechanism of action of narcotics in the production of menstrual dysfunction in women. Fertility and Sterility 26(6):538–548, 1975.236938
Sartor, C.E., Lynskey, M.T., Bucholz, K.K., McCutcheon, V.V., Nelson, E.C., Waldron, M., and Heath, A.C. Childhood sexual abuse and the course of alcohol dependence development: Findings from a female twin sample. Drug and Alcohol Dependence 89(2–3):139–144, 2007.17227698
Satre, D.D., Mertens, J.R., and Weisner, C. Gender differences in treatment outcomes for alcohol dependence among older adults. Journal of Studies on Alcohol 65(5):638–642, 2004.15536774
Saunders, E.J. A new model of residential care for substance-abusing women and their children. Adult Residential Care Journal 7(2):104–117, 1993.
Saylors, K., and Daliparthy, N. Violence against Native women in substance abuse treatment. American Indian and Alaska Native Mental Health Research 13(1):32–51, 2006.17602396
Schauer, C., Everett, A., del, V.P., and Anderson, L. Promoting the value and practice of shared decision-making in mental health care. Psychiatric Rehabilitation Journal 31(1):54–61, 2007.17694716
Schilit, R., Lie, G.Y., and Montagne, M. Substance use as a correlate of violence in intimate lesbian relationships. Journal of Homosexuality 19(3):51–65, 1990.2212630
Schnoll, R.A., Patterson, F., and Lerman, C. Treating tobacco dependence in women. Journal of Women's Health (Larchmt.) 16(8):1211–1218, 2007.
Schuck, A.M., and Widom, C.S. Childhood victimization and alcohol symptoms in females: causal inferences and hypothesized mediators. Child Abuse and Neglect 25(8):1069–1092, 2001.11601598
Schweinsburg, B.C., Alhassoon, O.M., Taylor, M.J., Gonzalez, R., Videen, J.S., Brown, G.G., Patterson, T.L., and Grant, I. Effects of alcoholism and gender on brain metabolism. American Journal of Psychiatry 160(6):1180–1183, 2003.
Scogin, F., Morthland, M., Kaufman, A., Burgio, L., Chaplin, W., Kong, G., and ‘. Improving quality of life in diverse rural older adults: A randomized trial of a psychological treatment. Psychology and Aging 22(4):657–665, 2007.18179286
Scott-Lennox, J., Rose, R., Bohlig, A., and Lennox, R. The impact of women's family status on completion of substance abuse treatment. Journal of Behavioral Health Services and Research 27(4):366–379, 2000.11070631
Setiawan, V.W., Monroe, K.R., Goodman, M.T., Kolonel, L.N., Pike, M.C., and Henderson, B.E. Alcohol consumption and endometrial cancer risk: the multiethnic cohort. International Journal of Cancer 122(3):634–638, 2008.17764072
Severance, T.A. Concerns and coping strategies of women inmates concerning release: “It's going to take somebody in my corner.” Journal of Offender Rehabilitation 38(4):73–97, 2004.
Sheehan, D., Janavs, J., Baker, R., Harnett-Sheehan, K., Knapp, E., Sheehan, M., Lecrubier, Y., Weiller, E., Hergueta, T., Amorim, P., Bonora, L.I., and Lepine, J.P. M.I.N.I.: Mini International Neuropsychiatric Interview. English Version 5.0.0. n.p.: Medical Outcome Systems 2002.
Sherman, C. Drugs Affect Men's and Women's Brains Differently. NIDA Notes vol. 20:6 2006.
Shieh, C., and Kravitz, M. Severity of drug use, initiation of prenatal care, and maternalfetal attachment in pregnant marijuana and cocaine/heroin users. Journal of Obstetric, Gynecologic, & Neonatal Nursing: Clinical Scholarship for the Care of Women, Child-bearing Families, & Newborns 35(4):499–508, 2006.
Shiffman, S., and Balabanis, M. Associations between alcohol and tobacco. In: Fertig, J.B., and Allen, J.P., eds. Alcohol and Tobacco: From Basic Science to Clinical Practice. NIAAA Research Monograph No. 30. Bethesda, MD: National Institute on Alcohol Abuse and Alcoholism, 1995. pp. 17–36.
Silverman, J.G., Raj, A., and Clements, K. Dating violence and associated sexual risk and pregnancy among adolescent girls in the United States. Pediatrics 114(2):e220–e225, 2004.15286260
Silverman, J.G., Raj, A., Mucci, L.A., and Hathaway, J.E. Dating violence against adolescent girls and associated substance use, unhealthy weight control, sexual risk behavior, pregnancy, and suicidality. Journal of the American Medical Association 286(5):572–579, 2001.11476659
Silverstein, B. Women show higher rates of anxious somatic depression but maybe not “pure” depression. Clinician's Research Digest 20(10):3, 2002.
Simoni, J.M., Sehgal, S., and Walters, K.L. Triangle of risk: urban American Indian women's sexual trauma, injection drug use, and HIV sexual risk behaviors. AIDS and Behavior 8(1):33–45, 2004.15146132
Simoni-Wastila, L. The use of abusable prescription drugs: The role of gender. Journal of Women's Health and Gender-Based Medicine 9(3):289–297, 2000.
Simpson, D.D. Patient Engagement and Duration of Treatment. Bethesda, MD: National Institute on Drug Abuse, 1997.
Simpson, D.D., and Knight, D.K. TCU Data Collection Forms for Women and Children Residential Treatment: Intake. Fort Worth, TX: Texas Christian University, Institute of Behavioral Research, 1997.
Simpson, T.L. Childhood sexual abuse, PTSD and the functional roles of alcohol use among women drinkers. Substance Use & Misuse 38(2):249–270, 2003.12625430
Singer, L.T., Arendt, R., Minnes, S., Farkas, K., and Salvator, A. Neurobehavioral outcomes of cocaine-exposed infants. Neurotoxicology and Teratology 22(5):653–666, 2000.11106858
Singer, L.T., Minnes, S., Short, E., Arendt, R., Farkas, K., Lewis, B., Klein, N., Russ, S., Min, M.O., and Kirchner, H.L. Cognitive outcomes of preschool children with prenatal cocaine exposure. JAMA 291(20):2448–2456, 2004.15161895
Singletary, K.W., and Gapstur, S.M. Alcohol and breast cancer: Review of epidemiologic and experimental evidence and potential mechanisms. Journal of the American Medical Association 286(17):2143–2151, 2001.11694156
Slade, A., and Cohen, L.J. The process of parenting and the remembrance of things past. Infant Mental Health Journal 17(3):217–238, 1996.
Slaymaker, V.J., and Owen, P.L. Employed men and women substance abusers: Job troubles and treatment outcomes. Journal of Substance Abuse Treatment 31(4):347–354, 2006.17084788
Smith, C., and Erford, B.T. Test Review: Beck Depression Inventory - II. Greensboro, NC: Association for Assessment in Counseling, 2001.
Smith, D.E., Moser, C., Wesson, D.R., Apter, M., Buxton, M.E., Davison, J.V., Orgel, M., and Buffum, J. A clinical guide to the diagnosis and treatment of heroin-related sexual dysfunction. Journal of Psychoactive Drugs 14(1-2):91–99, 1982.7119946
Smith, J.W. Medical manifestations of alcoholism in the elderly. International Journal of the Addictions 30(13-14):1749–1798, 1995.
Smith, L.M., LaGasse, L.L., Derauf, C., Grant, P., Shah, R., Arria, A., Huestis, M., Haning, W., Strauss, A., Della, G.S., Liu, J., and Lester, B.M. The infant development, environment, and lifestyle study: Effects of prenatal methamphetamine exposure, polydrug exposure, and poverty on intrauterine growth. Pediatrics 118(3):1149–1156, 2006.16951010
Smith, S.S., Jorenby, D.E., Leischow, S.J., Nides, M.A., Rennard, S.I., Johnston, J.A., Jamerson, B., Fiore, M.C., and Baker, T.B. Targeting smokers at increased risk for relapse: treating women and those with a history of depression. Nicotine and Tobacco Research 5(1):99–109, 2003.12745511
Smolak, L., and Murnen, S.K. Gender and eating problems. In: Striegel-Moore, R.H., and Smolak, L., eds. Eating Disorders: Innovative Directions in Research and Practice. 1-55798-778-5 (hardcover). American Psychological Association: Washington, 2001. pp. 91–110.
Sobell, L.C., Cunningham, J.A., and Sobell, M.B. Recovery from alcohol problems with and without treatment: Prevalence in two population surveys. American Journal of Public Health 86(7):966–972, 1996.8669520
Sohrabji, F. Neurodegeneration in women. Alcohol Research & Health 26(4):316–318, 2002.12875043
Sokol, R.J., and Clarren, S.K. Guidelines for use of terminology describing the impact of prenatal alcohol on the offspring. Alcoholism: Clinical and Experimental Research 13(4):597–598, 1989.
Sokol, R.J., Martier, S.S., and Ager, J.W. The T-ACE questions: practical prenatal detection of risk-drinking. American Journal of Obstetrics and Gynecology 160(4):863–868, 1989.2712118
Solarz, A.L. (Ed.) Lesbian Health: Current Assessment And Directions For The Future. Washington, D.C.: National Academy Press, 1999.
Solomon, S.D., and Johnson, D.M. Psychosocial treatment of posttraumatic stress disorder: A practice-friendly review of outcome research. Journal of Clinical Psychology 58(8):947–959, 2002.12115717
Sorensen, J.L., Masson, C.L., Delucchi, K., Sporer, K., Barnett, P.G., Mitsuishi, F., Lin, C., Song, Y., Chen, T., and Hall, S.M. Randomized trial of drug abuse treatment-linkage strategies. Journal of Consulting & Clinical Psychology 73(6):1026–1035, 2005.16392976
Specker, S., Westermeyer, J., and Thuras, P. Course and severity of substance abuse in women with comorbid eating disorders. Substance Abuse 21(3):137–147, 2000.12466654
Stahler, G.J., Shipley, T.E., Kirby, K.C., Godboldte, C., Kerwin, M.E., Shandler, I., and Simons, L. Development and initial demonstration of a community-based intervention for homeless, cocaine-using, African-American Women. Journal of Substance Abuse Treatment 28(2):171–179, 2005.15780547
Stamler, V.L., Christiansen, M.D., Staley, K.H., and agno-Shang, L. Client preference for counselor gender. Psychology of Women Quarterly 15(2):317–321, 1991.
Steele, C.T. Providing clinical treatment to substance abusing trauma survivors. Alcoholism Treatment Quarterly 18(3):71–82, 2000.
Steer, R.A., Beck, A.T., and Brown, G. Sex differences on the revised Beck Depression Inventory for outpatients with affective disorders. Journal of Personality Assessment 53(4):693–702, 1989.2607401
Steffens, A.A., Moreira, L.B., Fuchs, S.C., Wiehe, M., Gus, M., and Fuchs, F.D. Incidence of hypertension by alcohol consumption: is it modified by race? Journal of Hypertension 24(8):1489–1492, 2006.16877949
Steinberg, M.B., Akincigil, A., Delnevo, C.D., Crystal, S., and Carson, J.L. Gender and age disparities for smoking-cessation treatment. American Journal of Preventive Medicine 30(5):405–412, 2006.16627128
Steiner, M. Perinatal mood disorders: Position paper. Psychopharmacology Bulletin 34(3):301–306, 1998.9803759
Steiner, M. Postnatal depression: A few simple questions. Family Practice 19(5):469–470, 2002.12356696
Steinhausen, H.C. The outcome of anorexia nervosa in the 20th century. American Journal of Psychiatry 159(8):1284–1293, 2002.
Sterling, R.C., Gottheil, E., Weinstein, S.P., and Serota, R. Therapist/patient race and sex matching: Treatment retention and 9-month follow-up outcome. Addiction 93(7):1043–1050, 1998.9744135
Stevens, S.J. American-Indian women and health. In: Wechsberg, W.M., ed. Prevention issues for women's health in the new millennium. Binghamton, NY: Haworth Press, 2001. pp. 97–109.
Stevens, S.J., and Estrada, B. Substance involved women: Ethnic differences, contraceptive practices and HIV sex risk behaviors. Presented at the Society for Menstrual Cycle Research Biennial Conference, Tucson, AZ, June, 1999.
Stevens, S.J., and Murphy, B.S. Women's-Specific Health Assessment. Tucson, AZ: University of Arizona, Southwest Institute for Research on Women, 1998.
Stevens, S.J., and Patton, T. Residential treatment for drug addicted women and their children: Effective treatment strategies. In: Stevens, S.J., and Wexler, H.K., eds. Women and Substance Abuse: Gender Transparency. New York: Haworth Press, 1998a. pp. 235–249.
Stevens, S.J., and Patton, T. Residential treatment for drug addicted women and their children: Effective treatment strategies. Drugs & Society 13(1/2):235–249, 1998b.
Stevens, S.J., Estrada, A.L., and Estrada, B.D. HIV sex and drug risk behavior and behavior change in a national sample of injection drug and crack cocaine using women. Women & Health 27(1-2):25–48, 1998.9640633
Stewart, D.E. Menopause: A Mental Health Practitioner's Guide. 1st ed ed. Washington, DC: American Psychiatric Pub, 2005.
Stewart, S.H., Conrod, P.J., Samoluk, S.B., Pihl, R.O., and Dongier, M. Posttraumatic stress disorder symptoms and situation-specific drinking in women substance abusers. Alcoholism Treatment Quarterly 18(3):31–47, 2000.
Strantz, I.H., and Welch, S.P. Postpartum women in outpatient drug abuse treatment: Correlates of retention/completion. Journal of Psychoactive Drugs 27(4):357–373, 1995.8788692
Stratton, K., Howe, C., and Battaglia, F. (Eds.) Fetal Alcohol Syndrome: Diagnosis, Epidemiology, Prevention, and Treatment. Washington, DC: National Academy Press, 1996.
Stromwall, L.K., and Larson, N.C. Women's experience of co-occurring substance abuse and mental health conditions. Journal of Social Work Practice in the Addictions 4(1):81–96, 2004.
Substance Abuse and Mental Health Administration. Blueprint for change: Ending chronic homelessness for persons with serious mental illnesses and co-occurring substance use disorders. HHS Pub. No. SMA-04-3870 Rockville, MD: Center for Mental Health Services, Substance Abuse and Mental Health Services Administration, 2003a.
Substance Abuse and Mental Health Services Administration. Questions About Sexual Abuse. Women, Violence and Co-Occurring Disorders Grant. TI 98-004. Unpublished instrument, 2003b.
Substance Abuse and Mental Health Services Administration. Results from the 2003 National Survey on Drug Use and Health: National Findings. (Office of Applied Studies, NSDUH Series: H-25, HHS Publication No. SMA 04-3964). Rockville, MD, 2004.
Substance Abuse and Mental Health Services Administration. Recovery Community Services Program. Rockville, MD: Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services Administration, 2006a.
Substance Abuse and Mental Health Services Administration. Results from the 2005 National Survey on Drug Use and Health: National Findings. HHS Publication No. SMA 06-4194 Rockville, MD: Office of Applied Studies, 2006b.
Substance Abuse and Mental Health Services Administration. Results from the 2006 National Survey on Drug Use and Health: National Findings. HHS Publication No. SMA SMA 07-4293 Rockville, MD: Office of Applied Studies, 2007.
Substance Abuse and Mental Health Services Administration. Results from the 2007 National Survey on Drug Use and Health: National Findings. (Office of Applied Studies, NSDUH Series H-34, HHS Publication No.SMA 08-4343) 2008.
Substance Abuse and Mental Health Services Administration, and Office of Applied Studies. Treatment Episode Data Set (TEDS): 1992–2000. National Admissions to Substance Abuse Treatment Services. Drug and Alcohol Services Information System Series: S-17. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2002.
Substance Abuse and Mental Health Services Administration, and Office of Applied Studies. Overview of Findings from the 2002 National Survey on Drug Use and Health. (Office of Applied Studies, NHSDA Series H-21, HHS Publication No. SMA 03-3774). Rockville, MD: Substance Abuse and Mental Health Services Administration, 2003.
Substance Abuse and Mental Health Services Administration, and Office of Applied Studies. Table 4.11b. Facility services offered, by facility operation: March 31, 2003. National Survey of Substance Abuse Treatment Services (N-SSATS): 2003 Data on Substance Abuse Treatment Facilities Rockville, MD, 2004a.
Substance Abuse and Mental Health Services Administration and Office of Applied Studies. Treatment Episode Data Set (TEDS). Highlights – 2002. National Admissions to Substance Abuse Treatment Services, DASIS Series: S-22 HHS Publication No. (SMA) 04-3946 Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004b.
Substance Abuse and Mental Health Services Administration, Office of Applied Studies. Treatment Episode Data Set (TEDS): 1992-2002. National Admissions to Substance Abuse Treatment Services. HHS Publication No. (SMA) 04-3965 Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004c.
Substance Abuse and Mental Health Services Administration, Office of Applied Studies. The National Survey of Substance Abuse Treatment Services: 2003. The DASIS Report (March 11, 2005): Rockville, MD: Substance Abuse and Mental Health Services Administration 2005a.
Substance Abuse and Mental Health Services Administration, Office of Applied Studies. Treatment Episode Data Set (TEDS). Highlights - 2003. National Admissions to Substance Abuse Treatment Services, DASIS Series: S-27 HHS Publication No. (SMA) 05-4043 Rockville, MD: Substance Abuse and Mental Health Services Administration 2005b.
Substance Abuse and Mental Health Services Administration, Office of Applied Studies. National Survey of Substance Abuse Treatment Services (N-SSATS): 2005. Data on Substance Abuse Treatment Facilities. DASIS Series: S-34. HHS Publication No. (SMA) 06-4206. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2006.
Substance Abuse and Mental Health Services Administration and Office of Applied Studies. Gender differences in alcohol use and alcohol dependence or abuse: 2004 and 2005. The NSDUH Report April 2, 2007a.
Substance Abuse and Mental Health Services Administration, Office of Applied Studies. Hispanic female admissions in substance abuse treatment: 2005. The DASIS Report April 13 Rockville, MD, 2007b.
Substance Abuse and Mental Health Services Administration, Office of Applied Studies. Treatment Admissions with Medicaid as the Primary expected or Actual Payment source: 2005. The DASIS Report July 12 Rockville, MD: Substance Abuse and Mental Health Services Administration 2007c.
Substance Abuse and Mental Health Services Administration, Office of Applied Studies. Results from the 2007 National Survey on Drug Use and Health: National Findings. (Office of Applied Studies, NSDUH Series H-34, HHS Publication No. SMA 08-4343) Rockville, MD: Office of Applied Studies, 2008.
Suchman, N., Mayes, L., Conti, J., Slade, A., and Rounsaville, B. Rethinking parenting interventions for drug-dependent mothers: From behavior management to fostering emotional bonds. Journal of Substance Abuse Treatment 27(3):179–185, 2004.15501370
Suchman, N., Pajulo, M., DeCoste, C., and Mayes, L. Parenting interventions for drug-dependent mothers and their young children: The case for an attachment-based approach. Family Relations 55(2):211–226, 2006.17417669
Suchman, N.E., Rounsaville, B., DeCoste, C., and Luthar, S. Parental control, parental warmth, and psychosocial adjustment in a sample of substance-abusing mothers and their school-aged and adolescent children. Journal of Substance Abuse Treatment 32(1):1–10, 2007.17175393
Sue, D.W., and Sue, D. Counseling the Culturally Different: Theory and Practice. 3d ed. New York: John Wiley and Sons, 1999.
Sue, D.W., and Sue, D. Counseling the Culturally Diverse: Theory and Practice. 4th ed. New York: John Wiley and Sons, 2003.
Sullivan, E.V., Fama, R., Rosenbloom, M.J., and Pfefferbaum, A. A profile of neuropsychological deficits in alcoholic women. Neuropsychology 16(1):74–83, 2002.11853359
Sullivan, J.M., and Evans, K. Integrated treatment for the survivor of childhood trauma who is chemically dependent. Journal of Psychoactive Drugs 26(4):369–378, 1994.7884599
Sullivan, J.T., Sykora, K., Schneiderman, J., Naranjo, C.A., and Sellers, E.M. Assessment of alcohol withdrawal: The revised Clinical Institute Withdrawal Assessment for alcohol scale (CIWA-Ar). British Journal of Addiction 84(11):1353–1357, 1989.2597811
Sun, A.P. Helping substance-abusing mothers in the child-welfare system: Turning crisis into opportunity. Families in Society 81(2):142–151, 2000.
Sun, A.P. Program factors related to women's substance abuse treatment retention and other outcomes: A review and critique. Journal of Substance Abuse Treatment 30(1):1–20, 2006.16377448
Sun, A.P. Relapse among substance-abusing women: Components and processes. Substance Use and Misuse 42(1):1–21, 2007.17366123
Sussman, S. Smoking cessation among persons in recovery. Substance Use & Misuse 37(8–10):1275–1298, 2002.12180567
Swan, G.E., and Denk, C.E. Dynamic models for the maintenance of smoking cessation: event history analysis of late relapse. Journal of Behavioral Medicine 10(6):527–554, 1987.3437445
Swan, S., Farber, S., and Campbell, D. Violence in the lives of women in substance abuse treatment: Service and policy implications. Report to the New York State Office of the Prevention of Domestic Violence. Rensselear, NY: Author, 2000.
Sylvestre, D.L., and Zweben, J.E. Integrating HCV services for drug users: a model to improve engagement and outcomes. International Journal of Drug Policy 18(5):406–410, 2007.17854729
Szuster, R.R., Rich, L.L., Chung, A., and Bisconer, S.W. Treatment retention in women's residential chemical dependency treatment: The effect of admission with children. Substance Use and Misuse 31(8):1001–1013, 1996.8806165
Tafoya, T., and Roeder, K.R. Spiritual exiles in their own homelands: Gays, lesbians and Native Americans. Journal of Chemical Dependency Treatment 5(2):179–197, 1995.
Tatum, T. Rural women's recovery program and women's outreach: Serving rural Appalachian women and families in Ohio. In: Center for Substance Abuse Treatment, ed. Treating Alcohol and Other Drug Abusers in Rural and Frontier Areas. Technical Assistance Publication Series 17. HHS Publication No. (SMA) 99–3339. Rockville, MD: Center for Substance Abuse Treatment, 1995. pp. 13–20.
Taylor, T.R., Williams, C.D., Makambi, K.H., Mouton, C., Harrell, J.P., Cozier, Y., Palmer, J.R., Rosenberg, L., and dams-Campbell, L.L. Racial discrimination and breast cancer incidence in us black women: The black women's health study. American Journal of Epidemiology 166(1):46–54, 2007.17400570
Terner, J.M., and de Wit, H. Menstrual cycle phase and responses to drugs of abuse in humans. Drug and Alcohol Dependence 84(1):1–13, 2006.16413143
Testa, M., Livingston, J.A., and Leonard, K.E. Women's substance use and experiences of intimate partner violence: A longitudinal investigation among a community sample. Addictive Behaviors 28(9):1649–1664, 2003.14656551
Teusch, R. Substance-abusing women and sexual abuse. In: Straussner, S.L.A., and Zelvin, E., eds. Gender and Addictions: Men and Women in Treatment. Northvale, NJ: Jason Aronson, 1997. pp. 97–122.
Thaithumyanon, P., Limpongsanurak, S., Praisuwanna, P., and Punnahitanon, S. Perinatal effects of amphetamine and heroin use during pregnancy on the mother and infant. Journal of the Medical Association of Thailand 88(11):1506–1513, 2005.16471094
The C. Everett Koop Institute. High risk Groups - United States. Hepatitis C: An Epidemic for Anyone Hanover, NH: Dartmouth Medical School, 2008.
Theall, K.P., Sterk, C.E., and Elifson, K. Illicit drug use and women's sexual and reproductive health. In: Wingood, G.M., and DiClemente, R.J., eds. Handbook of Women's Sexual and Reproductive Health. New York, NY: Kluwer Academic/Plenum Publishers, 2002. pp. 129–152.
Thevos, A.K., Roberts, J.S., Thomas, S.E., and Randall, C.L. Cognitive behavioral therapy delays relapse in female socially phobic alcoholics. Addictive Behaviors 25(3):333–345, 2000.10890288
Thom, B. Sex differences in help-seeking for alcohol problems: I. The barriers to help-seeking. British Journal of Addiction 81(6):777–788, 1986.3467777
Thom, B. Sex differences in help-seeking for alcohol problems: II. Entry into treatment. British Journal of Addiction 82(9):989–997, 1987.3479184
Thomasson, H. Alcohol elimination: Faster in women? Alcoholism: Clinical and Experimental Research 24(4):419–420, 2000.
Thompson, R.S., Bonomi, A.E., Anderson, M., Reid, R.J., Dimer, J.A., Carrell, D., and Rivara, F.P. Intimate partner violence: prevalence, types, and chronicity in adult women. American Journal of Preventive Medicine 30(6):447–457, 2006.16704937
Thornberry, J., Bhaskar, B., Krulewitch, C.J., Wesley, B., Hubbard, M.L., Das, A., Foudin, L., and Adamson, M. Audio computerized self-report interview use in prenatal clinics: Audio computer-assisted self interview with touch screen to detect alcohol consumption in pregnant women. Application of a new technology to an old problem. Computers, Informatics, Nursing 20(2):46–52, 2002.
Thorpe, L.E., Frederick, M., Pitt, J., Cheng, I., Watts, D.H., Buschur, S., Green, K., Zorrilla, C., Landesman, S.H., and Hershow, R.C. Effect of hard-drug use on CD4 cell percentage, HIV RNA level, and progression to AIDS-defining class C events among HIV-infected women. Journal of Acquired Immune Deficiency Syndromes 37(3):1423–1430, 2004.15483472
Tiemersma, E.W., Wark, P.A., Ocke, M.C., Bunschoten, A., Otten, M.H., Kok, F.J., and Kampman, E. Alcohol Consumption, Alcohol Dehydrogenase 3 Polymorphism, and Colorectal Adenomas. Cancer Epidemiology Biomarkers Prevention 12(5):419–425, 2003.
Timko, C., Moos, R.H., Finney, J.W., and Connell, E.G. Gender differences in help-utilization and the 8-year course of alcohol abuse. Addiction 97(7):877–889, 2002.12133127
Timko, C., Sutkowi, A., Pavao, J., and Kimerling, R. Women's childhood and adult adverse experiences, mental health, and binge drinking: The California Women's Health Survey. Substance Abuse Treatment, Prevention and Policy 3(1):15, 2008.
Tjaden, P., and Thoennes, N. Prevalence, Incidence, and Consequences of Violence Against Women: Findings from the National Violence Against Women Survey. National Institute of Justice / Centers for Disease Control Prevention Research in Brief Washington, DC: National Institute of Justice, 1998.
Tjaden, P., and Thoennes, N. Extent, nature, and consequences of intimate partner violence. Findings From the National Violence Against Women Survey (July):NCJ 181867 Washington, D.C.: U.S. Department of Justice, 2000.
Tjaden, P., and Thoennes, N. Extent, nature, and consequences of rape victimization: Findings from the National Violence Against Women Survey. Findings From the National Violence Against Women Survey Washington, DC: U.S. Department of Justice, National Institute of Justice, 2006.
Tolin, D.F., and Foa, E.B. Sex differences in trauma and posttraumatic stress disorder: A quantitative review of 25 years of research. Psychological Bulletin 132(6):959–992, 2006.17073529
Tolstrup, J.S., Kjaer, S.K., Holst, C., Sharif, H., Munk, C., Osler, M., Schmidt, L., Andersen, A.M., and Gronbaek, M. Alcohol use as predictor for infertility in a representative population of Danish women. Acta Obstetricia Et Gynecologica Scandinavica 82(8):744–749, 2003.12848646
Tonigan, J.S., and Miller, W.R. The inventory of drug use consequences (InDUC): test-retest stability and sensitivity to detect change. Psychology of Addictive Behaviors 16(2):165–168, 2002.12079257
Torabi, M.R., Bailey, W.J., and Majd-Jabbari, M. Cigarette smoking as a predictor of alcohol and other drug use by children and adolescents: Evidence of the “gateway drug effect.” Journal of School Health 63(7):302–306, 1993.
Torsch, V.L., and Xueqin Ma, G. Cross-cultural comparison of health perceptions, concerns, and coping strategies among Asian and Pacific Islander American elders. Qualitative Health Research 10(4):471–489, 2000.11010073
Tough, S., Tofflemire, K., Clarke, M., and Newburn-Cook, C. Do women change their drinking behaviors while trying to conceive? An opportunity for preconception counseling. Clinical Medicine and Research 4(2):97–105, 2006.16809401
Tourangeau, R., and Smith, T.W. Asking sensitive questions: The impact of data collection mode, question format, and question context. Public Opinion Quarterly 60(2):275–304, 1996.
Towle, L.H. Japanese-American drinking: Some results from the Joint Japanese-U.S. Alcohol Epidemiology Project. Alcohol Health and Research World 12(3):216–223, 1988.
Tracy, E.M., and Martin, T.C. Children's roles in the social networks of women in substance abuse treatment. Journal of Substance Abuse Treatment 32(1):81–88, 2007.17175401
Trepper, T.S., McCollum, E.E., Dankoski, M.E., Davis, S.K., and LaFazia, M.A. Couples therapy for drug abusing women in an inpatient setting: A pilot study. Contemporary Family Therapy 22(2):201–221, 2000.
Triffleman, E. Gender differences in a controlled pilot study of psychosocial treatment in substance dependent patients with posttraumatic stress disorder: Design considerations and outcomes. Alcoholism Treatment Quarterly 18(3):113–126, 2000.
Triffleman, E. Issues in implementing posttraumatic stress disorder treatment outcome research in community-based treatment programs. In: Sorensen, J.L., Rawson, R.A., Guydish, J., and Zweben, J.E., eds. Drug Abuse Treatment Through Collaboration: Practice and Research Partnerships that Work. 1-55798-985-0 (hardcover). American Psychological Association: Washington, 2003. pp. 227–247.
Trimble, J.E., and Jumper Thurman, P. Ethnocultural considerations and strategies for providing counseling services to Native American Indians. In: Pedersen, P.B., Draguns, J.G., Lonner, W.J., and Trimble, J.E., eds. Counseling Across Cultures. Thousand Oaks, CA: Sage, 2002. pp. 53–91.
Tronick, E.Z., and Beeghly, M. Prenatal cocaine exposure, child development, and the compromising effects of cumulative risk. Clinics in Perinatology 26(1):151–171, 1999.10214547
Tuten, M., and Jones, H.E. A partner's drug-using status impacts women's drug treatment outcome. Drug and Alcohol Dependence 70(3):327–330, 2003.12757970
Tuten, M., Jones, H.E., Tran, G., and Svikis, D.S. Partner violence impacts the psychosocial and psychiatric status of pregnant, drug-dependent women. Addictive Behaviors 29(5):1029–1034, 2004.15219353
Ullman, S.E., Filipas, H.H., Townsend, S.M., and Starzynski, L.L. Trauma exposure, posttraumatic stress disorder and problem drinking in sexual assault survivors. Journal of Studies on Alcohol 66(5):610–619, 2005.16331846
Underhill, B.L., and Ostermann, S.E. The pain of invisibility: Issues for lesbians. In: Roth, P., ed. Alcohol and Drugs Are Women's Issues: Vol. 1. A Review of the Issues. Metuchen, NJ: Scarecrow Press, 1991. pp. 71–77.
United Nations General Assembly. Declaration on the Elimination of Violence Against Women. A/RES/48/104 New York: United Nations, 1993.
Urbano-Marquez, A., Estruch, R., Fernandez-Sola, J., Nicolas, J.M., Pare, J.C., and Rubin, E. The greater risk of alcoholic cardiomyopathy and myopathy in women compared with men. Journal of the American Medical Association 274(2):149–154, 1995.7596003
U.S. Census Bureau. Census Bureau Projects Doubling of Nation's Population by 2100. Washington, DC: U.S. Census Bureau, 2000a.
U.S. Census Bureau. Projections of the Total Resident Population by 5-Year Age Groups, Race, and Hispanic Origin, with Special Age Categories: Middle Series, 2050 to 2070. Washington, DC: U.S. Census Bureau, 2000b.
U.S. Census Bureau. Census 2000 PHC-T-10: Hispanic or Latino Origin for the United States, Regions, Divisions, States, and for Puerto Rico. Washington, DC: U.S. Census Bureau, 2001a.
U.S. Census Bureau. Profile of General Demographic Characteristics for the United States: 2000. Washington, DC: U.S. Census Bureau, 2001b.
U.S. Census Bureau. Statistical Abstract of the United States, 2001: The National Data Book. Washington, DC: U.S. Census Bureau, 2001c.
U.S. Census Bureau. Table 1: Male-female ratio by race alone or in combination and Hispanic or Latino origin for the United States. 2000. Washington, DC: U.S. Census Bureau, 2001d.
U.S. Census Bureau. Table 1: Population by race and Hispanic or Latino origin, for all ages and for 18 years and over, for the United States. 2000. Washington, DC: U.S. Census Bureau, 2001e.
U.S. Census Bureau. Table 2: Percent of population by race and Hispanic or Latino origin, for the United States, Regions, divisions, and states, and for Puerto Rico. 2000. Washington, DC: U.S. Census Bureau, 2001f.
U.S. Census Bureau. Table 4: Difference in population by race and Hispanic or Latino origin, for the United States. 1990 to 2000. Census 2000: PHC-T-1 Washington, DC: U.S. Census Bureau, 2001g.
U.S. Census Bureau. DP-2: Profile of selected social characteristics. 2000. Census 2000 Summary File 3 (SF-3) Sample data. United States. Washington, DC: U.S. Census Bureau, 2002.
U.S. Census Bureau. Table 8. Foreign-born population by sex, citizenship status, and year of entry, for Asian alone and White alone, not Hispanic: March 2004. Current Population Survey, 2004 2004.
U.S. Census Bureau. The American Community—Asians: 2004. U.S. Department of Commerce, U.S. Census Bureau 2007a.
U.S. Census Bureau. The American Community—Hispanics: 2004. American Community Survey Reports Washington, DC: U.S. Census Bureau, 2007b.
U.S. Census Bureau. U.S. Hispanic Population Surpasses 45 Million Now 15 Percent of Total. U.S. Census Bureau News May 1, 2008 Washington, DC: U.S. Census Bureau, 2008.
U.S. Department of Agriculture, Economic Research Service. Rural population and migration. ERS/USDA Briefing Room Washington, DC: U.S. Department of Agriculture, 2007.
U.S. Department of Health and Human Services. Center for Substance Abuse Treatment comprehensive treatment model for alcohol and other drug abusing women and their children. Blending Perspectives and Building Common Ground: A Report to Congress on Substance Abuse and Child Protection: Appendix B. Washington, D.C.: U.S. Government Printing Office, 1999.
U.S. Department of Health and Human Services - Office on Women's Health. Eating Disorders. Washington, DC, 2000.
U.S. Department of Health and Human Services - Office for Civil Rights. Standards of Privacy for Individually Identifiable Health Information: Unofficial Version, 45 CFR Parts 160 and 164. Washington, DC: U.S. Department of Health and Human Services, Office for Civil Rights, 2002.
U.S. Department of Health and Human Services, Substance Abuse and Mental Health Services Administration, Office of Applied Studies, and Prepared by Synetics for Management Decisions Incorporated. Treatment Episode Data Set (TEDS), 2006. Ann Arbor, MI: Consortium for Political and Social Research, 2008a.
U.S. Department of Health and Human Services, Substance Abuse and Mental Health Services Administration, and Office of Applied Studies. Treatment Episode Data Set (TEDS), 2006 [Computer file]. Prepared by Synectics for Management Decisions, Incorporated. ICPSR21540-V2 Ann Arbor, MI: Inter-university Consortium for Political and Social Research [producer and distributor], 2008-05-07, 2008b.
U.S. Department of Health and Human Services, and Office of Women's Health. Depression during and after pregnancy, 2009. http://www.womenshealth.gov/faq/depres
U.S. Department of Health and Human Services, National Institute on Drug Abuse, and Center for Substance Abuse Treatment. DRAFT—CSAT's Comprehensive Substance Abuse Treatment Model for Women and Their Children. Unpublished manuscript.
U.S. Department of Housing and Urban Development. The annual homeless assessment report to Congress. Washington, DC: U.S. Department of Housing and Urban Development, 2007.
U.S. Department of Housing and Urban Development. The second annual homeless assessment report to Congress. Washington, DC: Office of Community Planning and Development, 2008.
U.S. Department of Labor. Women in the Labor Force: A Databook. 2006. Available on-line: http://www.bls.gov/cps/wlf-databook-2006.pdf
U.S. Preventive Services Task Force. Screening for depression: Recommendations and rationale. Annals of Internal Medicine 136(10):760–764, 2002.12020145
van der Kolk, B.A., McFarlane, A.C., and Van der Hart, O. A general approach to treatment of posttraumatic stress disorder. In: van der Kolk, B.A., McFarlane, A.C., and Weisaeth, L., eds. Traumatic Stress: The Effects of Overwhelming Experience on Mind, Body, and Society. New York: Guilford Press, 1996. pp. 417–440.
van Etten, M.L., and Anthony, J.C. Male–female differences in transitions from first drug opportunity to first use: Searching for subgroup variation by age, race, region, and urban status. Journal of Women's Health & Gender-Based Medicine 10(8):797–804, 2001.
van Etten, M.L., and Neumark, Y.D. Male-female differences in the earliest stages of drug involvement. Addiction 94(9):1413–1419, 1999.10615725
Van Gundy, K. Substance abuse in rural and small town America. Reports on Rural America Volume 1, Number 2 Durham, New Hampshire: Carsey Institute, 2006.
Van Thiel, D.H., Gavaler, J.S., Rosenblum, E., and Tarter, R.E. Ethanol, its metabolism and hepatotoxicity as well as its gonadal effects: Effects of sex. Pharmacology and Therapeutics 41(1-2):27–48, 1989.2652152
van Wormer, K., and Askew, E. Substance-abusing women and eating disorders. In: Straussner, S.L.A., and Zelvin, E., eds. Gender and Addictions: Men and Women in Treatment. Northvale, NJ: Jason Aronson, 1997. pp. 243–262.
VanDeMark, N.R., Russell, L.A., O'Keefe, M., Finkelstein, N., Noether, C.D., and Gampel, J.C. Children of mothers with histories of substance abuse, mental illness, and trauma. Journal of Community Psychology 33(4):445–459, 2005.
Vannicelli, M. Treatment outcome of alcoholic women: The state of the art in relation to sex bias and expectancy effects. In: Wilsnack, S.C., and Beckman, L., eds. Alcohol Problems in Women: Antecedents, Consequences, and Intervention. New York: Guilford, 1984. pp. 369–412.
VanZile-Tamsen, C., Testa, M., Harlow, L.L., and Livingston, J.A. A measurement model of women's behavioral risk taking. Health Psychology 25(2):249–254, 2006.16569118
Varan, L.R., Gillieson, M.S., Skene, D.S., and Sarwer-Foner, G.J. ECT in an acutely psychotic pregnant woman with actively aggressive (homicidal) impulses. Canadian Journal of Psychiatry 30(5):363–367, 1985.4027861
Vega, W.A., Alderete, E., Kolody, B., and Aguilar-Gaxiola, S. Illicit drug use among Mexicans and Mexican Americans in California: The effects of gender and acculturation. Addiction 93(12):1839–1850, 1998.9926572
Vega, W.A., Sribney, W.M., and Achara-Abrahams, I. Co-Occurring alcohol, drug and other psychiatric disorders among Mexican-Origin people in the United States. American Journal of Public Health 93(7):1057–1064, 2003.12835179
Velez, M.L., Jansson, L.M., Montoya, I.D., Schweitzer, W., Golden, A., and Svikis, D. Parenting knowledge among substance abusing women in treatment. Journal of Substance Abuse Treatment 27(3):215–222, 2004.15501374
Velez, M.L., Montoya, I.D., Jansson, L.M., Walters, V., Svikis, D., Jones, H.E., Chilcoat, H., and Campbell, J. Exposure to violence among substance-dependent pregnant women and their children. Journal of Substance Abuse Treatment 30(1):31–38, 2006.16377450
Vernon, I., and Jumper Thurman, P. The changing face of HIV/AIDS among native populations. Journal of Psychoactive Drugs 37(3):247–255, 2005.16295007
Vernon, I.S. American Indian women, HIV/AIDS, and health disparity. Substance Use & Misuse 42(4):741–752, 2007.17558961
Visscher, W.A., Feder, M., Burns, A.M., Brady, T.M., and Bray, R.M. The impact of smoking and other substance use by urban women on the birthweight of their infants. Substance Use & Misuse 38(8):1063–1093, 2003.12901449
Vogel, L.C., and Marshall, L.L. PTSD symptoms and partner abuse: low income women at risk. Journal of Traumatic Stress 14(3):569–584, 2001.11534886
Volk, R.J., Steinbauer, J.R., and Cantor, SB. Patient factors influencing variation in the use of preventive interventions for alcohol abuse by primary care physicians. Journal of Studies on Alcohol 57(2):203–209, 1996.8683970
Volkman, S. Music therapy and the treatment of trauma-induced dissociative disorders. Arts in Psychotherapy 20(3):243–251, 1993.
Volpicelli, J.R., Markman, I., Monterosso, J., Filing, J., and O'Brien, C.P. Psychosocially enhanced treatment for cocaine-dependent mothers: Evidence of efficacy. Journal of Substance Abuse Treatment 18(1):41–49, 2000.10636605
Wagner, C.L., Katikaneni, L.D., Cox, T.H., and Ryan, R.M. The impact of prenatal drug exposure on the neonate. Obstetrics and Gynecology Clinics of North America 25(1):169–194, 1998.9547766
Wakabayashi, C., and Donato, K.M. Does caregiving increase poverty among women in later life? Evidence from the health and retirement survey. Journal of Health and Social Behavior 47(3):258–274, 2006.17066776
Wakschlag, L.S., Leventhal, B.L., Pine, D.S., Pickett, K.E., and Carter, A.S. Elucidating early mechanisms of developmental psychopathology: the case of prenatal smoking and disruptive behavior. Child Development 77(4):893–906, 2006.16942496
Wakschlag, L.S., Pickett, K.E., Cook, E Jr, Benowitz, N.L., and Leventhal, B.L. Maternal smoking during pregnancy and severe antisocial behavior in offspring: a review. American Journal of Public Health 92(6):966–974, 2002.12036791
Walitzer, K.S., and Dearing, R.L. Gender differences in alcohol and substance use relapse. Clinical Psychology Review 26(2):128–148, 2006.16412541
Wallace, B.C. Crack cocaine smokers as adult children of alcoholics: The dysfunctional family link. Journal of Substance Abuse Treatment 7(2):89–100, 1990.2388314
Walton-Moss, B., and McCaul, M.E. Factors associated with lifetime history of drug treatment among substance dependent women. Addictive Behaviors 31(2):246–253, 2006.15979246
Wampold, B.E. The Great Psychotherapy Debate: Models, Methods, and Findings. Mahwah, NJ: Lawrence Erlbaum Associates, Publishers, 2001.
Wang, J., and Patten, S.B. Prospective study of frequent heavy alcohol use and the risk of major depression in the Canadian general population. Depression and Anxiety 15(1):42–45, 2002.11816052
Warren, M., Frost-Pineda, K., and Gold, M. Body mass index and marijuana use. Journal of Addictive Diseases 24(3):95–100, 2005.16186086
Washington, O.G., and Moxley, D.P. Group interventions with low-income African American women recovering from chemical dependency. Health and Social Work 28(2):146–156, 2003.12774536
Waterson, E.J., and Murray-Lyon, I.M. Are the CAGE question outdated? British Journal of Addiction 83(9):1113–1115, 1988.3224192
Waxman, B.F. Hatred: The unacknowledged dimension in violence against disabled people. Sexuality and Disability 9(3):185–199, 1991.
Wayment, H.A., and Peplau, L.A. Social support and well-being among lesbian and heterosexual women: A structural modeling approach. Personality & Social Psychology Bulletin 21(11):1189–1199, 1995.
Weathers, F.W., Litz, B.T., Herman, D.S., Huska, J.A., and Keane, T.M. The PTSD Checklist: Reliability, Validity, & Diagnostic Utility. Paper presented at the Annual Meeting of the International Society for Traumatic Stress Studies, San Antonio, TX, October. 1993.
Weatherspoon, A.J., Park, J.Y., and Johnson, R.C. A family study of homeland Korean alcohol use. Addictive Behaviors 26(1):101–113, 2001.11196283
Webster, J., Linnane, J.W., Dibley, L.M., and Pritchard, M. Improving antenatal recognition of women at risk for postnatal depression. Australian and New Zealand Journal of Obstetrics and Gynaecology 40(4):409–412, 2000.11194425
Wechsberg, W.M., Zule, W.A., Riehman, K.S., Luseno, W.K., and Lam, W.K. African-American crack abusers and drug treatment initiation: Barriers and effects of a pretreatment intervention. Substance Abuse Treatment, Prevention and Policy 2:10, 2007.
Weiderpass, E., Ye, W., Tamimi, R., Trichopolous, D., Nyren, O., Vainio, H., and Adami, H.O. Alcoholism and risk for cancer of the cervix uteri, vagina, and vulva. Cancer Epidemiology, Biomarkers and Prevention 10(8):899–901, 2001.
Weir, B.W., Stark, M.J., Fleming, D.W., He, H., and Tesselaar, H. Revealing drug use to prenatal providers: Who tells or who is asked? In: Stevens, S.J., and Wexler, H.K., eds. Women and Substance Abuse: Gender Transparency. New York: Haworth Press, 1998. pp. 161–176.
Weisner, C., Delucchi, K., Matzger, H., and Schmidt, L. The role of community services and informal support on five-year drinking trajectories of alcohol dependent and problem drinkers. Journal of Studies on Alcohol 64(6):862–873, 2003a.14743951
Weisner, C., Matzger, H., and Kaskutas, L.A. How important is treatment? One-year outcomes of treated and untreated alcohol-dependent individuals. Addiction 98(7):901–911, 2003b.12814496
Weisner, C., Mertens, J., Tam, T., and Moore, C. Factors affecting the initiation of substance abuse treatment in managed care. Addiction 96(5):705–716, 2001.11331029
Weiss, R.D., Martinez-Raga, J., Griffin, M.L., Greenfield, S.F., and Hufford, C. Gender differences in cocaine dependent patients: A 6 month follow-up study. Drug and Alcohol Dependence 44(1):35–40, 1997.9031818
Welch, S.S. A review of the literature on the epidemiology of parasuicide in the general population. Psychiatric Services 52(3):368–375, 2001.11239107
Welle, D., Falkin, G.P., and Jainchill, N. Current approaches to drug treatment for women offenders: Project WORTH, Women's Options for Recovery, Treatment, and Health. Journal of Substance Abuse Treatment 15(2):151–163, 1998.9561955
Wellisch, J., Prendergast, M.L., and Anglin, M.D. Needs assessment and services for drug-abusing women offenders: Results from a national survey of community-based treatment programs. Women and Criminal Justice 8(1):27–60, 1996.
West, C., and Zimmerman, D.H. Doing gender. Gender and Society 1:125–151, 1987.
Wetter, D.W., Fiore, M.C., Jorenby, D.E., Kenford, S.L., Smith, S.S., and Baker, T.B. Gender differences in smoking cessation. Journal of Consulting and Clinical Psychology 67(4):555–562, 1999.10450626
Wexler, H.K., Cuadrado, M., and Stevens, S.J. Residential treatment for women: Behavioral and psychological outcomes. In: Stevens, S.J., and Wexler, H.K., eds. Women and Substance Abuse: Gender Transparency. New York: Haworth Press, 1998. pp. 213–233.
White, W.L. Recovery across the life cycle from alcohol/other drug problems: Pathways, styles, developmental stages. Alcoholism Treatment Quarterly 24(1–2):185–201, 2006.
White, W.L., and Whiters, D.L. Faith-based recovery: Its historical roots. Counselor Magazine 6(5):58–62, 2005.
Wilcox, S., Evenson, K.R., Aragaki, A., Wassertheil-Smoller, S., Mouton, C.P., and Loevinger, B.L. The effects of widowhood on physical and mental health, health behaviors, and health outcomes: The Women's Health Initiative. Health Psychology 22(5):513–522, 2003.14570535
Wilkins, A. Substance Abuse and TANF. Welfare Reform: 1–12. Denver, CO: National Conference of State Legislators 2003.
Williams, D.R. Race and health: Basic questions, emerging directions. Annals of Epidemiology 7(5):322–333, 1997.9250627
Williams, D. R. Racial/ethnic variations in women's health: the social embeddedness of health. American Journal of Public Health, 92, 588–597, 2002.11919058
Wilsnack, R.W., and Cheloha, R. Women's roles and problem drinking across the lifespan. Social Problems 34(3):231–248, 1987.
Wilsnack, R.W., Wilsnack, S.C., Kristjanson, A.F., and Harris, T.B. Ten-year prediction of women's drinking behavior in a nationally representative sample. Women's Health 4(3):199–230, 1998a.9787649
Wilsnack, R.W., Wilsnack, S.C., Kristjanson, A.F., Harris, T.R., and Vogeltanz, N.D. “Drinking in couples: How is partners' consumption connected?” Paper presented at the Annual Scientific Meeting of the Research Society on Alcoholism, Hilton Head, SC, June, 1998b.
Wilsnack, S.C. Barriers to treatment for alcoholic women. Addiction and Recovery 11(4):10–12, 1991.
Wilson, D.J. Drug Use, Testing, and Treatment in Jails. Washington, DC: Bureau of Justice Statistics 2000.
Wilt, S., and Olson, S. Prevalence of domestic violence in the United States. Journal of the American Medical Women's Association 51(3):77–82, 1996.
Winhusen, T., Kropp, F., Babcock, D., Hague, D., Erickson, S.J., Renz, C., Rau, L., Lewis, D., Leimberger, J., and Somoza, E. Motivational enhancement therapy to improve treatment utilization and outcome in pregnant substance users. Journal of Substance Abuse Treatment 2007.
Winslow, B.T., Voorhees, K.I., and Pehl, K.A. Methamphetamine abuse. American Family Physician 76(8):1169–1174, 2007.17990840
Winters, J., Fals-Stewart, W., O'Farrell, T.J., Birchler, G.R., and Kelley, M.L. Behavioral couples therapy for female substance-abusing patients: Effects on substance use and relationship adjustment. Journal of Consulting and Clinical Psychology 70(2):344–355, 2002.11952192
Wise, L., and Correia, A. A review of nonpharmacologic and pharmacologic therapies for smoking cessation. (cover story). Formulary 43(2):44–64, 2008.
Wobie, K., Eyler, F.D., Conlon, M., Clarke, L., and Behnke, M. Women and children in residential treatment: Outcomes for mothers and their infants. Journal of Drug Issues 27(3):585–606, 1997.
Wolpe, J. The practice of behavior therapy. 1st ed. ed. New York: Pergamon Press, 1969.
Wright, N.M., Tompkins, C.N., and Sheard, L. Is peer injecting a form of intimate partner abuse? A qualitative study of the experiences of women drug users. Health & Social Care in the Community 15(5):417–425, 2007.17685987
Young, A.M., and Boyd, C. Sexual trauma, substance abuse, and treatment success in a sample of African American women who smoke crack cocaine. Substance Abuse 21(1):9–19, 2000.12466644
Young, N.K., and Gardner, S.L. Implementing Welfare Reform: Solutions to the Substance Abuse Problem. Irvine, CA: Children and Family Futures, 1997.
Young, N.K., Gardner, S.L., and Dennis, K. Responding to Alcohol and Other Drug Problems in Child Welfare: Weaving Together Practice and Policy. Washington, DC: Child Welfare League of America, 1998.
Young, R.M., Friedman, S.R., and Case, P. Exploring an HIV paradox: an ethnography of sexual minority women injectors. Journal of Lesbian Studies. 9(3):103–116, 2005.17548289
Zambrana, R.E., Ell, K., Dorrington, C., Wachsman, L., and Hodge, D. The relationship between psychosocial status of immigrant Latino mothers and use of emergency pediatric services. Health and Social Work 19(2):93–102, 1994.8045452
Zanis, D.A., McLellan, A.T., Cnaan, R.A., and Randall, M. Reliability and validity of the Addiction Severity Index with a homeless sample. Journal of Substance Abuse Treatment 11(6):541–548, 1994.7884837
Zerbe, K.J. The Body Betrayed: Women, Eating Disorders, and Treatment. Washington, DC: American Psychiatric Press, 1993.
Zhang, S.M., Lee, I.M., Manson, J.E., Cook, N.R., Willett, W.C., and Buring, J.E. Alcohol consumption and breast cancer risk in the Women's Health Study. American Journal of Epidemiology 165(6):667–676, 2007.17204515
Zilberman, M.L., Tavares, H., Andrade, A.G., and el-Guebaly, N. The impact of an outpatient program for women with substance use-related disorders on retention. Substance Use and Misuse 38(14):2109–2124, 2003.14677784
Zilm, D.H., and Sellers, E.M. The quantitative assessment of physical dependence on opiates. Drug and Alcohol Dependence 3(6):419–428, 1978.720211
Zlotnick, C., Franchino, K., St Claire, N., Cox, K., and St John, M. The impact of outpatient drug services on abstinence among pregnant and parenting women. Journal of Substance Abuse Treatment 13(3):195–202, 1996.9017561
Zlotnick, C., Najavits, L.M., Rohsenow, D.J., and Johnson, D.M. A cognitive–behavioral treatment for incarcerated women with substance abuse disorder and posttraumatic stress disorder: findings from a pilot study. Journal of Substance Abuse Treatment 25(2):99–105, 2003.14629992
Zolopa, A.R., Hahn, J.A., Gorter, R., Miranda, J., Wlodarczyk, D., Peterson, J., Pilote, L., and Moss, A.R. HIV and tuberculosis infection in San Francisco's homeless adults. Prevalence and risk factors in a representative sample. JAMA: The Journal of the American Medical Association 272(6):455–461, 1994.8040981
Zuckerman, B., Frank, D., and Brown, E. Overview of the effects of abuse and drugs on pregnancy and offspring. In: Chiang, C.N., and Finnegan, L.P., eds. Medications Development for the Treatment of Pregnant Addicts and Their Infants. NIDA Research Monograph 149. NIH Publication No. 95–3891. Rockville, MD: National Institute on Drug Abuse, 1995. pp. 16–38.
Zule, W.A., Flannery, B.A., Wechsberg, W.M., and Lam, W.K. Alcohol use among out-of-treatment crack using African-American women. American Journal of Drug & Alcohol Abuse 28(3):525, 2002.
Zule, W.A., Lam, W.K., and Wechsberg, W.M. Treatment readiness among out-of-treatment African-American crack users. Journal of Psychoactive Drugs 35(4):503–510, 2003.14986880
Zweben, J.E. Psychiatric problems among alcohol and other drug dependent women. Journal of Psychoactive Drugs 28(4):345–366, 1996.9017556
Zywiak, W.H., Stout, R.L., Trefry, W.B., Glasser, I., Connors, G.J., Maisto, S.A., and Westerberg, V.S. Alcohol relapse repetition, gender, and predictive validity. Journal of Substance Abuse Treatment 30(4):349–353, 2006.16716850