# Appendix I: Field Reviewers

Sharon K. Amatetti, M.P.H.
Sr. Public Health Analyst
Office of Program Analysis and Coordination
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Duiona R. Baker, M.P.H.
Associate Administrator for Women's Services
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Peggy Bean
Analyst
Perinatal Substance Abuse
California Department of Alcohol and Drug Programs
Sacramento, California

Faye Belgrave, Ph.D.
Professor of Psychology
Department of Psychology
Virginia Commonwealth University
Richmond, Virginia

Mary R. Boyd, Ph.D., R.N.
Associate Professor
College of Nursing
University of South Carolina
Columbia, South Carolina

Suzette E. Brann, J.D., M.B.A.
President
Unlimited Horizons, LLC
Port Tobacco, Maryland

Catherine J. Brow
Specialized Female Services Coordinator
Commission on Alcohol and Drug Abuse
Austin, Texas

Jutta H. Butler, B.S.N., M.S.
Public Health Advisor
Practice Improvement Branch
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Donna L. Caldwell, Ph.D.
Director of Evaluation and Research
National Perinatal Information Center
Providence, Rhode Island

Sherry Dyche Ceperich
Assistant Professor
Division of Addiction Psychiatry
Virginia Commonwealth University
Richmond, Virginia

Redonna K. Chandler, Ph.D.
Health Scientist Administrator
Services Research Branch
Division of Epidemiology, Services, and Prevention Research
National Institute on Drug Abuse
Bethesda, Maryland

Charlotte Chapman, M.S., LPC, CAC
Training Director
Division of Addiction Psychiatry
Mid-Atlantic Addiction Technology Transfer Center
Virginia Commonwealth University
Richmond, Virginia

Kaye Chavis
Treatment Consultant
Public Health Programs Director
Bureau of Alcohol and Drug Abuse Services
Tennessee Department of Health
Nashville, Tennessee

Stephanie S. Covington, Ph.D., LCSW
Co-Director
Center for Gender and Justice
Institute for Relational Development
La Jolla, California

Margaret A. Cramer, Ph.D.
Clinical Psychologist/Instructor
Harvard Medical School
Boston, Massachusetts

A. Rebecca Crowell, LCDC, LPC
Executive Director
Nexus Recovery Center
Dallas, Texas

Carol S. D'Agostino, C.S.W., CASAC
Director
Geriatric Addictions Program
LIFESPAN of Greater Rochester, Inc.
Rochester, New York

Sharon DeEsch, M.A., MAC, LCDC
Genesis Counseling Associates, P.C.
Dallas, Texas

Herman Diesenhaus
Social Science Analyst
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Marlene EchoHawk, Ph.D.
Health Science Administrator
Division of Behavioral Health
Indian Health Service
Rockville, Maryland

Darcy Edwards, Ph.D., M.S.W., CADC I
Alcohol and Drug/HIV Services Manager
Counseling and Treatment Services
Oregon Department of Corrections
Salem, Oregon

Saul Feldman, Ph.D.
Chairman & C.E.O.
United Behavioral Health
San Francisco, California

Nancy Ferreyra
Executive Director
Pacific Research and Training Alliance
Berkeley, California

Norma B. Finkelstein, Ph.D., M.S.W.
Executive Director
Institute for Health & Recovery
Cambridge, Massachusetts

Jo Ann Ford, M.A.
Assistant Director
Substance Abuse Resources and Disability
Issues School of Medicine
Wright State University

Dayton, Ohio
Joanne Gampel
Social Science Analyst
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Mary M. Gillespie, Psy.D., CASAC
Psychologist
Hudson Valley Community College
Private Practice
Saratoga Springs, New York

Jennifer Glover, M.S., LPC
Programs Field Representative
Oklahoma Department of Mental Health and Substance Abuse Services
Oklahoma City, Oklahoma

Valerie A. Gruber, Ph.D., M.P.H.
Assistant Clinical Professor
University of California
Senior Psychologist Division of Substance Abuse and Addiction Medicine
San Francisco General Hospital
San Francisco, California

Joanne M. Hall, Ph.D., R.N.
Associate Professor
College of Nursing
University of Tennessee
Knoxville, Tennessee

Deborah Hollis, M.A.
Director
Division of Substance Abuse Quality and Planning
Michigan Department of Community Health
Lansing, Michigan

Kathryn S. Icenhower, Ph.D., LCSW
Executive Director
SHIELDS for Families Project, Inc.
Los Angeles, California

Lauren Jansson, M.D.
Director of Pediatrics
Center for Addiction and Pregnancy
Johns Hopkins Bayview Medical Center
Baltimore, Maryland

Hendree E. Jones, Ph.D.
Assistant Professor
CAP Research Director
Department of Psychiatry and Behavioral Sciences
Johns Hopkins University Center
Baltimore, Maryland

Karol A. Kaltenbach, Ph.D.
Clinical Associate Professor of Pediatrics, Psychiatry and Human Behavior
Director, Maternal Addiction Treatment Education and Research
Department of Pediatrics
Jefferson Medical College
Thomas Jefferson University
Philadelphia, Pennsylvania

George Kanuck, D.N.Sc.
Public Health Analyst
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Cheryl Ann Kennedy, M.S.W.
Assistant Director
Institute for Health & Recovery
Cambridge, Massachusetts

Nancy Kennedy, Dr.P.H.
Scientific Advisor to the Director
Center for Substance Abuse Prevention
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Mary V. Ker, Ph.D.
Executive Director
Optimal Research and Evaluation
Tucson, Arizona

Michael Warren Kirby, Jr., Ph.D., M.A., CAC III
Chief Executive Officer
Arapahoe House, Inc.
Thornton, Colorado

Danica Kalling Knight, Ph.D.
Research Scientist
Institute of Behavioral Research
Texas Christian University
Fort Worth, Texas

Hillary Kunins, M.D., M.P.H.
Medical Director, HUB II Clinic Program Coordinator
Division of Substance Abuse
Albert Einstein College of Medicine
Bronx, New York

Carol L. Kuprevich, M.A.
Training Education Administrator
Division of Alcoholism, Drug Abuse and Mental Health
Delaware Health and Social Services
New Castle, Delaware

Martha Kurgans, M.A.
Women's Services Program Specialist
Virginia Department of Mental Health, Mental Retardation and Substance Abuse Services
Richmond, Virginia

Linda Christina Latta, Ph.D.
Women's Treatment Coordinator
Chemical Dependency Bureau
Montana State Department of Public Health and Human Services
Helena, Montana

Kayla Mary Leopold, LCSW
Site Manager
New Directions Family Treatment Center
CODA, Inc.
Portland, Oregon

Helen J. Levine, Ph.D.
Senior Research Scientist
JSI Research and Training
Boston, Massachusetts

Kimberly A. Lucas
Treatment Specialist
Women's Treatment Coordinator
Delaware Division of Substance Abuse and Mental Health
New Castle, Delaware

Ruby J. Martinez, Ph.D., R.N., CS
Assistant Professor
School of Nursing
University of Colorado
Denver, Colorado

Kathleen B. Masis, M.D.
Medical Officer for Behavioral Health
Billings Area Indian Health Service
Billings, Montana

Lisa A. Melchior, Ph.D.
Vice President
The Measurement Group, LLC
Culver City, California

Juana Mora, Ph.D.
Professor
Northridge Chicano/a Studies Department
California State University
Northridge, California

Ruby Neville
Public Health Advisor
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Joanne Nicholson, Ph.D.
Associate Professor
Psychiatry and Family Medicine
University of Massachusetts Medical School
Worcester, Massachusetts

Nancy Nikkinnen, M.D.
Medical Director
Children and Parents Program
Penn-Silver Health Center
Prince George's County Health Department
Forestville, Maryland

William (Bill) Francis Northey, Jr., Ph.D.
Research Specialist
American Association for Marriage and Family Therapy
Alexandria, Virginia

Gwen M. Olitsky, M.S.
Founder and C.E.O.
The Self-Help Institute for Training and Therapy
Lansdale, Pennsylvania

Dorothy Payne, M.B.A.
AOD Program Consultant
Alcohol and Drug Abuse Prevention
Arkansas Department of Health
Freeway Medical Center
Little Rock, Arkansas

Thomas A. Peltz, LMHC, CAS, M.Ed.
Therapist
Private Practice
Beverly Farms, Massachusetts

David J. Powell, Ph.D.
President
International Center for Health Concerns, Inc.
East Granby, Connecticut

Beverly A. Pringle, Ph.D.
Health Scientist Administrator
National Institute on Drug Abuse
Bethesda, Maryland

Melissa Rael, CAPT., USPHS
Senior Program Management Officer
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Barbara E. Ramlow
Acting Director
Institute on Women and Substance Abuse
University of Kentucky
Lexington, Kentucky

José Rivera, J.D.
President
Rivera, Sierra and Company, Inc.
Brooklyn, New York

Valerie Robinson, M.S., LPC
Director of Training
Danya Institute, Inc.
Silver Spring, Maryland

Maurilia Rodriguez, Ph.D., R.N., CDE
Diabetes Consultant
Houston, Texas

Laurie Roehrich, Ph.D.
Associate Professor
Department of Psychology
Indiana University of Pennsylvania
Indiana, Pennsylvania

James Rowan, M.A., CAC III
Program Manager
Case Management and Offender Services
Arapahoe House, Inc.
Thornton, Colorado

Paula G. Ruane
Marketing Director
Gaudenzia, Inc.
Harrisburg, Pennsylvania

Judith Rubin
Instructor
School of Social Work
San Francisco State University
San Francisco, California

Suzanne A. Rymer
Director
Health and Social Work Services
Mature Services, Inc.
Akron, Ohio

JoAnn Y. Sacks, Ph.D.
Principal Investigator
National Development and Research
Institutes, Inc.
New York, New York

Andrea Savage, Ph.D.
Associate Professor
School of Social Work
Hunter College
New York, New York

Karen Saylors, Ph.D.
Director of Research and Evaluation
Family and Child Guidance Clinic
Native American Health Center
Oakland, California

Sheryl A. Schrepf, M.S.W.
Consultant
Nebraska Coalition for Women's Treatment
Lincoln, Nebraska

Meri Shadley, Ph.D., M.F.T., LADC
Associate Professor
Center for the Application of Substance Abuse Technologies
College of Education
University of Nevada, Reno Reno, Nevada

David E. Smith, M.D.
Founder and President
Haight Ashbury Free Clinics, Inc.
San Francisco, California

Diane Batt Smith, LADC
Substance Abuse Program Coordinator
Division of Alcohol and Drug Abuse
Vermont Department of Health
Burlington, Vermont

Virginia Steadman
Director of Women's Issues
Alcohol and Substance Abuse Services
Mississippi Department of Mental Health
Jackson, Mississippi

Marceil Ten Eyck, MC
Psychotherapist/Consultant
Kirkland, Washington

Elaine Tophia, M.S.W.
Executive Director
National Opioid Treatment Clinician Association
Decatur, Georgia

Karen Urbany
Public Health Advisor
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Nancy R. VanDeMark, M.S.W.
Director
Research and Program Evaluation
Arapahoe House, Inc.
Thornton, Colorado

Beverly Vayhinger, Ph.D.
Program Director
Children and Parents Program
Prince George's County Health Department
Forestville, Maryland

Suzanne L. Wenzel, Ph.D.
Senior Behavioral Scientist
RAND
Santa Monica, California

Sharon Wilsnack, Ph.D.
Professor
School of Medicine & Health Sciences
Department of Neuroscience
University of North Dakota
Grand Forks, North Dakota

Helen Wolstenholme, M.S.W., LCSW, CCAS
Women's Treatment Coordinator
Substance Abuse Services Section
North Carolina Division of Mental
Health/Developmental Disabilities/Substance Abuse Services
Raleigh, North Carolina

Carolyn A. Work, M.A.
Training Director
Institute for Research, Education and Training in Addictions
Pittsburgh, Pennsylvania

Loretta Young Silvia, M.Ed., Ph.D.
Associate Professor of Psychiatry
Department of Psychiatry and Behavioral Medicine
Wake Forest University School of Medicine
Winston-Salem, North Carolina

Nancy Young, Ph.D.
Director
Children and Family Futures
Irvine, California

Shaila Yeh, M.S.W.
Senior Associate
Children and Family Futures
Irvine, California

Joan E. Zweben, Ph.D.
Executive Director
The 14th Street Clinic and Medical Group
East Bay Community Recovery Project
University of California
Berkeley, California

Janet K. Zwick
Director
Division of Health Promotion, Prevention and Addictive Behaviors
Iowa Department of Public Health
Des Moines, Iowa