# Appendix H: Cultural Competency and Diversity Network Participants

Jacqueline P. Butler, M.S.W., CCDC, LISW
Professor of Clinical Psychiatry
College of Medicine
Substance Abuse Division
University of Cincinnati
Cincinnati, Ohio
African American Workgroup

Deion Cash
Executive Director
Community Treatment & Correction
Center, Inc.
Canton, Ohio
African American Workgroup

Carol S. D'Agostino, C.S.W., CASAC
Director
Geriatric Addictions Program
LIFESPAN of Greater Rochester, Inc.
Rochester, New York
Aging Workgroup

Marty Estrada
Regional Administrator
Correctional Treatment
Florida Addictions and Correctional
Treatment Services, Inc.
Tallahassee, Florida
Hispanic/Latino Workgroup

Nancy Ferreyra
Executive Director
Pacific Research and Training Alliance
Berkeley, California
Disabilities Workgroup

Tonda L. Hughes, Ph.D., R.N.
Associate Professor
College of Nursing
University of Illinois at Chicago
Chicago, Illinois
LGBT Workgroup

Ting-Fun May Lai, M.S.W., CASAC
Director
Asian American Recovery Services, Inc.
New York, New York
Disabilities/Asian Workgroup

Lorene Lake, M.A., Ed.
Executive Director
Chrysalis House, Inc.
Crownsville, Maryland
African American Workgroup

Rachelle A. Martin
Provider Relations Manager
Alcohol, Drug and Mental Health
Board of Franklin County
Columbus, Ohio
African American Workgroup

Alixe McNeill
Assistant Vice President
The National Council on the Aging
Washington, D.C.
Aging Workgroup

Valerie Robinson, M.S., LPC
Director of Training
Danya Institute, Inc.
Central East Addictions Technology Transfer Center
Silver Spring, Maryland
African American Workgroup

Hector Sanchez, M.S.W.
Team Leader
Performance Partnership Grant Branch
Division of State and Community Assistance
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland
Hispanic/Latino Workgroup

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation
Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, D.C.
Disabilities Workgroup