# Appendix G: Resource Panel Members

Ana Anders, LICSW
Senior Advisor
Special Populations Office
National Institute on Drug Abuse
National Institutes of Health
Bethesda, Maryland

Nancy Bateman, LCSW-C, CAC
Senior Staff Associate
Division of Professional Development and Advocacy
National Association of Social Workers
Washington, D.C.

Duchy Brecht-Trachtenberg, LCSW-C

Jutta H. Butler, B.S.N., M.S.
Public Health Advisor
Practice Improvement Branch
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services
Administration
Rockville, Maryland

Colevia Carter
Program Officer
Women's Program
District of Columbia Department of Health
Washington, D.C.

Teresa Chapa, Ph.D.
Senior Social Science Analyst
Center for Mental Health Services
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

H. Westley Clark, M.D., J.D., M.P.H., CAS, FASAM
Director
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Christina Currier
Public Health Analyst
Practice Improvement Branch
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Dorynne Czechowicz, M.D.
Medical Officer
Treatment Development Branch
Division of Treatment Research and Development
National Institute on Drug Abuse
National Institutes of Health
Bethesda, Maryland

Sandra Dodge, CNP
Women's Health Coordinator
Nursing Division
Indian Health Service
Rockville, Maryland

Marlene EchoHawk, Ph.D.
Health Science Administrator
Division of Behavioral Health
Indian Health Service
Rockville, Maryland

Isabel Ellis, M.S.W.
Public Health Analyst
National Institute on Alcohol Abuse and Alcoholism
National Institutes of Health
Rockville, Maryland

Krista Evans
Coordinator
Women's Program
Office of Women's Programs
District of Columbia Department of Health
Washington, D.C.

Jennifer Fiedelholtz
Public Health Analyst
Office of Policy and Program Coordination
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Loretta P. Finnegan, M.D.
Medical Advisor for the Director
Office of the Director
Office of Research on Women's Health
National Institutes of Health
Bethesda, Maryland

Bettie Foley, M.S., CMAC
Associate Director
National Association of Addiction Treatment Providers
Chicago, Illinois

Jennifer Godfrey
Intern
Maternal and Child Health Bureau
Health Resources and Services Administration
Rockville, Maryland

Kathrine Hollinger, D.V.M., M.P.H.
Health Program Coordinator
Office of Women's Health
Food and Drug Administration
Rockville, Maryland

Sharon L. Holmes
Director
Office of Equal Employment Opportunity and Civil Rights
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Leah Holmes-Bonilla
National Mental Health Association
Alexandria, Virginia

Arthur MacNeill Horton, Ed.D., ABPN, APP
Office of the Director
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Ellen Hutchins, M.S.W., M.P.H.
Social Work Consultant
Maternal and Child Health Bureau
Health Resources and Services Administration
Rockville, Maryland

Gwendolyn P. Kieta, Ph.D.
Director
Women's Programs Office
American Psychological Association
Washington, D.C.

Lisa King
Women's Health Specialist
Maternal and Child Health Bureau
Health Resources and Services Administration
Rockville, Maryland

Sheila P. Litzky, M.A.
Statewide Coordinator for Women's Services
Alcohol and Drug Abuse Administration
Spring Grove Hospital Center
Catonsville, Maryland

James J. Manlandro, D.O., FAOAAM, FACOFP
Medical Director
Family Addiction Treatment Services, Inc.
Rio Grande, New Jersey

Carmen Martinez
Manager
Office of Equal Employment Opportunity and Civil Rights
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Ann Maskell
Office Manager
Family Addiction Treatment Services, Inc.
Dennisville, New Jersey

Alixe McNeill
Assistant Vice President
The National Council on the Aging
Washington, D.C.

Kathleen Mitchell
Program Director
National Organization on Fetal Alcohol Syndrome
Washington, D.C.

Susana Perry
Office of State and Community Programs
Administration on Aging
United States Department of Health and Human Services
Washington, D.C.

Melissa V. Rael, USPHS
Senior Program Management Officer
Co-occurring and Homeless Branch
Division of State and Community Assistance
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Rosa M. Reyes
Intern
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Gwen Rubinstein, M.P.H.
Director of Policy Research
Legal Action Center
Washington, D.C.

Hector Sanchez, M.S.W.
Team Leader
Performance Partnership Grant Branch
Division of State and Community Assistance
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Steven J. Shapiro, M.C.J.
Public Health Advisor
Division of Practice and Systems Development
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

June Susan Sivilli
Senior Policy Analyst
Office of National Drug Control Policy
Executive Office of the President
Washington, D.C.

Lany Sivongsay
Intern
Office of Policy Coordination and Planning
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Arlene Stanton, Ph.D., NCC
Social Science Analyst
Office of Evaluation, Scientific Analysis and Synthesis
Data Infrastructure Branch Center for Substance Abuse Treatment Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation
Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, D.C.