# Appendix F: Integration Self-Assessment for Providers

The Women Embracing Life and Living (WELL) Toolkit is designed to help organizations develop plans to improve the quality of care offered to women with co-occurring substance abuse and mental health difficulties and histories of experiencing violence. The toolkit includes

• Instructions for using the WELL Toolkit
• Principles for the Trauma-Informed Treatment of Women with Co-occurring Mental Health and Substance Abuse Disorders (WELL Project 1999)
• Self-Assessment for Providers
• Organizational Self-Assessment
• WELL Planning Tool
• Example of the use of the WELL Planning Tool

The assessment instruments can be used to take an initial measure of an organization's strengths and weaknesses, and to track progress in moving in the desired direction. Organizations that provide direct services to families should use the Self-Assessment for Providers, while State agencies and funding or regulatory agencies should use the Organizational/Agency Self-Assessment. The information from the Self-Assessment can be used in conjunction with the Planning Tool to develop concrete plans to strengthen quality of service in particular areas.

There are many ways of using the Self-Assessment for Providers, depending on the priorities of the organization. The general approach is to

1. Look at one subscale at a time.
2. List the items on which you are not satisfied with your scores.
3. Prioritize them in terms of importance to your agency.
4. Choose a certain target number of items.
5. Develop remedies, steps, and timelines for those items.

An organization can prioritize the subscales and work on only one at a time, or can select items from a number of subscales and then prioritize the items, without reference to subscale. It is a good idea to re-administer the assessment tool on a yearly basis in order to track progress. This assessment should be done for each program administered by your organization. Following is the Self-Assessment for Providers.

Items to be scored on the following Likert Scale:

1. Rarely
2. Occasionally
3. Sometimes
4. Often
5. Consistently

## Integration—General

1. ___ Staff is knowledgeable about the way trauma, substance abuse, and mental illness interact.
2. ___ Consumers are provided with psychoeducation about the ways in which trauma, substance abuse, and mental illness interact.
3. ___ Service plans address substance abuse, mental illness, and trauma when appropriate.
4. ___ Case management is available which integrates substance abuse, mental health, and violence/trauma services.
5. ___ Multidisciplinary teams can be consulted to address service plan difficulties.
6. ___ Policies and procedures encourage direct care providers to have regular contact (with consent of the consumer) with other service providers who serve the same client.
6. ___ Aftercare plans address substance abuse, mental illness, and trauma.
7. ___ The program appropriately supports direct care staff in participating in supervision and obtaining training.

___Total

## Trauma Integrated Into Other Services

7. ___ Staff is knowledgeable about symptoms of trauma.
8. ___ Staff is knowledgeable about domestic violence.
9. ___ Staff is knowledgeable about the risk for retraumatization of victims of violence by staff and peers.
10. ___ Staff is knowledgeable about vicarious traumatization and self-care.
11. ___ Staff is knowledgeable of nonviolent de-escalation techniques.
12. ___ Consumers are assessed regarding their history of experiencing violence.
13. ___ Consumers are assessed regarding their current safety from perpetrators.
14. ___ Consumers are assessed regarding the safety of their current living situation.
15. ___ Psychoeducation is provided for consumers about domestic violence.
16. ___ Psychoeducation is provided for consumers about the symptoms of trauma.
17. ___ Psychoeducation is provided for consumers regarding skills for dealing with trauma symptoms such as grounding and self-soothing.
18. ___ Consumers have access to services for healing from trauma.
19. ___ Consumers have access to safety planning.
20. ___ Consumers have access to legal services.
21. ___ Crisis Prevention Plans are developed in which consumers and providers agree regarding what to do if the behavior of the consumer begins to escalate.
22. ___ Advanced Directives are developed regarding what consumers would like providers to do in the event of a crisis (i.e., who should be notified, where she might be transferred if necessary).
23. ___ Physical restraints are used only as an extreme exception and last resort in accordance with the recommendations of the report of the Massachusetts Department of Mental Health task force on the restraint and seclusion of persons who have been physically or sexually abused.
24. ___ Consumers are instructed in procedures for maintaining each other's confidentiality in order to maintain safety.
25. ___ Procedures are in place to protect both staff and clients if a perpetrator attempts to enter.
26. ___ A “quick response” agreement is in place with local law enforcement should a perpetrator attempt to enter the program.
27. ___ Procedures are in place (which protect the confidentiality of current consumers) for screening new admissions to determine whether they are victimizers of current consumers.
28. ___ A policy is in place to deny admission to the victimizers of a current consumer and refer elsewhere (including certified batterers intervention).
29. ___ Procedures are in place to assist a consumer in accessing a corresponding level of care in another community if it is not safe for her to use the services in her local area.
30. ___ Consumers are helped to grieve the loss of family when it is necessary in order to maintain safety.
31. ___ There is no arbitrary exclusion based on domestic violence.
32. ___ Linkages exist with domestic violence providers for referral purposes.
33. ___ Linkages exist with domestic violence providers for consultation purposes.

___Total

## Substance Abuse Treatment Integrated Into Other Services

34. ___Staff has basic knowledge about substance abuse.
35. ___Psychoeducation is provided for consumers about substance abuse.
36. ___Consumers are assessed for substance abuse.
37. ___Linkages exist with substance abuse providers for referral purposes.
38. ___Linkages exist with methadone providers for referral purposes.
39. ___Linkages exist with substance abuse providers for consultation purposes.
40. ___Consumers can participate in the program if they are on methadone.
41. ___There is no arbitrary exclusion based on substance abuse. ___Total

## Mental Health Integrated Into Other Services

42. ___Staff has basic knowledge about mental disorders.
43. ___Consumers are assessed for mental health problems.
44. ___Linkages exist with mental health providers for referral purposes.
45. ___Linkages exist with mental health providers for consultation purposes.
46. ___Staff has basic knowledge about common side effects of psychotropic medications.
47. ___Psychoeducation is provided for consumers regarding mental disorders.
48. ___Policies are in place and provided for consumers regarding what to do if a consumer decompensates psychiatrically.
49. ___Referrals are made for psychotropic medication evaluation and monitoring.
50. ___Consumers can participate in the program if they are taking psychotropic medication.
51. ___There is no arbitrary exclusion based on mental health diagnosis or symptoms.

___Total

## Empowerment

52. ___Staff is knowledgeable about informed consent and confidentiality.
53. ___Staff is knowledgeable about stigmas.
54. ___Staff has received training in empowerment-based treatment.
55. ___Intake assessments include the strengths of consumers.
56. ___Consumers are given choices regarding which services they access.
57. ___Consumers may change individual providers of services if they are not satisfied.
58. ___Service plans are individualized.
59. ___Advanced Directives are developed in which consumers indicate what they would like providers to do in the event of a crisis (i.e., whom to notify, where she would like to be transferred to).
60. ___The program meets the Federal guidelines for confidentiality that apply to substance abuse.
61. ___The program meets State confidentiality statutes regarding domestic violence and substance abuse counselors.
62. ___Limits on confidentiality, how records are kept, who has access to information, and how information could be used to the consumer's detriment are carefully explained to consumers before information is collected.
63. ___All discussions of consumer information are done in private settings.
64. ___Policies and procedures are in place for collecting information from diverse groups of consumers about quality of services and for incorporating that feedback into service planning.
65. ___Staff and Board members across the hierarchy of positions include significant numbers of diverse consumers.
66. ___There is appropriate support for consumers moving into a professional role, such as peer leadership training, mentoring, and opportunities to function in an advocacy role.
67. ___All consumers have access to peer support.

___Total

## Gender Specific

68. ___Staff is knowledgeable about the specific needs of women.
69. ___Gender-specific services are provided.
70. ___Female consumers can work with female providers if that is their preference.
71. ___Female role models in positions of leadership are available.

___Total

## Family Focus

72. ___Psychoeducation is provided for consumers on the intergenerational transmission of substance abuse, mental illness, and violence.
73. ___When a consumer requests services, information is collected regarding her children.
74. ___When a consumer requests services, information is collected regarding her children's need for services.
75. ___There is a means in place for screening children of consumers regarding their need for services.
76. ___Linkages are in place for helping a consumer obtain appropriate services for her children.
77. ___Linkages are in place for helping a consumer obtain appropriate services for other family members.
78. ___In a residential program, there is someone who can assist a consumer in arranging for education of children while she is a resident.
79. ___The program provides a level of parenting education that is appropriate to the level of care (a minimal level being assistance and education regarding communication with children about substance abuse, mental illness, and violence).
80. ___Child care is provided or there is someone who can help a consumer arrange child care that may be necessary for a consumer to receive services.
81. ___Education is provided for a consumer's family (as defined by the consumer) or support system (excluding unsafe relationships).
82. ___Providers work with consumers in advance to develop plans for their children that would be followed in the event that the consumer must be transferred to a more acute level of care.

___Total

## Cultural Competence

83. ___Staff is knowledgeable about cultural competence.
84. ___Staff is knowledgeable about the cultures represented by the consumers served.
85. ___Information is collected regarding a consumer's primary language at intake.
86. ___Information is collected regarding a consumer's sexual orientation and identity at intake.
87. ___When a consumer requests services, information is collected regarding her cultural/ethnic/racial identity.
88. ___Differences, including those attributable to class, income, culture, race, ethnicity, disability, language, sexual orientation, religion, and age are incorporated into service planning.
89. ___Language in all intake and training materials is gender neutral and nonviolent.
90. ___Services are available in all languages that are the first language of a large number of the population served.
91. ___Professional translators are provided when necessary, rather than using persons with a personal relationship with the consumer.
92. ___Policies and resources are in place for referring to or obtaining services for consumers who speak languages other than those in which the program provides services.
93. ___There are staff members with the same cultural, racial, and ethnic backgrounds as the consumers being served.
94. ___Policies are in place that state that racism, sexism, homophobia, ageism, and other forms of hatred will not be tolerated.

___Total

## Holistic

95. ___Information is collected regarding a consumer's current support system at intake.
96. ___Information is collected regarding a consumer's medical status at intake.
97. ___Information is collected regarding a consumer's legal status at intake.
98. ___Information is collected regarding a consumer's housing status at intake.
99. ___Information is collected regarding a consumer's financial status at intake.
100. ___Psychoeducation is provided for consumers regarding sexually transmitted diseases/HIV/AIDS/Hepatitis C.

___Total

Total scores:

- # of 1s—Rarely ___
- # of 2s—Occasionally ___
- # of 3s—Sometimes ___
- # of 4s—Often ___
- # of 5s—Consistently ___

Source: WELL Project, Institute for Health and Recovery 2002. For more information about the toolkit contact The Institute for Health and Recovery, (617) 661-3991, or http://www.healthrecovery.org.