# Appendix C: Screening and Assessment Instruments

## Addiction Severity Index (ASI)

Purpose: The ASI is most useful as a general intake screening tool. It effectively assesses a client's status in several areas, and the composite score measures how a client's need for treatment changes over time.

Clinical utility: The ASI has been used extensively for treatment planning and outcome evaluation. Outcome evaluation packages for individual programs or for treatment systems are available.

Groups with whom this instrument has been used: Designed for adults of both sexes who are not intoxicated (drugs or alcohol) when interviewed.

Norms: The ASI has been used with males and females with drug and alcohol disorders in both inpatient and outpatient settings. Female version: ASI-F.

Format: Structured interview

Administration time: 50 minutes to 1 hour

Scoring time: 5 minutes for severity rating

Computer scoring? Yes

Administrator training and qualifications: A self-training packet is available as is onsite training by experienced trainers.

Available from:

A. Thomas McLellan, Ph.D.

Building 7

PVAMC

University Avenue

Philadelphia, PA 19104

Ph: (800) 238-2433

## Clinical Institute Withdrawal Assessment (CIWA-Ar)

Purpose: To track severity of withdrawal and measure severity of alcohol withdrawal.

Clinical utility: Aid to adjustment of care related to withdrawal severity.

Groups with whom this instrument has been used: Adults

Norms: N/A

Format: A 10-item scale for clinical quantification of the severity of the alcohol withdrawal syndrome.

Administration time: 2 minutes

Scoring time: 4 to 5 minutes

Computer scoring? No

Administrator training and qualifications: Training is required, and the CIWA is administered by nurses, doctors, research associates/detoxification unit workers.

Fee for use: No

Available from:

Dr. E.M. Sellers

Ventana Clinical Research Corporation

340 College Street, Suite 400

Toronto, Canada

M5T 3A9

Phone: 416-963-9338

Fax: 416-963-9732

www.ventana-crc.com/

## Level of Care Utilization System (LOCUS)

Purpose: To assess immediate service needs (e.g., for clients in crisis); to plan resource needs over time, as in assessing service requirements for defined populations; to monitor changes in status or placement at different points in time.

Clinical utility: LOCUS is divided into three sections. The first defines six evaluation parameters or dimensions: (1) Risk of Harm, (2) Functional Status, (3) Medical, Addictive, and Psychiatric Co-Morbidity, (4) Recovery Environment, (5) Treatment and Recovery History, and (6) Engagement. A five-point scale is constructed for each dimension, and the criteria for assigning a given rating or score in that dimension are elaborated. In dimension IV, two subscales are defined, whereas all other dimensions contain only one scale.

Groups with whom this instrument has been used: Adults

Norms: N/A

Format: A document that is divided into three sections.

Administration time: 15 to 30 minutes

Scoring time: 20 minutes

Computer scoring? No

Administrator training and qualifications: N/A

Fee for use: No

Available from: American Association of Community Psychiatrists

www.wpic.pitt.edu/aacp/find.html

Eating Attitudes Test (EAT-26)

## Spiritual Well-Being Scale (SWBS)

Purpose: A general indicator of well-being that may be used for the assessment of both individual and group spiritual well-being. It provides an overall measure of the perception of spiritual quality of life, as well as subscale scores for Religious and Existential Well-Being. The Religious Well-Being subscale provides a self-assessment of one's relationship with God, while the Existential Well-Being Subscale gives a self-assessment of one's sense of life purpose and life satisfaction.

Clinical utility: The SWBS is composed of 20 items, 10 of which assess religious well-being specifically, and 10 of which assess existential well-being.

Groups with whom this instrument has been used: Adults and children

Norms: Yes

Format: The SWBS is a paper-pencil instrument currently available in English and Spanish.

Administration time: 10–15 minutes

Scoring time: Information not available

Computer scoring? Information not available

Administrator training and qualifications: Information not available

Fee for use: Yes

Available from:

Life Advance, Inc.

81 Front Street Nyak, NY 10960

Lifeadvance.com

## Drinker Inventory of Consequences (DrInC-2L)

Instructions: Here are a number of events that drinkers sometimes experience. Read each one carefully, and circle the number that indicates whether this has EVER happened to you (0 = No, 1 = Yes). If an item does not apply to you, circle zero (0).

Has this EVER happened to you? | No | Yes
1. I have had a hangover or felt bad after drinking. | 0 | 1
2. I have felt bad about myself because of my drinking. | 0 | 1
3. I have missed days of work or school because of my drinking. | 0 | 1
4. My family or friends have worried or complained about my drinking. | 0 | 1
5. I have enjoyed the taste of beer, wine, or liquor. | 0 | 1
6. The quality of my work has suffered because of my drinking. | 0 | 1
7. My ability to be a good parent has been harmed by my drinking. | 0 | 1
8. After drinking, I have had trouble with sleeping, staying asleep, or nightmares. | 0 | 1
9. I have driven a motor vehicle after having three or more drinks. | 0 | 1
10. My drinking has caused me to use other drugs more. | 0 | 1
11. I have been sick and vomited after drinking. | 0 | 1
12. I have been unhappy because of my drinking. | 0 | 1
13. Because of my drinking, I have not eaten properly. | 0 | 1
14. I have failed to do what is expected of me because of my drinking. | 0 | 1
15. Drinking has helped me to relax. | 0 | 1
16. I have felt guilty or ashamed because of my drinking. | 0 | 1
Has this EVER happened to you? | No | Yes
17. While drinking I have said or done embarrassing things. | 0 | 1
18. When drinking, my personality has changed for the worse. | 0 | 1
19. I have taken foolish risks when I have been drinking. | 0 | 1
20. I have gotten into trouble because of drinking. | 0 | 1
21. While drinking or using drugs, I have said harsh or cruel things to someone. | 0 | 1
22. When drinking, I have done impulsive things that I regretted later. | 0 | 1
23. I have gotten into a physical fight while drinking. | 0 | 1
24. My physical health has been harmed by my drinking. | 0 | 1
25. Drinking has helped me to have a more positive outlook on life. | 0 | 1
26. I have had money problems because of my drinking. | 0 | 1
27. My marriage or love relationship has been harmed by my drinking. | 0 | 1
28. I have smoked tobacco more when I am drinking. | 0 | 1
29. My physical appearance has been harmed by my drinking. | 0 | 1
30. My family has been hurt by my drinking. | 0 | 1
31. A friendship or close relationship has been damaged by my drinking. | 0 | 1
32. I have been overweight because of my drinking. | 0 | 1
33. My sex life has suffered because of my drinking. | 0 | 1
34. I have lost interest in activities and hobbies because of my drinking. | 0 | 1
35. When drinking, my social life has been more enjoyable. | 0 | 1
36. My spiritual or moral life has been harmed by my drinking. | 0 | 1
37. Because of my drinking, I have not had the kind of life that I want. | 0 | 1
Has this EVER happened to you? | No | Yes
38. My drinking has gotten in the way of my growth as a person. | 0 | 1
39. My drinking has damaged my social life, popularity, or reputation. | 0 | 1
40. I have spent too much or lost a lot of money because of my drinking. | 0 | 1
41. I have been arrested for driving under the influence of alcohol. | 0 | 1
42. I have had trouble with the law (other than driving while intoxicated) because of my drinking. | 0 | 1
43. I have lost a marriage or a close love relationship because of my drinking. | 0 | 1
44. I have been suspended/fired from or left a job or school because of my drinking. | 0 | 1
45. I drank alcohol normally, without any problems. | 0 | 1
46. I have lost a friend because of my drinking. | 0 | 1
47. I have had an accident while drinking or intoxicated. | 0 | 1
48. While drinking or intoxicated, I have been physically hurt, injured, or burned. | 0 | 1
49. While drinking or intoxicated, I have injured someone else. | 0 | 1
50. I have broken things while drinking or intoxicated. | 0 | 1

The Drinker Inventory of Consequences (DrInC)