# Appendix J: Acknowledgments

Numerous people contributed to the development of this TIP, including the TIP Consensus Panel (see p. xi), the KAP Expert Panel (see p. xv), the Federal Resource Panel, (see appendix G), the KAP Cultural Competency and Diversity Network (see appendix H), and TIP Field Reviewers (see appendix I).

In addition, Rose M. Urban, M.S.W., J.D., LCSW, LCAS, served as the CDM KAP Executive Deputy Project Director. Roberta Hochberg served as the CDM KAP Managing Project Co-Director. Claudia A. Blackburn, M.S., Psy.D., served as the CDM KAP Expert Content Director. Other CDM KAP personnel included Susan Kimner, Deputy Project Director/Editorial Director; Jessica L. Culotta, Managing Editor; Amy Conklin, Editor; Janet Humphrey, M.A., former Editor; Virgie D. Paul, M.L.S., Librarian; Lee Ann Knapp, Quality Assurance Editor.

JBS KAP personnel included Barbara Fink, R.N., M.P.H., KAP Managing Project Co-Director; Dennis Burke, M.S., M.A., former Product Development Manager; Wendy Caron, Senior QA Editor; Leah Bogden, Junior Editor; and Frances Nebesky, Senior QA Editor.

Sandra Clunies, M.S., I.C.A.D.C., served as Content Advisor. Catalina Bartlett, M.A., Randi Henderson, B.A., Susan Hills, Ph.D., Helen Oliff, and Mary Lou Rife, Ph.D., were writers.