# CSAT TIPs and Publications Based on TIPs

## What Is a TIP?

Treatment Improvement Protocols (TIPs) are the products of a systematic and innovative process that brings together clinicians, researchers, program managers, policymakers, and other Federal and non-Federal experts to reach consensus on state-of-the-art treatment practices. TIPs are developed under CSAT's Knowledge Application Program to improve the treatment capabilities of the Nation's alcohol and drug abuse treatment service system.

## What Is a Quick Guide?

A Quick Guide clearly and concisely presents the primary information from a TIP in a pocket-sized booklet. Each Quick Guide is divided into sections to help readers quickly locate relevant material. Some contain glossaries of terms or lists of resources. Page numbers from the original TIP are referenced so providers can refer back to the source document for more information.

## What Are KAP Keys?

Also based on TIPs, KAP Keys are handy, durable tools. Keys may include assessment or screening instruments, checklists, and summaries of treatment phases. Printed on coated paper, each KAP Keys set is fastened together with a key ring and can be kept within a treatment provider's reach and consulted frequently. The Keys allow you, the busy clinician or program administrator, to locate information easily and to use this information to enhance treatment services.

## Ordering Information

Publications may be ordered from or downloaded from SAMHSA's Publications Ordering Web page at http://store.samhsa.gov. Or, please call 1-877-SAMHSA-7 (1-877-726-4727) (English and Español).

TIP 1 State Methadone Treatment Guidelines—Replaced by TIP 43
TIP 2 Pregnant, Substance-Using Women—Replaced by TIP 51
TIP 3 Screening and Assessment of Alcohol- and Other Drug-Abusing Adolescents—Replaced by TIP 31
TIP 4 Guidelines for the Treatment of Alcohol and Other Drug-Abusing Adolescents—Replaced by TIP 32
TIP 5 Improving Treatment for Drug-Exposed Infants—BKD110
TIP 6 Screening for Infectious Diseases Among Substance Abusers—Archived
TIP 7 Screening and Assessment for Alcohol and Other Drug Abuse Among Adults in the Criminal Justice System—Replaced by TIP 44
TIP 8 Intensive Outpatient Treatment for Alcohol and Other Drug Abuse—Replaced by TIPs 46 and 47
TIP 9 Assessment and Treatment of Patients With Coexisting Mental Illness and Alcohol and Other Drug Abuse—Replaced by TIP 42
TIP 10 Assessment and Treatment of Cocaine-Abusing Methadone-Maintained Patients—Replaced by TIP 43
TIP 11 Simple Screening Instruments for Outreach for Alcohol and Other Drug Abuse and Infectious Diseases—Replaced by TIP 53
TIP 12 Combining Substance Abuse Treatment With Intermediate Sanctions for Adults in the Criminal Justice System—Replaced by TIP 44
TIP 13 Role and Current Status of Patient Placement Criteria in the Treatment of Substance Use Disorders—BKD161
  Quick Guide for Clinicians QGCT13
  Quick Guide for Administrators QGAT13
  KAP Keys for Clinicians KAPT13
TIP 14 Developing State Outcomes Monitoring Systems for Alcohol and Other Drug Abuse Treatment—BKD162
TIP 15 Treatment for HIV-Infected Alcohol and Other Drug Abusers—Replaced by TIP 37
TIP 16 Alcohol and Other Drug Screening of Hospitalized Trauma Patients—(SMA) 12-3686
  Quick Guide for Clinicians QGCT16
  KAP Keys for Clinicians KAPT16
TIP 17 Planning for Alcohol and Other Drug Abuse Treatment for Adults in the Criminal Justice System—Replaced by TIP 44
TIP 18 The Tuberculosis Epidemic: Legal and Ethical Issues for Alcohol and Other Drug Abuse Treatment Providers—Archived
TIP 19 Detoxification From Alcohol and Other Drugs—Replaced by TIP 45
TIP 20 Matching Treatment to Patient Needs in Opioid Substitution Therapy—Replaced by TIP 43
TIP 21 Combining Alcohol and Other Drug Abuse Treatment With Diversion for Juveniles in the Justice System—(SMA) 12-4073
  Quick Guide for Clinicians and Administrators QGCA21
TIP 22 LAAM in the Treatment of Opiate Addiction—Replaced by TIP 43
TIP 23 Treatment Drug Courts: Integrating Substance Abuse Treatment With Legal Case Processing—(SMA) 12-3917
  Quick Guide for Administrators QGAT23
TIP 24 A Guide to Substance Abuse Services for Primary Care Clinicians—(SMA) 08-4075
  Concise Desk Reference Guide BKD123
  Quick Guide for Clinicians QGCT24
  KAP Keys for Clinicians KAPT24
TIP 25 Substance Abuse Treatment and Domestic Violence—(SMA) 12-4076
  Linking Substance Abuse Treatment and Domestic Violence Services: A Guide for Treatment Providers MS668
  Linking Substance Abuse Treatment and Domestic Violence Services: A Guide for Administrators MS667
  Quick Guide for Clinicians QGCT25
  KAP Keys for Clinicians (SMA) 12-3584
TIP 26 Substance Abuse Among Older Adults—(SMA) 12-3918
  Substance Abuse Among Older Adults: A Guide for Treatment Providers MS669
  Substance Abuse Among Older Adults: A Guide for Social Service Providers MS670
  Substance Abuse Among Older Adults: Physician's Guide MS671
  Quick Guide for Clinicians QGCT26
  KAP Keys for Clinicians KAPT26
TIP 27 Comprehensive Case Management for Substance Abuse Treatment—(SMA) 12-4215
  Case Management for Substance Abuse Treatment: A Guide for Treatment Providers MS673
  Case Management for Substance Abuse Treatment: A Guide for Administrators MS672
  Quick Guide for Clinicians QGCT27
  Quick Guide for Administrators QGAT27
TIP 28 Naltrexone and Alcoholism Treatment—Replaced by TIP 49
TIP 29 Substance Use Disorder Treatment for People With Physical and Cognitive Disabilities—(SMA) 12-4078
  Quick Guide for Clinicians QGCT29
  Quick Guide for Administrators (SMA) 08-3592
  KAP Keys for Clinicians KAPT29
TIP 30 Continuity of Offender Treatment for Substance Use Disorders From Institution to Community—(SMA) 12-3920
  Quick Guide for Clinicians QGCT30
  KAP Keys for Clinicians KAPT30
TIP 31 Screening and Assessing Adolescents for Substance Use Disorders—(SMA) 12-4079 See companion products for TIP 32.
TIP 32 Treatment of Adolescents With Substance Use Disorders—(SMA) 12-4080
  Quick Guide for Clinicians QGC312
  KAP Keys for Clinicians KAPT312
TIP 33 Treatment for Stimulant Use Disorders—(SMA) 09-4209
  Quick Guide for Clinicians QGCT33
  KAP Keys for Clinicians KAPT33
TIP 34 Brief Interventions and Brief Therapies for Substance Abuse—(SMA) 12-3952
  Quick Guide for Clinicians QGCT34
  KAP Keys for Clinicians KAPT34
TIP 35 Enhancing Motivation for Change in Substance Abuse Treatment—(SMA) 13-4212
  Quick Guide for Clinicians—(SMA) 12-4097
  KAP Keys for Clinicians (SMA) 12-4091
TIP 36 Substance Abuse Treatment for Persons With Child Abuse and Neglect Issues—(SMA) 12-3923
  Quick Guide for Clinicians QGCT36
  KAP Keys for Clinicians KAPT36
  Helping Yourself Heal: A Recovering Woman's Guide to Coping With Childhood Abuse Issues (SMA) 08-4132
  Available in Spanish: PHD981S
  Helping Yourself Heal: A Recovering Man's Guide to Coping With the Effects of Childhood Abuse (SMA) 08-4134
  Available in Spanish: PHD1059S
TIP 37 Substance Abuse Treatment for Persons With HIV/AIDS—(SMA) 12-4137
  Quick Guide for Clinicians MS678
  KAP Keys for Clinicians KAPT37
  Drugs, Alcohol, and HIV/AIDS: A Consumer Guide (SMA) 08-4127
  Available in Spanish: PHD1134
  Drugs, Alcohol, and HIV/AIDS: A Consumer Guide for African Americans (SMA) 07-4248
TIP 38 Integrating Substance Abuse Treatment and Vocational Services—(SMA) 12-4216
  Quick Guide for Clinicians QGCT38
  Quick Guide for Administrators QGAT38
  KAP Keys for Clinicians KAPT38
TIP 39 Substance Abuse Treatment and Family Therapy—(SMA) 12-4219
  Quick Guide for Clinicians QGCT39
  Quick Guide for Administrators QGAT39
TIP 40 Clinical Guidelines for the Use of Buprenorphine in the Treatment of Opioid Addiction—(SMA) 07-3939
  Quick Guide for Physicians QGPT40
  KAP Keys for Physicians KAPT40
TIP 41 Substance Abuse Treatment: Group Therapy—(SMA) 12-3991
  Quick Guide for Clinicians (SMA) 12-4024
TIP 42 Substance Abuse Treatment for Persons With Co-Occurring Disorders—(SMA) 13-3992
  Quick Guide for Clinicians (SMA) 07-4034
  Quick Guide for Administrators (SMA) 12-4035
  KAP Keys for Clinicians (SMA) 08-4036
TIP 43 Medication-Assisted Treatment for Opioid Addiction in Opioid Treatment Programs—(SMA) 08-4214
  Quick Guide for Clinicians QGCT43
  KAP Keys for Clinicians (SMA) 07-4108
TIP 44 Substance Abuse Treatment for Adults in the Criminal Justice System—(SMA) 13-4056
  Quick Guide for Clinicians QGCT44
  KAP Keys for Clinicians (SMA) 07-4150
TIP 45 Detoxification and Substance Abuse Treatment—(SMA) 13-4131
  Quick Guide for Clinicians (SMA) 06-4225
  Quick Guide for Administrators (SMA) 06-4226
  KAP Keys for Clinicians (SMA) 06-4224
TIP 46 Substance Abuse: Administrative Issues in Outpatient Treatment—(SMA) 12-4157
  Quick Guide for Administrators—(SMA) 07-4232
TIP 47 Substance Abuse: Clinical Issues in Outpatient Treatment—(SMA) 12-4182
  Quick Guide for Clinicians—(SMA) 07-4233
  KAP Keys for Clinicians—(SMA) 07-4251
TIP 48 Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery—(SMA) 13-4353
TIP 49 Incorporating Alcohol Pharmacotherapies Into Medical Practice—(SMA) 12-4380
  Quick Guide for Counselors (SMA) 10-4542
  Quick Guide for Physicians (SMA) 10-4543
  KAP Keys for Clinicians (SMA) 10-4544
TIP 50 Addressing Suicidal Thoughts and Behaviors in Substance Abuse Treatment—(SMA) 09-4381
TIP 51 Substance Abuse Treatment: Addressing the Specific Needs of Women—(SMA) 13-4426
TIP 52 Clinical Supervision and Professional Development of the Substance Abuse Counselor—(SMA) 09-4435
TIP 53 Addressing Viral Hepatitis in People With Substance Use Disorders—(SMA) 11-4656
TIP 54 Managing Chronic Pain in Adults With or in Recovery From Substance Use Disorders—(SMA) 12-4671
TIP 55 Behavioral Health Services for People Who Are Homeless—(SMA) 13-4734
TIP 56 Addressing the Specific Behavioral Health Needs of Men—(SMA) 13-4736