# Part 2 Addressing Suicidal Thoughts and Behaviors: An Implementation Guide for Administrators

## An Overview of Part 2

This guide for administrators has two chapters:

Chapter 1 surveys pertinent issues for administrators regarding how suicidal thoughts and behaviors can and should be addressed in substance abuse treatment, including:

• The role of administrators and mid-level staff in providing care for clients with suicidal thoughts and behaviors.
• Different levels of program involvement in addressing the needs of substance abuse clients with suicidal thoughts and behaviors.
• Legal and ethical issues for consideration in managing and providing treatment to clients with suicidal thoughts and behaviors.

Chapter 2 presents specific protocols, policies, and procedures useful in:

• Helping an agency become capable of handling suicide prevention and intervention.
• Helping a program develop and improve staff capabilities in working with clients who are suicidal.
• Helping an agency develop and improve its response to suicidal crises.
• Building administrative support for all components of GATE.