# Part 1 Addressing Suicidal Thoughts and Behaviors in Substance Abuse Treatment

## Overview of Part 1

### Chapter 1: Information You Need to Know

Introduction (pp. 3–4)

Getting Ready To Address Suicidality provides basic principles about your role in working with clients who are suicidal (pp. 4–9)

Background Information concerning substance abuse and suicidality (pp. 9–14)

GATE, a four-step process (Gather information, Access supervision, Take responsible action, Extend the action) for addressing suicidal thoughts and behaviors in substance abuse treatment (pp. 14–25)

Competencies for working with clients with suicidal thoughts and behaviors (pp. 25–31)

### Chapter 2: Clinical Vignettes Demonstrating How to Apply the Information

To illustrate and reinforce the material presented in chapter 1, six realistic scenarios involving suicidal behaviors that might arise during the course of substance abuse treatment are provided. The vignettes emphasize the GATE process and the responsible actions modeled by a counselor and his or her supervisor. Master Clinician Notes are provided to explain the thinking behind these actions. How-To Notes provide instructions for specific methods and interventions.