# Consensus Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

## Chair, Part 1 and Part 2 Consensus Panels

Kenneth R. Conner, Psy.D., M.P.H.
Associate Professor of Psychiatry
University of Rochester Medical Center
Rochester, New York

## Part 1 Consensus Panel Members

Bruce Carruth, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Sean Joe, Ph.D., M.S.W.
School of Social Work
University of Michigan
Ann Arbor, Michigan

M. David Rudd, Ph.D., ABPP
Texas Tech University
Department of Psychology
Lubbock, Texas

Barbara M. Teal, M.A., M.B.A., ICADC, CET II
Consultant
Rehoboth, Delaware

James D. Wines, Jr., M.D., M.P.H.
McLean Hospital/Harvard Medical School
Alcohol and Drug Abuse Research Center (ADARC)
Belmont, Massachusetts

## Part 2 Consensus Panel Members

Bruce Carruth, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Lisa Laitman, M.S.Ed., LCADC
Rutgers, The State University of New Jersey
Rutgers University Health Services
Alcohol and Other Drug Assistance Program for Students
New Brunswick, New Jersey

Edna Meziere, M.S., M.L.S., R.N.
Consultant
Tulsa, Oklahoma