# Appendix E—Acknowledgments

Numerous people contributed to the development of this TIP, including the TIP Consensus Panel (see page v), the Knowledge Application Program (KAP) Advisory Meeting Panel (see Appendix B), the Stakeholders Meeting Participants (see Appendix C), and TIP Field Reviewers (see Appendix D).

This publication was produced under KAP, a Joint Venture of The CDM Group, Inc. (CDM), and JBS International, Inc. (JBS), for the Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment.

CDM KAP personnel included Rose M. Urban, M.S.W., J.D., LCSW, LCAS, KAP Executive Deputy Project Director; Susan Kimner, KAP Managing Project Co-Director; Jessica Culotta, M.A., Managing Editor; Bruce Carruth, Ph.D., Expert Content Director; Janet Humphrey, M.A., former Editor; Sheldon R. Weinberg, Ph.D., Senior Researcher/Applied Psychologist; Jonathan Gilbert, Ph.D., Writer/Editor; Virgie D. Paul, M.L.S., Librarian; Maggie Nelson, KAP Project Coordinator; Marion Munford, KAP Project Assistant; Lee Ann Knapp, Quality Assurance Editor.

Special thanks go to Caron Treatment Centers for their contributions to this TIP.