# Appendix D: Field Reviewers

Note: The information given indicates each participant's affiliation during the time the review was conducted and may no longer reflect the individual's current affiliation.

Lanny Berman, Ph.D.
Executive Director
American Association of Suicidology
Washington, D.C.

Yolanda Bogan, Ph.D.
Associate Professor
Florida A & M University
Tallahassee, Florida

Gary Forrest, Ph.D.
Private Practice
Colorado Springs, Colorado

Joyce Fowler, Ph.D.
Licensed Psychologist
Fowler Institute
Little Rock, Arkansas

Scarlett Harris, LCSW
Private Practice Social Worker
Adjunct Faculty, University of Arkansas at Little Rock
Little Rock, Arkansas

David C. Hill, Ph.D.
Professor and Licensed Psychologist
Millersville University of Pennsylvania
Millersville, Pennsylvania

Denise A. Horton, Ph.D., LPC, CEAP
Alcohol/Drug Control Officer/Employee Assistance
Professional Army Substance Abuse Program
Fort Dix, New Jersey

Thomas Joiner, Ph.D.
Distinguished Research Professor of Psychology
Florida State University
Tallahassee, Florida

Charlene Le Fauve
Branch Chief, Co-Occurring and Homeless Activities Branch
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Pamela Mattel, LCSW-R, CASAC
Deputy Executive Director
Basics, Inc.
New York, New York

Mary Ellen McAlevey, M.A., LPC, ATR-BC
Art Therapist
Temada Associates
Toms River, New Jersey

Richard McKeon, Ph.D., M.P.H.
Special Advisor Suicide Prevention
Center for Mental Health Services
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Hunter L. McQuistion, M.D.
Director, Division of Integrated Psychiatric Services, Department of Psychiatry
The St. Luke's–Roosevelt Hospitals
New York, New York

Sherry Davis Molock, Ph.D.
Associate Professor
George Washington University
Washington, D.C.

Richard K. Ries, M.D.
Professor of Psychiatry
University of Washington School of Medicine
Seattle, Washington

Stephen Roggenbaum, M.A.
Assistant in Research
Louis de la Parte Florida Mental Health Institute
University of South Florida
Tampa, Florida

Bette Ann Weinstein, Ph.D., LCSW
Private Practice
Delray Beach, Florida

Amy Wenzel, Ph.D.
Research Assistant Professor
University of Pennsylvania
Philadelphia, Pennsylvania

Michael Wolf-Branigin, M.S.W., Ph.D.
Associate Professor
George Mason University
Arlington, Virginia

Harry Zerler, M.A., LCADC, MAC
Psychotherapist
Emergency Services, Hunterdon Medical Center
Hackettstown, New Jersey