# Appendix C—Stakeholders Meeting Participants

Note: The information given indicates each participant's affiliation during the time the meeting was convened and may no longer reflect the individual's current affiliation.

Brenda Bruun
Special Assistant to the Director
Division of Prevention, Traumatic Stress and Special Programs
Center for Mental Health Services
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Page Chiapella, Ph.D.
Division of Biometry and Epidemiology
National Institute on Alcohol Abuse and Alcoholism
Rockville, Maryland

H. Westley Clark, M.D., J.D., M.P.H., CAS, FASAM
Director
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Kenneth R. Conner, Psy.D., M.P.H. (TIP Chair)
Associate Professor of Psychiatry
University of Rochester Medical Center
Rochester, New York

Christina Currier
Government Project Officer
Knowledge Application Program
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Anne M. Herron, M.S.W.
Director
Division of State and Community Assistance
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Larke Huang, Ph.D.
Special Expert
Office of the Administrator
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Richard Kopanda, M.A.
Deputy Director
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Andrea Kopstein, Ph.D.
Practice Improvement Branch Chief
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Charlene LeFauve, Ph.D.
Co-Occurring and Homeless Activities Branch Chief
Division of State and Community Assistance
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Richard McKeon, Ph.D., M.P.H.
Special Advisor Suicide Prevention
Division of Prevention, Traumatic Stress and Special Programs
Center for Mental Health Services
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Cathy Nugent
Public Health Advisor
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Lisa Onken, Ph.D.
Associate Director
Chief, Behavioral and Integrative Treatment Branch
Division of Clinical Neuroscience and Behavioral Research
National Institution on Drug Abuse
Bethesda, Maryland

Lisa Park, M.S.W.
Public Health Analyst
Office of the Administrator
Office of Policy, Planning and Budget
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Jane Pearson, Ph.D.
Health Scientist Administrator
National Institute of Mental Health
Rockville, Maryland

Jerry Reed, M.S.W.
Executive Director
Suicide Prevention Action Network USA (SPAN-USA)
Washington, DC

Beatrice Rouse, Ph.D.
Team Leader
Office of Applied Studies
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Leslie J. Scallet, J.D.
Principal
Suicide Prevention Action Network
Washington, DC

Joel Sherrill, Ph.D.
Chief, Psychosocial Treatment Research Program
National Institute of Mental Health
Rockville, Maryland

Jack Stein, M.S.W., Ph.D.
Director
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Shannon Taitt, MPA
Public Health Analyst
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Douglas Tipperman, M.S.W., LCSW-C
Public Health Advisor
Center for Substance Abuse Prevention
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Ivette A. Torres, M.Ed. M.S.
Associate Director of Consumer Affairs
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Mark Weber
Director
Office of Communications
Substance Abuse and Mental Health Services Administration
Rockville, Maryland